# WHAT IS THE RELATIONSHIP BETWEEN SEAFOOD CONSUMPTION DURING CHILDHOOD AND ADOLESCENCE (UP TO 18 YEARS OF AGE) AND RISK OF CARDIOVASCULAR DISEASE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between seafood consumption during childhood and adolescence (up to 18 years of age) and risk of cardiovascular disease?

### What is the answer to the question?

- Insufficient evidence is currently available to accurately determine the relationship between seafood consumption during childhood and adolescence and risk of developing cardiovascular disease.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Fats and Seafood Subcommittee, conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- For the intervention or exposure, generally healthy children and adolescents, ages 18 years and younger. For the outcome, children and adolescents, ages 2 years and older, and adults, ages 19 years and older for blood lipids or blood pressure and adults for cardiovascular disease endpoint outcomes.

### What evidence was found?

- This review identified four articles that met inclusion criteria.
- Few studies examined the relationship between seafood intake during childhood and adolescence and blood pressure and/or lipid levels in childhood and adulthood, or cardiovascular-related mortality in adulthood.
- The 2020 Advisory Committee could not draw conclusions due to serious methodological limitations of the included studies.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to July 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between seafood consumption during childhood and adolescence (up to 18 years of age) and risk of cardiovascular disease?

### Conclusion statement and grade

Insufficient evidence is currently available to accurately determine the relationship between seafood consumption during childhood and adolescence and risk of developing cardiovascular disease. (Grade: Grade not assignable)

### Summary of the evidence

- Four articles,^1–4^ two randomized controlled trials and two prospective cohort studies, met inclusion criteria for this systematic review.
- Seafood was defined as marine animals that live in the sea and in freshwater lakes and rivers. Seafood includes fish (e.g., salmon, tuna, trout, and tilapia) and shellfish (e.g., shrimp, crab, and oysters).
- Few articles were identified that examined the relationship between seafood intake during childhood and adolescence and blood pressure, lipid levels, and cardiovascular-related mortality, and no articles examined the relationship with incidence of cardiovascular disease.
- Studies had serious methodological limitations that made interpretation of the results difficult.
- Evidence was insufficient and no conclusion could be drawn.

### Description of the evidence

Four articles,^1–4^ two randomized controlled trials (RCTs)^1,3^ and two prospective cohort studies (PCSs),^2,4^ met inclusion criteria for this systematic review that examined the relationship between seafood consumption during childhood and adolescence (up to 18 years of age) and risk of cardiovascular disease (CVD; Table 1).

#### Randomized controlled trial characteristics

Two RCTs evaluated the effect of oily fish (i.e., grouper, sea bream, kingfish, emperor, snapper)^1^ or tuna,^3^ among schoolchildren on intermediate CVD outcomes. In the Fish Feeding Study conducted in Oman, children age 10 years were randomized to receive a school meal with either 100 grams of oily fish (n=96) or a cheese/salad sandwich (control; n=102) five times per week for 12 weeks.^1^ Total cholesterol, high-density lipoprotein (HDL) cholesterol, low-density lipoprotein (LDL) cholesterol, and triglycerides were measured at post-intervention. An RCT conducted in Mexico examined the effect of 6, 7, or 8 grams of tuna (n~20-32); however, the number of meals provided, length of intervention, and control conditions were not described. Blood pressure, total cholesterol, and triglycerides were assessed following an unknown period, and results were stratified by sex.^3^ Compliance was not reported in either study.

#### Prospective cohort study characteristics

Two PCSs, one from the OPUS School Meal Study (Denmark) and one from the Boyd Orr Cohort (United Kingdom [U.K.]) assessed fish intake, analyzed continuously^2^ or in quartiles,^4^ respectively. The OPUS School Meal Study, assessed fish intake at age 10 years using a 7-day dietary record at baseline, 3 months follow-up, and 6 months follow-up.^2^ Intermediate outcomes were assessed after 3 and 6 months, including diastolic blood pressure, HDL cholesterol, and triglycerides. In the Boyd Orr Cohort, fish intake at age 7.5 years was indirectly assessed between 1937 and 1939 using a 7-day household inventory, dividing the total food expenditure by the total number of household members.^4^ This long-term longitudinal study followed these children for 60 years at which time stroke mortality and coronary heart disease (CHD) mortality were assessed.^4^

### Evidence synthesis

#### Intermediate outcomes (cardiovascular risk factor assessment)

[underlined: Blood pressure:] One RCT and one PCS did not find a significant relationship between intake of 6, 7, or 8 grams of tuna (length of intervention unknown and control group unspecified) or fish intake (grams per day), respectively, and blood pressure at approximately age 10-12 years.^2,3^

[underlined: Blood lipid levels:] One RCT found a statistically significant relationship between fish intake and blood lipids: obese girls age 11-12 years who consumed 6, 7, or 8 grams of tuna had lower total cholesterol levels compared to controls. This was not significant in obese boys. Additionally, obese boys and girls age 11-12 years who consumed 6, 7, or 8 grams of tuna had significantly lower triglycerides compared to the control group.^3^ This study did not report the frequency or duration of the intervention; therefore, it was difficult to interpret the effect of the intervention. The OPUS PCS detected a statistically significant association between fish intake at age 10 years and fasting triglyceride levels three months later; these data were not reported.^2^ However, interpretation of data on triglyceride change is difficult when not reported concurrently with a validated surrogate endpoint for CVD such as LDL cholesterol. In contrast, an RCT did not find an effect of an oily fish meal intervention (100 grams per meal, 5 times per week for 12 weeks; n=96) on triglyceride levels compared to cheese/salad sandwich (control, n=102).^1^

Two studies (one RCT and one PCS) did not find a significant relationship between fish intake and HDL cholesterol levels.^1,2^ Only one study (an RCT) assessed LDL cholesterol levels and did not find a statistically significant effect of oily fish intake.^1^

#### CVD Endpoint outcomes

[underlined: CVD-related mortality:] One PCS (N=4,028) detected a statistically significant linear trend between greater fish intake at age 7.5 years and greater risk of stroke mortality after 60 years of follow-up. When examining comparisons between quartiles of intake, there was a statistically significant association between the highest quartile of fish intake at age 7.5 years (mean=44.5 grams, standard deviation [SD]=15.5), compared to the lowest quartile (mean=1.8 grams, SD=2.4) of intake and greater risk of stroke mortality approximately 60 years later.^4^ There was not a statistically significant difference in risk of stroke mortality between the second and third quartiles of fish intake (means=11.3 and 21.6 grams, respectively) and the lowest intake quartile. No association was detected between oily fish intake at age 7.5 years and stroke mortality (n=4,028). However, there was no statistically significant association between either fish intake or oily fish intake at age 7.5 years and CHD mortality after approximately 60 years. Results were interpreted with caution because this study had a serious limitation related to the method of fish assessment. Specifically, the dietary assessment completed between 1937 and 1939 was based on a weighed inventory of all foods available in the household divided by the total number of household members. Thus, no information was provided regarding the validity or accuracy of the actual intake of fish among children.

#### Assessment of the evidence^ii^

As outlined and described below, the body of evidence examining seafood consumption during childhood and adolescence and risk of CVD was assessed for the following elements used when grading the strength of evidence.

- Risk of Bias:
  - RCTs (Table 2)
    ○ Risk of bias due to randomization: it was unclear whether one trial randomized participants using a non-biased method.^3^
    ○ Risk of bias due to deviations from intended interventions:
      ■ Dietary compliance was not reported in either trial.^1,3^
      ■ Results were difficult to interpret due to incomplete information on fish intake, the control group, and timing of outcome assessment in one trial.^3^
  - PCSs (Table 3)
    ○ Risk of bias due to confounding: both studies did not control for all key confounders, particularly family history of CVD.^2,4^
    ○ Risk of bias due to selection of participants: follow-up period may have been different for all participants in one study.^4^
    ○ Risk of bias due to classification of exposures: fish intake was measured indirectly using a non-validated 7-day household inventory and a non-validated 7-day dietary record.^2,4^
    ○ Risk of bias due to missing data: participants were excluded for missing data on other variables besides the exposure and outcome data in both studies.^2^
- Consistency:
  - Consistency could not be assessed due to an insufficient number of studies and serious methodological limitations.
- Directness:
  - Three studies were designed to examine seafood intake during childhood and adolescence and CVD outcomes.
  - One PCS was derived from a cluster randomized crossover trial designed to examine the effect of school lunches based on the new Nordic diet on metabolic syndrome and cognition.^2^
- Precision:
  - In one study, subgroupings had relatively small sample sizes.^3^
- Generalizability:
  - Two studies were conducted in Europe (U.K. and Denmark),^2,4^ one in Mexico,^3^ and one in Oman.^1^
  - One study exclusively enrolled obese adolescents.^3^
  - In the one study that provided information on parental education level, 66% reported having had “higher education”.^2^

#### Other considerations

A large, comprehensive search was conducted in multiple databases for this systematic review. Risk of publication bias is always of potential concern, however, both relatively small and large studies were included in this review, reporting both null and statistically significant results. Therefore, risk of publication bias is likely low across this body of evidence.

### Research recommendations

In order to better assess the relationship between seafood consumption during childhood and adolescence and risk of cardiovascular disease, additional research is warranted that:

- Employs validated and reliable dietary assessment methods to quantify amount, frequency, type, source, and preparation method of seafood consumed during childhood, accompanied by clinical measures of cardiovascular risk factors including systolic and diastolic blood pressure, fasting blood lipid/lipoprotein measures, and body mass index (BMI);
- Specifies the frequency, duration, type, source and preparation method of the seafood intervention, controls for baseline levels of seafood and non-seafood intakes, adjusts for and reports in detail how compliance was derived;
- Employs RCTs and PCSs to explore seafood consumption during childhood and adolescence and validated short-term intermediate CVD risk factor measures and long-term cardiovascular outcomes;
- Accounts for or examines mercury contamination (if relevant) and key confounders, particularly family history of CVD;
- Includes diverse populations.

### Included articles

1 Al-Ghannami SS, Sedlak E, Hussein IS, . DHA-enriched re-esterified triacylglycerol fish oil supplementation and oily fish consumption enhance red blood n-3 fatty acid index in Omani pre-adolescent schoolchildren. Prostaglandins Leukot Essent Fatty Acids. 2018;135:74–82. doi:10.1016/j.plefa.2018.07.005.30103936
2 Damsgaard CT, Ritz C, Dalskov SM, . Associations between school meal-induced dietary changes and metabolic syndrome markers in 8-11-year-old Danish children. Eur J Nutr. 2016;55(5):1973–1984. doi:10.1007/s00394-015-1013-z.27084093
3 García-Cervera E, Figueroa-Valverde L, Gómez EP, . Effect of omega-3 fatty acids on triglycerides and BMI levels in obese children. Curr Pediatr Res. 2015;19(1–2):1–8.
4 Ness AR, Maynard M, Frankel S, . Diet in childhood and adult cardiovascular and all cause mortality: the Boyd Orr cohort. Heart. 2005;91(7):894–898. doi:10.1136/hrt.2004.043489.15958357

Table 1 Evidence examining the relationship between seafood intake during childhood and adolescence and risk of cardiovascular disease^iii^

Article and Population Characteristics | Intervention/Exposure and Outcomes | Results (statistically significant results bolded) | Key Confounders, Study Limitations and Funding
Randomized Controlled Trials
Al-Ghannami, 2018 (https://pubmed.ncbi.nlm.nih.gov/30103936/) ^1^; RCT Cluster, Fish Feeding Study, Oman; Baseline N=NR Analytic N=198 (Attrition: NA); Participant characteristics at baseline:; - Child age (Mean±SD): 9.8y ± 0.4; - Female: 53.5%; - Race/ethnicity: NR; - SES: NR; - Health characteristics (Mean±SD): Weight (kg): 29.6±7.5; Height (cm): 133.3±6.6; - Infant feeding practices: NR; - Smoking: NR; - SBP (Mean±SD): 107.2±10.4 mmHg; - DBP (Mean±SD): 63.8±10.3 mmHg; - Triglycerides (Mean±SD): 0.61±0.3 mmol/L; - TC (Mean±SD): 4.32±0.68 mmol/L; - HDL (Mean±SD): 1.38±0.32 mmol/L; - LDL (Mean±SD): 2.66±0.55 mmol/L; Child seafood intake: NR; Seafood nutrient exposure, (Mean±SD):; - Baseline RBC FA composition: EPA: 0.36% ±0.14; DHA: 3.63% ±1.45; - n-3 content of study fish: 243.9mg ± 60.5 (range: 200-390mg); Summary of findings: Following oily fish (100 grams) or cheese/salad sandwich consumption 5x/wk for 12 wk, no differences in blood pressure, triglyceride, total cholesterol, HDL cholesterol, or LDL cholesterol were detected between groups. | Intervention:; Three groups of children (9-10y) received school meals 5x/wk for 12wk containing either:; - Oily fish (n=96): 100g lightly grilled fish (grouper, sea bream, kingfish, emperor, snapper) sandwich; - Control (n=102): Cheese/salad sandwich; - Fish oil (n=77): DHA enriched fish oil with cheese/salad sandwich (Fish oil is out of scope for review); [underlined: Compliance assessment]: Dietary compliance monitored by teachers (NR); post RBC DHA and EPA statistically higher in the oily fish group compared to the control.; Outcomes and assessment methods:; - [underlined: Blood lipids:] TC, LDL-C, HDL-C, Triglyceride; [underlined: Assessment timing:] 12wk post-intervention | Oily fish vs control, categorical; [underlined: TC], post-intervention (mean ± SD); [underlined: All:] Oily fish (n=96): 4.49 mmol/L ± 0.71; Control (n=102): 4.47 mmol/L ± 0.65, P>0.05; [underlined: Males:] Oily fish (n=46): 4.57 mmol/L ± 0.80; Control (n=46): 4.52 mmol/L ± 0.65, P>0.05; [underlined: Females:] Oily fish (n=50): 4.43 mmol/L ± 0.63; Control (n=50): 4.44 mmol/L ± 0.65, P>0.05; [underlined: HDL], post-intervention (mean ± SD); [underlined: All:] Oily fish (n=96): 1.41 mmol/L ± 0.33; Control (n=102): 1.39 mmol/L ± 0.29, P>0.05; [underlined: Males:] Oily fish (n=46): 1.46 mmol/L ± 0.33; Control (n=46): 1.41 mmol/L ± 0.28, P>0.05; [underlined: Females:] Oily fish (n=50): 1.37 mmol/L ± 0.32; Control (n=56): 1.38 mmol/L ± 0.31, P>0.05; [underlined: LDL], post-intervention (mean ± SD); [underlined: All:] Oily fish (n=96): 2.79 mmol/L ± 0.54; Control (n=102): 2.80 mmol/L ± 0.54, P>0.05; [underlined: Males:] Oily fish (n=46): 2.81 mmol/L ± 0.66; Control (n=46): 2.83 mmol/L ± 0.56; [underlined: Females:] Oily fish (n=50): 2.76 mmol/L ± 0.44; Control (n=56): 2.75 mmol/L ± 0.52; [underlined: Triglyceride], post-intervention (mean ± SD); [underlined: All:] Oily fish (n=96): 0.65 mmol/L ± 0.23; Control (n=102): 0.64 mmol/L ± 0.35, P>0.05; [underlined: Males:] Oily fish (n=46): 0.64 mmol/L ± 0.24; Control (n=46): 0.59 mmol/L ± 0.37, P>0.05; [underlined: Females:] Oily fish (n=50): 0.65 mmol/L ± 0.22; Control (n=56): 0.67 mmol/L ± 0.33, P>0.05 | Model adjustments:; Child age, race/ethnicity, SES; Limitations:; - Baseline sample size NR and therefore, attrition is unknown.; - Did not adjust for or report compliance.; - Did not account for baseline lipid/BP measures.; Funding sources:; 8th Five year Development Plan; Ministry of Agriculture and Fisheries Wealth, Sultanate of Oman
Garcia-Cervera, 2015 ^3^; RCT, Mexico; Baseline N=152 Analytic N=152 (Attrition: 0%); Participant characteristics at baseline:; - Child age: ~11-12y; - Female: 49.3%; - Race/ethnicity: NR; - SES: NR; - Health characteristics: 100% obese; - Infant feeding practices: NR; - Smoking: NR; - Baseline lipids: NR; Child seafood intake: NR; Seafood nutrient exposure: NR; Summary of findings: Children who consumed 6, 7 or 8g of tuna, compared to control, had significantly lower triglycerides, but not blood pressure and cholesterol. (Note: statistical tests NR) | Intervention:; - Fish (tuna) intake of 6, 7, or 8g for unknown duration and unknown frequency; - Control not described; [underlined: Compliance assessment]: NR; Outcomes and assessment methods:; - [underlined: Blood pressure:] NR; - [underlined: Blood lipids:] Fasting blood sample was collected; [underlined: Assessment timing:] NR | [underlined: SBP], post-intervention (mean ± SE); Tuna fish, 6g vs Control; [underlined: Boys (n=20):] Tuna: 107.60 mmHg ± 1.2; Control: 110.22 mmHg ± 1.4; [underlined: Girls (n=28):] Tuna: 102.10 mmHg ± 2.3; Control: 108.18 mmHg ± 1.6; Tuna fish, 7g vs Control; [underlined: Boys (n=32):] Tuna: 109.22 mmHg ± 1.2; Control: 100.44 mmHg ± 1.6; [underlined: Girls (n=22):] Tuna: 100.60 mmHg ± 1.2; Control: 104.00 mmHg ± 1.4; Tuna fish, 8g vs Control; [underlined: Boys (n=25):] Tuna: 102.40 mmHg ± 1.2; Control: 99.44 mmHg ± 1.6; [underlined: Girls (n=25):] Tuna: 100.02 mmHg ± 1.2; Control: 106.00 mmHg ± 1.6; [underlined: TC], post-intervention (mean ± SE); Tuna fish, 6g vs Control; [underlined: Boys (n=20):] Tuna: 165.14 mg/dL ± 2.1; Control: 168.10 mg/dL ± 1.6; [underlined: Girls (n=28):] Tuna: 166.04 mg/dL ± 1.4; Control: 170.24 mg/dL ± 1.2; Tuna fish, 7g vs Control; [underlined: Boys (n=32):] Tuna: 167.12 mg/dL ± 2.1; Control: 172.02 mg/dL ± 1.3; [underlined: Girls (n=22):] Tuna: 160.14 mg/dL ± 2.1; Control: 168.24 mg/dL ± 1.2; Tuna fish, 8g vs Control; [underlined: Boys (n=25):] Tuna: 158.14 mg/dL ± 2.1; Control: 168.02 mg/dL ± 1.3; [underlined: Girls (n=25):] Tuna: 144.18 mg/dL ± 2.4; Control: 166.02 mg/dL ± 1.2; [underlined: Triglycerides], post-intervention (mean ± SE); Tuna fish, 6g vs Control; [underlined: Boys (n=20):] Tuna: 198.00 mg/dL ± 18.0; Control: 217.40 mg/dL ± 14.0; [underlined: Girls (n=28):] Tuna: 200.00 mg/dL ± 18.0; Control: 220.00 mg/dL ± 14.0; Tuna fish, 7g vs Control; [underlined: Boys (n=32):] Tuna: 190.00 mg/dL ± 17.0; Control: 217.40 mg/dL ± 14.0; [underlined: Girls (n=22):] Tuna: 178.00 mg/dL ± 17.0; Control: 220.00 mg/dL ± 14.0; Tuna fish, 8g vs Control; [underlined: Boys (n=25):] Tuna: 160.00 mg/dL ± 15.0; Control: 217.40 mg/dL ± 14.0; [underlined: Girls (n=25):] Tuna: 144.00 mg/dL ± 15.0; Control: 220.00 mg/dL ± 14.0 | Model adjustments: None; Limitations:; - Intervention duration and frequency is unknown; - Compliance was not reported; - Study did not control for baseline levels; - Statistical test is unknown and NR; - Only SBP reported; - Small sample size in the 3 intervention arms; Funding sources: NR
Prospective Cohort Studies
Damsgaard, 2016 (https://www.ncbi.nlm.nih.gov/pubmed/27084093) ^2^; PCS, OPUS School Meal Study, Denmark; Baseline N=834 Analytic N=523 (Attrition: 37%); Participant characteristics at baseline:; - Child age: Mean=10.0y, SD=0.6; - Female: 48.6%; - Race/ethnicity: Non-Danish (two parents born outside Denmark): 10.5%; - SES: Parental education: Short education (upper and lower secondary and vocational education) 34%, Higher education (shorter higher education, bachelor’s degree and higher) 66%; - Health characteristics: Weight status: underweight 10.3%, normal weight 78.2%, overweight/obese 11.5%; BMI-for-age z-score: Mean=0.09, SD=1.03; Waist circumference (cm): Mean=62.3 (range: 59.1, 67.3); - Infant feeding practices: NR; - Smoking: NR; - DBP (Mean±SD): 68±7 mmHg; - HDL (Mean±SD): 1.44±0.30 mmol/L; - Triglyceride (Median, IQR): 0.60 (0.50-0.77) mmol/L; Child seafood intake: Baseline fish intake: Median: 13g/d (IQR: 2-29); Seafood nutrient exposure: NR; Summary of findings: Higher fish intake was associated with lower triglyceride levels (data NR), but not diastolic blood pressure and HDL cholesterol levels. | Exposure:; - Fish intake (g/d) at 10y (continuous); [underlined: Assessment method]: dietary intake measured for 7 consecutive days at baseline, 3 and 6mo using web-based dietary assessment software developed for the age group with parental help; [underlined: Assessment timing]: Baseline, 3mo follow-up, 6mo follow-up; Outcomes and assessment methods:; - [underlined: Blood pressure:] measured by automated device following 10 minute rest performed in triplicate (last 2 measurements averaged for outcome); - [underlined: Triglycerides and HDL cholesterol:] at baseline, 3 and 6mo in morning after overnight fast; [underlined: Assessment timing:] Baseline, 3mo follow-up, 6mo follow-up | Fish intake at 10y, continuous (per g/d increase), longitudinal associations; [underlined: DBP:] N=523; NR, P>0.05; [underlined: HDL:] N=523; NR, P>0.05; [underlined: Triglyceride:] N=523; NR, P<0.05 | Key confounders accounted for:; - Child sex, child age, non-fish dietary exposure to n-3 PUFA, anthropometry; Confounders NOT accounted for:; - Race/ethnicity, SES, smoking, family history of CVD; Additional model adjustments: Puberty, height at all visits, energy under-, normal- and over-reporting, outcome baseline values; random effects: child, sibling, class, year group, school; Limitations:; - Did not account for all key confounders; - Directness: Cohort derived from cluster randomized trial designed to examine whether whole-blood DHA and intakes of whole-grain, coarse vegetables and potatoes, dietary fiber, protein and fat were associated with metabolic syndrome markers; Funding sources:; Nordea Foundation; Danaeg A/S, Naturmaelk, Lantmannen A/S, Skaertoft Molle A/S, Kartoffelpartnerskabet, AkzoNobel Danmark, Gloria Mundi and Rose Pountry A/S provided food for study
Ness, 2005 (https://www.ncbi.nlm.nih.gov/pubmed/15958357) ^4^; PCS, Boyd Orr Cohort, U.K.; Baseline N=4,999 Analytic N=4,028 (Attrition: 19%); Participant characteristics at baseline:; - Child age: Mean=7.5y, SD=4.8 (IQR: 3.5-11.2); - Female: 50.5%; - Race/ethnicity: NR; - SES: Father’s social class: I 1.5%, II 7.2%, III 19.6%, IV 23.0%, V 14.3%, Unemployed 26.2%, Unclassifiable 8.2%; Townsend score (sum of standardized scores for levels of car ownership, house ownership, overcrowding, unemployment; negative values indicate less deprivation): −1.6 (Range: −2.8 to 0.9); - Health characteristics: NR; - Infant feeding practices: NR; - Smoking: NR; - Baseline lipids: NR; Child seafood intake: Oily fish intake: Some 43%, No 57%; Summary of findings: Highest level of fish intake at ~7.5y (SD=4.8), compared to the lowest level of fish intake, was associated with a higher rate of stroke mortality. Fish intake was not associated with coronary heart disease mortality. | Exposure:; - Fish intake in quartiles (Q):; - Q1 (Ref, lowest, Mean=1.8g, SD=2.4); - vs Q2 (Mean=11.3g, SD=2.5); - vs Q3 (Mean=21.6g, SD=3.9); - vs Q4 (highest, Mean=44.5g, SD=15.5); [underlined: Assessment method]: Data collection conducted between 1937 and 1939. Seven-day household inventory. Weighed inventory of all foods available in the household was recorded in a diary at baseline and after survey period. Per capita food and nutrient intake was calculated by dividing daily total food expenditure by total number of household members, taking into account meals missed by family members and meals consumed by visitors.; [underlined: Assessment timing]: Baseline; Outcomes and assessment methods:; - [underlined: CVD mortality:] Death certificate; [underlined: Assessment timing:] Length of follow-up: ~60y | Fish intake at 7.5y (RR=Rate Ratio); [underlined: Stroke mortality:] N=4,028; Q1 vs Q2: RR: 0.79, 95% CI: 0.39, 1.60; Q1 vs Q3: RR: 1.13, 95% CI: 0.58, 2.18; Q1 vs Q4: RR: 2.01, 95% CI: 1.09, 3.69; P for linear trend = 0.01; [underlined: Coronary heart disease mortality:] N=4,028; Q1 vs Q2: RR: 0.99, 95% CI: 0.68, 1.43; Q1 vs Q3: RR: 0.85, 95% CI: 0.58, 1.25; Q1 vs Q4: RR: 1.18, 95% CI: 0.80, 1.76; P for linear trend = 0.6; Oily fish intake at 7.5y; [underlined: Stroke mortality:] N=4,028; No oily fish (57%) vs Some oily fish (43%): NR, P>0.05; [underlined: Coronary heart disease mortality:] N=4,028; No oily fish (57%) vs Some oily fish (43%): NR, P>0.05 | Key confounders accounted for:; - Child sex, child age, SES; Key confounders NOT accounted for:; - Race/ethnicity, non-fish dietary exposure to n-3 PUFA, smoking, anthropometry, family history of CVD; Additional model adjustments: Energy, childhood family food expenditure, district of residence as a child, period of birth, season when studied as a child, Townsend score for current address or place of death; Limitations:; - Did not account for all key confounders; - Fish exposure was measured indirectly using a 7d weighed family food inventory divided by total number of household members irrespective of age or sex; Funding sources:; World Cancer Research Fund, Medical Research Council, British Heart Foundation

Table 2 Risk of bias for randomized controlled trials examining seafood consumption during childhood and adolescence and risk of cardiovascular disease^iv,v^

| Randomization | Identification of participants - randomization | Deviations from intended interventions - Intention to treat | Missing outcome data | Outcome measurement | Selection of the reported result
Al-Ghannami, 2018,^1^ RCT cluster | Low | Low | Some concerns | Low | Low | Low
Garcia-Cervera, 2015,^3^ RCT | Some concerns | Not applicable | Some concerns | Low | Low | Some concerns

Table 3 Risk of bias for observational studies examining seafood consumption during childhood and adolescence and risk of cardiovascular disease^vi^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Damsgaard, 2015^2^ | Serious | Low | Moderate | Low | Moderate | Low | Moderate
Ness, 2005^4^ | Serious | Moderate | Serious | Low | Moderate | Low | Moderate

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii Abbreviations: CI – confidence interval, d – day(s), DBP – diastolic blood pressure, DHA – docosahexaenoic acid, EPA – eicosapentaenoic acid, FA – fatty acids, HDL – HDL cholesterol, IQR – interquartile range, LDL – LDL cholesterol, mo – month(s), n-3 – omega-3, NA – not applicable, NR – not reported, RBC – red blood cell, RR – rate ratio, SBP – systolic blood pressure, SD – standard deviation, SE – standard error, SES – socioeconomic status, TC – total cholesterol, wk – week(s), x – times, y – year(s)

iv A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC..

v Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (https://www.riskofbias.info/welcome/rob-2-0-tool) (RoB 2.0) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

vi Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )