# References of the articles included in the rapid review

1 Anderson AS, Porteous LE, Foster E, . The impact of a school-based nutrition education intervention on dietary intake and cognitive and attitudinal variables relating to fruits and vegetables. Public Health Nutr. 2005;8(6):650–656. doi:10.1079/phn2004721.16236195
2 Bauer KW, Foster GD, Weeks HM, . Breakfast in the classroom initiative and students’ breakfast consumption behaviors: a group randomized trial. Am J Public Health. 2020;110(4):540–546. doi:10.2105/AJPH.2019.305511.32078356
3 Blom-Hoffman J, Kelleher C, Power TJ, Leff SS. Promoting healthy food consumption among young children: evaluation of a multi-component nutrition education program. J Sch Psychol. 2004;42(1):45–60. doi:10.1016/j.jsp.2003.08.004.
4 Blom-Hoffman J, Wilcox KR, Dunn L, Leff SS, Power TJ. Family involvement in school-based health promotion: bringing nutrition information home. School Psych Rev. 2008;37(4):567–577. doi:10.1080/02796015.2008.12087868.19633724
5 Evans CE, Ransley JK, Christian MS, Greenwood DC, Thomas JD, Cade JE. A cluster-randomised controlled trial of a school-based fruit and vegetable intervention: Project Tomato. Public Health Nutr. 2013;16(6):1073–1081. doi:10.1017/S1368980012005290.23237386
6 Foster GD, Sherman S, Borradaile KE, . A policy-based school intervention to prevent overweight and obesity. Pediatrics. 2008;121(4):e794–802. doi:10.1542/peds.2007-1365.18381508
7 Franken SCM, Smit CR, Buijzen M. Promoting water consumption on a Caribbean island: an intervention using children’s social networks at schools. Int J Environ Res Public Health. 2018;15(4). doi:10.3390/ijerph15040713.
8 Habib-Mourad C, Ghandour LA, Maliha C, Dagher M, Kharroubi S, Hwalla N. Impact of a three-year obesity prevention study on healthy behaviors and BMI among Lebanese schoolchildren: findings from Ajyal Salima Program. Nutrients. 2020;12(9). doi:10.3390/nu12092687.
9 Habib-Mourad C, Ghandour LA, Moore HJ, . Promoting healthy eating and physical activity among school children: findings from Health-E-PALS, the first pilot intervention from Lebanon. BMC Public Health. 2014;14:940. doi:10.1186/1471-2458-14-940.25208853
10 Hoffman JA, Franko DL, Thompson DR, Power TJ, Stallings VA. Longitudinal behavioral effects of a school-based fruit and vegetable promotion program. J Pediatr Psychol. 2010;35(1):61–71. doi:10.1093/jpepsy/jsp041.19439567
11 Hoffman JA, Thompson DR, Franko DL, Power TJ, Leff SS, Stallings VA. Decaying behavioral effects in a randomized, multi-year fruit and vegetable intake intervention. Prev Med. 2011;52(5):370–375. doi:10.1016/j.ypmed.2011.02.013.21371499
12 Horne PJ, Hardman CA, Lowe CF, . Increasing parental provision and children’s consumption of lunchbox fruit and vegetables in Ireland: the Food Dudes intervention. Eur J Clin Nutr. 2009;63(5):613–618. doi:10.1038/ejcn.2008.34.18493261
13 Lien N, Haerens L, te Velde SJ, . Exploring subgroup effects by socioeconomic position of three effective school-based dietary interventions: the European TEENAGE project. Int J Public Health. 2014;59(3):493–502. doi:10.1007/s00038-013-0524-8.24212326
14 Liz Martins M, Rodrigues SS, Cunha LM, Rocha A. Strategies to reduce plate waste in primary schools - experimental evaluation. Public Health Nutr. 2016;19(8):1517–1525. doi:10.1017/S1368980015002797.26507607
15 Morrill BA, Madden GJ, Wengreen HJ, Fargo JD, Aguilar SS. A randomized controlled trial of the Food Dudes program: tangible rewards are more effective than social rewards for increasing short- and long-term fruit and vegetable consumption. J Acad Nutr Diet. 2016;116(4):618–629. doi:10.1016/j.jand.2015.07.001.26297598
16 Qian L, Newman IM, Yuen LW, Du W, Shell DF. Effects of a comprehensive nutrition education programme to change grade 4 primary-school students’ eating behaviours in China. Public Health Nutr. 2019;22(5):903–911. doi:10.1017/S1368980018003713.30616695
17 Reynolds KD, Franklin FA, Binkley D, . Increasing the fruit and vegetable consumption of fourth-graders: results from the high 5 project. Prev Med. 2000;30(4):309–319. doi:10.1006/pmed.1999.0630.10731460
18 Scherr RE, Linnell JD, Dharmar M, . A multicomponent, school-based intervention, the shaping healthy choices program, improves nutrition-related outcomes. J Nutr Educ Behav. 2017;49(5):368–379.e361. doi:10.1016/j.jneb.2016.12.007.28189500
19 Sichieri R, Paula Trotte A, e Souza RA, Veiga GV. School randomised trial on prevention of excessive weight gain by discouraging students from drinking sodas. Public Health Nutr. 2009;12(2):197–202. doi:10.1017/S1368980008002644.18559131
20 Te Velde SJ, Brug J, Wind M, . Effects of a comprehensive fruit- and vegetable-promoting school-based intervention in three European countries: the Pro Children Study. Br J Nutr. 2008;99(4):893–903. doi:10.1017/S000711450782513X.17953787
21 Ashfield-Watt PA, Stewart EA, Scheffer JA. A pilot study of the effect of providing daily free fruit to primary-school children in Auckland, New Zealand. Public Health Nutr. 2009;12(5):693–701. doi:10.1017/S1368980008002954.18664310
22 Belot M, James J, Nolen P. Incentives and children’s dietary choices: a field experiment in primary schools. J Health Econ. 2016;50:213–229. doi:10.1016/j.jhealeco.2016.07.003.27545409
23 Brauchla M, McCabe GP, Miller KB, Kranz S. The effect of high fiber snacks on digestive function and diet quality in a sample of school-age children. Nutr J. 2013;12:153. doi:10.1186/1475-2891-12-153.24274323
24 Cohen JF, Richardson SA, Cluggish SA, Parker E, Catalano PJ, Rimm EB. Effects of choice architecture and chef-enhanced meals on the selection and consumption of healthier school foods: a randomized clinical trial. JAMA Pediatr. 2015;169(5):431–437. doi:10.1001/jamapediatrics.2014.3805.25798990
25 Coleman KJ, Shordon M, Caparosa SL, Pomichowski ME, Dzewaltowski DA. The healthy options for nutrition environments in schools (Healthy ONES) group randomized trial: using implementation models to change nutrition policy and environments in low income schools. Int J Behav Nutr Phys Act. 2012;9:80. doi:10.1186/1479-5868-9-80.22734945
26 Cullen KW, Chen TA, Dave JM, Jensen H. Differential improvements in student fruit and vegetable selection and consumption in response to the new national school lunch program regulations: a pilot study. J Acad Nutr Diet. 2015;115(5):743–750. doi:10.1016/j.jand.2014.10.021.25556770
27 Delaney T, Wyse R, Yoong SL, . Cluster randomized controlled trial of a consumer behavior intervention to improve healthy food purchases from online canteens. Am J Clin Nutr. 2017;106(5):1311–1320. doi:10.3945/ajcn.117.158329.28971849
28 Folta SC, Goldberg JP, Economos C, Bell R, Landers S, Hyatt R. Assessing the use of school public address systems to deliver nutrition messages to children: Shape up Somerville--audio adventures. J Sch Health. 2006;76(9):459–464; quiz 482-454. doi:10.1111/j.1746-1561.2006.00141.x.17026639
29 Goto K, Waite A, Wolff C, Chan K, Giovanni M. Do environmental interventions impact elementary school students’ lunchtime milk selection? Appl Econ Perspect Policy. 2013;35(2):360–376. doi:10.1093/aepp/ppt004.
30 Gray C, Lytle LA, Perry C, Story M, Taylor G, Bishop D. Fruits and vegetables taken can serve as a proxy measure for amounts eaten in a school lunch. J Am Diet Assoc. 2007;107(6):1019–1023. doi:10.1016/j.jada.2007.03.001.17524724
31 Hendy HM, Williams KE, Camise TS. “Kids Choice” school lunch program increases children’s fruit and vegetable acceptance. Appetite. 2005;45(3):250–263. doi:10.1016/j.appet.2005.07.006.16157415
32 Lai CY, List JA, Samek A. Got milk? Using nudges to reduce consumption of added sugar. Am J Agric Econ. 2020;102(1):154–168. doi:10.1093/ajae/aaz022.
33 Loewenstein G, Price J, Volpp K. Habit formation in children: evidence from incentives for healthy eating. J Health Econ. 2016;45:47–54. doi:10.1016/j.jhealeco.2015.11.004.26717440
34 Mazzeo SE, Bean MK, Palmberg AA, . A pilot intervention targeting dietary intake in school cafeterias. Health Behav Policy Rev. 2017;4(3):256–264. doi:10.14485/hbpr.4.3.6.32864385
35 Moore L, Tapper K. The impact of school fruit tuck shops and school food policies on children’s fruit consumption: a cluster randomised trial of schools in deprived areas. J Epidemiol Community Health. 2008;62(10):926–931. doi:10.1136/jech.2007.070953.18483061
36 Morizet D, Depezay L, Combris P, Picard D, Giboreau A. Effect of labeling on new vegetable dish acceptance in preadolescent children. Appetite. 2012;59(2):399–402. doi:10.1016/j.appet.2012.05.030.22664298
37 Olsen A, Ritz C, Kraaij LW, Moller P. Children’s liking and intake of vegetables: a school-based intervention study. Food Qual Prefer. 2012;23(2):90–98. doi:10.1016/j.foodqual.2011.10.004.
38 Perry CL, Bishop DB, Taylor GL, . A randomized school trial of environmental strategies to encourage fruit and vegetable consumption among children. Health Educ Behav. 2004;31(1):65–76. doi:10.1177/1090198103255530.14768658
39 Raju S, Rajagopal P, Gilbride TJ. Marketing healthful eating to children: the effectiveness of incentives, pledges, and competitions. J Mark. 2010;74(3):93–106. doi:10.1509/jmkg.74.3.093.
40 Reinaerts E, Crutzen R, Candel M, De Vries NK, De Nooijer J. Increasing fruit and vegetable intake among children: comparing long-term effects of a free distribution and a multicomponent program. Health Educ Res. 2008;23(6):987–996. doi:10.1093/her/cyn027.18550582
41 Reinaerts E, e Nooijer J, Candel M, e Vries N. Increasing children’s fruit and vegetable consumption: distribution or a multicomponent programme? Public Health Nutr. 2007;10(9):939–947. doi:10.1017/S1368980007665495.17381944
42 Samek A. Gifts and goals: behavioral nudges to improve child food choice at school. J Econ Behav Organ. 2019;164:1–12. doi:10.1016/j.jebo.2019.05.008.
43 Schwartz MB. The influence of a verbal prompt on school lunch fruit consumption: a pilot study. Int J Behav Nutr Phys Act. 2007;4:6. doi:10.1186/1479-5868-4-6.17338812
44 Shemilt I, Harvey I, Shepstone L, . A national evaluation of school breakfast clubs: evidence from a cluster randomized controlled trial and an observational analysis. Child Care Health Dev. 2004;30(5):413–427. doi:10.1111/j.1365-2214.2004.00453.x.15320919
45 van Kleef E, Bruggers I, e Vet E. Encouraging vegetable intake as a snack among children: the influence of portion and unit size. Public Health Nutr. 2015;18(15):2736–2741. doi:10.1017/S1368980015001329.25926006
46 van Kleef E, Vrijhof M, Polet IA, Vingerhoeds MH, e Wijk RA. Nudging children towards whole wheat bread: a field experiment on the influence of fun bread roll shape on breakfast consumption. BMC Public Health. 2014;14:906. doi:10.1186/1471-2458-14-906.25181935
47 Vandeweghe L, Verbeken S, Braet C, Loeys T, De Henauw S, Moens E. Strategies to increase preschoolers’ vegetable liking and consumption: The role of reward sensitivity. Food Qual Prefer. 2018;66:153–159. doi:10.1016/j.foodqual.2018.01.009.
48 Wolfenden L, Nathan N, Janssen LM, . Multi-strategic intervention to enhance implementation of healthy canteen policy: a randomised controlled trial. Implement Sci. 2017;12(1):6. doi:10.1186/s13012-016-0537-9.28077151
49 Wyse R, Gabrielyan G, Wolfenden L, . Can changing the position of online menu items increase selection of fruit and vegetable snacks? A cluster randomized trial within an online canteen ordering system in Australian primary schools. Am J Clin Nutr. 2019;109(5):1422–1430. doi:10.1093/ajcn/nqy351.30949660
50 Abdel Gawwad ES, Fetohy EM, Fiala L, Al Orf SM, Al Saif M. Impact evaluation of nutrition education intervention for an elementary school in Riyadh City. J Egypt Public Health Assoc. 2006;81(1–2):75–97.17382085
51 Arrizabalaga-López M, Rada-Fernández de Jáuregui D, Portillo MDP, . A theory-based randomized controlled trial in promoting fruit and vegetable intake among schoolchildren: PROFRUVE study. Eur J Nutr. 2020;59(8):3517–3526. doi:10.1007/s00394-020-02185-5.32008063
52 Bannon K, Schwartz MB. Impact of nutrition messages on children’s food choice: pilot study. Appetite. 2006;46(2):124–129. doi:10.1016/j.appet.2005.10.009.16442667
53 Baranowski T, Baranowski J, Cullen KW, . Squire’s Quest! Dietary outcome evaluation of a multimedia game. Am J Prev Med. 2003;24(1):52–61. doi:10.1016/s0749-3797(02)00570-6.12554024
54 Baranowski T, Davis M, Resnicow K, . Gimme 5 fruit, juice, and vegetables for fun and health: outcome evaluation. Health Educ Behav. 2000;27(1):96–111. doi:10.1177/109019810002700109.10709795
55 Bashirian S, Allahverdipour H, Moeini B. Fruit and vegetable intakes among elementary schools’ pupils: Using five-a-day educational program. J Res Health Sci. 2008;8(1):56–63. http://jrhs.umsha.ac.ir/index.php/JRHS/article/view/277/.23343998
56 Battjes-Fries MCE, Haveman-Nies A, Zeinstra GG, . Effectiveness of taste lessons with and without additional experiential learning activities on children’s willingness to taste vegetables. Appetite. 2017;109:201–208. doi:10.1016/j.appet.2016.05.020.27215840
57 Christian MS, Evans CE, Nykjaer C, Hancock N, Cade JE. Evaluation of the impact of a school gardening intervention on children’s fruit and vegetable intake: a randomised controlled trial. Int J Behav Nutr Phys Act. 2014;11:99. doi:10.1186/s12966-014-0099-7.25128211
58 Cotter J, Cotter MJ, Oliveira P, Cunha P, Polónia J. Salt intake in children 10-12 years old and its modification by active working practices in a school garden. J Hypertens. 2013;31(10):1966–1971. doi:10.1097/HJH.0b013e328363572f.24107730
59 Cullen KW, Watson K, Baranowski T, Baranowski JH, Zakeri I. Squire’s Quest: intervention changes occurred at lunch and snack meals. Appetite. 2005;45(2):148–151. doi:10.1016/j.appet.2005.04.001.15927302
60 Cunha DB, e Souza Bda S, Pereira RA, Sichieri R. Effectiveness of a randomized school-based intervention involving families and teachers to prevent excessive weight gain among adolescents in Brazil. PLoS One. 2013;8(2):e57498. doi:10.1371/journal.pone.0057498.23451237
61 Drapeau V, Savard M, Gallant A, Nadeau L, Gagnon J. The effectiveness of a school-based nutrition intervention on children’s fruit, vegetables, and dairy product intake. J Sch Health. 2016;86(5):353–362. doi:10.1111/josh.12385.27040473
62 Gatto NM, Martinez LC, Spruijt-Metz D, Davis JN. LA sprouts randomized controlled nutrition, cooking and gardening programme reduces obesity and metabolic risk in Hispanic/Latino youth. Pediatr Obes. 2017;12(1):28–37. doi:10.1111/ijpo.12102.26909882
63 Gold A, Larson M, Tucker J, Strang M. Classroom nutrition education combined with fruit and vegetable taste testing improves children’s dietary intake. J Sch Health. 2017;87(2):106–113. doi:10.1111/josh.12478.28076921
64 Griffin TL, Jackson DM, McNeill G, Aucott LS, Macdiarmid JI. A brief educational intervention increases knowledge of the sugar content of foods and drinks but does not decrease intakes in Scottish children aged 10-12 Years. J Nutr Educ Behav. 2015;47(4):367–373.e361. doi:10.1016/j.jneb.2015.03.009.25956017
65 He FJ, Wu Y, Feng XX, . School based education programme to reduce salt intake in children and their families (School-EduSalt): cluster randomised controlled trial. BMJ. 2015;350:h770. doi:10.1136/bmj.h770.25788018
66 Jamelske EM, Vernon E. The sustained impact of teacher encouragement on elementary students’ vegetable snack consumption: initial findings from a Wisconsin study. J Child Nutr Manag. 2018;42(1). https://schoolnutrition.org/uploadedFiles/5_News_and_Publications/4_The_Journal_of_Child_Nutrition_and_Management/Spring_2018/Sustained-Impact-of-Teacher-Encouragement-on-Elementary-Students-Spring2018.pdf.
67 James J, Thomas P, Cavan D, Kerr D. Preventing childhood obesity by reducing consumption of carbonated drinks: cluster randomised controlled trial. BMJ. 2004;328(7450):1237. doi:10.1136/bmj.38077.458438.EE.15107313
68 Katz DL, Katz CS, Treu JA, . Teaching healthful food choices to elementary school students and their parents: the Nutrition Detectives™ program. J Sch Health. 2011;81(1):21–28. doi:10.1111/j.1746-1561.2010.00553.x.21158862
69 Kaufman-Shriqui V, Fraser D, Friger M, . Effect of a school-based intervention on nutritional knowledge and habits of low-socioeconomic school children in Israel: a cluster-randomized controlled trial. Nutrients. 2016;8(4):234. doi:10.3390/nu8040234.27110817
70 LaChausse RG. A clustered randomized controlled trial to determine impacts of the Harvest of the Month program. Health Educ Res. 2017;32(5):375–383. doi:10.1093/her/cyx056.28931166
71 Larsen AL, Robertson T, Dunton G. RE-AIM analysis of a randomized school-based nutrition intervention among fourth-grade classrooms in California. Transl Behav Med. 2015;5(3):315–326. doi:10.1007/s13142-015-0311-6.26327937
72 Lehto R, Määttä S, Lehto E, . The PRO GREENS intervention in Finnish schoolchildren - the degree of implementation affects both mediators and the intake of fruits and vegetables. Br J Nutr. 2014;112(7):1185–1194. doi:10.1017/S0007114514001767.25106046
73 Llauradó E, Tarro L, Moriña D, Queral R, Giralt M, Solà R. EdAl-2 (Educació en Alimentació) programme: reproducibility of a cluster randomised, interventional, primary-school-based study to induce healthier lifestyle activities in children. BMJ Open. 2014;4(11):e005496. doi:10.1136/bmjopen-2014-005496.
74 Mangunkusumo RT, Brug J, e Koning HJ, van der Lei J, Raat H. School-based internet-tailored fruit and vegetable education combined with brief counselling increases children’s awareness of intake levels. Public Health Nutr. 2007;10(3):273–279. doi:10.1017/S1368980007246671.17288625
75 Panunzio MF, Antoniciello A, Pisano A, Dalton S. Nutrition education intervention by teachers may promote fruit and vegetable consumption in Italian students. Nutrition Research. 2007;27(9):524–528. doi:10.1016/J.NUTRES.2007.06.012.
76 Panunzio MF, Caporizzi R, Antoniciello A, . Training the teachers for improving primary schoolchildren’s fruit and vegetables intake: a randomized controlled trial. Ann Ig. 2011;23(3):249–260. https://pubmed.ncbi.nlm.nih.gov/22013704/.22013704
77 Perikkou A, Gavrieli A, Kougioufa MM, Tzirkali M, Yannakoulia M. A novel approach for increasing fruit consumption in children. J Acad Nutr Diet. 2013;113(9):1188–1193. doi:10.1016/j.jand.2013.05.024.23871109
78 Perry CL, Zauner M, Oakes JM, Taylor G, Bishop DB. Evaluation of a theater production about eating behavior of children. J Sch Health. 2002;72(6):256–261. doi:10.1111/j.1746-1561.2002.tb07339.x.12212411
79 Ribeiro-Silva RD, Silva LA, Cangussu MCT. Effect of actions promoting healthy eating on students’ lipid profile: a controlled trial. Revista de Nutrição. 2014;27(2):183–192. doi:10.1590/1415-52732014000200005.
80 Rosário R, Araújo A, Oliveira B, . The impact of an intervention taught by trained teachers on childhood fruit and vegetable intake: a randomized trial. J Obes. 2012;2012:342138. doi:10.1155/2012/342138.22523664
81 Rosário R, Araújo A, Oliveira B, . Impact of an intervention through teachers to prevent consumption of low nutrition, energy-dense foods and beverages: a randomized trial. Prev Med. 2013;57(1):20–25. doi:10.1016/j.ypmed.2013.02.027.23583478
82 Rosário R, Araújo A, Padrão P, . Impact of a school-based intervention to promote fruit intake: a cluster randomized controlled trial. Public Health. 2016;136:94–100. doi:10.1016/j.puhe.2016.03.013.27101881
83 Rosário R, Araújo A, Padrão P, . Health promotion intervention to improve diet quality in children. Health Promot Pract. 2017;18(2):253–262. doi:10.1177/1524839916634096.27095035
84 Serebrennikov D, Katare B, Kirkham L, Schmitt S. Effect of classroom intervention on student food selection and plate waste: Evidence from a randomized control trial. PLoS One. 2020;15(1):e0226181. doi:10.1371/journal.pone.0226181.31918437
85 Sgambato MR, Cunha DB, Souza BSN, . Effectiveness of school-home intervention for adolescent obesity prevention: parallel school randomised study. Br J Nutr. 2019;122(9):1073–1080. doi:10.1017/S0007114519001818.31342893
86 Sharma SV, Shegog R, Chow J, . Effects of the Quest to Lava Mountain computer game on dietary and physical activity behaviors of elementary school children: a pilot group-randomized controlled trial. J Acad Nutr Diet. 2015;115(8):1260–1271. doi:10.1016/j.jand.2015.02.022.25912520
87 Smith DK, Mandal B, Wallace ML, . Exploring pulses through math, science, and nutrition activities. J Child Nutr Manag. 2016;40(1). https://schoolnutrition.org/uploadedFiles/5_News_and_Publications/4_The_Journal_of_Child_Nutrition_and_Management/Spring_2016/10-ExploringPulses.pdf.
88 Struempler BJ, Parmer SM, Mastropietro LM, Arsiwalla D, Bubb RR. Changes in fruit and vegetable consumption of third-grade students in body quest: food of the warrior, a 17-class childhood obesity prevention program. J Nutr Educ Behav. 2014;46(4):286–292. doi:10.1016/j.jneb.2014.03.001.24767729
89 Taghdisi MH, Babazadeh T, Moradi F, Shariat F. Effect of educational intervention on the fruit and vegetables consumption among the students: applying theory of planned behavior. J Res Health Sci. 2016;16(4):195–199.28087851
90 Tarro L, Llauradó E, Aceves-Martins M, . Impact of a youth-led social marketing intervention run by adolescents to encourage healthy lifestyles among younger school peers (EYTO-Kids project): a parallel-cluster randomised controlled pilot study. J Epidemiol Community Health. 2019;73(4):324–333. doi:10.1136/jech-2017-210163.30683803
91 Tarro L, Llauradó E, Albaladejo R, . A primary-school-based study to reduce the prevalence of childhood obesity--the EdAl (Educació en Alimentació) study: a randomized controlled trial. Trials. 2014;15:58. doi:10.1186/1745-6215-15-58.24529258
92 Tarro L, Llauradó E, Moriña D, Solà R, Giralt M. Follow-up of a healthy lifestyle education program (the Educació en Alimentació Study): 2 years after cessation of intervention. J Adolesc Health. 2014;55(6):782–789. doi:10.1016/j.jadohealth.2014.06.020.25193385
93 Turnin MC, Tauber MT, Couvaras O, . Evaluation of microcomputer nutritional teaching games in 1,876 children at school. Diabetes Metab. 2001;27(4 Pt 1):459–464. https://pubmed.ncbi.nlm.nih.gov/11547219/.11547219
94 Vardanjani AE, Reisi M, Javadzade H, Pour ZG, Tavassoli E. The effect of nutrition education on knowledge, attitude, and performance about junk food consumption among students of female primary schools. J Educ Health Promot. 2015;4:53. doi:10.4103/2277-9531.162349.26430680
95 van den Berg A, Warren JL, McIntosh A, . Impact of a gardening and physical activity intervention in Title 1 schools: The TGEG Study. Child Obes. 2020;16(S1):S44–s54. doi:10.1089/chi.2019.0238.32857610
96 Viggiano E, Viggiano A, Di Costanzo A, . Healthy lifestyle promotion in primary schools through the board game Kaledo: a pilot cluster randomized trial. Eur J Pediatr. 2018;177(9):1371–1375. doi:10.1007/s00431-018-3091-4.29353440
97 Williams O, DeSorbo A, Sawyer V, . Hip Hop HEALS: pilot study of a culturally targeted calorie label intervention to improve food purchases of children. Health Educ Behav. 2016;43(1):68–75. doi:10.1177/1090198115596733.26272785
98 Zota D, Dalma A, Petralias A, . Promotion of healthy nutrition among students participating in a school food aid program: a randomized trial. Int J Public Health. 2016;61(5):583–592. doi:10.1007/s00038-016-0813-0.27022997
99 Vale A, Schumacher JR, Cullen RW, Gam HJ. Vegetable purée: a pilot study to increase vegetable consumption among school lunch participants in US elementary schools. J Child Nutr Manag. 2014;38(2). https://schoolnutrition.org/uploadedFiles/5_News_and_Publications/4_The_Journal_of_Child_Nutrition_and_Management/Fall_2014/Vegetable%20Pure%C3%A9.pdf.
100 Miller GF, Gupta S, Kropp JD, Grogan KA, Mathews A. The effects of pre-ordering and behavioral nudges on National School Lunch Program participants’ food item selection. J Econ Psychol. 2016;55:4–16. doi:10.1016/j.joep.2016.02.010.
101 Marchiori D, Waroquier L, Klein O. “Split them!” smaller item sizes of cookies lead to a decrease in energy intake in children. J Nutr Educ Behav. 2012;44(3):251–255. doi:10.1016/j.jneb.2011.07.007.22391143
102 de Droog SM, Buijzen M, Valkenburg PM. Enhancing children’s vegetable consumption using vegetable-promoting picture books. The impact of interactive shared reading and character-product congruence. Appetite. 2014;73:73–80. doi:10.1016/j.appet.2013.10.018.24216486
103 Gonçalves S, Ferreira R, Conceição EM, . The impact of exposure to cartoons promoting healthy eating on children’s food preferences and choices. J Nutr Educ Behav. 2018;50(5):451–457. doi:10.1016/j.jneb.2017.12.015.29478953
104 Hermans RCJ, van den Broek N, Nederkoorn C, Otten R, Ruiter ELM, Johnson-Glenberg MC. Feed the Alien! The effects of a nutrition instruction game on children’s nutritional knowledge and food intake. Games Health J. 2018;7(3):164–174. doi:10.1089/g4h.2017.0055.29634366
105 Leung MM, Tripicchio G, Agaronov A, Hou N. Manga comic influences snack selection in Black and Hispanic New York City youth. J Nutr Educ Behav. 2014;46(2):142–147. doi:10.1016/j.jneb.2013.11.004.24433817
106 Warren JM, Henry CJ, Lightowler HJ, Bradshaw SM, Perwaiz S. Evaluation of a pilot school programme aimed at the prevention of obesity in children. Health Promot Int. 2003;18(4):287–296. doi:10.1093/heapro/dag402.14695360
107 Amaro S, Viggiano A, Di Costanzo A, . Kalèdo, a new educational board-game, gives nutritional rudiments and encourages healthy eating in children: a pilot cluster randomized trial. Eur J Pediatr. 2006;165(9):630–635. doi:10.1007/s00431-006-0153-9.16733670
108 Bere E, Veierød MB, Bjelland M, Klepp KI. Outcome and process evaluation of a Norwegian school-randomized fruit and vegetable intervention: Fruits and Vegetables Make the Marks (FVMM). Health Educ Res. 2006;21(2):258–267. doi:10.1093/her/cyh062.16219631
109 Bessems KM, van Assema P, Martens MK, . Healthier food choices as a result of the revised healthy diet programme Krachtvoer for students of prevocational schools. Int J Behav Nutr Phys Act. 2012;9:60. doi:10.1186/1479-5868-9-60.22625222
110 Brito Beck da Silva K, Leovigildo Fiaccone R, Couto RD, Ribeiro-Silva Rde C. Evaluation of the effects of a programme promoting adequate and healthy eating on adolescent health markers: an interventional study. Nutr Hosp. 2015;32(4):1582–1590. doi:10.3305/nh.2015.32.4.9512.26545521
111 Brito Beck da Silva K, Ortelan N, Giardini Murta S, . Evaluation of the computer-based intervention program Stayingfit Brazil to promote healthy eating habits: the results from a school cluster-randomized controlled trial. Int J Environ Res Public Health. 2019;16(10). doi:10.3390/ijerph16101674.
112 Chamberland K, Sanchez M, Panahi S, Provencher V, Gagnon J, Drapeau V. The impact of an innovative web-based school nutrition intervention to increase fruits and vegetables and milk and alternatives in adolescents: a clustered randomized trial. Int J Behav Nutr Phys Act. 2017;14(1):140. doi:10.1186/s12966-017-0595-7.29037203
113 Chung LMY, Fong SSM. Role of behavioural feedback in nutrition education for enhancing nutrition knowledge and improving nutritional behaviour among adolescents. Asia Pac J Clin Nutr. 2018;27(2):466–472. doi:10.6133/apjcn.042017.03.29384337
114 Dehdari T, Rahimi T, Aryaeian N, Gohari MR. Effect of nutrition education intervention based on Pender’s Health Promotion Model in improving the frequency and nutrient intake of breakfast consumption among female Iranian students. Public Health Nutr. 2014;17(3):657–666. doi:10.1017/S1368980013000049.23360695
115 Dehdari T, Yekehfallah F, Rahimzadeh M, Aryaeian N, Rahimi T. Dairy foods intake among female Iranian students: a nutrition education intervention using a health promotion model. Glob J Health Sci. 2016;8(10):54893. doi:10.5539/gjhs.v8n10p192.27302436
116 Dohnke B, Dewitt T, Steinhilber A. A prototype-targeting intervention for the promotion of healthy eating in adolescents: development and evaluation using intervention mapping. Health Educ. 2018;118(6):450–469. doi:10.1108/HE-11-2017-0065.
117 Forneris T, Fries E, Meyer A, . Results of a rural school-based peer-led intervention for youth: goals for health. J Sch Health. 2010;80(2):57–65. doi:10.1111/j.1746-1561.2009.00466.x.20236403
118 Karimi-Shahanjarini A, Rashidian A, Omidvar N, Majdzadeh R. Assessing and comparing the short-term effects of TPB only and TPB plus implementation intentions interventions on snacking behavior in Iranian adolescent girls: a cluster randomized trial. Am J Health Promot. 2013;27(3):152–161. doi:10.4278/ajhp.110311-QUAN-113.23286591
119 Keshani P, Hossein Kaveh M, Faghih S, Salehi M. Improving diet quality among adolescents, using health belief model in a collaborative learning context: a randomized field trial study. Health Educ Res. 2019;34(3):279–288. doi:10.1093/her/cyz009.30915431
120 Lane H, Porter KJ, Hecht E, Harris P, Kraak V, Zoellner J. Kids SIP smartER: a feasibility study to reduce sugar-sweetened beverage consumption among middle school youth in Central Appalachia. Am J Health Promot. 2018;32(6):1386–1401. doi:10.1177/0890117117715052.28731385
121 Martens MK, Van Assema P, Paulussen TG, Van Breukelen G, Brug J. Krachtvoer: effect evaluation of a Dutch healthful diet promotion curriculum for lower vocational schools. Public Health Nutr. 2008;11(3):271–278. doi:10.1017/S1368980007000298.17605839
122 Mora T, Lopez-Valcarcel BG. Breakfast choice: an experiment combining a nutritional training workshop targeting adolescents and the promotion of unhealthy products. Health Econ. 2018;27(2):306–319. doi:10.1002/hec.3549.28744931
123 Øvrebø B, Stea TH, Te Velde SJ, Bjelland M, Klepp KI, Bere E. A comprehensive multicomponent school-based educational intervention did not affect fruit and vegetable intake at the 14-year follow-up. Prev Med. 2019;121:79–85. doi:10.1016/j.ypmed.2019.02.015.30753861
124 Rees G, Bakhshi S, Surujlal-Harry A, Stasinopoulos M, Baker A. A computerised tailored intervention for increasing intakes of fruit, vegetables, brown bread and wholegrain cereals in adolescent girls. Public Health Nutr. 2010;13(8):1271–1278. doi:10.1017/S1368980009992953.20059794
125 Rennie LJ, Bazillier-Bruneau C, Rouëssé J. CaPSCA: evaluation of a brief cancer prevention education programme to promote balanced diet in French school children. J Cancer Educ. 2015;30(4):759–765. doi:10.1007/s13187-014-0773-0.25527069
126 Sahingoz SA, Dogan L. The implementation and evaluation of a nutrition education programme about Mediterranean diet for adolescents. Prog Nutr. 2019;21(2):316–326. doi:10.23751/pn.v21i2.7529.
127 Ghasab Shirazi M, Kazemi A, Kelishadi R, Mostafavi F. The improvement of dietary behaviors among Iranian adolescent girls: a theory-based randomized controlled trial. Health Educ Res. 2019;34(2):159–172. doi:10.1093/her/cyz004.30789207
128 Takacs H, Martos E, Kovacs VA. Effects of a practice-focused nutrition intervention in Hungarian adolescents. Ann Ist Super Sanita. 2020;56(1):99–106. doi:10.4415/ANN_20_01_14.32242541
129 Toral N, Slater B. Intervention based exclusively on stage-matched printed educational materials regarding healthy eating does not result in changes to adolescents’ dietary behavior. Sci World J. 2012;2012:174640. doi:10.1100/2012/174640.
130 Viggiano A, Viggiano E, Di Costanzo A, . Kaledo, a board game for nutrition education of children and adolescents at school: cluster randomized controlled trial of healthy lifestyle promotion. Eur J Pediatr. 2015;174(2):217–228. doi:10.1007/s00431-014-2381-8.25048788
131 Wang D, Stewart D, Chang C, Shi Y. Effect of a school-based nutrition education program on adolescents’ nutrition-related knowledge, attitudes and behaviour in rural areas of China. Environ Health Prev Med. 2015;20(4):271–278. doi:10.1007/s12199-015-0456-4.25773683
132 Wang D, Stewart D, Yuan Y, Chang C. Do health-promoting schools improve nutrition in China? Health Promot Int. 2015;30(2):359–368. doi:10.1093/heapro/dat047.23828912
133 Yamaoka K, Watanabe M, Hida E, Tango T. Impact of group-based dietary education on the dietary habits of female adolescents: a cluster randomized trial. Public Health Nutr. 2011;14(4):702–708. doi:10.1017/S1368980010002405.20843402
134 French SA, Story M, Fulkerson JA, Hannan P. An environmental intervention to promote lower-fat food choices in secondary schools: outcomes of the TACOS Study. Am J Public Health. 2004;94(9):1507–1512. doi:10.2105/ajph.94.9.1507.15333303
135 Greene KN, Gabrielyan G, Just DR, Wansink B. Fruit-promoting smarter lunchrooms interventions: results From a cluster RCT. Am J Prev Med. 2017;52(4):451–458. doi:10.1016/j.amepre.2016.12.015.28214248
136 Johnston CA, Palcic JL, Tyler C, Stansberry S, Reeves RS, Foreyt JP. Increasing vegetable intake in Mexican-American youth: a randomized controlled trial. J Am Diet Assoc. 2011;111(5):716–720. doi:10.1016/j.jada.2011.02.006.21515118
137 Kocken PL, Eeuwijk J, Van Kesteren NM, . Promoting the purchase of low-calorie foods from school vending machines: a cluster-randomized controlled study. J Sch Health. 2012;82(3):115–122. doi:10.1111/j.1746-1561.2011.00674.x.22320335
138 Wansink B, Just DR, Hanks AS, Smith LE. Pre-sliced fruit in school cafeterias: children’s selection and intake. Am J Prev Med. 2013;44(5):477–480. doi:10.1016/j.amepre.2013.02.003.23597811
139 Prell HC, Berg MC, Jonsson LM, Lissner L. A school-based intervention to promote dietary change. J Adolesc Health. 2005;36(6):529. doi:10.1016/j.jadohealth.2004.08.009.
140 He M, Beynon C, Sangster Bouck M, . Impact evaluation of the Northern Fruit and Vegetable Pilot Programme - a cluster-randomised controlled trial. Public Health Nutr. 2009;12(11):2199–2208. doi:10.1017/S1368980009005801.19476675
141 Anttonen V, Seppä L, Niinimaa A, Hausen H. Dietary and oral hygiene intervention in secondary school pupils. Int J Paediatr Dent. 2011;21(2):81–88. doi:10.1111/j.1365-263X.2010.01095.x.20731735
142 Bere E, Veierød MB, Bjelland M, Klepp KI. Free school fruit--sustained effect 1 year later. Health Educ Res. 2006;21(2):268–275. doi:10.1093/her/cyh063.16219630
143 Birnbaum AS, Lytle LA, Story M, Perry CL, Murray DM. Are differences in exposure to a multicomponent school-based intervention associated with varying dietary outcomes in adolescents? Health Educ Behav. 2002;29(4):427–443. doi:10.1177/109019810202900404.12137237
144 Bogart LM, Cowgill BO, Elliott MN, . A randomized controlled trial of students for nutrition and eXercise: a community-based participatory research study. J Adolesc Health. 2014;55(3):415–422. doi:10.1016/j.jadohealth.2014.03.003.24784545
145 Hoppu U, Lehtisalo J, Kujala J, . The diet of adolescents can be improved by school intervention. Public Health Nutr. 2010;13(6a):973–979. doi:10.1017/S1368980010001163.20513268
146 Ickovics JR, Duffany KO, Shebl FM, . Implementing school-based policies to prevent obesity: cluster randomized trial. Am J Prev Med. 2019;56(1):e1–e11. doi:10.1016/j.amepre.2018.08.026.30573151
147 Kocken PL, van Kesteren NM, Buijs G, Snel J, Dusseldorp E. Students’ beliefs and behaviour regarding low-calorie beverages, sweets or snacks: are they affected by lessons on healthy food and by changes to school vending machines? Public Health Nutr. 2015;18(9):1545–1553. doi:10.1017/S1368980014002985.25591446
148 Lytle LA, Kubik MY, Perry C, Story M, Birnbaum AS, Murray DM. Influencing healthful food choices in school and home environments: results from the TEENS study. Prev Med. 2006;43(1):8–13. doi:10.1016/j.ypmed.2006.03.020.16697452
149 Lytle LA, Murray DM, Perry CL, . School-based approaches to affect adolescents’ diets: results from the TEENS study. Health Educ Behav. 2004;31(2):270–287. doi:10.1177/1090198103260635.15090126
150 Pedersen S, Grønhøj A, Thøgersen J. Texting your way to healthier eating? Effects of participating in a feedback intervention using text messaging on adolescents’ fruit and vegetable intake. Health Educ Res. 2016;31(2):171–184. doi:10.1093/her/cyv104.26850061
151 Wang D, Stewart D, Chang C. Is an ecological school-based nutrition intervention effective to improve adolescents’ nutrition-related knowledge, attitudes and behaviour in rural areas of China? Glob Health Promot. 2017;24(4):81–89. doi:10.1177/1757975915626864.27216873
152 Gratton L, Povey R, Clark-Carter D. Promoting children’s fruit and vegetable consumption: interventions using the Theory of Planned Behaviour as a framework. Br J Health Psychol. 2007;12(Pt 4):639–650. doi:10.1348/135910706X171504.17535489
153 Boehm R, Read M, Henderson KE, Schwartz MB. Removing competitive foods v. nudging and marketing school meals: a pilot study in high-school cafeterias. Public Health Nutr. 2020;23(2):366–373. doi:10.1017/S136898001900329X.31796143
154 Fonseca LG, Bertolin MNT, Gubert MB, Silva EF. Effects of a nutritional intervention using pictorial representations for promoting knowledge and practices of healthy eating among Brazilian adolescents. PLoS One. 2019;14(3):e0213277. doi:10.1371/journal.pone.0213277.30856205
155 Langlet B, Fagerberg P, Glossner A, Ioakimidis I. Objective quantification of the food proximity effect on grapes, chocolate and cracker consumption in a Swedish high school. A temporal analysis. PLoS One. 2017;12(8):e0182172. doi:10.1371/journal.pone.0182172.28797048
156 Lin CY, Scheerman JFM, Yaseri M, Pakpour AH, Webb TL. A cluster randomised controlled trial of an intervention based on the Health Action Process Approach for increasing fruit and vegetable consumption in Iranian adolescents. Psychol Health. 2017;32(12):1449–1468. doi:10.1080/08870446.2017.1341516.28681612
157 O’Neil CE, Nicklas TA. Gimme 5: an innovative, school-based nutrition intervention for high school students. J Am Diet Assoc. 2002;102(3 Suppl):S93–96. doi:10.1016/s0002-8223(02)90432-3.11902399
158 Santaló MI, Gibbons S, Naylor PJ. Using food models to enhance sugar literacy among older adolescents: evaluation of a brief experiential nutrition education intervention. Nutrients. 2019;11(8). doi:10.3390/nu11081763.
159 Somsri P, Satheannoppakao W, Tipayamongkholgul M, Vatanasomboon P, Kasemsup R. A cosmetic content-based nutrition education program improves fruit and vegetable consumption among grade 11 Thai students. J Nutr Educ Behav. 2016;48(3):190–198.e191. doi:10.1016/j.jneb.2015.11.002.26747200
160 Barnes VA, Kristeller JL. Impact of mindfulness-based eating awareness on diet and exercise habits in adolescents. Int J Complement Altern Med. 2016;3(2). doi:10.15406/ijcam.2016.03.00070.
161 Bukhari A, Fredericks L, Wylie-Rosett J. Strategies to promote high school students’ healthful food choices. J Nutr Educ Behav. 2011;43(5):414–418. doi:10.1016/j.jneb.2011.01.008.21906554
162 Stok FM, e Ridder DT, e Vet E, e Wit JB. Don’t tell me what I should do, but what others do: the influence of descriptive and injunctive peer norms on fruit consumption in adolescents. Br J Health Psychol. 2014;19(1):52–64. doi:10.1111/bjhp.12030.23406475