# Abstract

### Background

The Nutrition Evidence Systematic Review (NESR) in the Center for Nutrition Policy and Promotion, Food and Nutrition Service, U.S. Department of Agriculture (USDA) specializes in conducting food- and nutrition-related reviews using rigorous, protocol-driven methodology. To inform Federal communication, research, and program guidance, the Office of Policy Support (OPS), FNS, USDA requested that the NESR team conduct a rapid review to answer the following question: What is the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake and dietary intake-related behaviors?

### Methods

The NESR team developed a rapid review protocol in response to a request from the review sponsor, the OPS Special Nutrition Research and Analysis Division team. Updates to the rapid review protocol were made following completion of literature screening, but prior to data extraction, to tailor the scope of the review to meet decision requirements and focus on the strongest available evidence. The interventions were school-based strategies to improve acceptance of new foods and encourage healthier dietary patterns in children and adolescents. The comparators were standard curriculum or environmental policies in place at school, different strategies implemented through or outside schools to improve acceptance of new foods and encourage healthier dietary patterns, school-based interventions that do no pertain to improving acceptance of new foods and encouraging healthier dietary patterns, and identical school-based strategies without the component(s) that address improved acceptance of new foods and encouragement of healthier dietary patterns. The outcomes were measures of dietary intake (including diet quality, dietary patterns, and food and beverage groups), select macronutrient and micronutrient intake (saturated fat, added sugars, fiber, and dietary intake-related behaviors). Additional inclusion criteria were that studies must: a) use a randomized controlled trial (RCT) study design, b) be published in English in peer-reviewed journals, c) be from countries with high or very high level of human development, and d) enroll participants with a range of health statuses. The review excluded studies that were not predominantly focused on food and nutrition, were delivered primarily outside of school, or were delivered primarily to parents or caregivers of the students.

A NESR librarian conducted a literature search in PubMed, Web of Science, and Education Resources Information Center to identify articles published between January 2000 and September 2020. Two NESR analysts independently screened all electronic results based on pre-determined criteria. NESR analysts extracted data from each included article, with a second analyst verifying accuracy of the extraction. One NESR analyst independently conducted a formal risk of bias assessment, by study design, for each included article. A second NESR analyst verified the accuracy of the risk of bias assessment and then reconciled any differences in the assessment. The NESR team qualitatively synthesized the evidence, with attention given to the overarching themes or key concepts from the findings, similarities and differences between studies, and factors that may have affected the results. The NESR team then developed conclusion statements and graded the evidence based on its risk of bias, consistency, directness, precision, and generalizability. Three Federal government and two non-government content experts, who completed conflict of interest requirements, peer reviewed the draft report and it was revised to address their comments.

### Results

One-hundred-sixty-two articles met the inclusion criteria for this review. Of these, 106 articles provided evidence for elementary school, 57 articles provided evidence for middle and junior high school, and 18 articles provided evidence for high school, with some overlap in articles across the school levels.

#### Elementary School

##### Conclusion statements and grades

Moderate evidence from this rapid review indicates that curriculum-based nutrition education of 3 months or longer duration improves food and beverage intake (particularly fruit intake) in elementary school children. Common components of successful curricula include parental involvement, games, and taste testing or cooking/meal preparation. (Grade: Moderate)

Limited evidence from this rapid review suggests that curriculum-based nutrition education of 3 months or longer duration may reduce sodium intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that playing school-based nutrition games (board or electronic) for multiple weeks may have beneficial effects on dietary intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that school-based nutrition education involving brief use of books or videos may have a beneficial impact on expressed food choice immediately following exposure to the intervention in younger elementary school children (5- to 6-years old). (Grade: Limited)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions, particularly those that utilize nudges or change the presentation of food, improve in-school food and beverage selection, including fruit, vegetables, and milk, among elementary school children. (Grade: Moderate)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions improve in-school vegetable intake among elementary school children. (Grade: Moderate)

Moderate evidence from this rapid review indicates that elementary school-based interventions that combine educational strategies with behavioral and/or environmental strategies, improve intake of food and beverages, particularly fruit, among children. Interventions tend to be at least 1 academic year in duration and common strategies in successful interventions include pairing a nutrition curriculum with increased promotion and availability of more favorable food and beverages at school. (Grade: Moderate)

##### Summary of the evidence

The body of evidence on elementary school children included 106 articles from 97 RCTs, of which 89 were cluster-RCTs and 8 were parallel RCTs. Fifty-six articles (from 50 RCTs) examined teaching and educational interventions. Many studies examined curriculum-based nutrition education and most significantly improved one or more aspects of food and beverage intake, particularly fruit intake. A few curriculum-based studies found significant reductions in sodium intake. Other food items, beverages, and nutrients either had less consistent results or were measured in few studies. Successful curriculum-based interventions tended to be 3 months or longer in duration, and often included parental involvement, games, and taste testing or cooking/meal preparation. The few studies examining educational games tended to find significant improvement in dietary intake when played for several weeks. A small number of studies examined brief use of books or videos and tended to find beneficial improvements on the immediate choice of food among young children (age 5 to 6 years).

Thirty-two articles (from 30 RCTs) examined behavioral and environmental interventions. Approximately half of these studies assessed food and beverage selection in school and most reported beneficial effects of the interventions, most commonly for fruit, vegetable, and milk selection; other food and beverage items were not commonly assessed. Interventions utilizing nudges or changing the presentation of food in-school most consistently improved food and beverage selection. Approximately two-thirds of these studies examined the effect of behavioral and environmental interventions on in-school food and beverage intake and most found significant beneficial effects; however, the consistency of results varied across food and beverage items. Vegetable intake was frequently assessed and results were consistently beneficial, whereas other food and beverages either had less consistent results or were measured in few studies.

Twenty articles (from 17 RCTs) examined interventions that combined teaching and educational strategies with behavioral and environmental strategies. Studies found that combined strategies several months duration or longer improved food and beverage intake, particularly fruit intake. Other food items, beverages, and nutrients either had less consistent results or were measured in few studies. Some studies reported diminishing effects of the intervention over the multiple years they were implemented. Successful interventions commonly paired a nutrition curriculum with increased promotion and availability of more favorable food and beverage choices at school.

Across interventions, the body of evidence on elementary school children was limited by risk of bias due to selection of reported result and missing outcome data, heterogeneity in the types and combination of strategies tested, as well as the small number of studies targeting particular types of strategies and the short duration of several interventions tested, such as nudges and changes to food presentation.

#### Middle and Junior High School

##### Conclusion statements and grades

Moderate evidence from this rapid review indicates that curriculum-based nutrition education improves dietary intake (particularly overall dietary quality and vegetable intake) in middle and junior high school adolescents. Common components of successful curricula include parental involvement or use of internet- or computer-based technology. (Grade: Moderate)

Insufficient evidence from this rapid review is available to determine the relationship between non-curriculum-based teaching and educational interventions (such as games and reading materials) and dietary intake in middle and junior high school adolescents. (Grade: Grade not assignable)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions beneficially affect in-school food and beverage selection among middle and junior high school adolescents. (Grade: Moderate)

Limited evidence from this rapid review suggests that some school-based behavioral and environmental interventions, particularly those targeting food palatability or presentation, may improve in-school intake of fruit and vegetables among middle and junior high school adolescents. (Grade: Limited)

Moderate evidence from this rapid review indicates school-based interventions that combine educational and environmental strategies targeting promotion and increased availability of nutrient dense foods and beverages improve middle and junior high school adolescent food purchasing behaviors and dietary intake, particularly for fruit, vegetables and foods and beverages of lower nutritional quality. (Grade: Moderate)

Limited evidence from this rapid review suggests school-based interventions that combine educational and environmental strategies promoting and increasing availability of nutrient dense foods, may have a greater beneficial effect on middle and junior high school adolescent dietary intake, particularly fruit and vegetable intake, than interventions that use either strategy alone. (Grade: Limited)

##### Summary of the evidence

The body of evidence on middle and junior high school adolescents included 57 articles from 54 studies, of which 52 were cluster-RCTs and 2 were parallel RCTs. Thirty-two articles (from 30 RCTs) examined teaching and educational interventions. Among studies that examined curriculum-based nutrition education, most significantly improved one or more aspects of dietary intake, particularly overall diet quality and vegetables. Other food and beverage items assessed either had less consistent results or were measured in few studies. Successful curricula tended to include parental involvement or internet- or computer-based technology. Few studies examined other types of teaching and educational interventions, such as educational games or reading materials, and the evidence was too heterogeneous to draw conclusions.

Fourteen articles (from 14 RCTs) examined behavioral and environmental interventions. In-school food and beverage selection were beneficially affected by these interventions in all but 1 study; a variety of behavioral and environmental strategies were tested and successful. Results for in-school food and beverage intake were less consistent. Approximately half the studies that assessed fruit and/or vegetable intake reported beneficial effects of these interventions, particularly those targeting the palatability or presentation of food; however, this represented a small number of studies. Other food and beverages were examined in few studies, were not a primary target of the intervention, or had inconsistent results.

Fourteen articles (from 10 RCTs) examined the effect of educational interventions combined with behavioral and/or environmental interventions. Studies with strong fidelity to the intervention found that combined strategies, particularly those that promoted and increased availability of nutrient dense foods, improved adolescent food purchasing behaviors and food and beverage intake. The few studies that compared combined interventions to interventions that utilized educational or environmental strategies alone tended to find greater positive effects of the combined interventions on dietary intake; however, the generalizability and precision of this small group of studies was relatively low.

Across interventions, the body of evidence on middle and junior high school adolescents was limited by risk of bias due to selection of reported result and missing outcome data, as well as the small number of studies that examined effects beyond the immediate post-intervention period. Additionally, a large proportion of studies that assessed behavioral and environmental interventions also included elementary or high school students but did not report separate analyses by age or grade level.

#### High School

##### Conclusion statements and grades

Limited evidence from this rapid review suggests curriculum-based nutrition education may improve dietary intake (particularly vegetable intake) in high school adolescents. (Grade: Limited)

Insufficient evidence is available from this rapid review to determine the relationship between non-curriculum-based nutrition education (such as games and reading materials) and dietary intake in high school adolescents. (Grade: Grade not assignable)

Insufficient evidence is available from this rapid review to determine the relationship between behavioral or environmental interventions or those that combine behavioral or environmental components with teaching or educational components and dietary intake in high school adolescents. (Grade: Grade not assignable)

Insufficient evidence is available from this rapid review to determine the relationship between any intervention type and food selection in high school adolescents. (Grade: Grade not assignable)

##### Summary of the evidence

The body of evidence on high school adolescents included 18 articles, 14 of which were cluster-RCTs, while the remainder were parallel RCTs. The majority (12 studies) examined curriculum-based nutrition education interventions aimed at improving dietary intake and quality in high school aged adolescents. Consistent evidence showed improvements in overall dietary quality, particularly vegetable intake. Other food and beverage items showed mixed results, though the general trend was toward improved dietary quality. Intervention components such as longer duration, parent involvement, and self-monitoring appear to relate to beneficial outcomes. Of the curriculum-based interventions, few were conducted in the United States, which may limit generalizability to the specific school settings. High attrition and limited follow up also impacted multiple studies.

Non-curriculum-based nutrition education interventions, behavioral or environmental interventions, or those combining education with a behavioral or environmental component were too few in number and too diverse in intervention target to allow synthesis. However, these studies did reveal promising targets for future research.