# Plain-language summary

### What is the question?

The question is: What is the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake and dietary intake-related behaviors?

### What is the answer to the question?

#### Elementary school

- Moderate evidence from this rapid review indicates that curriculum-based nutrition education of 3 months or longer duration improves food and beverage intake (particularly fruit intake) in elementary school children. Common components of successful curricula include parental involvement, games, and taste testing or cooking/meal preparation.
- Limited evidence from this rapid review suggests that curriculum-based nutrition education of 3 months or longer duration may reduce sodium intake in elementary school children.
- Limited evidence from this rapid review suggests that playing school-based nutrition games (board or electronic) for multiple weeks may have beneficial effects on dietary intake in elementary school children.
- Limited evidence from this rapid review suggests that school-based nutrition education involving brief use of books or videos may have a beneficial impact on expressed food choice immediately following exposure to the intervention in younger elementary school children (5- to 6-years old).
- Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions, particularly those that utilize nudges or change the presentation of food, improve in-school food and beverage selection, including fruit, vegetables, and milk, among elementary school children.
- Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions improve in-school vegetable intake among elementary school children.
- Moderate evidence from this rapid review indicates that elementary school-based interventions that combine educational strategies with behavioral and/or environmental strategies, improve intake of food and beverages, particularly fruit, among children. Interventions tend to be at least 1 academic year in duration and common strategies in successful interventions include pairing a nutrition curriculum with increased promotion and availability of more favorable food and beverages at school.

#### Middle and junior high school

- Moderate evidence from this rapid review indicates that curriculum-based nutrition education improves dietary intake (particularly overall dietary quality and vegetable intake) in middle and junior high school adolescents. Common components of successful curricula include parental involvement or use of internet- or computer-based technology.
- Insufficient evidence from this rapid review is available to determine the relationship between non-curriculum-based teaching and educational interventions (such as games and reading materials) and dietary intake in middle and junior high school adolescents.
- Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions beneficially affect in-school food and beverage selection among middle and junior high school adolescents.
- Limited evidence from this rapid review suggests that some school-based behavioral and environmental interventions, particularly those targeting food palatability or presentation, may improve in-school intake of fruit and vegetables among middle and junior high school adolescents.
- Moderate evidence from this rapid review indicates school-based interventions that combine educational and environmental strategies targeting promotion and increased availability of nutrient dense foods and beverages improve middle and junior high school adolescent food purchasing behaviors and dietary intake, particularly for fruit, vegetables and foods and beverages of lower nutritional quality.
- Limited evidence from this rapid review suggests school-based interventions that combine educational and environmental strategies promoting and increasing availability of nutrient dense foods, may have a greater beneficial effect on middle and junior high school adolescent dietary intake, particularly fruit and vegetable intake, than interventions that use either strategy alone.

#### High school

- Limited evidence from this rapid review suggests curriculum-based nutrition education may improve dietary intake (particularly vegetable intake) in high school adolescents.
- Insufficient evidence is available from this rapid review to determine the relationship between non-curriculum-based nutrition education (such as games and reading materials) and dietary intake in high school adolescents.
- Insufficient evidence is available from this rapid review to determine the relationship between behavioral or environmental interventions or those that combine behavioral or environmental components with teaching or educational components and dietary intake in high school adolescents.
- Insufficient evidence is available from this rapid review to determine the relationship between any intervention type and food selection in high school adolescents.

### Why was this question asked?

The Office of Policy Support’s Special Nutrition Research and Analysis Division team requested that the Nutrition Evidence Systematic Review team answer this question to inform Federal communication, research, and program guidance around childhood nutrition programs.

### How was this question answered?

A rapid review was conducted to answer this question.

### What is the population of interest?

School-aged children and adolescents during the intervention; school-aged children and adolescents, and adults at outcome assessment.

### What evidence was found?

#### Elementary School

- This review includes 56 articles on teaching and educational interventions. Most studies found that curriculum-based interventions improved food and beverage intake (particularly fruit). A few curriculum-based interventions reduced sodium intake. Curriculum-based interventions at least 3 months long tended to have benefits. Successful curricula usually involved parents, games, and/or taste testing and food preparation. Some studies found that playing educational games for several weeks improved dietary intake. Few studies found that brief educational books and videos improved immediate food choice. Most of these studies were in young children (age 5 to 6 years).
- This review includes 32 articles on behavioral and environmental interventions. Most studies found benefits on food and beverage selection in school, particularly fruit, vegetables, and milk. Studies that nudged children towards better food choices or changed the presentation of food had consistent benefits. Most studies improved food and beverage intake. Results were more or less consistent depending on the food or beverage measured. Several studies found improvements in vegetable intake, while results were less consistent for fruit intake.
- This review includes 20 articles on combined interventions (teaching/educational with behavioral/environmental). Combined interventions improved food and beverage intake. Results were most consistent for fruit intake. Most interventions with beneficial effects were several months or longer. Some studies found decreased benefits after several years of the intervention. Successful interventions often paired nutrition curricula with increased promotion and availability of better food and beverage choices at school.
- The included articles had several limitations. These include risk of bias, and often only measuring diet immediately after the intervention finished with no long-term follow-up.

#### Middle and Junior High School

- This review includes 32 articles on teaching and educational interventions. Many studies found that curriculum-based interventions improved dietary intake. Results were most consistent for diet quality and vegetables. Successful curricula often included parents or internet- or computer-based technology. NESR could not draw conclusions on other interventions due to the lack of evidence.
- This review includes 14 articles on behavioral and environmental interventions. Interventions improved food and beverage selection in school. The results for food and beverage intake in school were less consistent. Some studies found that interventions improved fruit and/or vegetable intake, but several others did not. Interventions that improved the taste or presentation of food had benefits on intake, but few studies examined this type of intervention.
- This review includes 14 articles on combined interventions (teaching/educational with behavioral/environmental). Several studies found that combined strategies improved diet and dietary behavior, while some did not. Successful interventions often promoted and increased availability of nutritious foods. Few studies compared combined interventions to educational or environmental interventions alone, but combined interventions tended to show benefits.
- The included articles had several limitations. These include risk of bias, and not measuring diet after the intervention finished.

#### High School

- This review includes 12 articles on teaching and educational interventions. Some studies found that curriculum-based interventions improved dietary intake, while others did not. Vegetable intake usually improved, but fruit intake was less consistent. Potential characteristics of successful interventions include longer-term curricula and involving parents or self-monitoring. NESR could not draw conclusions on other interventions due to the lack of evidence.
- This review includes four articles on behavioral and environmental interventions. NESR could not draw conclusions due to the lack of evidence.
- This review includes two articles on combined interventions (teaching/educational with behavioral/environmental). NESR could not draw conclusions due to the lack of evidence.
- The included articles had several limitations. These include variety in strategies studied and not measuring diet after intervention finished.

### How up-to-date is this rapid review?

This review searched for studies published between January 2000 and September 2020.