# Conclusions

## Conclusion statements and grades

The rapid review question was answered with the following conclusion statements and grades. The grades reflect the strength of the evidence underlying the conclusion statements.

#### Elementary school

Moderate evidence from this rapid review indicates that curriculum-based nutrition education of 3 months or longer duration improves food and beverage intake (particularly fruit intake) in elementary school children. Common components of successful curricula include parental involvement, games, and taste testing or cooking/meal preparation. (Grade: Moderate)

Limited evidence from this rapid review suggests that curriculum-based nutrition education of 3 months or longer duration may reduce sodium intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that playing school-based nutrition games (board or electronic) for multiple weeks may have beneficial effects on dietary intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that school-based nutrition education involving brief use of reading or audio-visual materials may have a beneficial impact on expressed food choice immediately following exposure to the intervention in younger elementary school children (5- to 6-years old). (Grade: Limited)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions, particularly those that utilize nudges or change the presentation of food, improve in-school food and beverage selection, including fruit, vegetables, and milk, among elementary school children. (Grade: Moderate)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions improve in-school vegetable intake among elementary school children. (Grade: Moderate)

Moderate evidence from this rapid review indicates that elementary school-based interventions that combine educational strategies with behavioral and/or environmental strategies, improve intake of food and beverages, particularly fruit, among children. Interventions tend to be at least 1 academic year in duration and common strategies in successful interventions include pairing a nutrition curriculum with increased promotion and availability of more favorable food and beverages at school. (Grade: Moderate)

#### Middle and junior high school

Moderate evidence from this rapid review indicates that curriculum-based nutrition education improves dietary intake (particularly overall dietary quality and vegetable intake) in middle and junior high school adolescents. Common components of successful curricula include parental involvement or use of internet- or computer-based technology. (Grade: Moderate)

Insufficient evidence from this rapid review is available to determine the relationship between non-curriculum-based teaching and educational interventions (such as games and reading materials) and dietary intake in middle and junior high school adolescents. (Grade: Grade not assignable)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions beneficially affect in-school food and beverage selection among middle and junior high school adolescents. (Grade: Moderate)

Limited evidence from this rapid review suggests that some school-based behavioral and environmental interventions, particularly those targeting food palatability or presentation, may improve in-school intake of fruit and vegetables among middle and junior high school adolescents. (Grade: Limited)

Moderate evidence from this rapid review indicates school-based interventions that combine educational and environmental strategies targeting promotion and increased availability of nutrient dense foods and beverages improve middle and junior high school adolescent food purchasing behaviors and dietary intake, particularly for fruit, vegetables and foods and beverages of lower nutritional quality. (Grade: Moderate)

Limited evidence from this rapid review suggests school-based interventions that combine educational and environmental strategies promoting and increasing availability of nutrient dense foods, may have a greater beneficial effect on middle and junior high school adolescent dietary intake, particularly fruit and vegetable intake, than interventions that use either strategy alone. (Grade: Limited)

#### High school

Limited evidence from this rapid review suggests curriculum-based nutrition education may improve dietary intake (particularly vegetable intake) in high school adolescents. (Grade: Limited)

Insufficient evidence is available from this rapid review to determine the relationship between non-curriculum-based nutrition education (such as games and reading materials) and dietary intake in high school adolescents. (Grade: Grade not assignable)

Insufficient evidence is available from this rapid review to determine the relationship between behavioral or environmental interventions or those that combine behavioral or environmental components with teaching or educational components and dietary intake in high school adolescents. (Grade: Grade not assignable)

Insufficient evidence is available from this rapid review to determine the relationship between any intervention type and food selection in high school adolescents. (Grade: Grade not assignable)

## Research recommendations

To address the gaps in and limitations of this body of evidence on school-based strategies to improve acceptance of healthier foods and dietary patterns, several research recommendations have been identified:

1. Assess what components and characteristics of school-based interventions contribute to their effectiveness, such as:
  ○ Intervention dose attributes (duration, amount, frequency, and intensity) of the overall intervention and its individual components,
  ○ The type of strategies included in a nutrition curriculum (e.g., taste testing, cooking or meal preparation, games, goal setting or self-monitoring, parental involvement),
  ○ The type of educator that delivers the intervention (e.g., researchers, teachers, nutritionists, peers), and
  ○ The theoretical underpinnings of the intervention.
2. Evaluate and implement strategies to enhance and maintain intervention fidelity and uptake.
3. Further investigate the effects of individual strategies that showed positive effects on diet and diet-related behavior in children and adolescents, but with minimal evidence, such as:
  ○ Improving the palatability of healthy food choices,
  ○ Using game-based learning to build and retain nutrition knowledge and produce diet-related behavior change, and
  ○ Using educational books or videos to change immediate food selection and intake.
4. Target and assess choice and/or intake of foods, beverages, and nutrients that were less commonly studied but are relevant to school nutrition programs due to under- or over-consumption (such as whole grains and sodium).
5. Compare efficacy of broad nutrition interventions to those targeting a specific food or beverage group.
6. Conduct more RCTs that assess the effects of school-based interventions among high school adolescents.
7. Examine how intervention component effectiveness may vary across participant characteristics such as age, race/ethnicity, and SES groups.
8. Conduct short- and long-term follow-ups to evaluate the broader effects of school-based interventions on diet and diet-related behavior.