# Results

## Literature search and screening results

The literature search yielded 9,292 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 5,547 titles, 2,657 abstracts, and 915 full-texts articles. Reasons for full-text exclusion are in Appendix 4. The body of evidence included 162 articles^*^:

- Elementary school provides evidence from 106 articles
- Middle and junior high school provides evidence from 57 articles
- High school provides evidence from 18 articles

* Some articles include data for multiple school level categories.

Figure 2 Literature search and screen flowchart^*^

Literature search and screen flowchart. Three databases were searched (PubMed, Web of Science, ERI), yielding 12,806 records (9,292 after removal of duplicates). Through screening, 5,547 were excluded at the title level, 2,657 were excluded at the abstract level, and 915 were excluded at the full-text level. One-hundred-sixty-two articles were included: 106 in elementary school, 57 in middle and junior high school, and 18 in high school.

## Elementary school

### Conclusion statements and grades

#### Teaching and educational interventions

Moderate evidence from this rapid review indicates that curriculum-based nutrition education of 3 months or longer duration improves food and beverage intake (particularly fruit intake) in elementary school children. Common components of successful curricula include parental involvement, games, and taste testing or cooking/meal preparation. (Grade: Moderate)

Limited evidence from this rapid review suggests that curriculum-based nutrition education of 3 months or longer duration may reduce sodium intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that playing school-based nutrition games (board or electronic) for multiple weeks may have beneficial effects on dietary intake in elementary school children. (Grade: Limited)

Limited evidence from this rapid review suggests that school-based nutrition education involving brief use of books or videos may have a beneficial impact on expressed food choice immediately following exposure to the intervention in younger elementary school children (5- to 6-years old). (Grade: Limited)

#### Behavioral and environmental interventions

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions, particularly those that utilize nudges or change the presentation of food, improve in-school food and beverage selection, including fruit, vegetables, and milk, among elementary school children. (Grade: Moderate)

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions improve in-school vegetable intake among elementary school children. (Grade: Moderate)

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

Moderate evidence from this rapid review indicates that elementary school-based interventions that combine educational strategies with behavioral and/or environmental strategies, improve intake of food and beverages, particularly fruit, among children. Interventions tend to be at least 1 academic year in duration and common strategies in successful interventions include pairing a nutrition curriculum with increased promotion and availability of more favorable food and beverages at school. (Grade: Moderate)

### Summary of the evidence

#### Teaching and educational interventions

- Fifty RCTs (56 articles) examined the effect of teaching and educational interventions in elementary school children on dietary intake (including intake of select macronutrients and micronutrients) and dietary intake-related behaviors
  ○ Thirty-six RCTs examined curriculum-based nutrition education
    ■ Twenty-two out of 29 RCTs found beneficial effects on intake of at least 1 food and beverage item
      - Interventions with beneficial outcomes tended to be 3 months or longer in duration, and successful curricula often included parental involvement, games, or a taste testing and cooking/meal preparation component
      - Fruit intake was a commonly studied outcome that tended to be beneficially impacted by the interventions
      - Other commonly studied outcomes include intake of vegetables, and food and beverages of lower nutritional quality; however, these showed inconsistent results
      - Findings for dairy, whole grains, and beans/legumes were measured in too few studies to draw conclusions
    ■ Seven RCTs examined nutrient intake (added sugars, fiber, sodium, and saturated fat)
      - Three out of four RCTs found beneficial effects on sodium intake at post-intervention; interventions with beneficial outcomes tended to be 3 months or longer in duration
      - Fiber intake was another commonly studied nutrient, but results were inconsistent
      - Added sugars and saturated fat were measured in too few studies to draw conclusions
  ○ Five RCTs examined game-based interventions (e.g., board games, video or computer games)
    ■ Four RCTs found that game-based interventions of 5 weeks or longer duration significantly improved dietary intake, although additional research is needed to determine if effects on dietary intake are sustained long-term after the intervention
  ○ Four RCTs examined educational reading materials or videos
    ■ All studies found that brief exposure to educational books or videos significantly improved children’s expressed food choice immediately following exposure to the intervention, although additional research is needed to determine if effects on expressed food choice are sustained after the intervention
    ■ Three of the RCTs were conducted in younger elementary school children (age 5-6 years)
  ○ Five RCTs examined other unique teaching and educational strategies and dietary intake in elementary school children
    ■ Heterogeneity in strategies and targeted outcomes limits ability to draw conclusions
    ■ Interventions with potential include using individual- and team-based consumption goals to build autonomy over food choices, as well as using teacher encouragement and role modeling in the classroom to promote vegetable intake; however, additional research is needed
  ○ The bodies of evidence were limited by the:
    ■ Risk of bias related to concerns of selective reporting;
    ■ Heterogeneity in the content, delivery, and dose of curriculum-based interventions;
    ■ Minimal evidence to determine the impact on diet beyond the immediate post-intervention period; and
    ■ Small number of studies on game-based interventions and those that used educational reading materials or videos.

#### Behavioral and environmental interventions

- Thirty RCTs (32 articles) examined behavioral and environmental interventions in elementary school children
  ○ Sixteen RCTS (16 articles) examined the effect of behavioral and environmental interventions on food and beverage selection, all assessed in school
    ■ Most studies detected beneficial effects of these interventions on the selection of at least one targeted food or beverage
      - Fruit, vegetables, and white milk selection were the most common outcomes in this subset of the evidence and were predominantly beneficially impacted by the interventions
      - Selection of other types or categories of food and beverages, such as juice or lower nutritional quality foods, were not commonly targeted or assessed
    ■ Among the interventions assessed, those that implemented nudges (verbally or through online ordering systems) and those that changed food presentation most consistently detected beneficial impacts on food and beverage selection; other types of strategies were implemented in very few studies or their results were less consistent
  ○ Twenty RCTs (21 articles) examined the effect of behavioral and environmental interventions on food and beverage intake
    ■ Most studies detected beneficial effects on the intake of at least one targeted food or beverage, predominantly in school; however, some studies reported null or detrimental impacts of interventions on targeted food or beverage items
      - Vegetable intake was frequently assessed (11 RCTs [12 articles]) and effects of interventions on this outcome were predominantly beneficial
      - Fruit intake or combined fruit and vegetable intake were also commonly assessed, but results were less consistent
      - Intake of other food, beverages, or nutrients was assessed in few studies
    ■ A wide variety of behavioral and environmental interventions were tested across the body of evidence
  ○ The bodies of evidence for both selection and intake were limited by the:
    ■ Risk of bias due to selection of reported result and missing outcome data;
    ■ Heterogeneity in the types of behavioral and environmental interventions tested and the dietary components or behaviors targeted;
    ■ Brief duration of several interventions, particularly those targeting nudges or food presentation; and
    ■ Small number of studies targeting any single type of behavioral or environmental intervention.

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

- Seventeen RCTS (20 articles) examined the effect of combined interventions, pairing teaching and educational strategies with behavioral and environmental strategies, on food and beverage selection and intake in elementary school children
  ○ Most studies assessed intake, while one also assessed selection and one assessed plate waste
  ○ Approximately 75 percent of the studies detected beneficial effects of combined interventions on one or more aspects of food and beverage intake
    ■ Fruit intake was commonly measured across studies and effects of combined interventions tended to be beneficial
    ■ Effects on sugar-sweetened beverage (SSB) and soft drink intake were also predominantly beneficial; however, these outcomes were assessed less frequently
    ■ Less consistent results were observed for vegetable intake and combined fruit and vegetable intake
    ■ Other food items, beverages, and nutrients were assessed in few studies
    ■ Some studies that implemented interventions for multiple years reported diminishing effects over time, although it was not always clear if the content of interventions was similar across each year
  ○ A variety of strategies were utilized across successful interventions; however, common components in successful interventions included nutrition curriculum paired with increased promotion and availability of more favorable food and beverage choices at school
  ○ Although a few studies assessed brief interventions lasting several days or weeks, most studies implemented interventions for 2 months or longer, the majority lasting for 1 or more academic years
  ○ No studies compared the effect of combined interventions to interventions that used either teaching and educational strategies or behavioral and environmental strategies alone
  ○ The body of evidence was limited by the:
    ■ Risk of bias due to selection of reported result and missing outcome data; and
    ■ Heterogeneity in the combination of strategies utilized in interventions across studies.

### Synthesis of the evidence

The body of evidence on elementary school children includes 106 articles from 97 RCTs, including 89 cluster-RCTs^1–98^ and 8 parallel RCTs.^99–106^ Half of the studies utilized teaching and educational strategies, and about a third utilized behavioral and/or environmental strategies; fewer studies assessed combined teaching and educational strategies with behavioral and environmental strategies.

#### Teaching and educational interventions

##### Description of the evidence

Fifty-six articles from 50 RCTs examined the effect of school-based teaching and educational interventions on diet and diet-related behaviors in elementary school-aged children.^40,41,50–98,102–106^ Most studies were cluster-randomized, while five studies were parallel, randomizing participants at the individual level.^102–106^ The majority of studies were conducted solely in elementary schools, but three were conducted in conjunction with middle or junior high schools,^79,90,105^ and one was conducted across all grade levels.^98^ About one-third of studies were conducted in the United States^52–54,59,62,63,66,68,70,71,78,84,86–88,95,97,105^ and approximately half were conducted in Europe (specifically Cyprus,^77^ Finland,^72^ France,^93^ Greece,^98^ Italy,^75,76,96^ the Netherlands,^40,41,56,74,102,104^ Portugal,^58,80–83,103^ Spain,^51,73,90–92^ and the United Kingdom^57,64,67,106^); other high and very high human development index (HDI) countries included Brazil,^60,79,85^ Canada,^61^ China,^65^ Iran,^55,89,94^ Israel,^69^ and Saudi Arabia.^50^ Among studies providing socioeconomic status (SES) data, about half reported lower caregiver education levels^76,79–83,91,92,94^ or large proportions of students who were eligible for free and reduced price meals.^62,63,70,71,86,88,95,105^ Among studies providing race/ethnicity data, some were conducted in schools with a predominantly White student population^52,54,63,66,84,106^ while others had high proportions of Black and/or Hispanic students.^53,59,62,70,71,78,85,86,88,95,105^ The majority of studies enrolled both male and female participants, but two were conducted exclusively with female participants^50,94^ and one was conducted exclusively with male participants.^89^ The analytic sample size of the cluster-RCTs ranged from 2^73,79,89,91,92,94^ to 146^98^ clusters and 50^52^ to 3,627^98^ individual participants; most studies enrolled multiple clusters per study arm and analyzed between 100 and 1,000 participants. The analytic sample sizes of the 5 parallel-RCTs ranged from 59^105^ to 160^102^ individual participants.

The majority of teaching and educational interventions utilized a new or enhanced nutrition curriculum involving a combination of strategies (e.g., taste testing, school gardening). Approximately half the trials reported the theoretical foundation or framework for the intervention,^40,41,50–54,57,59,60,62,63,69,71,72,74,77,78,80–86,88,89,95,97,104–106^ a large proportion of which were based on Social Cognitive Theory (SCT).^50,53,54,57,59,63,71,77,78,80–83,86,95,97,105^ Some studies focused on game-based learning (e.g., board games, video or computer games), short-term use of educational reading materials or videos, or other unique strategies, as described below. Intervention durations ranged from a single session to 2 years, with varied session frequency and length. Most interventions were compared to usual care or no intervention, while 14 studies had interventions that were compared to a different strategy or an identical intervention without the component of interest.^40,41,51,52,57,61,66,75,76,93,98,103–106^ Target behaviors included increasing fruit and/or vegetable consumption,^40,41,51,53–57,59,61–63,66,72,74–77,79,80,82,84,88,89,95^ improving snacking behaviors (including decreased intake of sugar-sweetened beverages [SSBs] and added sugars),^52,64,67,81,94,96,97,102–105^ and improving overall diet and general eating behaviors (including decreased intake of saturated fat and sodium, and increased intake of fiber).^50,58,60,65,68–73,78,83,85–87,90–93,98,106^ The majority of studies assessed outcomes through self-reported^50,53–56,59–63,67,68,70–72,74–76,78–83,85–89,93–96^ or parent-reported^40,41,51,57,64,69,73,77,90–92,98,106^ measures, using food frequency questionnaires (FFQs) and/or 24-hour dietary recalls; other assessment methods included 24-hour urine collection^58,65^ or direct observation of food purchased, selected, or consumed at school.^52,66,84,97,102–105^ Most studies assessed overall intake, but a few studies assessed selection or intake at school.^52,66,84,88,97,102–105^ Evidence from these studies and participant characteristics are described in Table 3; the risk of bias assessments are described in Table 4. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Curriculum-based nutrition education

Thirty-six RCTs (41 articles) examined the effect of curriculum-based interventions involving a combination of teaching and educational strategies on diet and diet-related behaviors in elementary school children,^40,41,50,51,54–56,58,60,62–77,79–85,87–92,94,95,97,98,106^ with primarily beneficial effects on the targeted outcomes. Several curriculum-based interventions were implemented over an academic year or longer,^40,41,51,60,67,72,73,77,79,90–92,98,106^ but the majority were 1 to 6 months in duration,^54–56,58,62,63,65,68–71,75,76,80–85,88,95^ and a handful were less than 4 weeks.^50,64,87,89,94,97^ Interventions were delivered by a variety of educators, including classroom teachers,^40,41,54,56,58,68,71,72,77,80–85,87,95^ external educators (e.g., researchers, health professionals such as nutritionists),^50,51,55,60,62–65,67,69,70,79,88,89,94,97,98,106^ and older students^73,90–92^; two studies directly compared the type of educator who delivered the intervention.^75,76^

Twelve RCTs were implemented over an academic year or longer.^40,41,51,60,67,72,73,77,79,90–92,98,106^

The Educació en Alimentació study examined a 28-month nutrition education program delivered by trained university students over 12 sessions (1 hour each, delivered every 2 weeks over a 2-month period each academic year for 3 academic years) in a large sample of Spanish children aged 7-8 years.^91,92^ The intervention focused on a healthy lifestyle and included booklets, parental involvement, and opportunities to taste free food items provided by local producers (including fruit, vegetables, nuts, legumes, and cheese). Questionnaires completed by parents assessed eating habits for a variety of foods and beverages, including dairy products, cereals, fruit, juice, soft drinks, vegetables, fish, fast food, legumes, candy, pasta/rice, pastry, and sandwiches. There were no significant differences between the intervention group and the control group at post-intervention^91^ or a 2-year follow-up.^92^ When analyzed by gender, boys in the intervention group had a significantly greater increase in midmorning snack consumption compared to the control group.^92^ Another study examined the same program delivered over 22 months in a different region of Spain and its impact on the same foods and beverages.^73^ The intervention group had significantly higher intake of fruit, vegetables, legumes, pastry for breakfast, and fast food at post-intervention compared to the control group. No other foods or beverages were significantly different between groups. When analyzed by gender, girls in the intervention group had significantly higher intake of fruit, vegetables, and fast food, as well as lower intake of cereals at breakfast and legumes compared to the control group. Boys in the intervention group had significantly higher intake of vegetables and pastry at breakfast.

Another study in Spain examined a theory-based intervention delivered by a trained nutritionist over 14 sessions (1 hour each) during an academic year in a sample of children aged 7-10 years.^51^ The intervention focused on fruits and vegetables, and included classroom activities, fruit and vegetable cooking sessions, visits to a local produce market and farm, and a goal diary with parents. The control group received two 1-hour lessons delivered by a nutritionist during the school year with general information about the benefits of fruit and vegetable intake; the lessons were not theory-based. Intake was assessed by caregivers using a 7-day food record pre- and post-intervention. The intervention group had a significant increase in fruit and vegetable intake (combined and separated) compared to the control group. When analyzed by type of food, both fresh fruit and homemade fruit juice intake were increased in the intervention group compared to the control, but there were no significant differences between groups in intake of raw or cooked vegetables.

A parallel RCT conducted in the United Kingdom investigated a nutrition program consisting of 20 lunchtime clubs (25 minutes each) delivered weekly/bi-weekly by researchers over 4 school terms (~14 months) in a small sample of children aged 5-7 years.^106^ The intervention focused on healthy eating and included games, fruit and vegetable tasting sessions, quizzes, and crafts. The control group received non-nutrition food education, such as topics on food traditions and food processing. Intake was assessed by parents using an FFQ and 24-hour dietary recall; scores for fiber intake were based on intake of vegetarian alternatives, whole wheat bread and breakfast cereals, potatoes, vegetables, salads, and fruit. At 1-month follow-up, there was no significant difference in fiber scores between the intervention and control groups.

Perikkou et al^77^ conducted a study in Cyprus examining two different teaching interventions, compared to a control group, over 1 school year in a sample of third grade children. The first intervention consisted of a theory-based educational curriculum delivered by trained teachers over 29 weekly lessons (15 minutes each); the curriculum focused on a healthy lifestyle and involved active learning and tasting. The second intervention did not include educational content but involved exposure to the consumption of fruit or a healthy snack by the teacher, who acted as a role model at least three times per week. Intake was assessed using a 2-day food record completed by parents. Both intervention groups had significantly higher fruit intake compared to the control group at post-intervention; results were sustained at 1-year follow-up for the teacher role modeling group only, which had significantly higher fruit intake compared to the curriculum group.

One study conducted in the Netherlands compared a multi-component nutrition education program delivered by teachers to a free fruit and vegetable program, both implemented for 1 academic year, in a sample of children aged 4-12 years.^40,41^ The nutrition education program consisted of an age-adapted class curriculum (12-14 lessons) promoting fruit and vegetable consumption through activities such as art, games, videos, taste testing, as well as parental involvement through recurrent newsletters and homework. Intake was assessed by parents using an FFQ and 24-hour dietary recall. At post-intervention, there was no significant difference between groups in fruit intake or combined intake of fruit, juice, and vegetables.^41^ Analyses for vegetable intake were conducted by age group, gender, and ethnicity. The nutrition education group reported significantly lower vegetable intake at post-intervention among fourth through sixth grade children, boys, and those of non-native Dutch origin, compared to the group receiving the free fruit and vegetable program. At 1-year follow-up, similar to earlier findings, the nutrition education group reported lower vegetable intake compared to the group receiving the free fruit and vegetable program and there was no significant difference for fruit intake or combined intake of fruit, juice, and vegetables; subgroup analyses were not conducted.^40^

Cunha et al^60^ investigated a nutrition education program delivered by trained nutritionists over nine monthly sessions (1 hour each) in a sample of fifth grade students from a low-SES area in Brazil. The intervention focused on healthy eating habits and sessions included games, theater sketches, movies, puppet shows, contests, and take-home materials for the family in the form of booklets and recipes. Children reported their intake using an FFQ at baseline, after 6 months of intervention, and at post-intervention. The intervention group reported a significant reduction in daily intake of cookies and sodas, and a significant increase in daily intake of fruit compared to the control group. There were no significant differences between groups for daily intake of juice or beans.

Another study conducted in a low-SES area of Brazil examined a 9-month nutrition education intervention delivered by a dietitian over six classes (50 minutes each) in a sample of elementary and middle school-aged children (7-14 years).^79^ The intervention focused on a healthy lifestyle, and activities included videos, three 1-hour workshops for teachers and food service staff on food preparation and minimally processed foods, and two 1-hour workshops on healthy eating for families. Combined fruit and vegetable intake was assessed with an FFQ. At post-intervention, the intervention group reported more frequent consumption of combined fruit and vegetables compared to the control group. Results were not separated by age group. Notably, the study had a very high attrition rate (62 percent) and the control group had much higher attrition (77 percent) than the intervention group (48 percent).

Lehto et al^72^ assessed the impact of different implementation levels of a seven-lesson nutrition education program (PRO GREENS) over 1 school year in a sample of Finnish children aged 10-11 years. The intervention focused on fruits and vegetables, and included posters, taste testing, daily fruit and vegetable snacks, weekly fruit and vegetable bring-a-dish events, home assignments, and parental involvement. Overall data on intervention versus control groups were not presented; rather, the degree of implementation was determined from teachers’ responses at follow-up on the quantity (dose) of components implemented during the intervention. Children reported their intake using an FFQ at baseline and 1 year after baseline. High implementation of the program (but not low implementation) significantly increased weekly fruit intake compared to the no-intervention control group. There was no significant difference in vegetable intake between the intervention groups and the control.

The European Youth Tackling Obesity-Kids project in Spain assessed a social marketing intervention in which children aged 9-11 years received four activities (1 hour each) over 10 months that were designed and implemented by trained adolescent students (see Middle and junior high school for results in adolescents).^90^ The activities focused on healthy lifestyle habits, and included fruit and vegetable tastings, contests, games, and team-based physical activity. Intake was assessed using questionnaires completed by parents at baseline and post-intervention. There were significant increases in the percentage of children in the intervention group who did not consume sweets or fast food weekly compared to the control group. There were no significant differences between groups in intake of fruit, vegetables, or sugary drinks. Furthermore, there were no significant differences between groups when sugary drinks were analyzed separately (commercial juice, soft drinks, and carbonated drinks). When analyses were conducted by sex, there were significant increases in the percentage of female children in the intervention group who did not consume sweets or fast food weekly, as well as never consumed soft drinks, compared to the control group. There were no significant between group differences for male children.

The Christchurch Obesity Prevention Project in Schools assessed the effect of a nutrition education program, which was delivered by the lead researcher with teacher assistance over four sessions (1 hour each) during the school year in a sample of children aged 7-11 years in the United Kingdom.^67^ The program focused on reducing the intake of sweetened and unsweetened “fizzy” drinks and activities included fruit tasting to learn about the sweetness of natural products, a music competition, art, and a game. Children completed a 3-day diet diary at baseline and post-intervention. The intervention group had significantly reduced intake of total and diet carbonated drinks compared to the control. There were no significant between-group differences for carbonated drinks with sugar or with caffeine.

Zota et al^98^ conducted a study in Greece examining the effect of adding a nutrition education program to the daily free, healthy boxed meal received by a large sample of elementary, middle, and high school students (the DIATROFI Program; see Middle and junior high school and High school for results in adolescents). The educational program was delivered over 1 school year by external educators (including a nutrition specialist and chef) and focused on healthy nutrition; elementary school materials included age-specific workbooks and posters, and informational leaflets for parents and school staff. The control group received the daily free, healthy meal but no educational program. Intake was assessed using an FFQ completed by parents. Children (aged 4-11 years) who received the educational program had significantly greater weekly consumption of milk/yogurt and fruit at post-intervention compared to the control group. There were no significant between-group differences in the consumption of vegetables or whole grains. Notably, loss to follow-up was high (76 percent) due to missing questionnaires or information required to link participant information pre-and post-intervention.

Eighteen RCTs were 1 to 6 months in duration.^54–56,58,62,63,65,68–71,75,76,80–85,88,95^

Cotter et al^58^ examined the effects of a 6-month multi-component intervention on reducing salt intake delivered by teachers in a sample of Portuguese children aged 10-12 years. The intervention consisted of weekly lessons on the potential dangers of excessive salt intake. A second group received the same intervention with the addition of 2 hours per week of a school gardening project, from which they took home herbs as salt substitutes. Salt intake was estimated by 24-hour urine collection at baseline and post-intervention. The group receiving hands-on gardening experience had significant reductions in salt intake (−1.1 grams/day), whereas the education only and control groups did not show significant change. However, between-group differences in estimated salt intake were not significant. When change in salt intake was examined categorically, significantly more children in the gardening group reduced their salt intake by ≥1 gram/day compared to the other groups.

The Texas, Grow! Eat! Go! study^95^ examined a 6-month multi-component school gardening intervention (Learn!Grow!Eat!Go!) delivered by teachers in a low-income sample of third grade children in the United States. The intervention consisted of a 32-lesson curriculum centered on vegetables grown in the school garden, fresh vegetable sampling, classroom recipe demonstrations, and take-home materials for the family in the form of recipe cards and an activity booklet. Children responded to three questions on vegetable intake at baseline and post-intervention. There was no significant difference for change in vegetable intake between the intervention and control groups. Results may be limited by variations in implementation fidelity across classrooms and schools since lessons were not implemented by study staff.

One study in Portugal examined a nutrition intervention in which classroom teachers received 12 sessions (3 hours each) of professional development training from researchers over 6 months to support a nutrition program in a sample of first through third grade children.^80–83^ The sessions included topics on healthy lifestyle and general nutrition. After training, teachers delivered the learned content in their classrooms and developed classroom activities about the addressed topics, including cooking and family involvement. Intake was assessed using a single 24-hour dietary recall conducted by nutritionists and/or trained interviewers at baseline and post-intervention. The intervention group had significant increases in fruit and vegetable intake (combined and separated) compared to the no-intervention control group,^80^ and significantly greater intake of fruit for dessert at lunch and dinner at post-intervention.^82^ When examining low-nutrient energy-dense (LNED) foods and beverages (e.g., chips, French fries, desserts, SSBs), the intervention group reported significantly lower intake of solid LNED foods at post-intervention and lower odds of increased solid LNED food intake compared to the control group; there was no significant difference between groups for LNED beverages.^81^ When examining food and nutrient components of the Diet Quality Index-International, the intervention resulted in significantly higher adequacy for vegetable intake and moderation in sodium intake compared to the control group; there were no significant differences between groups for fruit, grains, or dietary fiber intake.^83^

Sgambato et al^85^ investigated an obesity prevention program delivered by trained teachers over six monthly sessions (50 minutes each) in a large sample of fifth and sixth grade children in Brazil. The intervention focused on healthy eating and included games, group debates, a culinary class, and take-home materials for the family; a subgroup of children with overweight or obesity also received a home-based secondary prevention program delivered by community health professionals. Children completed FFQs that assessed daily intake of milk, beans, fruit, vegetables, cookies, sodas, processed meats, and fruit-based drinks. None were significantly different between groups at post-intervention. When food groups were summed and analyses was stratified by sex, female children in the intervention group increased their daily intake of healthy food items from baseline to post-intervention compared to the control group; there was no significant difference among male children. Among a random subsample of children who completed 24-hour recalls at baseline and post-intervention, there was a significant decrease in fruit juice intake in the intervention group compared to the control.

A study conducted in Italy compared the effect of receiving the same nutrition curriculum delivered by either nutritionists or classroom teachers over three 12-week periods in a sample of fourth grade children.^75^ There was no control group. The nutritionist-delivered intervention group received nutrition education for 2 hours a week during the first 24 weeks; there were no classes or activities with the nutritionist during the last 12 weeks (control period). In the teacher-delivered intervention group, teachers received training on nutrition topics and communication strategies from nutritionists for 2 hours a week during the first 12 weeks, followed by 12 weeks of additional training emphasizing teaching aids to incorporate into lessons; during the last 12 weeks, teachers provided nutrition education to students by integrating the nutrition concepts into all school curricula. The lessons in both groups included posters, songs, poems, and stories. Children completed daily food diaries under teacher supervision that assessed intake of fruit, vegetables, legumes, chips, and SSBs. There were no significant between-group differences in intake for all foods during the first two periods. However, during the last period, children in the nutritionist group had significantly decreased intake of fruit, vegetables, and legumes, and increased intake of chips and SSBs compared to children in the teacher group. Findings from this study are limited since children received different levels of intervention in terms of the timing and dose of nutrition education. A similar study implemented the same educational content over a shorter period of time (three 5-week periods) to compare the effect of nutrition education delivered by teachers trained by nutritionists or by self-trained teachers in a sample of children from second through fifth grade.^76^ During the first and second periods, teachers completed the training sessions (2 hours per week); during the second and third periods, the teachers delivered the nutrition education by integrating information into multiple subject areas. Additionally, parents received education from the nutritionist or teacher, based on group assignment. Daily food diaries assessed intake of fruit and vegetables only. There were no significant between-group differences in fruit and vegetable intake during the first 5 weeks, but children that received education by nutritionist-trained teachers increased their fruit and vegetable intake during the last 10 weeks compared to children that received education by self-trained teachers.

Struempler et al^88^ examined a 17-week nutrition education program (Body Quest: Food of the Warrior) delivered over 17 weekly classes (45 minutes each) in a large US sample of third grade children from schools eligible for Supplemental Nutrition Assistance Program-Education (SNAP-Ed). The program was delivered by SNAP-Ed extension educators and aimed to increase fruit and vegetable consumption through activities such as tasting a weekly rotation of fruits and vegetables, education via an iPad app, and weekly take-home activities for the family. Children completed a school lunch checklist with assistance from teachers at pre- and post-intervention. The intervention group significantly increased their weekly intake of fruit and vegetables compared to the control, although the effect size was modest (small to moderate).

Gatto et al^62^ examined an after-school garden program (LA Sprouts) delivered over 12 weekly sessions (90 minutes each) in a low-income, primarily Hispanic/Latino sample of US children from third through fifth grade. The intervention consisted of interactive lessons on gardening and nutrition/cooking delivered by educators with a gardening or nutrition background. Children participated in planting, growing, and harvesting organic fruits and vegetables, and prepared a recipe each week emphasizing fruits and/or vegetables; parallel classes were offered bimonthly to parents. Children reported their intake using an FFQ at pre- and post-intervention. Compared to the control group, the gardening group increased dietary fiber intake and had a smaller decrease in vegetable intake. There were no significant between-group differences in intake of fruit, meat, dairy, whole grains, fruit juice, or added sugars.

Baranowski et al^54^ examined a theory-based curriculum (Gimme 5) consisting of 12 weekly sessions (45-55 minutes each) delivered by trained teachers over two 6-week intervention periods 1 year apart in a large sample of US fourth grade children. The curriculum targeted fruit, juice, and vegetables; weekly activities included taste testing snacks prepared by school food service, preparing and tasting fruit and vegetable recipes, videos, and goal setting. Parents were sent weekly newsletters with home assignments and were invited to attend an education session at a commonly frequented grocery store. Children reported their intake using a 7-day food record at pre-, mid-, and post-intervention. Although there was low fidelity of curriculum implementation, the intervention mitigated an age-related decline in intake of combined fruit, juice, and vegetables (and vegetables alone) compared to the control group. However, the effects were small. Group by time effects for fruit/juices was not significant.

A study conducted in Israel examined a 3-month nutrition intervention delivered by a clinical dietitian over 10 weekly lessons (45 minutes each) in a sample of 4-7 year old children.^69^ The lessons focused on affordable nutrition and included stories, games, songs, and weekly newsletters for parents; mothers also participated in three meetings on food preparation. Teachers received training on health leadership and how to compliment children who brought and ate healthy packed lunches. Intake was assessed with an FFQ completed by the child’s mother at baseline, post-intervention, and 3-month follow-up. The intervention significantly increased the dietary quality of packed lunches during the school year compared to the control group. However, assessment of packed lunches prepared at home likely represents parental feeding behaviors rather than children’s dietary choices. Compared to the control group, the intervention significantly increased the percentage of children eating a variety of foods and fruits/vegetables daily and decreased the percentage of children consuming SSBs daily. There was no significant between-group difference for sweets/candy intake.

The School-EduSalt study in China assessed the effect of a 3.5 month intervention focused on salt intake and delivered by trained health educators over eight lessons (40 minutes each) every 2 weeks in a sample of fifth grade children.^65^ The intervention included homework, competitions, plays, and parent newsletters. Salt intake was estimated from 24-hour urine collection and baseline and post-intervention. The intervention group had significant reductions in salt intake compared to the control group (mean effect was −1.9 grams/day).

Gold et al^63^ examined a nutrition curriculum (Go Wild With Fruits and Veggies!) delivered by extension educators over seven weekly lessons (45-60 minutes each) in a sample of US third grade children. The curriculum focused on fruit and vegetable consumption, and consisted of classroom education, take-home challenges, parent newsletters, and the opportunity to taste fruit and vegetables from five color groups. Some extension educators did not offer the taste testing component, and therefore this subset of the intervention group was analyzed separately. At post-intervention, self-reported intake of fruit was significantly higher among the intervention group that received the taste testing component compared to the control group; there were no significant between-group differences for vegetable intake. There were no significant differences in fruit or vegetable intake between the intervention group who did not receive the taste testing component and the control group.

One study involved the Nutrition Pathfinders program, which was delivered by classroom teachers over seven lessons (approximately 55 minutes each over a 4-10 week period) in a racially/ethnically diverse sample of US fourth grade children.^71^ The theory-based program focused on healthy eating behaviors and attitudes and utilized interactive activities, simulations, reflections, and family homework to teach students about food groups, serving sizes, and physical activity. Intake from the previous day was assessed with a questionnaire completed by the child (pre-intervention, post-intervention, and 3-month follow-up), and included a broad list of categories: low-nutrient high-density foods (e.g., chips, candy), SSBs, protein, dairy, grains, white bread, dark bread, vegetables, fruit/fruit juice, and a healthy foods latent variable (milk, vegetables, fruit, 100% fruit juice). Compared to the control group, the intervention group significantly decreased their intake of low-nutrient high-density foods and SSBs post-intervention, and increased their intake of protein foods, grains, and white bread at 3-month follow-up. No other food or beverage intake was significantly different between groups.

Serebrennikov et al^84^ investigated a nutrition curriculum broadly based on the Health Belief Model, consisting of two lessons per week (15-20 minutes each) and delivered by teachers over 6 weeks in a small sample of US second grade children. The curriculum focused on healthy meals and included a book and a final project.

Teachers in the intervention group were trained by researchers in all components of the curriculum. The control group received a usual curriculum and no training from the researchers. Digital photographs of plates before and after lunch were used to assess the amount of fruit and vegetables selected, consumed, and wasted. There were no significant differences between groups at post-intervention.

LaChausse et al^70^ examined a 4-month after-school program (Harvest of the Month) delivered by project staff over monthly sessions (30-40 minutes each) in a low-income, racially/ethnically sample of US fourth through sixth grade students. The program consisted of 14 activities focused on fruit and vegetables, such as tastings, student workbooks, nutritional information presentations, story books, farm-to-school presentations, and parent newsletters. A self-administered survey assessed intake of fruit, vegetables, cheese, milk, yogurt, cereal, French fries, sports drinks, fruit juice, soda, or sweets. At a 3-month follow-up, there were no significant differences between groups for intake of any food or beverage item. However, short-term changes in dietary intake may have been missed since outcomes were not measured immediately post-intervention.

One study in the Netherlands examined a 3-month multi-component intervention (Taste Lessons) delivered by teachers over five lessons (45 minutes each) in a sample of children aged 10-11 years.^56^ The intervention targeted vegetables and focused on taste development, healthy eating, food production, and consumer skills through hands-on activities, such as taste testing, experiments, and cooking. A second group received the same intervention, with the addition of extra hands-on activities, including a vegetable quiz, a trip to a vegetable grower, a home assignment with parents in the supermarket, and an extended cooking lesson with a dietitian and parents. Both intervention groups were compared to a no-intervention control group. Self-reported vegetable intake was assessed by three questions regarding the frequency of eating vegetables at supper, the quantity of vegetables eaten at supper, and the frequency of eating vegetables besides at supper. There were no significant changes in vegetable intake between any of the groups from baseline to post-intervention.

Bashirian et al^55^ investigated a 2-month educational program delivered by researchers over five sessions in a sample of fifth grade students in Iran. The intervention consisted of preparing fruits and vegetables to eat as snacks at the beginning of each lesson, additional taste testing activities and opportunities to try various fruit and vegetable dishes, and parental involvement. A food recall read to students by a project worker assessed intake of citrus, banana, vegetables, cucumber, tomato, carrot, lettuce, and cabbage. At post-intervention, there was visible improvement in the consumption of fruit and vegetables in the intervention group compared to the control, but these differences were not significant when corrected for multiple comparisons.

The Nutrition Detectives program consisted of four sessions (20 minutes each) delivered by physical education instructors over 1 month in a sample of US children from second through fourth grade.^68^ The program focused on selecting healthful foods and involved slide show presentations, a food label demonstration, and a game; a booster session was provided 3 months after the initial program. Intake was assessed with a questionnaire completed by children, with assistance from caregivers, at baseline and post-booster. There were no significant changes in intake of fiber, saturated fat, or sodium between the intervention and control groups. Short-term changes in intake may have been missed since diet outcomes were not measured immediately after the 1-month intervention ended.

Six RCTs were less than 4 weeks in duration.^50,64,87,89,94,97^

Smith et al^87^ examined a school garden curriculum (Pulse on Health) delivered by teachers over 3 weeks in a sample of US fourth grade children. The intervention consisted of nutrition, math, and science lessons focused on pulses (dry beans, dry peas, garbanzo beans, and lentils) and a school garden where students planted and harvested dry beans. The outcome measure was a single question asking students how frequently they eat beans at pre- and post-intervention. There was no significant difference in bean intake between the intervention and control groups.

One study conducted in the United Kingdom examined a nutrition education intervention consisting of two sessions (45 minutes each) delivered by the lead researcher over 7-10 days in a small sample of children aged 10-12 years.^64^ The sessions focused on improving knowledge and intake of sugar from food and beverages and included an informational booklet summarizing the curriculum to share with caregivers; an educational poster on the sugar content of popular foods and beverages was displayed in the classroom for 34 weeks. Parents completed an FFQ with input from the child at baseline, 10-week follow-up, and 34-week follow-up. There was no significant change in added sugars intake between the intervention group and a delayed intervention control. Short-term changes in added sugars intake may have been missed since diet outcomes were not measured immediately after the education sessions ended.

Vardanjani et al^94^ examined a nutrition education intervention consisting of four sessions (45-90 minutes each) delivered over 1 week in a small sample of female children in Iran. The sessions focused on reducing junk food intake and involved group discussions, brainstorming, posters, and pamphlets. At 2-months follow-up, self-reported junk food consumption was significantly lower in the intervention group compared to the control group.

Another study in Iran did not report the duration of the intervention, which consisted of four sessions (45 minutes each) promoting fruit and vegetable consumption in a sample of male children.^89^ The intervention was theory-based and included a food pyramid poster, educational booklet, pamphlet, and a 60-minute training session for teachers and parents. Children completed a 24-hour recall with parent supervision. At 3-months follow-up, the intervention group consumed significantly more fruit and vegetables compared to the control group.

Williams et al^97^ examined Hip Hop HEALS (Healthy Eating and Living in Schools), a culturally-tailored education program comprised of three sessions (1 hour each) delivered over consecutive days in a sample of US children from third through fifth grade. The program included musical cartoons, video games, songs, comic books, homework assignments, and parental involvement to teach concepts of energy balance and food label literacy. Food purchases were assessed through snack sales the day after the intervention from kiosks set up by study staff; one snack was permitted per child at each sale. Snacks were categorized into three groups based on nutrient density: “Go” foods (apples, grapes, fruit cup); “Slow” foods (granola bar, Rice Krispies treat, Goldfish crackers); and “Whoa” foods (Cheez-Its, chocolate chip cookies, chocolate cake). Compared to the control group, the intervention increased the proportion of children purchasing grapes and decreased the proportion of children purchasing chocolate chip cookies. There were no significant differences between groups in purchases of other individual snacks or nutrient density categories.

A study conducted in Saudi Arabia examined the effect of a single nutrition education session (120 minutes) delivered by physicians and dietitians in a sample of fifth and sixth grade girls.^50^ The intervention focused on healthy eating and consisted of games, computer presentations, discussion, quizzes, a puppet show, food models, role play, and opportunities to taste healthy prepared snacks. Children completed a questionnaire on their usual intake habits. The intervention group reported lower dietary quality habits compared to a delayed intervention control. However, usual intake was assessed the same day as the education session and likely does not reflect the actual long-term impact of the intervention on diet.

##### Game-based learning

Five RCTs^53,59,86,93,96,104^ examined the effect of educational board or electronic games on child dietary intake, with primarily beneficial effects on the targeted behaviors.

One study examined the effects of playing an educational board game (Kalèdo) for 20 weekly sessions (15-30 minutes per session) in a sample of Italian children aged 7-11 years.^96^ The game was designed to improve knowledge of the Mediterranean diet and promote a healthy lifestyle. Children, with teacher assistance, reported their intake using a 7-day food diary for junk food (i.e., candies, chocolate, gum, chips, crackers, fruit juice beverage, snacks, and sugary drinks) and healthy food (i.e., fruit, fresh-squeezed orange juice, vegetables, and yogurt). Compared to a control group, the intervention group had a greater intake of healthy food at post-intervention and 10-month follow-up, and a lower intake of junk food at 10-month follow-up (intake at post-intervention did not reach statistical significance).

Sharma et al^86^ examined the effects of playing a theoretically grounded, web-based computer game (Quest to Lava Mountain) as part of an afterschool program for a minimum of 90 minutes a week for 6 weeks in a small, racially/ethnically diverse sample of US fourth and fifth grade children. The game focused on food, nutrition, and physical activity for optimal health and required students to make simulated appropriate food choices. At post-intervention, the games group had a significant decrease in self-reported intake of sugar compared to the control group. There were no significant differences between groups for intake of fruit, vegetables, or dietary fiber. The authors noted that optimal intervention dosage of 90 minutes per week was not achieved.

A study conducted in France examined the impact of playing educational computer games about food, nutrition, and balanced meals for 2 hours a week for 5 weeks in a large sample of children aged 7-12 years.^93^ The intervention group played computer games during the conventional nutritional teaching period, and the control group received conventional classroom nutrition education from teachers. At post-intervention, the games group consumed less sugar, meat, delicatessen food, sweetened dairy desserts, and green vegetables, and more fiber, plain dairy products, starchy food, and fruit compared to the control group. More children in the games group reported eating fruit and vegetables every day compared to the control group, but this did not reach statistical significance.

One US study examined the impact of playing an interactive, theory-based multimedia game (Squire’s Quest!) for two sessions per week (25 minutes each) for 5 weeks in a large, racially/ethnically diverse sample of fourth grade students.^53,59^ The game focused on meal-specific behavior change techniques, such as food preparation, produce shopping, and goal setting. At post-intervention, the games group consumed more fruit, regular vegetables, and total fruit, 100% fruit juice, and vegetables compared to the control group; there were no significant differences between groups in intake of juice alone or high-fat vegetables.^53^ Additional analyses were conducted to identify changes at specific meal times and found increased intake of fruit and 100% fruit juice for snacks, and regular vegetables for lunch in the intervention group compared to the control group; there were no significant effects on high fat vegetable intake or intake of any measured items at breakfast and dinner.^59^

Hermans et al^104^ conducted a parallel RCT to examine the effects of playing a virtual reality videogame (Alien Health Game) for 30-minute sessions on 2 consecutive days in a Dutch sample of fifth and sixth grade children aged 10 to 13 years. The game was designed to increase children’s nutritional knowledge of everyday foods and macronutrients and stimulate healthy food choices. The control group played a different nutrition-related computer game on selecting groceries that was not designed to teach children about healthy food choices. Children were offered energy-dense foods (salted potato chips and chocolate candies) and nutrient-dense foods (green grapes and cucumber slices) as part of a taste test at post-intervention and a 2-week follow-up; intake was calculated based on pre- and post-weighing. Main effects of the intervention group, as well as group by time interactions, were not significant for intake of energy-dense or nutrient-dense foods at post-intervention and the 2-week follow-up.

##### Educational reading materials and videos

Four RCTs^52,102,103,105^ examined the impact of short-term exposure to educational books or videos on expressed food choice, with primarily beneficial effects on the targeted behaviors.

One parallel RCT conducted in the Netherlands examined the impact of shared reading sessions using a picture book about carrots for 5 consecutive days in a sample of 4-6 year old children.^102^ The reading style was either passive (listening to the story) or interactive (answering questions about the story), and the character in the book was either congruent (rabbit) or incongruent (turtle) with carrots. Children were randomized to a control group or one of four intervention groups: interactive/congruent, interactive/incongruent, passive/congruent, and passive/incongruent. After the final reading session on day 5, intake of four foods (carrot, cucumber, salty snacks, and cheese) was measured and proportional intake of each food was calculated. All intervention groups consumed a higher proportion of carrots and lower proportion of cucumber and cheese compared to the control group; there was no effect on intake of salty snacks. An interactive reading style was related to higher carrot intake compared to passive reading, while character congruence did not affect carrot intake.

Leung et al^105^ conducted a parallel RCT to investigate a 1-hour exposure to a Manga comic (Japanese comic art) promoting fruit intake in a small US sample of low-income, predominantly Black and/or Hispanic elementary and middle school children attending an after-school program. Thirty pages of the comic were narrative and one page was non-narrative to reinforce the health messages. The attention-control group read non-health related materials. After reading the materials, children were offered a choice of snack from eight items (four fruits and four energy-dense items). More children in the intervention group chose fruit as a snack compared to the control group. Results were not provided by age group.

A parallel RCT conducted in Portugal examined the impact of a single exposure to a 20-minute cartoon show (Nutri Ventures) with healthy eating messages in a sample of children aged 4-8 years.^103^ The control group watched a popular cartoon show without content on eating or food. After viewing the videos, children could eat ad libitum from four individual bowls of healthy and less healthy foods (grapes, baby carrots, chips, and chocolates); the exact number of food items consumed in a 10-minute period was recorded. The intervention group consumed more healthy food items compared to the control group. There were no significant differences between groups in intake of less healthy food items.

Bannon et al^52^ examined the influence of nutrition message framing on snack choice using a 60-second video in a small sample of US kindergarteners. Three classrooms were randomly assigned to watch one of the following videos: 1) a gain-framed video highlighting the positive benefits of eating apples; 2) a loss-framed video highlighting the negative consequences of not eating apples; or 3) a control video unrelated to nutrition. Following the video, children were offered a choice of animal crackers or an apple for snack. More children in the loss-framed intervention group (and both intervention groups combined) chose apples compared to the control group. The gain-framed intervention had similar effects but did not reach statistical significance.

##### Other strategies

Five cluster-RCTs^57,61,66,74,78^ utilized other educational strategies that did not fit cleanly into curriculum-based interventions, game-based learning, or educational books or videos.

One study conducted in the United Kingdom examined the impact of an 18-month school gardening intervention led by the Royal Horticultural Society in a racially/ethnically diverse sample of children aged 7-11 years.^57^ The intervention group received: regular visits with a Society regional advisor to work in the garden; ongoing advice, free seeds, and tools; and evening training by a Society regional advisor once per term. The intervention did not include an educational curriculum. The control group was a school garden program led by teachers, who were offered evening training by a Society regional advisor once per term. At post-intervention, there were no significant differences in intake of fruit, vegetables, combined fruit and vegetables, sodium, sugar, or fiber between the school garden program and the control.

Jamelske et al^66^ examined the impact of an 8-week nutrition intervention involving different levels of teacher encouragement to taste three vegetable snacks in a sample of US children from kindergarten through third grade. Teachers served each vegetable once a week, providing varying levels of assigned encouragement for the first six servings of each vegetable and refraining from any form of encouragement for the last two servings. In the moderate encouragement group, teachers discussed the benefits of healthy eating while distributing vegetable snacks and suggested trying, smelling, or licking the vegetable; teachers were asked to model good behavior by eating the vegetables themselves. The high encouragement group received the same intervention with the addition of more substantial conversation with the teacher, such as vegetable songs during snack time and short educational projects related to vegetables. The control group was served vegetable snacks but received no teacher encouragement; teachers were instructed to not draw attention to themselves if they chose to consume the vegetable. Proportion of intake was calculated based on pre- and post-weighing. After the first weekly serving, both intervention groups consumed significantly higher proportions of vegetables compared to the control group; in addition, the high encouragement group consumed a significantly higher proportion of vegetables compared to the moderate encouragement group. At post-intervention, when no encouragement was provided, significantly higher vegetable consumption remained for the high encouragement group compared to the control, but not for the moderate encouragement group.

A study in Canada investigated an 8-week nutrition extracurricular program (Team Nutriathlon) delivered by trained teachers in a sample of fifth and sixth grade children.^61^ The intervention aimed to improve students’ feeling of competency regarding their eating habits and promote the development of autonomy over their food choices. Children were encouraged to reach team (five-six students) and individual goals regarding the volume and variety of fruit, vegetable, and dairy product (and dairy alternatives) consumption according to age- and sex-based recommendations of Canada’s Food Guide. Students recorded their daily intake on Team Nutriathlon record sheets and were taught how to read computer-generated summary reports of their consumption with respect to individual and team goals. At the end of the intervention, final consumption results were determined, and students were awarded with individual and team awards. The control group recorded their daily intake on plain record sheets and were told to record their actual consumption without changing their eating habits. Compared to the control group, the intervention group had significantly higher intake of fruit and vegetables (combined) and dairy products during the intervention, at post-intervention, and at 10-week follow-up.

Mangunkusumo et al^74^ investigated the impact of Internet-tailored nutrition advice and brief dietary counseling to promote fruit and vegetable intake in a sample of Dutch children aged 9-12 years. All children completed online questionnaires on fruit and vegetable intake and related determinants. Children in the intervention group received immediate online feedback and a printout of individually tailored dietary advice; two weeks later, children received a 5-minute dietary counseling session from a nurse in the presence of a parent to discuss the online questionnaire and tailored advice. At a 3-month follow-up, there were no significant differences in self-reported intake of fruit or vegetables between the intervention and control groups. However, short-term changes in dietary intake may have been missed because outcomes were not measured immediately post-intervention.

Perry et al^78^ evaluated the impact of a 45-minute educational theater production (All’s Well That Eats Well) about eating behaviors and the benefits of a healthy diet in a large, racially/ethnically diverse sample of US children from fourth through sixth grade. Follow-up classroom and home activities included food fact sheets, vocabulary words, a food guide review, a food label exercise, and an interview for students to conduct with their parents about fruits and vegetables; the duration of these follow-up activities was not reported. The previous day’s intake was assessed with a 14-item food recall survey focused on fruits and vegetables and administered to students. At 3-week follow-up, there was no significant difference in food recall score between the intervention and control group.

##### Summary

There is a large body of evidence on teaching and educational interventions in elementary school children targeting the acceptance of healthier foods and dietary patterns. The majority of these studies implemented a nutrition curriculum, with primarily beneficial effects on diet and dietary behaviors. Curriculum-based interventions consisted of a heterogeneous combination of strategies, but several trends are worth noting. First, curricula were often supplemented with parental involvement and games, which both tended to show beneficial effects. Another strategy that was frequently implemented was taste testing and cooking/meal preparation, which tended to have more substantial, beneficial effects when interventions were longer than 3 months duration. Second, interventions that were delivered by external educators (such as researchers and/or health professionals) tended to have beneficial effects, whereas the evidence was mixed for classroom teachers. Few curriculum-based studies compared types of educators. Additional research is needed to determine if certain types of educators are more effective at changing children’s diet and dietary behaviors. Third, effective interventions tended to have curricula that were delivered at a greater dose in terms of the duration, frequency, and amount. Specifically, there was a trend toward more beneficial effects from interventions of longer duration (i.e., 3 months or longer), more frequent delivery of the curriculum (e.g., weekly instead of monthly), and greater total amount of curriculum content (e.g., 10 hours total vs 2 hours total). Most studies assessed outcomes immediately post-intervention; additional research is needed to determine if the effects on diet are sustained after the intervention. Finally, interventions with broad nutrition curricula (e.g., general nutrition, fruit and vegetables combined) tended to have beneficial effects, while interventions focusing on a single food group or nutrient tended to have null findings. Further research is needed to confirm these trends.

Fewer studies used non-curriculum-based interventions to target diet and dietary behaviors. Game-based learning interventions, with consistent opportunities to play over the course of several weeks, tended to have beneficial effects on children’s dietary intake. More research is needed to assess the long-term effects of game-based learning strategies beyond the immediate post-intervention period. Studies examining the effect of brief exposure to nutrition-related reading materials and videos found beneficial effects on children’s expressed food choices immediately following exposure to the media. More research is needed to confirm these findings and to assess whether the benefits are sustained long-term, or whether longer-term, more frequent exposure to these materials confer similar, positive effects. Other types of interventions were administered in single studies and showed beneficial outcomes, such as using individual- and team-based consumption goals to build autonomy over food choices or using teacher encouragement and role modeling in the classroom to promote vegetable intake; additional research is needed before conclusions can be drawn regarding these interventions.

In general, teaching and educational interventions in elementary school children tended to have the most consistent benefits on fruit and sodium intake. The evidence was a mix of positive and null results for vegetables, food and beverages of lower nutritional quality, and fiber. Dairy, whole grains, protein foods (such as beans and legumes), added sugars, and saturated fat were measured in too few studies to draw conclusions. More research is needed to assess whether dietary intake is differentially affected by certain types of strategies. A few studies investigated the impact of non-curriculum-based interventions, with positive results; further investigation into games and short-term exposure to nutrition-related reading materials and videos is warranted for food and beverage intake. Overall, more research is needed to determine which teaching and educational strategies have the greatest impact on diet and dietary behaviors in elementary school children.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates that curriculum-based nutrition education of 3 months or longer duration improves food and beverage intake (particularly fruit intake) in elementary school children. Common components of successful curricula include parental involvement, games, and taste testing or cooking/meal preparation. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: In the body of evidence on food and beverage intake, the main area of potential risk of bias was related to concerns of selective reporting; most studies lacked information on an a priori analysis plan, such as a pre-registered protocol or clinical trial registration. Additionally, almost half of the studies had some concerns due to missing outcome data. Several studies had some concerns or high risk of bias related to the randomization process, as well as bias arising from participant identification and recruitment. Most studies were assessed as having low risk of bias related to deviations from intended interventions and measurement of the outcome.
- Consistency: Studies in this body of evidence utilized diverse teaching and educational strategies. In addition, there was large variation in the delivery, dose, and targeted dietary outcome of the interventions. Despite this heterogeneity, interventions 3 months or longer duration reported some beneficial effect. Curricula were often supplemented with parental involvement, games, or a taste testing and cooking/meal preparation component – all tended to confer benefits. For the evidence on food and beverage intake, about 75 percent of the studies found significant improvement in at least one measure of food and beverage intake. Among the six studies with primarily null findings for food and beverage intake, five studies were less than 3 months duration^55,56,70,84,87^ and one 6-month study noted variation in implementation fidelity across classrooms and schools.^95^ Findings were most consistent for fruit intake, which tended to be beneficially impacted in interventions 3 months or longer duration. Approximately two-thirds of the studies found significant improvement in fruit intake. Among the 10 studies with primarily null findings for fruit intake, 5 studies were less than 3 months duration,^54,55,62,71,84^ 1 study had high risk of bias for participant identification and recruitment,^91,92^ 1 study reported lower adherence to the intervention,^85^ and 2 studies involved a lower intensity intervention with less than 4 hours of total curricula content.^70,90^ One study found that curriculum-based nutrition education resulted in lower vegetable intake (but no differences in fruit intake) compared to a free fruit and vegetable program in schools.^40,41^ Less consistent results were observed for intake of vegetables, and food and beverages of lower nutritional quality. Other dietary components (including dairy, whole grains, and beans/legumes) were examined in too few of studies to assess consistency.
- Directness: Studies in this body of evidence directly assessed the research question in terms of the population, intervention, comparators, and outcomes. Two studies directly compared the type of educator delivering the intervention (without a no-intervention control group)^75,76^ and one study compared a nutrition curriculum to an environmental intervention.^40,41^
- Precision: In the body of evidence on food and beverage intake, over half of the studies did not report a power calculation. Of the 16 studies that reported power calculations, 1 did not meet their pre-specified sample size goal^90^ and 3 were completed for an outcome unrelated to dietary intake.^73,85,91,92^ Sample size varied greatly across the body of evidence, but most of the included studies enrolled a relatively large number of individual participants and clusters. Most interventions were conducted over several months or years; three studies tested interventions that were less than a month duration.^87,89,94^
- Generalizability: The body of evidence is largely generalizable to elementary school children in the United States. Approximately one-third of the studies were conducted in the United States and a third were conducted in Europe; the remaining studies were conducted in a wide variety of countries assessed as high or very high HDI. All but one study was conducted exclusively with elementary school children.^79^ Schools enrolled students from a range of SES and racial/ethnic backgrounds; however, about half of the studies did not report this information.

Limited evidence from this rapid review suggests that curriculum-based nutrition education of 3 months or longer duration may reduce sodium intake in elementary school children. This conclusion statement received a grade of Limited. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: The main area of potential risk of bias was related to concerns of selective reporting; only one study had information on an a priori analysis plan.^65^ One study had high risk of bias related to missing outcome data.^68^ All studies had low risk of bias related to randomization, participant identification/recruitment, deviations from intended interventions, and outcome measurement.
- Consistency: Studies in this body of evidence utilized diverse teaching and educational interventions that varied in content and delivery. Despite this heterogeneity, interventions 3 months or longer duration reported some beneficial effect. Three out of four studies found significant reduction in sodium intake at post-intervention; however, it was difficult to compare the magnitude of effect across the small number of studies. The study with primarily null findings was 1-month in duration and had high risk of bias related to missing outcome data (61 percent attrition).^68^ Less consistent results were observed for studies examining fiber intake. Added sugars and saturated fat were examined in too few of studies to assess consistency.
- Directness: Studies in this body of evidence directly assessed the research question in terms of the population, intervention, comparators, and outcomes.
- Precision: There are limits to the precision of this body of evidence based on the small number of studies underlying this conclusion statement. One study reported a power calculation for sodium intake.^65^ Sample sizes ranged from 127 to 305 participants, and 5 to 28 clusters. Most of the studies were more than 3 months duration. Two interventions were specifically designed to target sodium intake.
- Generalizability: There are limits to the generalizability of this body of evidence to elementary school children in the United States. Two studies were from Portugal,^58,83^ one study was from China,^65^ and one study was from the United States.^68^ All studies were conducted exclusively with elementary school children. Schools enrolled participants from a range of SES backgrounds, but most studies did not report data on race/ethnicity.

Limited evidence from this rapid review suggests that playing school-based nutrition games (board or electronic) for multiple weeks may have beneficial effects on dietary intake in elementary school children. This conclusion statement received a grade of Limited. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of bias: The main area of potential risk of bias was related to concerns of selective reporting; no study had information on an a priori analysis plan, such as a pre-registered protocol or clinical trial registration. There were some concerns related to missing outcome data and lack of information on the randomization process. One study had concerns with deviations from the intended intervention.^104^ All studies had low risk of bias related to measurement of the outcome.
- Consistency: Findings across the five game-based interventions were consistent in direction. All interventions that were played for multiple weeks reported significant improvement in at least one measure of dietary intake; however, it was difficult to compare the magnitude of effect across the small number of studies. One study found primarily null results between playing a nutrition game for 2 consecutive days compared to an active control group that played a different game.^104^ The targeted outcomes varied widely across studies and outcomes of specific food groups were examined too infrequently to assess consistency.
- Directness: Studies in this body of evidence directly assessed the research question in terms of the population, intervention, comparators, and outcomes.
- Precision: There are limits to the precision of this body of evidence based on the small number of studies underlying this conclusion statement. One study was sufficiently powered.^53,59^ In addition, there was wide variation in the targeted outcome, making it difficult to compare the magnitude of effects. Sample and cluster sizes varied across the body of evidence, ranging from 94 to 1,576 participants and 6 to 26 clusters. Most studies tested interventions that were at least 1-month duration, but one study implemented the intervention over only 2 consecutive days.^104^ For some statistically significant results, practical significance may be limited given the small increases in dietary intake reported.
- Generalizability: The body of evidence on game-based interventions is generalizable to elementary school children in the United States. All studies were conducted exclusively in elementary schools. Half of the articles were from the United States, and half were from high or very high HDI countries in Europe. The US studies enrolled participants from diverse racial/ethnic backgrounds, but the European studies did not report data on race/ethnicity.

Limited evidence from this rapid review suggests that school-based nutrition education involving brief use of books or videos may have a beneficial impact on expressed food choice immediately following exposure to the intervention in younger elementary school children (5- to 6-years old). This conclusion statement received a grade of Limited. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence

- Risk of bias: The main area of potential risk of bias in this body of evidence was related to concerns of selective reporting; no study had a pre-registered protocol or clinical trial registration. In addition, half of the studies lacked information on the randomization process. However, all studies had low risk of bias related to missing outcome data, measurement of the outcome, and deviations from the intended intervention. The single cluster RCT had low risk of bias for identification and recruitment of participants in relation to timing of randomization.^52^
- Consistency: All studies in this body of evidence found beneficial changes in children’s expressed food choice immediately following exposure to the intervention. However, it is difficult to compare the magnitude of effect across this relatively small number of studies. Most studies tested interventions that were implemented on single occasions; one study was conducted over 5 consecutive days.^102^ In addition, half of the interventions involved educational reading materials and half involved educational videos. The targeted outcomes varied widely across studies and outcomes of specific food groups were examined too infrequently to assess consistency.
- Directness: Studies in this body of evidence directly assessed the research question in terms of the intervention, comparators, and outcomes. All studies in this body of evidence were designed to directly examine the effect of brief exposure to educational books or videos on expressed food choice immediately following exposure to the intervention. However, the broader research question was not directly assessed since one study did not examine elementary school children exclusively.^105^
- Precision: There are limits to the precision of this body of evidence based on the small number of studies underlying this conclusion statement. One study was sufficiently powered.^103^ In addition, sample sizes were relatively small and ranged from 50-160 participants.
- Generalizability: The body of evidence on educational books or videos is generalizable to elementary school children in the United States. Three out of four studies were conducted exclusively in younger elementary school children (age 5-6 years).^52,102,103^ Half of the studies were from the United States, and half were from high or very high HDI countries in Europe. However, there was limited data on race/ethnicity and SES.

#### Behavioral and environmental interventions

##### Description of the evidence

Thirty-two articles from 30 RCTs examined the effect of school-based behavioral and environmental interventions on diet and diet-related behaviors in elementary school-aged children.^21–49,99–101^ All RCTs were cluster randomized except for three, which were individually randomized.^99–101^ Most studies were conducted solely in elementary schools, but seven were conducted in conjunction with middle or junior high schools.^24–26,28,32,39,44^ Half of the studies were conducted in the United States^23–26,28–34,38,39,42,43,99,100^; the remaining studies were conducted in Australia,^27,48,49^ Belgium,^47,101^ Denmark,^37^ France,^36^ the Netherlands,^40,41,45,46^ New Zealand,^21^ and the United Kingdom.^22,35,44^ The analytic sample sizes of the cluster-RCTs ranged from 2^34,43^ to 90^42^ clusters and 67^23^ to ~8,000^33^ individual participants; most cluster-RCTs enrolled multiple clusters per study arm and analyzed several hundred to several thousand individual participants. The analytic sample sizes of the 3 parallel-RCTs were 71,^100^ 77,^101^ and 820^99^ individual participants. Studies enrolled participants with a range of SES, including some studies that were specifically conducted in schools with a high proportion of students eligible for free/reduced price meals^24,25,28,29,32–35,42,99,100^ or located in lower SES regions.^21,49^ Race and ethnicity varied across the studies, including some studies conducted in schools with a predominantly White student population,^22,23,26,30,31,33,37,38,43,44,100^ and other studies conducted in schools that enrolled high proportions of Black and/or Hispanic students.^24,25,28,29,32,34,42^ However, several studies did not report information on SES^23,31,36,39–41,45–47,101^ or race/ethnicity.^27,35,36,39,45–49,99^

A variety of behavioral and environmental strategies were examined across the studies, including using rewards, incentives, and nudges; targeting food palatability, presentation, and promotion; modifying food availability and school food policies; and implementing a combination of strategies, which are detailed below. Interventions were compared to usual care/no intervention,^21–27,29,30,32,34–36,38,43,44,47–49,99^ or to a different intervention or intervention without the component of interest.^22,28,31,33,36,37,39–41,45–47,100,101^ Approximately half the studies reported the theoretical foundation or framework underlying the intervention^22,24,25,27–32,37–42,47,48^; a variety of theories or frameworks were cited. Outcomes were primarily assessed by study personnel via direct observation or weighing of the food selected or consumed at school,^22,24–26,28–34,36–39,42,43,45–48,99,101^ although some studies used sales records^27,49,100^ or measures of self- or parent-reported intake.^21,23,35,40,41,44,46^ Sixteen studies assessed food or beverage selection,^24–30,32,36,39,42,43,48,49,100^ while 20 studies assessed food or beverage intake.^21–24,26,31–35,37,38,40,41,43–47,99,101^ Most studies assessed in-school selection or intake,^21,22,24–39,42,43,45–49,99–101^ but a few assessed overall selection or intake.^21,23,35,40,41,44^ Evidence from these studies and participant characteristics are described in Table 5; the risk of bias assessments are described in Table 6. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Rewards, incentives, prompts, and nudges

Six studies assessed the effect of offering incentives for selecting or consuming fruit and/or vegetables at lunch or during a taste test,^22,31,33,34,39,47^ and results varied.

A Belgian study tested the effect of three strategies to increase consumption of a generally disliked vegetable (chicory) for 8 weeks: repeated exposure, repeated exposure with verbal praise for tasting the vegetable, or repeated exposure with a tangible reward for tasting the vegetable.^47^ Intake was assessed by weighing the portion of vegetable initially served and the portion remaining after the taste test. All three strategies increased consumption of the disliked vegetable compared to a control group during a taste test at post-intervention and 8-week follow-up; however, there were no group differences between the group that received repeated exposure to the vegetable and the groups that added verbal praise or a tangible reward to repeated exposure. the three strategies.

Mazzeo et al^34^ conducted a study in the United States that assessed the effect of providing verbal encouragement, praise, and stickers to try small portions of fruit and vegetables that would be available in future school lunches twice a week for 8 weeks. Although between-group differences in plate waste assessed by trained observers were not detected immediately post-intervention, schools that received the incentivized tasting intervention wasted less vegetables and fruit (juice included) at lunch in the cafeteria at 6-week follow-up compared to schools that received no intervention.

Another study conducted in the United States assessed the effect of providing a small prize for consuming a small portion of either fruit or vegetables for 6 weeks on consumption assessed by trained observers.^31^ One group had fruit incentivized, while the other group had vegetables incentivized; a no-intervention control group was not included. Both groups were provided with an additional fresh fruit and fresh vegetable on their lunch tray to give all children choices. Children who received incentives for fruit increased their lunchtime fruit consumption during the study compared to children who received incentives for vegetables; similarly, children who had vegetables incentivized increased their lunchtime vegetable consumption compared to children who had fruit incentivized.

A third study conducted in the United States among elementary and middle school students examined the effect of a 6-week intervention that combined incentives for selecting fruit and vegetables at lunch with personal pledges or with a group competition.^39^ In the first intervention group, students were asked to make a personal pledge to eat more fruit and vegetables and were incentivized to select two or more fruits and/or vegetables through small prizes that could be earned daily, as well as the opportunity to win a larger prize through a random drawing if they selected at least two fruits and/or vegetables each day of the week. Students in the second intervention group were told they were in a healthy eating competition with other schools and were offered the same incentives. Students in the comparison group only received the incentives. Choice of at least two fruits and/or vegetables were recorded by trained cafeteria staff. Both intervention groups, competition with incentives and personal pledges with incentives, increased the proportion of older children and adolescents (third-eighth grade) who selected two or more fruits or vegetables at 10-weeks follow-up, compared to incentives alone. However, among the youngest children enrolled in this study (first and second grade), the effects of competition with incentives were more pronounced and there was no effect of personal pledges with incentives compared to incentives alone. Due to the lack of a no-intervention control group, the independent effect of the incentives, with or without the addition of competition or personal pledges, cannot be discerned.

Loewenstein et al^33^ compared the effect of providing small incentives for consuming a serving of fruit or vegetables at lunch for two different durations in US elementary schools. One group received incentives for 3 weeks, while the other group received incentives for 5 weeks. Intake was assessed through observation by research assistants in the cafeteria. Although both groups increased fruit and vegetable intake at lunch, there was no significant difference between groups during the intervention or at 1- and 2-months follow-up. Due to the lack of a no-intervention control group, the independent effect of the incentives also cannot be assessed in this study.

Finally, a study from the United Kingdom assessed the effect of small incentives (stickers) for choosing fruit and vegetables at lunch, with the opportunity to earn an extra reward, for 4 weeks.^22^ Children in the first intervention group were eligible for the extra reward if they collected at least four stickers in a week (individual incentive program), while children in the second intervention group were eligible for the extra reward only if they collected the most stickers out of all children in small, randomly assigned groups (competitive incentive program). A third group received no intervention. Lunch monitors assessed whether students chose or brought fruit or vegetables to lunch and whether the student subsequently consumed at least half of the served fruit or vegetable. Among the full sample of children, there was no significant difference in choice or intake of fruit or vegetables at lunch between either of the incentive programs and the control group during the intervention, at post-intervention, or at 6-month follow-up. However, results tended to vary by child age and baseline selection of fruit and vegetables. Among younger children (6-7 years old), the individual incentive program reduced choice of fruit or vegetables during and immediately post- intervention; effects on choice at 6-month follow-up and effects on intake were not statistically significant. Among older children (9-10 years old) the individual incentive program tended to increase choice of fruit or vegetables during the intervention; however, this effect was not statistically significant. When analyses were limited to children who did not already select a daily fruit or vegetable during lunch at baseline, the competitive incentive program resulted in greater choice and consumption of fruit and vegetables during and immediately post-intervention. There was not an overall significant effect of the individual incentive program among children with less than daily selection of fruit or vegetables at baseline; however, analyses by age found that the individual incentive program decreased choice and intake of fruit or vegetables during the intervention and post-intervention among younger children, while it increased choice and intake of fruit or vegetables during the intervention among older children.

Three studies, all conducted in the Unites States, assessed the effects of verbal nudges on food and beverage selection,^32,42,43^ primarily observing beneficial effects.

The first study assessed the effect of cafeteria staff asking children whether they would like fruit or juice with lunch compared to no verbal prompt.^43^ Parent volunteers observed children in the cafeteria to assess selection and consumption of fruit and juice. After 5 months of the intervention, children in the intervention group had higher odds of selecting and consuming fruit compared to the control group; after 7 months of the intervention, children in the intervention group had higher odds of selecting and consuming both fruit and juice.

Lai and colleagues^32^ separately assessed the effects of four different nudge or incentive strategies in the cafeteria line over 5 days to influence elementary and middle school students’ milk choice: a verbal prompt to try white milk, a verbal prompt to try white milk because it is healthy, a verbal prompt to try white milk because it tastes good, or a small incentive attached to the white milk carton. No prompt or incentive was provided in the control group. Choice of milk was recorded by researchers and intake was assessed by weight. During the intervention, all four strategies increased the proportion of students choosing white milk over chocolate milk compared to the control group. There were no significant differences between the three verbal prompt groups, or between the incentive group and any of the verbal prompt groups. Furthermore, all verbal prompt groups consumed less added sugars than the control group without decreasing the amount of milk consumed; the incentive group consumed less added sugars than the control group but also decreased the amount of milk consumed. Similar but less consistent results were obtained during 2 days of follow-up, when prompts and incentives were discontinued. Separate analyses for elementary and middle school-aged children were not conducted.

The third study assessed the effect of three different verbal nudges delivered in the classroom immediately prior to lunch on a single day to encourage selection of white milk.^42^ The control group received a brief educational prompt that described the health benefits of choosing white milk over chocolate milk. One intervention group received the same educational prompt along with a sticker to encourage selection of white milk, while the second intervention group received the educational prompt and were encouraged to set a goal to drink white milk. Selection of white and chocolate milk at lunch was observed by research assistants. The proportion of children selecting white milk increased in all three groups; however, a significantly greater proportion of children in both intervention groups selected white milk compared to children in the control group. When results were analyzed by grade, effects were stronger among younger children (kindergarten-third grade).

Three studies assessed the effect of nudging students toward more healthful choices using targeted online ordering systems for school meals,^27,49,100^ and tended to observe positive results.

An Australian study assessed the effect of implementing a broad suite of changes to an existing online ordering system for 2 months.^27^ Changes to the online menu including labeling items based on their nutritional value, placing healthier menu items first, prompting users to add a healthier item to their lunch if they selected items of lower nutritional value, and providing a positive prompt when a healthier menu item was selected. The control group received the original online menu. Purchases were assessed via report from the online ordering system. The intervention group purchased a higher proportion of lunch items of high nutritional value and a lower proportion of lunch items of low nutritional value compared to the control group; in addition, the intervention group purchased lunch orders with lower saturated fat and sodium content. The mean percentage of energy from sugar significantly increased in the intervention group compared to the control group; however, there was no significant difference in the sugar content of lunch orders between groups. Notably, the identity of the individual placing the order was unknown; therefore, it is unclear whether the study measured choices made by students or caregivers.

Wyse et al^49^ tested the effect of listing fruit and vegetable snacks first and last in an online ordering menu for 4 weeks in Australian primary schools. Purchases were assessed via report from the online ordering system. The study found no effect of the redesigned menu on the odds of ordering fruit and vegetables, compared to individuals exposed to the original online menu.^49^ As with the other Australian study, the identity of the individual placing the order was unknown; therefore, it is unclear whether the study measured choices made by students or caregivers.

The third study, conducted in the United States, assessed the effect of implementing an online pre-ordering system for 2 weeks, with and without nudges based on MyPlate recommendations.^100^ Selection of meal components were recorded by the online system. Over the 2-week intervention, children who received the additional nudge ordered a significantly greater proportion of meals containing fruit, vegetables, and low-fat milk compared to children that did not receive a nudge. When the first and second weeks of the intervention were analyzed separately, significant effects on fruit and low-fat milk selection were present during the first (but not the second) week, whereas significant effects on vegetable selection were not present until the second week.

##### Food palatability, presentation, and promotion

Eight studies assessed the effects of strategies that targeted the palatability, presentation, and/or promotion of foods in school,^24,28,29,36,37,45,46,101^ with most detecting some positive impacts on the outcomes of interest. Of these studies, six implemented interventions primarily focused on modifying how food is presented for snacks or school meals,^29,36,37,45,46,101^ one focused on food promotion,^28^ and one examined interventions focusing on food palatability and/or presentation.^24^ The studies primarily implemented interventions over a brief period of time and focused on a variety of food items.

One study (Shape Up Somerville: Audio Adventures), conducted with US elementary and middle school-aged students, focused on food promotion.^28^ This study assessed the effects of daily bean-promoting audio messages played over the public address system for approximately 3 months on the selection of bean dishes at lunch. In both the intervention and control schools, two new bean dishes were incorporated into the school lunch menu 1-2 times per month. The odds of choosing a bean dish, as observed by trained data collectors, did not differ between the intervention and control groups during the study. When the two types of dishes were analyzed separately, there was no effect of study group on selection of the bean taco dish, but the odds of choosing the bean chili dish were greater in the intervention group compared to the control group. The level of implementation, and its effect on choosing bean dishes, varied greatly across schools. Specifically, the school with the lowest level of implementation had lower odds of choosing bean dishes and the school with the highest level of implementation had higher odds of choosing bean dishes, suggesting that greater implementation of this intervention may be important to its efficacy. Analyses by grade level were not conducted.

Olsen et al^37^ conducted a study in Denmark that assessed the effect of exposing children to pre-lunch vegetable snacks that were liked, neutrally-liked, and disliked by children. During the first week of the study, children received one of three combinations of vegetables: cauliflower (a neutrally liked vegetable) alone, a combination of cauliflower and celery (a disliked vegetable), or a combination of cauliflower and sugar snap peas (a liked vegetable). In the second week, children were provided with all three vegetable snacks. Intake of the snacks was assessed by subtracting the weight of vegetables remaining from the weight of the portion offered. Groups did not differ in intake of sugar snap peas or celery during the pre-lunch snack; however, children who were initially provided with the vegetable snack that combined cauliflower and sugar snap peas had higher intake of cauliflower compared to children who were initially provided with cauliflower alone or cauliflower with celery.

In another study conducted in the United States, investigators assessed the effect of two changes to the presentation of white and chocolate milk in the lunch line for 1 week: removing chocolate milk from the lunch line and requiring children to ask for it, or modifying the ratio of milk types displayed in the lunch line to favor white milk.^29^ The control group was exposed to the usual presentation of equal amounts of white and chocolate milk in the lunch line. Observed selection was assessed by trained research assistants. Removing chocolate milk from the lunch line resulted in a greater proportion of children selecting white milk at least once during 5 days of observations. Modifying the ratio of milk types displayed in the lunch line did not result in different levels of selection compared to the control condition.

One study assessed the effect of offering whole wheat and white bread rolls in regular- and fun-shaped varieties on a single day as part of a national school breakfast event in the Netherlands.^46^ Classrooms were provided rolls in one of four combinations: regular-shaped whole wheat and white bread rolls, regular-shaped whole wheat and fun-shaped white bread rolls, fun-shaped whole wheat and regular-shaped white bread rolls, and fun-shaped whole wheat and white bread rolls. Based on classroom observation and weighing, consumption of whole wheat rolls was greater when they were offered in a fun shape, particularly when simultaneously offered white bread rolls in a regular shape. Conversely, when white bread rolls were offered in a fun shape, intake of whole wheat rolls was lower, particularly when offered in a regular shape. Similar results were obtained for self-reported intake.

Marchiori et al^101^ conducted a study conducted in Belgium that tested whether changing the number and size of equal portions of cookies for a school snack resulted in difference in intake on a single occasion. Consumption was assessed by subtracting the number of cookies remaining from the amount offered. Children who were given a greater number of small cookies consumed more individual cookies than children given a smaller number of regular sized cookies. However, children who were given the greater number of small cookies consumed less calories and gram weight of cookies during the snack compared to children who were given a smaller number of regular sized cookies.

A second study from the Netherlands tested the effects of varying the portion size and number of pieces of a cucumber snack on a single occasion.^45^ Children were offered a cucumber snack in one of four ways: a large portion served whole, a large portion pre-sliced, a small portion served whole, or a small portion pre-sliced. Intake was assessed by calculating the difference between the weight of cucumber offered and the weight remaining after the snack. Children who were offered a larger portion size consumed more cucumber than those offered a smaller portion size; however, whether the cucumber was served whole or pre-sliced had no effect on intake.

A French study assessed the effect of labeling a new vegetable dish in the cafeteria with basic information identifying it as a new recipe, with or without an additional attractive name, compared to no labeling.^36^ Selection of new and familiar vegetable dishes was assessed by video recording. Children exposed to either type of labeling chose a new carrot dish over a familiar dish in greater proportions compared to children in the control group; however, no effect of labeling was detected for a new broccoli dish. No significant differences between the two labeling groups were detected.

Finally, a long-term study (Modifying Eating and Lifestyles at School) conducted with elementary and middle school-aged students examined interventions focusing on food palatability and presentation.^24^ This US-based study assessed the effects of a 7-month chef training intervention and a 4-month “smart café” intervention, alone or combined, on the selection and consumption of fruit and vegetables. In the chef training intervention, a professional chef collaborated with school cafeteria staff 2-3 days per week to create recipes improving the palatability of foods while incorporating whole grains, produce, healthy fats, and seasonings without added salt or sugar. In the smart café intervention, a variety of choice architecture strategies were implemented (e.g., offering vegetables at the beginning of the lunch line, placing fruit in attractive containers by the register, and promoting fruit and vegetables with prominent signage). Selection and intake of foods were assessed by direct observation and weighing of foods by study staff. Following 3 months of the chef training intervention alone, children and adolescents had higher odds of selecting vegetables at lunch than those at control schools, but there were no significant effects on vegetable consumption or fruit selection and consumption. Following 7 months of the chef training intervention, children and adolescents had higher odds of selecting and consuming fruit and vegetables compared to those at control schools. The smart café intervention alone resulted in greater odds of selecting fruit and vegetables compared to no intervention; however, there was no effect on fruit or vegetable consumption. Effects of both interventions combined were similar to those of the chef training intervention alone. White milk was also targeted by the smart café intervention (e.g., placing white milk in front of sugar-sweetened milk), but no effect of this intervention on white milk selection or intake was detected. Some schools opted to only provide white milk on certain days instead of adhering to the intervention and were removed from analyses on milk. Remaining results were then collapsed across the two study groups that received the smart café intervention, limiting their usefulness. The study was conducted with both elementary and middle school-aged children, but analyses by grade level were not conducted.

##### Food availability and school policies

Three studies examined interventions that increased the availability of fruit and vegetable snacks at school^21,35,40,41^; results were mixed.

The first study assessed the effect of establishing tuck shops that sold affordably priced fruit at UK schools for 1 year; schools were asked to refrain from selling alternative foods, such as chips and desserts, at the tuck shops.^35^ Overall, there were no effects of the fruit tuck shop intervention on child fruit, dessert, or chip intake assessed by 24-hour recall, compared to no intervention. However, when the data were analyzed by existing school food policy for snacks at morning break, a significant, beneficial effect of the fruit tuck shop intervention was detected for schools with a “fruit only policy”, but not for schools with a “no food policy” or no existing policy.

The second study, conducted in the Netherlands, compared implementation of a free fruit and vegetable program to a multi-component nutrition education program over 1 academic year.^40,41^ At the end of the intervention, parent-reported fruit intake and 24-hour intake of fruit, juice, and vegetables combined did not differ between groups; however, vegetable intake was higher among late elementary school-aged children (fourth through sixth grade), boys, and children with at least 1 parent born outside of the Netherlands who received the free fruit and vegetable program, compared to those who received the nutrition education program.^41^ A follow-up conducted 1 year after the completion of both programs continued to show benefits of the free fruit and vegetable program, compared to the nutrition education program, on child vegetable intake; subgroup analyses were not reported at 1-year follow-up.^40^

Ashfield-Watt et al^21^ assessed the effect of a 10-week, daily free fruit program in New Zealand schools. Intake was self-reported via a questionnaire. During the final week of the program, children who received the free fruit reported consuming more fruit at school and throughout the whole day than children who did not receive the program. Furthermore, the intervention group had more positive changes in fruit intake at school from baseline to the final program week than the control group However, 6 weeks after the program ended, those in the intervention group reported a decrease in fruit intake from the final program week to 6-week follow-up compared to the control group; fruit intake at school and throughout the whole day were significantly lower in children who had received the free fruit program compared to children who had not received the program.

The five remaining studies focused on food availability targeted school meals, fiber-rich snacks, or diet quality more broadly.^23,26,44,48,99^

An Australian study assessed the effect of providing implementation support for a healthy canteen policy that targeted removal of lower nutritional quality foods and increased availability of higher nutritional quality foods in schools.^48^ Purchases were assessed via direct observation by research staff and nutritional content was calculated based on product labels and nutrient databases. After approximately 1 year of the intervention, sodium content of food purchased at school tended to be lower in intervention schools compared to control schools; however, this difference was not statistically significant.

Shemilt et al^44^ assessed the effect of funding to start school breakfast clubs in primary and secondary schools in the United Kingdom. The intervention had no effect on the odds of self-reported consumption of fruit for breakfast after 3 and 12 months of the intervention, compared to the control group; separate analyses by grade level were not conducted. However, there was a high level of contamination between the intervention and control groups by 12 months, with 77 percent of students in the control arm attending a school with a breakfast club compared to 72 percent of students in the intervention arm. Therefore, it is unlikely this study provides a strong test of the effect of establishing school breakfast clubs on diet and the results should be interpreted with caution.

A US-based study assessed the effect of implementing National School Lunch Program (NSLP) guidelines for 1 semester, specifically comparing the ability to select one fruit and two vegetable servings per reimbursable meal to the control group (i.e., previous pattern of two fruit and vegetable servings total).^26^ Both groups were served the same school menu. Selection and consumption of foods were directly observed in the cafeteria by trained research staff. Compared to the control group, a greater proportion of children in the intervention group selected total vegetables and starchy vegetables and a lower proportion selected juice, total fruit and juice, and whole grains. When the amount of food selected was analyzed, the intervention group selected more total, dark green, and starchy vegetables and selected less juice, total fruit and juice, whole grains, and protein food compared to the control group. Significant effects on consumption were also detected, with the intervention group consuming more total, starchy, and “other” vegetables but less juice, whole grains, and protein foods than the control group. When consumption was assessed as a percent of the food item selected, children in the intervention group consumed a greater proportion of “other” vegetables and a lower proportion of protein foods compared to the control group. This intervention was also implemented in middle schools, the results of which are reported in the Middle and junior high school section.

In another study conducted in the United States, investigators assessed the effect of providing high-fiber snacks with skim milk, compared to usual snacks alone, for 8 weeks on self-reported dietary intake assessed with multiple 24-hour recalls.^23^ Mid-intervention intake of grains, whole grains, and fiber was higher in children who received the high fiber snacks compared to the control group; groups did not differ significantly for fruit, vegetables, dairy, sweets, beverages, saturated fat, or added sugars. At post-intervention, most between-group differences were not statistically significant, the exceptions being a higher intake of grains and sweets in the intervention group compared to the control group.

Finally, a US-based study assessed the effect of increasing the vegetable content of a standard school lunch entrée from 0.25 cups to 0.40 or 0.45 cups on a single occasion.^99^ Intake was assessed by subtracting the weight of the entrée after lunch from the weight prior to serving. Vegetable intake at lunch was higher among children served both vegetable-enriched recipes, compared to the standard recipe.

##### Combination of strategies

Two studies conducted in the United States implemented a combination of behavioral and environmental strategies to influence child diet and diet-related behaviors.^25,30,38^

The 5-A-Day Cafeteria Power Plus study implemented a variety of strategies in the cafeteria over 2 academic years that targeted fruit and vegetables, including increasing the quality and quantity served, varying the preparation methods, presenting them in an attractive manner, and providing verbal encouragement to students to select and eat fruit and vegetables.^30,38^ Special events, including a promotional kick-off event and monthly fruit and vegetable tastings, were also implemented. Selection and intake of fruit and vegetables was assessed by trained observers. Although there was no difference in vegetable selection and intake between groups, post-intervention lunchtime fruit selection and intake (including and excluding juice) was modestly higher in the intervention group compared to the control group.

The Healthy Options for Nutrition Environments in Schools study assessed the effect of a broad set of changes to school nutrition policies in elementary and middle schools for 2 years.^25^ The intervention aimed to eliminate unhealthy foods and beverages at school, develop nutrition services as the primary source for healthful eating, and to have school staff model healthful eating; a variety of changes at the school were implemented to support these goals including, but not limited to, having teachers discourage students from bringing unhealthy snacks from home, implementing a daily fruit at recess program, advertising healthy snacks and beverages only, and having staff encourage students to try fruit and vegetables. Food brought from home was assessed by direct observation or observation of waste, depending on the location in school. Over the course of the 2-year intervention, the amount of unhealthy food and beverages brought to school by children and adolescents decreased in the intervention schools compared to the control schools. Healthy beverages brought to school did not differ between groups, but the amount of healthy food brought to school for lunch increased and the amount brought to school for recess decreased in intervention schools compared to control schools. Analyses by school level were not conducted. Because the study assessed food brought from home, the extent to which this measure represents actual choices made by students, versus their caregivers, is unclear.

##### Summary

These 32 articles provide evidence on a variety of behavioral and environmental interventions implemented among elementary school-aged children. Broadly, most studies reported beneficial effects of these diverse interventions on food and beverage selection and intake. Although positive impacts on selection and intake were seen for several types of food and beverages, the body of evidence regarding intake was most consistent for vegetables.

Studies that provided incentives to children for selecting or consuming certain foods, primarily fruit and vegetables, had mixed results. Although several studies observed a benefit of incentives on choice or consumption, others found no added benefit of incentives or, in some sub-groups, found a negative impact. Additionally, some studies did not include a no-intervention control group that would allow for a better assessment of the independent effect of incentives.

Nudges primarily had a beneficial effect on the selection of food items targeted by the study, including white milk, fruit, and meal components of higher and lower nutritional quality. The majority of studies that tested the effects of nudges implemented these interventions over a relatively short period of time and did not measure intake; further research on the effects of sustained implementation of these interventions and the effects on consumption are needed.

In general, interventions that changed how food was presented (such as varying the shape, size, and accessibility of food items) modified children’s selection of the targeted food; studies that implemented shorter-term interventions targeting the presentation of food also tended to observe effects on intake. However, a variety of manipulations were assessed across these studies and most were tested on a single occasion, limiting comparisons between studies and the ability to assess effects of longer-term implementation of these strategies.

Interventions targeting the availability of certain foods at school had mixed results on food selection and intake, potentially due to the variety of strategies used and food groups targeted. Although the specific strategies varied, both studies that implemented a combination of behavioral and/or environmental strategies did so over multiple years and detected positive impacts on diet and diet-related behavior. One of these studies (5-A-Day Cafeteria Power Plus)^30,38^ implemented strategies targeting fruit and vegetables that were also utilized in other, more narrowly focused interventions; however, benefits were only detected for fruit selection and intake and the effect was modest.

In sum, several behavioral and environmental interventions implemented among elementary school-aged children may have a positive impact on diet and diet-related behaviors, although more research is needed on individual strategies to confirm these trends and, in some cases, to assess their long-term impact.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions, particularly those that utilize nudges or change the presentation of food, improve in-school food and beverage selection, including fruit, vegetables, and milk, among elementary school children. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: Across the body of evidence, the primary area of potential risk of bias was related to concerns of selective reporting because the majority of studies did not have information on an a priori analysis plan. Additionally, over one-third of the articles had some concerns due to missing outcome data. Most studies were assessed as having low risk of bias due to randomization or identification of participants (in cluster-RCTs), or outcome measurements. All studies had low risk of bias due to deviations from intended interventions.
- Consistency: There was substantial variation throughout the body of evidence in the strategies used, the intervention dose and duration, and the targeted dietary components and behaviors. Despite this heterogeneity, which limits the assessment of consistency, several patterns in the results emerged both across and within types of behavioral and environmental interventions. Most broadly, although effects observed within studies sometimes varied by factors such as child age or implementation fidelity, all but two studies reported beneficial effects on the selection of one or more types of food or beverages at school. Across interventions, fruit, vegetable, and white milk selection were positively affected in most studies that examined these outcomes; impacts on combined fruit and vegetable selection were assessed less frequently and less consistently beneficial. The selection of other types of food or nutrients were assessed in far fewer studies and results were less consistent. Some types of behavioral or environmental interventions showed more consistent benefits than others. Studies that implemented nudges, either verbally^32,42,43^ or through online ordering systems,^27,49,100^ or modified how food was presented to children,^24,29,36^ improved food and beverage selection in most cases. Other behavioral and environmental strategies were implemented in too few of studies or were more variable in their results within studies.
- Directness: Most studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question. One notable exception is studies that assessed nudges through online ordering systems; two of three studies assessed the effect of the intervention on orders that could have been placed by either the parent or the child, therefore it is unclear how representative these outcomes were of student food selection.^27,49^
- Precision: Variability in the interventions, study duration, and targeted outcomes limits the assessment of precision across these studies. Most studies on behavioral and environmental interventions did not report a power calculation or were powered for a different outcome. Of the few studies that calculated power for an outcome related to diet,^26,27,48,49^ most^26,27,49^ reported meeting their estimated sample size requirement. Sample size varied greatly across the body of evidence, but many of the included studies did enroll a relatively large number of individual participants and clusters. Several studies tested interventions that were implemented for only a few days or weeks, particularly those that manipulated how food was presented to children, implemented nudges in person or through online ordering systems, or provided incentives for selecting or consuming certain types of food. Additionally, because few studies assessed specific types of behavioral or environmental intervention, it is more difficult to assess the relationships between specific interventions and outcomes.
- Generalizability: This body of evidence is generalizable to elementary school children in the United States. Most studies were conducted exclusively with elementary school students. Approximately two-thirds of the studies were conducted in the United States; the remaining studies were conducted in countries assessed as high or very high HDI. Participants enrolled in the studies were from a range of SES and racial/ethnic backgrounds; however, this information was not always reported.

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions improve in-school vegetable intake among elementary school children. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: Across the body of evidence, the primary area of potential risk of bias was related to concerns of selective reporting because all studies did not have information on an a priori analysis plan. Additionally, approximately one-third of the articles had some concerns due to missing outcome data. Most studies were assessed as having low risk of bias due to deviations from intended interventions, or outcome measurements. All cluster-RCTs were assessed as having low risk of bias due to timing of identification and recruitment of participants.
- Consistency: There was considerable variation throughout the body of evidence in the strategies used, the intervention dose and duration, and the comparator. Furthermore, although most studies examined vegetable intake at school, there was still variation in the intake measures and how they were operationalized (e.g., snack versus at a meal). Despite this heterogeneity, which limits the assessment of consistency, vegetable intake was consistently positively impacted by behavioral and environmental interventions, with few finding null results. One study in this body of evidence did not target fruit and vegetables, instead providing a daily high fiber snack to children, which may explain the null results observed in this particular instance.^23^
- Directness: Most studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: Among studies that measured vegetable intake, only one reported a power calculation; this study met its estimated sample size requirement.^26^ Sample size varied across the body of evidence, including both relatively small studies and relatively large studies, in terms of individual participants and clusters. Several studies tested interventions that were implemented on single occasions or for a few weeks, particularly those that manipulated how food was presented to children or provided incentives for selecting or consuming certain types of food; the rest implemented longer-term interventions, lasting months or years. Few studies assessed any particular type of behavioral or environmental intervention, making it difficult to assess the relationships between specific interventions and vegetable intake.
- Generalizability: This body of evidence is generalizable to elementary school children in the United States. Most studies were conducted exclusively with elementary school students. Approximately half of the studies were conducted in the United States; the remaining studies were conducted in countries assessed as high or very high HDI. Participants enrolled in the studies were from a range of SES and racial/ethnic backgrounds; however, this information was not always reported.

#### Combined interventions (teaching and educational strategies with behavioral and/or environmental strategies)

##### Description of the evidence

Twenty articles from 17 cluster-RCTs examined the effect of school-based interventions that combined teaching and educational strategies with behavioral and environmental strategies on diet and diet-related behaviors in elementary school-aged children.^1–20^ Approximately 40 percent of the studies were conducted in the United States^2–4,6,10,11,15,17,18^; the remaining studies were conducted in a variety of countries, including Brazil,^19^ China,^16^ Ireland,^12^ Lebanon,^8,9^ the Netherlands,^7,13,20^ Norway,^13,20^ Portugal,^14^ Spain,^13,20^ and the United Kingdom.^1,5^ Analytic sample size ranged from 2^12^ to 61 clusters^13,20^ and 80^4^ to 4,482 individual participants; most studies had multiple clusters per study arm and analyzed several hundred to several thousand participants. Studies enrolled participants with a range of SES backgrounds, including some studies that were conducted in schools with a high proportion of students eligible for free/reduced price meals or other measures of low SES.^1–4,6,10,11,19^ Among studies that reported race and/or ethnicity, most enrolled a diverse group of students or participants who were predominantly Black, Hispanic, and/or Asian^2–4,6,10,11,18,19^ with a few studies enrolling predominantly White participants^5,15,17^; however, several studies did not report this information.^1,7–9,12–14,16,20^

A variety of behavioral and environmental strategies were examined across the studies, including using rewards, incentives, nudges, and promotion; modifying food availability and school food policies; and implementing a combination of strategies. Nine RCTs reported the theoretical foundation of or framework to develop the intervention,^3–5,8–11,13,16–18,20^ the majority influenced by SCT^8,9,17,18^ or Social Learning Theory.^3,4,10,11,16^ The teaching and educational components of the interventions involved a variety of activities as part of a nutrition curriculum, including fruit and vegetable tastings,^1,5,12,15,17^ gardening,^5,18^ food preparation,^1,5,8,9,13,18,20^ games,^4,8–11,19^ music,^19^ books and videos,^1,4,10–12,15^ tailored feedback,^13,20^ and parental engagement.^1,3–6,8–13,15–18,20^ Almost all studies compared the interventions to no intervention or usual practice controls, except for a study that provided control schools with brief reading materials on fruit and vegetables to distribute to parents,^5^ another study that provided free fruit and vegetables to both the intervention and control groups,^12^ and a third study that included a second intervention group in addition to the no-intervention control group.^15^ Child intake and diet-related behaviors were primarily assessed by self-report^1,2,6–9,13,16–20^ or parent-report^4,5^ measures; other methods involved study personnel observing and/or weighing foods in the cafeteria.^3,10–12,17^ Nine articles assessed selection or intake in school^1–3,9–12,14,15,17^ and 11 articles assessed overall selection or intake.^4–6,8,9,13,16–20^ For the purposes of describing and synthesizing the evidence, studies are grouped by the behavioral and environmental strategies utilized. Evidence from these studies and participant characteristics are described in Table 7; the risk of bias assessments are described in Table 8. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Nutrition education with behavioral strategies targeting rewards, incentives, nudges, and prompts

Four cluster-RCTs combined educational strategies with rewards, incentives, nudges, or prompts in school,^3,12,14,15^ with most detecting positive effects.

The first study, conducted in Ireland, investigated a 16-day Food Dudes program with a 1-year maintenance phase.^12^ The intervention included daily video episodes and/or letters from the videos’ characters encouraging consumption of fruit and vegetables, followed by a fruit and vegetable snack in which children were rewarded with a small prize for tasting both fruit and vegetables (on the first 4 days) or consuming all of the fruit and vegetables provided (during the next 12 days); take-home materials were also provided, including materials for parents on healthy eating and a chart to record fruit and vegetable portions consumed at home. During the maintenance phase, children were provided with a Food Dudes lunchbox and were rewarded for bringing and consuming fruit and vegetables from home; the frequency and value of rewards decreased over time. Children in the control group were provided with free fruit and vegetables during the same periods of time as the intervention group. Consumption of school-provided fruit and vegetables was assessed by weight, while provision and consumption of food brought from home was assessed through observation by researchers. During the intervention, children who received the Food Dudes program had significantly higher intake of school-provided fruit and vegetables compared to the control group. At 1-year follow-up, the intervention group brought and consumed more fruit, vegetables and juice (combined) from home compared to the control group.

A second, shorter study assessed the Food Dudes program, this time testing two types of incentive programs in a sample of first through fifth grade US students.^15^ Similar to the first study, the Food Dudes videos were shown and letters were read to children, and children were rewarded for tasting fruit and vegetables or consuming all of the fruit and vegetables provided to them in the cafeteria for 16 days. One intervention group received tangible prizes as their reward, whereas a second intervention group received verbal praise. Over the following 3 months, children continued to receive prizes or verbal praise for consuming fruit and vegetables at lunch, but at a reduced frequency. Intake was ascertained by digital imaging of lunch trays before and after lunch and assessed by trained observers. During the first 16 days of the program, both intervention groups had higher observed consumption of fruit and vegetables compared to a no-intervention control group; fruit and vegetable intake was higher in children who received tangible prizes compared to children who received verbal praise. During the next 3 months of the program, while the intervention group receiving tangible prizes continued to have higher consumption of both fruit and vegetables compared to the control group, the intervention group receiving verbal praise only maintained a higher consumption of vegetables compared to the control group. At 6-month follow-up, children who received the tangible prizes consumed significantly more fruit and vegetables than both children in the control group and children who received verbal praise; no differences were detected between the verbal praise group and the control group.

Another US-based study conducted in kindergarten and first grade students assessed the effect of a 5-week fruit and vegetable promotion program.^3^ The intervention included 10 nutrition education lessons (Every Day, Lots of Way) co-taught by the classroom teacher and study personnel, brief newsletters for parents to accompany each lesson, and a lunchtime component in which children received verbal praise and stickers for consuming fruit and vegetables during lunch. Intake was assessed through observation by trained research assistants. At post-intervention, there was no significant difference in observed vegetable intake between intervention and control children. Data on fruit intake was not collected by the study due to concerns of a ceiling effect. Although the implementation level of the educational component was generally high, the behavioral component was implemented less consistently.

Liz Martins et al^14^ examined the effect of short-term nutrition interventions delivered by the lead researcher in a small sample of fourth grade children from Portugal. Children in the first intervention group received nutrition education (6 hours over 3 days), created posters on food waste reduction to display in the school canteen, and received stickers at lunch for following “no plate waste day”. The second intervention group consisted of food waste education for teachers in the form of a 1-hour debate session; teachers were asked to be present during school lunchtime and to play an active role encouraging children to eat their lunch. Both interventions were compared to a no-intervention control. Plate waste was assessed by weight of leftovers for two meal items: soup and main dishes. Children who received nutrition education had significant reductions in plate waste for both meal items compared to the control group at 1-week follow-up; at the 3-month follow-up, change in plate waste for soup and main dishes were no longer significantly different from the control group except when examining main dishes that were offered at all three time-points. Children in the teacher education group had significant reductions in soup waste at 1-week follow-up and for main dishes offered at all three time-points at 3-month follow-up, compared to the control group; all other comparisons were non-significant.

##### Nutrition education with environmental strategies targeting food presentation and promotion

In addition to a study that combined education with environmental strategies targeting presentation and promotion broadly,^17^ three studies focused on combining education with mainly promotional activities.^7,16,19^ Results were primarily beneficial.

The US High 5 Project assessed the effect of a 1-year, multi-component intervention focused on fruit and vegetables.^17^ The intervention included a 14-lesson nutrition curriculum delivered by study personnel and utilizing methods such as modeling, self-monitoring, and taste testing; involvement of parents through a kick-off event and encouragement to complete homework assignments related to the curriculum with their children; and training and continued guidance for food service personnel on purchasing, preparing, and promoting fruit and vegetables. Self-reported intake was assessed by a 24-hour dietary recall. The intervention group reported higher intake of fruit, vegetables, and fiber and lower intake of saturated fat at post-intervention and at 1-year follow-up compared to controls. In a smaller, random subset of children whose fruit and vegetable intake were observed by study personnel at lunch, no significant differences between intervention and control children were detected.

A study conducted in China assessed the effect of a comprehensive, 1-year nutrition program, which included nutrition education lessons with activities to integrate into classes, programs on nutrition and physical activity for teachers (twice per semester), a nutrition lesson for parents (once per semester), promotional messages on nutrition via social media and blackboard/posters (twice per semester), and community programs related to nutrition (once per semester).^16^ Dietary behaviors were assessed by self-report. Analyses were conducted by province, one with relatively higher SES than the other; the higher SES province had more successful implementation of the intervention than the lower SES province. In the higher SES province, beneficial effects on post-intervention intake of vegetables, fruit, dairy, fried food, and fast food were seen in intervention group children compared to controls. In contrast, in the analyses of the lower SES province, only vegetable intake was significantly greater in intervention children compared to controls.

Sichieri et al^19^ conducted a study in Brazil that assessed the effect of a 7-month intervention targeting beverage intake. Intervention components included 10 nutrition education activities facilitated by trained research personnel that focused on exchanging SSBs for water, in addition to promoting water consumption through banners hung in school and provision of water bottles with the campaign’s logo for all children and teachers. Intake was assessed by self-report using a 24-hour recall. Compared to children who received two sessions on general health issues, children in the intervention group reported greater decreases in carbonated beverage intake from baseline to post-intervention, as well as lower consumption of carbonated beverages at post-intervention; significant effects were not detected for juice intake.

Finally, a study conducted in Aruba (a constituent country of the Netherlands) assessed the effect of an 8-week peer promotion intervention.^7^ In the intervention group, children identified as peer influencers (approximately 20 percent of all intervention group children) received an initial 90-minute training session, and two follow-up training sessions, about the benefits of water intake and how to promote water intake among their peers, including encouraging the peer influencers to consume water around children in their social network; the peer influencers received a reusable water bottle to support this behavior. All other intervention group children were exposed only to the peer influencers and did not receive education or training. Self-reported post-intervention intake of SSBs was slightly, but significantly, lower in intervention group children compared to children in the no-intervention control group.

##### Nutrition education with environmental strategies targeting food availability and school food policies

Two cluster-RCTs combined educational strategies with changes to fruit and/or vegetable availability,^13,18,20^ with mixed results.

The Pro Children study assessed a 2-year multi-component intervention in schools across the Netherlands, Norway, and Spain.^13,20^ The intervention included a classroom curriculum (focused on: knowledge of recommend intakes for fruit and vegetables; awareness of children’s own intake, taste, and preferences for fruit and vegetables; and skills to prepare and ask for fruit and vegetables); family involvement through parental newsletters and activities; increased provision of fruit and vegetables at school through a subscription program (free or paid) or school meals (method varied by country); and an optional component that aimed to encourage community participation. The first year of the intervention was more intensive than the second. After the first intervention year, children who received the intervention reported higher intakes of both fruit and vegetables (alone and combined) via a pre-coded 24-hour recall, primarily due to increased intake outside of school.^20^ After the second intervention year, significant beneficial effects of the intervention only remained for fruit intake and combined fruit and vegetable intake among children from Norway, the country with the highest level of implementation of the educational program; effects on fruit and combined fruit and vegetable intake in the Netherlands and Spain and on vegetable intake in all countries were no longer present. Analyses by level of parental education revealed a similar overall pattern of results, with some variation by higher and lower parental education.^13^ After the first intervention year, significant effects of the intervention on fruit intake were detected for children with higher parental education and significant effects on vegetable intake were detected for children with lower parental education; beneficial effects on combined fruit and vegetable intake were detected across both levels of parental education. After the second intervention year, significant beneficial effects of the intervention on fruit and combined fruit and vegetable intake were detected among Norwegian children of parents with both higher and lower levels of education.

The US-based Shaping Healthy Choices Program was a 1-year multi-component intervention that included school garden-enhanced nutrition education (Discovering Healthy Choices), cooking demonstrations (Cooking Up Healthy Choices), family newsletters corresponding to educational modules, health fairs, installation of salad bars that offered fresh seasonal fruit and vegetables, and establishment of school-site wellness committees.^18^ Self-reported intake was assessed with an FFQ. Change in fruit and vegetable intake from pre- to post-intervention did not differ between children attending intervention and control schools. The level of intervention implementation varied by school district; however, results were similar when analyses were conducted for each school district separately.

##### Nutrition education with a combination of behavioral and environmental strategies

Seven cluster-RCTs combined educational strategies with multiple behavioral and/or environmental strategies,^1,2,4–6,8–11^ observing mixed results.

One study conducted in the United States assessed a 3-year fruit and vegetable promotion program beginning in kindergarten and first grade.^4,10,11^ The intervention included an educational computer game (5-A-Day Adventures), family involvement through interactive children’s books assigned as homework and a 5-A-Day Kids Cookbook, loudspeaker announcements and posters in the cafeteria promoting the fruit and vegetable of the day, and verbal praise and stickers for consuming fruit or vegetables at lunch. Parent-reported intake of fruit and vegetables combined did not differ between intervention and control children after the first and second year of the intervention; however, relatively few parents completed this measure compared to the full sample.^4^ Additional analyses assessed fruit and vegetable intake observed and weighed at lunch by trained research assistants. After the first year of the intervention, fruit and vegetable intake at lunch was higher in intervention children compared to controls.^10^ After the second year of the intervention, fruit intake at lunch remained higher in intervention children compared to controls; however, vegetable intake no longer varied significantly by group.^10^ By the third year of the intervention, neither fruit nor vegetable intake at lunch varied between intervention and control children; null results were also observed 1 year after the intervention was completed.^11^

A second US study assessed the effect of the One Healthy Breakfast initiative, which included 18 breakfast-specific nutrition education lessons, 24 newsletters for parents, universal breakfast in the classroom, and marketing at nearby corner stores to promote healthier breakfast foods and drinks, all delivered over 2.5 years.^2^ Children at control schools received the usual practice of universal breakfast in the cafeteria. Diet was self-reported via the Breakfast Patterns Survey. Mid-way through the intervention, children who attended schools with the One Healthy Breakfast initiative had higher odds of consuming milk, 100% juice, fruit, grain products, meat/meat alternatives, and a breakfast pattern meeting USDA School Breakfast Program (SBP) meal component requirements, as well as lower odds of consuming foods high in saturated fat and added sugars. Significant beneficial effects were maintained at post-intervention for consumption of a pattern meeting SBP meal component requirements, 100% juice, and foods high in saturated fat and added sugars; a beneficial effect of the intervention on the odds of consuming SSBs also emerged at post-intervention.

Foster et al^6^ assessed the effect of a 2-year school nutrition policy initiative in US elementary schools. The intervention included 50 hours of nutrition education integrated into multiple school subjects, staff training, family involvement through meetings and workshops, a school self-assessment to identify strategies to improve the school food environment, changes to food sold to meet nutritional standards based on the Dietary Guidelines for Americans, and a raffle entry for children who purchased or brought food and beverages from home that met the new nutritional standards. Fruit and vegetable intake were assessed via self-report with an FFQ. Change in combined fruit and vegetable intake from baseline to post-intervention did not vary between intervention and control school children.

Two Lebanese studies, from independent cohorts, assessed the effect of the multi-component Health-E-PALS intervention.^8,9^ The intervention consisted of 12 interactive classroom education sessions delivered by the researcher that focused on a variety of obesity-related behaviors. Other components included parental involvement through meetings, informational packets, health fairs, and a food service component that targeted food availability in school shops and encouraged students to choose healthier options and bring fruit and vegetables to school. In both studies, purchases and intake were assessed via self-report. In the pilot study, the Health-E-PALS intervention was delivered over 3 months with weekly education sessions and resulted in lower odds of purchasing chips, chocolate, and soft drinks from school shops, as well as lower odds of consuming chips and soft drinks, compared to the no-intervention control group.^9^ There were no significant effects of the pilot intervention on fruit purchases or consumption. In the expanded evaluation of this intervention, the 12 nutrition education sessions were delivered over 1 academic year and 6 additional nutrition education activities were delivered during the following academic year.^8^ Children attending intervention schools had greater odds of daily intake of fruit and raw vegetables and lower odds of daily intake of chips and soft drinks immediately post-intervention compared to children who did not receive the intervention. At 1-year follow-up, beneficial effects were maintained for intake of fruit, raw vegetables, and soft drinks. Results varied when private schools (high SES, lower levels of intervention implementation) and public schools (low SES, higher levels of intervention implementation) were analyzed separately, with significant sustained effects at 1-year follow-up only present among children from public schools.

Anderson et al^1^ implemented a whole school intervention focused on fruit and vegetables over the course of 1 academic year in UK schools. The intervention included: a nutrition curriculum focused on food preparation and tasting that incorporated hands-on activities, self-monitoring materials, videos, story books, and written work; child and parent newsletters; teacher information sessions; increased provision of fruit and vegetables in school through tuck shops and school lunches; and point-of-purchase marketing. Intake was assessed with 3-day food diaries supplemented by interviews with trained assistants. Children who attended intervention schools had a greater increase in fruit intake from baseline to post-intervention compared to children who attended control schools, with no differences detected for vegetable and sugar intake; when analyzed by sex, significant effects on fruit intake were only detected for girls.

Another study conducted in the United Kingdom assessed the effect of Project Tomato, a 10-month intervention that aimed to positively impact fruit and vegetable intake of children after they aged out of the country’s daily free fruit and vegetable program.^5^ Intervention activities included: gardening and cooking, fruit and vegetable exposure through tasting sessions and school meals, science experiments, adult and peer modeling, and fruit and vegetable promotion throughout the school environment. Materials provided to intervention schools consisted of 12 lesson plans, 2 newsletters, advice for parents, 3 take-home activity bags, and customized activities. The control schools received a booklet on fruit and vegetables and healthy eating leaflets for parents. Dietary intake was assessed by parents and trained field workers via a 24-hour diary list of multiple food and drink items. At post-intervention, no differences in intake were detected between intervention and control children for fruit, vegetables, dietary fiber, saturated fat, sugar, or sodium. Implementation of the intervention was notably low.

##### Summary

Studies of interventions that combined teaching and educational strategies with behavioral and environmental strategies provided the smallest contribution to the body of evidence in elementary school-aged children. Most studies detected beneficial effects of the tested interventions on at least one aspect of dietary intake, with few reporting exclusively null effects. There was some variability in what specific components of the diet were affected across the studies, however. Fruit and vegetable intake were the most commonly assessed outcomes, with more consistent benefits observed for fruit. Effects on SSB and soft drink intake were predominantly beneficial, but these outcomes were assessed less frequently.

Interventions were most commonly carried out over an entire school year or longer, but a few interventions were implemented for only a few weeks or months. Some longer-term interventions that observed significant effects during an initial stage of the program also saw that effects diminished after multiple years of implementation. Several studies suggested that higher fidelity to the intervention or more complete implementation of intervention components positively influences intervention success. Because the content of the interventions varied greatly across the studies, the ability to draw strong conclusions regarding individual educational, behavioral, or environmental strategies and programs is limited. However, successful interventions often targeted food availability and promotion within the school, implemented a nutrition curriculum, and/or included experiential activities such as fruit and vegetable tastings or food preparation; more research is needed to confirm these trends. Additionally, as multi-component interventions combine several strategies, it is difficult to discern if (and which) individual components may be responsible for the significant effects, or if the intervention package as a whole is needed to achieve the observed effects. None of the studies in elementary school-aged children compared combined interventions to those utilizing educational or behavioral and environmental strategies alone; further research is needed to determine if combining these strategies is more effective at improving diet and diet-related behaviors in elementary school-aged children compared to educational, behavioral, or environmental strategies alone.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates that elementary school-based interventions that combine educational strategies with behavioral and/or environmental strategies, improve intake of food and beverages, particularly fruit, among elementary school children. Interventions tend to be at least 1 academic year in duration and common strategies in successful interventions include pairing a nutrition curriculum with increased promotion and availability of more favorable food and beverages at school. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: Across the body of evidence, most studies did not have information on an a priori analysis plan. Additionally, approximately one-third of the articles had some concerns or high risk of bias due to missing outcome data. Most studies were assessed as having low risk of bias due to deviations from intended interventions, outcome measurement, randomization, or identification of participants in relation to the timing of randomization.
- Consistency: There was variation throughout the body of evidence regarding the intervention strategies used, the intervention dose and duration, and the targeted dietary components and behaviors. Despite this heterogeneity, which limits the assessment of consistency in the results, several patterns emerged. Most broadly, approximately 75 percent of the studies detected beneficial effects of combined interventions on one or more aspects of food or beverage intake. Of the four studies that reported no significant effects of the intervention, two reported incomplete or poor implementation of the intervention which may have contributed to the null results.^3,5^ Across interventions, the most consistent results were observed for fruit intake, with combined interventions having predominantly beneficial effects on this outcome. Effects on SSB or soft drink consumption also tended to be beneficial, although this outcome was assessed less frequently than fruit. Less consistent results were observed for vegetable intake and combined fruit and vegetable intake, with more equal proportions of studies reporting beneficial and null effects of interventions on these outcomes. Other components of the diet, such as juice, milk, saturated fat, and sodium, were assessed in few studies, limiting the ability to assess consistency for those outcomes. Although a variety of strategies and activities were used in successful interventions, common components included a nutrition curriculum paired with increased promotion and availability of more favorable food and beverages at school.
- Directness: Most studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: Approximately half of the studies reported a power calculation,^1–5,11,13,15,18–20^ of which about half appeared to be sufficiently powered.^1,3,11,19,20^ Sample size varied across the body of evidence. However, most of the included studies analyzed several hundred or thousand individual participants and approximately half enrolled 10 or more clusters. Although a few studies tested interventions that were relatively brief, most interventions lasted for 1 academic year or longer.
- Generalizability: This body of evidence is generalizable to elementary school children in the United States. All studies were conducted exclusively with elementary school students. Approximately half of the studies were conducted in the United States. The remaining studies were conducted in countries assessed as high or very high HDI, although some of the countries represented in these studies may have cultural differences that reduce generalizability to the US population. Studies enrolled participants from a range of SES and racial/ethnic backgrounds; however, this information was not always reported.

Table 3 Evidence examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in elementary school children^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Educació en Alimentació (EdAl)
Tarro, 2014,^91^ EdAl; Spain, RCT-Cluster; Total Baseline N: 2,350; Total Analytic N: 1,939; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Missing height/weight, no parental consent; Grade level: Elementary school; Age (Mean (SD)): 8.4 (0.6) y; Female: 49.9%; Race/ethnicity: Western European: ~78%; Eastern European: ~4%; Latin American: ~9%; North African Arab: ~8%; Chinese: ~1%; SubSaharan African, Indian, and North American: All <1%; SES: Maternal education: < High school: ~3%, High school: ~36%, Technical training: ~38%, Non-university higher education: ~2%, University degree: ~21% | Int: Educació en Alimentació (EdAl) nutrition education program, consisting of classroom practice, teaching practice, and parental activity components, delivered by university student health promoter agents in twelve 1-h sessions over 28 months. (N=1,222; Cluster N=1) Comp: No intervention (N=717; Cluster N=1); Theory/framework: NR; Intervention duration: 28 mo (3 academic y); Outcome measurement: Intake habits assessed with Krece Plus Questionnaire and the Avall Questionnaire completed by parents at baseline and post-intervention. | Intake at post-intervention (Krece Plus Questionnaire), %; [underlined: Dairy product at breakfast]: Int: 92.3%, Comp: 93.0%, p=0.09; [underlined: Cereals at breakfast]: Int: 72.9%, Comp: 74.5%, p=0.13; [underlined: Pastry at breakfast]: Int: 15.3%, Comp: 15.1%, p=0.70; [underlined: Daily fruit or natural juice]: Int: 72.9%, Comp: 78.9%, p=0.59; [underlined: Fruit, second/d]: Int: 42.6%, Comp: 37.6%, p=0.14; [underlined: Dairy product, second/d]: Int: 80.6%, Comp: 84.2%, p=0.81; [underlined: Vegetables, daily]: Int: 72.6%, Comp: 73.8%, p=0.42; [underlined: Vegetables, >1/d]: Int: 32.0%, Comp: 26.9%, p=0.50; [underlined: Fish, regularly]: Int: 74.8%, Comp: 74.3%, p=0.35; [underlined: Fast food, >1/wk]: Int: 8.9%, Comp: 8.7%, p=0.92; [underlined: Legumes, >1/wk]: Int: 75.2%, Comp: 70.9%, p=0.06; [underlined: Candy, >1/d]: Int: 12.0%, Comp: 9.9%, p=0.68; [underlined: Pasta or rice, daily]: Int: 57.9%, Comp: 62.2%, p=0.58; Intake at post-intervention (AVall questionnaire), %; [underlined: Before leaving home]; Dairy products: Int: 82.4%, Comp: 83.8%, p=0.65; Pastry: Int: 2.4%, Comp: 2.6%, p=0.50; Cereals: Int: 38.2%, Comp: 39.7%, p=0.94; Fresh fruit or natural juice: Int: 20.6%, Comp: 18.5%, p=0.93; Sandwich: Int: 25.2%, Comp: 22.1%, p=0.69; Juice packaged/soft drinks: Int: 7.2%, Comp: 8.9%, p=0.46; [underlined: Break (midmorning)]; Dairy products: Int: 12.7%, Comp: 10.1%, p=0.51; Pastry: Int: 1.7%, Comp: 2.2%, p=0.95; Cereals: Int: 5.6%, Comp: 4.7%, p=0.71; Fresh fruit or natural juice: Int: 12.7%, Comp: 15.5%, p=0.18; Sandwich: Int: 49.2%, Comp: 48.3%, p=0.71; Juice packaged/soft drinks: Int: 6.1%, Comp: 12.8%, p=0.41; Model adjustments: None; Funding source(s): Fundació Privada Reddis, Ajuntament de Reus, Spain, Conselleria de Salut de Generalitat de Catalunya, Mercat Central de Reus, Protected Designation of Origin Siurana, Spain, La Morella Nuts, S.A. Spain, Nutrition and Health Technology Centre-TECNIO, Reus (Spain), Diputació de Tarragona, Spain
Tarro, 2014,^92^ EdAl; Spain, RCT-Cluster; Total Baseline N: 2,350; Total Analytic N: 619; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Missing height/weight, no parental consent, birth date before 1999 or after 2000, moved; Grade level: Elementary school; Age: NR; Female: NR Race/ethnicity: NR; SES: NR | Int: Educació en Alimentació (EdAl) nutrition education program, consisting of classroom practice, teaching practice, and parental activity components, delivered by university student health promoter agents in twelve 1-h sessions over 28 months. (N=421; Cluster N=1); Comp: No intervention (N=198; Cluster N=1); Theory/framework: NR; Intervention duration: 28 mo (3 academic y); Outcome measurement: Intake habits assessed with Krece Plus Questionnaire at baseline (by parents) and 2-y follow-up | Change in intake from baseline to 2-y follow-up, %; [underlined: Midmorning snack]: 24% increase in intervention boys compared to control group boys, p=0.008 ↑; [underlined: Dairy product at breakfast, cereals at breakfast, pastry at breakfast, daily fruit or natural juice,][underlined: second fruit/d, second dairy product/d, fish eaten regularly, fast food >1/wk, legumes >1/wk,][underlined: candy >1/d, daily pasta or rice]: Data NR, all NS; Model adjustments: None; Funding source(s): Fundació Privada Reddis, Ajuntament de Reus, Vila-seca, Salou I Cambrils, Nutrition and Health Technology Centre-TECNIO Reus, Diputació de Tarragona
Squire’s Quest!
Baranowski, 2003 ^53^; United States (Houston, Texas), RCT-Cluster; Total Baseline N: 1,578; Total Analytic N: 1,489; Total Baseline Cluster N: 27; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Did not complete pre or post-assessment; Grade level: Elementary school; Age (Range): 8-12 y (~63% 9 y, ~29% 10 y); Female: ~52%; Race/ethnicity: White: ~45%; Black: ~17%; Hispanic: ~31%; Other: ~7%; SES: NR | Int: Squire’s Quest! nutrition education multimedia game based on SCT and focused on fruit, juice, and vegetables. (N=749; Cluster N=13); Comp: No intervention (N=740; Cluster N=13); Theory/framework: SCT; Intervention duration: 5 wk; Outcome measurement: Diet assessed by Food Intake Recording Software System (multiple pass 24-h dietary recall) completed by the child on 4 d (primarily non-consecutive) at baseline and post-intervention | Intake at post-intervention (svg), Mean difference (Int vs Comp [ref]); [underlined: Total fruit, juice, and vegetables with high-fat vegetables]: 1.01, p=0.0007 ↑; [underlined: Total fruit, juice, and vegetables without high-fat vegetables]: 0.91, p=0.002 ↑; [underlined: Fruit]: 0.52, p=0.002 ↑; [underlined: 100% fruit juice]: 0.17, p=0.156; [underlined: Regular vegetables]: 0.24, p=0.001 ↑; [underlined: High-fat vegetables]: 0.09, p=0.107; Alternative analyses of the data produced similar results (see paper for more information); Model adjustments: Pre-intervention intake; clustering effect of schools; Funding source(s): NIH, USDA/Agricultural Research Service
Cullen, 2005 ^59^; United States (Houston, Texas), RCT-Cluster; Total Baseline N: 1,578; Total Analytic N: 1,489; Total Baseline Cluster N: 27; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Did not complete pre- or post-assessment; Grade level: Elementary school; Age (Range): 8-12 y (~63% 9 y, ~29% 10 y); Female: ~52%; Race/ethnicity: White: ~45%; Black: ~17%; Hispanic: ~31%; Other: ~7%; SES: NR | Int: Squire’s Quest! nutrition education multimedia game based on Social Cognitive Theory and focused on fruit, juice, and vegetables. (N=749; Cluster N=13); Comp: No intervention (N=740; Cluster N=13); Theory/framework: SCT; Intervention duration: 5 wk; Outcome measurement: Diet assessed by Food Intake Recording Software System (multiple pass 24-h dietary recall) completed by the child on 4 d (primarily non-consecutive) at baseline and post-intervention | Intake at post-intervention by meal (svg), Mean (SE) and Mean difference (SE); [underlined: Breakfast]; Fruit: Int: 0.22 (0.03) vs Comp (ref): 0.17 (0.03), Difference: 0.04 (0.04), p=NS; Regular vegetables: Int: 0.03 (0.01) vs Comp (ref): 0.02 (0.01), Difference: 0.01 (0.01), p=NS; 100% fruit juice: Int: 0.26 (0.02) vs Comp (ref): 0.24 (0.02), Difference: 0.02 (0.03), p=NS; High-fat vegetables: Int: 0.05 (0.01) vs Comp (ref): 0.03 (0.01), Difference: 0.02 (0.01), p=NS; [underlined: Snacks]; Fruit: Int: 0.62 (0.03) vs Comp (ref): 0.36 (0.03), Difference: 0.26 (0.05), p<0.001 ↑; Regular vegetables: Int: 0.08 (0.01) vs Comp (ref): 0.08 (0.01), Difference: 0.00 (0.02), p=NS; 100% fruit juice: Int: 0.22 (0.02) vs Comp (ref): 0.15 (0.02), Difference: 0.06 (0.03), p<0.05 ↑; High-fat vegetables: Int: 0.05 (0.01) vs Comp (ref): 0.03 (0.01), Difference: 0.02 (0.01), p=NS; [underlined: Lunch]; Fruit: Int: 0.45 (0.04) vs Comp (ref): 0.37 (0.04), Difference: 0.08 (0.05), p=NS; Regular vegetables: Int: 0.44 (0.03) vs Comp (ref): 0.28 (0.03), Difference: 0.16 (0.05), p<0.01 ↑; 100% fruit juice: Int: 0.12 (0.02) vs Comp (ref): 0.12 (0.02), Difference: 0.00 (0.03), p=NS; High-fat vegetables: Int: 0.08 (0.01) vs Comp (ref): 0.11 (0.01), Difference: 0.03 (0.02), p=NS; [underlined: Dinner]; Fruit: Int: 0.25 (0.04) vs Comp (ref): 0.18 (0.04), Difference: 0.07 (0.06), p=NS; Regular vegetables: Int: 0.62 (0.05) vs Comp (ref): 0.53 (0.05), Difference: 0.09 (0.07), p=NS; 100% fruit juice: Int: 0.16 (0.02) vs Comp (ref): 0.13 (0.02), Difference: 0.03 (0.03), p=NS; High-fat vegetables: Int: 0.15 (0.02) vs Comp (ref): 0.13 (0.02), Difference: 0.02 (0.02), p=NS; Model adjustments: Pre-intervention intake; clustering effect of schools; Funding source(s): NIH, USDA/Agricultural Research Service
Unnamed study – the Netherlands
Reinaerts, 2007 ^41^; The Netherlands, RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): ~9 y; Female: ~52%; Race/ethnicity: Dutch native (both parents born in The Netherlands): ~69%; SES: NR | Int1: Free fruit and vegetable snack distributed each school day (N=NR; Cluster N=3); Int2: Age-appropriate classroom curriculum and parental involvement (N=NR; Cluster N=3); Theory/framework: Intervention mapping; Intervention duration: 1 academic y; Outcome measurement: Twenty-four hour fruit, juice, and vegetable intake assessed via pre-structured 24-h food recall completed by parents at baseline and post-intervention. Other intakes assessed via FFQ completed by parents at baseline and post-intervention. | Intake at post-intervention, Mean (SD) and Mean difference; [underlined: Fruit (portions/d)]: Int1 (n=270): 1.5 (0.9), Int2 (n=206): 1.5 (0.8); Int1 (ref) v Int2: 0.01, p=NS; [underlined: Vegetables (g/d), by grade group or Dutch origin]:; Pre-K: Int1 (n=52): 53 (23), Int2: NR; Int1 (ref) v Int2: −0.10, p=NS; 1st-3rd: Int1 (n=108): 63 (30), Int2: NR; Int1 (ref) v Int2: −0.13, p=NS; 4th-6th: Int1 (n=94): 78 (38), Int2: NR; Int1 (ref) v Int2: −10.34, p<0.001 ↓; Native: Int1 (n=125): 61 (28), Int2: NR; Int1 (ref) v Int2: −0.26, p=NS; Non-native: Int1 (n=117): 71 (37), Int2: NR; Int1 (ref) v Int2: −10.41, p<0.01 ↓; [underlined: Vegetable snack (between meals; x/d), by grade group or sex]:; Pre-K: Int1 (n=53): 0.3 (0.3), Int2 (n=53): 0.3 (0.3); Int1 (ref) v Int2: 0.01, p=NS; 1st-3rd: Int1 (n=108): 0.3 (0.3), Int2 (n=84): 0.3 (0.3); Int1 (ref) v Int2: 0.04, p=NS; 4th-6th: Int1 (n=97): 0.4 (0.3), Int2 (n=64): 0.3 (0.3); Int1 (ref) v Int2: −0.08, p<0.05 ↓; Boys: Int1: NR, Int2 (n=91): 0.2 (0.3); Int1 (ref) v Int2: −0.06, p<0.05 ↓; Girls: Int1: NR, Int2 (n=110): 0.3 (0.3); Int1 (ref) v Int2: 0.04, p=NS; [underlined: 24 h fruit, juice, and vegetables (x/d), by grade group or Dutch origin]:; Pre-K: Int1 (n=41): 3.1 (1.4), Int2: NR; Int1 (ref) v Int2: −0.33, p=NS; 1st-3rd: Int1 (n=92): 3.3 (1.3), Int2: NR; Int1 (ref) v Int2: 0.06, p=NS; 4th-6th: Int1 (n=85): 4.0 (1.7), Int2: NR; Int1 (ref) v Int2: −0.22, p=NS; Native: Int1: NR, Int2 (n=160): 3.0 (1.2); Int1 (ref) v Int2: −0.14, p=NS; Non-native: Int1: NR, Int2 (n=19): 3.8 (1.4); Int1 (ref) v Int2: 0.49, p=NS; Model adjustments: Baseline consumption; sex; grade group; ethnicity (Dutch native or non-native); nesting child within class within school; interactions between intervention and sex, ethnicity, and grade group; Funding source(s): The Netherlands Organization for Health Research and Development
Reinaerts, 2008 ^40^; The Netherlands, RCT-Cluster; Total Baseline N: 952; Total Analytic N: 209; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Missing data; Grade level: Elementary school; Age (Mean (SD)): ~8 y; Female: ~53%; Race/ethnicity: Dutch native (both parents born in The Netherlands): ~69%; SES: NR | Int1: Free fruit and vegetable snack distributed each school day (N=85; Cluster N=3); Int2: Age-appropriate classroom curriculum promoting fruit and vegetable consumption and parental involvement (N=124; Cluster N=3); Theory/framework: Intervention mapping; Intervention duration: 1 academic y; Outcome measurement: Twenty-four hour fruit, juice, and vegetable intake assessed via pre-structured 24-h food recall completed by parents at baseline, post-intervention, and 1 y follow-up. Other intakes assessed via FFQ completed by parents at baseline, post-intervention, and 1 y follow-up. | Intake at post-intervention and 1 y follow-up, Mean (SD); [underlined: Fruit (portions/d)]: Int1: 1.41 (0.83) at post-intervention, 1.25 (0.76) at 1 y follow-up, Int2: 1.27 (0.70) at post-intervention, 1.18 (0.75) at 1 y follow-up, p=NS; [underlined: Vegetable (g/d)]: Int1: 49.0 (26.5) at post-intervention, 49.6 (25.6) at 1 y follow-up, Int2: 43.6 24.7) at post-intervention, 48.4 (24.0) at 1 y follow-up, p<0.05 ↓; [underlined: Vegetable snack (between meals; x/d)]: Int1: 0.38 (0.28) at post-intervention, 0.40 (0.30) at 1 y follow-up, Int2: 0.31 (0.29) at post-intervention, 0.26 (0.24) at 1 y follow-up, p<0.05 ↓; [underlined: 24-h fruit, juice, and vegetables (x/d)]: Int1: 3.38 (1.18) at post-intervention, 3.22 (1.13) at 1 y follow-up, Int2: 3.10 (1.12) at post-intervention, 3.02 (1.29) at 1 y follow-up, p=NS; Model adjustments: Baseline consumption; age; ethnicity (Dutch native or non-native); time; child nested in school; Funding source(s): The Netherlands Organization for Health Research and Development
Unnamed study - Portugal
Rosário, 2012 ^80^; Portugal, RCT-Cluster; Total Baseline N: 464; Total Analytic N: 294; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Did not complete post-intervention assessment, Note: 4th graders at baseline were not included, since they moved to a different school during the intervention phase; Grade level: Elementary school; Age (Mean (SD)): 8.3 (1.2) y; Female: 51.5%; Race/ethnicity: NR; SES: Mother’s education: Up to 9 y: ~64%; 10-12 y: ~23%; >12 y: ~13% | Int: 12 session education intervention presented by classroom teachers who received in-service training. (N=151; Cluster N=3); Comp: No intervention (N=143; Cluster N=4); Theory/framework: SCT; HPM; Intervention duration: 6 mo; Outcome measurement: Fruit and vegetable intake on one weekday assessed via 24-h dietary recall by nutritionists and/or trained interviewers, conducted at baseline and post-intervention. Total vegetable intake included legumes, leafy, and orange vegetables and other vegetables assessed; vegetable soup was analyzed as a separate variable. Whole fruit, fruit juice, and total fruit (whole fruit and fruit juice) were assessed. | Change in intake from baseline to post-intervention (g), Mean (SD), Adjusted mean difference (95% CI); [underlined: Total fruit]; Comp: −70.0 (27.7), Int: 76.8 (27.6); Int vs Comp (ref): −282.8 (−495.1, −70.6), p=0.009 ↑; [underlined: Whole fruit]; Comp: −59.3 (24.6), Int: 26.1 (21.2); Int vs Comp (ref): −152.8 (−322.7, 17.2), p=0.078; [underlined: Fruit juice]; Comp: −10.7 (13.0), Int: 50.6 (18.3); Int vs Comp (ref): −118.8 (−240.0, 2.4), p=0.055; [underlined: Vegetable soup]; Comp: 21.4 (26.2), Int: −24.2 (23.6); Int vs Comp (ref): 67.8 (−109.3, 244.9), p=0.453; [underlined: Total vegetable]; Comp: 26.7 (8.8), Int: 48.3 (10.3); Int vs Comp (ref): −89.7 (−164.2, −15.2), p=0.018 ↑; [underlined: Green leafy vegetable]; Comp: 9.1 (5.7), Int: 24.2 (4.9); Int vs Comp (ref): −61.3 (−101.0, −21.6), p=0.002 ↑; [underlined: Other vegetable]; Comp: 17.6 (5.3), Int: 24.1 (8.1); Int vs Comp (ref): −28.4 (−82.0, 25.2), p=0.299; [underlined: Fruit and vegetable]; Comp: −43.2 (29.4), Int: 125.0 (28.7); Int vs Comp (ref): −377.5 (−598.1, −156.9), p=0.001 ↑; Model adjustments: Sex; age; baseline total energy intake; parents’ education; baseline BMI; baseline measures of the dependent variable; Funding source(s): NR
Rosário, 2013 ^81^; Portugal, RCT-Cluster; Total Baseline N: 464; Total Analytic N: 294; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Did not complete post-intervention assessment, Note: 4th graders at baseline were not included, since they moved to a different school during the intervention phase; Grade level: Elementary school; Age (Mean (SD)): 8.3 (1.2) y; Female: 51.5%; Race/ethnicity: NR; SES: Mother’s education: Up to 9 y: ~64%; 10-12 y: ~23%; >12 y: ~13% | Int: 12 session education intervention presented by classroom teachers who received in-service training. (N=151; Cluster N=3); Comp: No intervention (N=143; Cluster N=4); Theory/framework: SCT; HPM; Intervention duration: 6 mo; Outcome measurement: Low nutrient energy dense (LNED) food intake on one weekday assessed via 24-h dietary recall by nutritionists and/or trained interviewers, conducted at baseline and post-intervention. | Intake at pre- and adjusted post-intervention (g), Mean (95% CI); [underlined: Solid LNED foods (higher fat baked goods, candy and sweetened gum, dairy based adesserts, French fries and similar products, chips and salty snacks)]:; Pre: Int: 83.8 vs Comp: 92.3,; Post: Int: 82.9 (67.2, 102.2) vs Comp: 116.8 (92.9, 146.8), p=0.031 ↑; [underlined: LNED SSBs (carbonated soft drinks, fruit flavored juice drinks, lemonades, sweetened teas, and energy/sports drinks)]:; Pre: Int: 240.1 vs Comp: 225.1; Post: Int: 271.6 (196.5, 375.5) vs Comp: 240.5 (183.0, 316.1), p=0.578; Increased consumption of solid LNED foods and SSBs from pre- to post-intervention (%), OR (95% CI); Solid LNED foods: Int: 48.3% vs Comp (ref): 55.9%; OR: 0.48 (0.24, 0.95), p=0.036 ↑; LNED SSBs: Int: 49.7% vs Comp (ref): 53.1%; OR: 1.66 (0.69, 3.96), p=0.258; Model adjustments: School; gender; age; baseline energy intake; parents’ education; weight status; Physical Activity Index; baseline measure of dependent variable; Funding source(s): Fundação para a Ciência
Rosário, 2016 ^82^; Portugal, RCT-Cluster; Total Baseline N: 464; Total Analytic N: 294; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Did not complete post-intervention assessment, Note: 4th graders at baseline were not included, since they moved to a different school during the intervention phase; Grade level: Elementary school; Age (Mean (SD)): 8.3 (1.2) y; Female: 51.5%; Race/ethnicity: NR; SES: Mother’s education: Up to 9 y: ~64%; 10-12 y: ~23%; >12 y: ~13% | Int: 12 session education intervention presented by classroom teachers who received in-service training. (N=151; Cluster N=3); Comp: No intervention (N=143; Cluster N=4); Theory/framework: SCT; HPM; Intervention duration: 6 mo; Outcome measurement: Fruit intake for dessert (whole fruit, excluding fruit juice) on one weekday assessed via 24-h dietary recall by nutritionists and/or trained interviewers, conducted at baseline and post-intervention. | Intake at pre- and adjusted post-intervention (g), Mean (SE); [underlined: Fruit for dessert at lunch]:; Pre: Int: 85.6 (6.6) vs Comp: 105.5 (8.1); Post: Int: 94.6 (8.6) vs Comp: 50.9 (9.8), p=0.001 ↑; [underlined: Fruit for dessert at dinner]:; Pre: Int: 45.2 (6.5) vs Comp: 29.7 (5.8); Post: Int: 85.1 (9.5) vs Comp: 48.9 (10.9), p=0.012 ↑; Model adjustments: Gender; age; baseline energy intake; parents’ education; weight status; Physical Activity Index; underreporting (ratio of ratio energy intake:basal metabolic rate); baseline measures of the dependent variable; Funding source(s): NR
Rosário, 2017 ^83^; Portugal, RCT-Cluster; Total Baseline N: 464; Total Analytic N: 294; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Did not complete post-intervention assessment, Note: 4th graders at baseline were not included, since they moved to a different school during the intervention phase; Grade level: Elementary school; Age (Mean (SD)): 8.3 (1.2) y; Female: 51.5%; Race/ethnicity: NR; SES: Mother’s education: Up to 9 y: ~64%; 10-12 y: ~23%; >12 y: ~13% | Int: 12 session education intervention presented by classroom teachers who received in-service training. (N=151; Cluster N=3); Comp: No intervention (N=143; Cluster N=4); Theory/framework: SCT; HPM; Intervention duration: 6 mo; Outcome measurement: Dietary intake on one weekday assessed via 24-h dietary recall by nutritionists and/or trained interviewers, conducted at baseline and post-intervention and components of Diet Quality Index-International (DQI-I) were defined. | Intake at post-intervention based on DQI-I, Mean (SD) and Adjusted mean difference (SE); [underlined: Vegetable group]: Int: 0.64 (0.89), Comp: 0.46 (0.54); Int vs Comp (ref): −0.27 (0.12), p=0.018 ↑; [underlined: Fruit group]: Int: 2.40 (1.70), Comp: 2.59 (1.72); Int vs Comp (ref): −0.14 (0.12), p=0.474; [underlined: Grain group]: Int: 2.89 (0.98), Comp: 3.24 (0.88); Int vs Comp (ref): 0.27 (0.20), p=0.177; [underlined: Dietary fiber]: Int: 3.03 (1.05), Comp: 3.11 (1.01); Int vs Comp (ref): 0.03 (0.15), p=0.851; [underlined: Sodium]: Int: 2.98 (1.74), Comp: 2.86 (1.74); Int vs Comp (ref): −0.55 (0.26), p=0.032 ↑; Model adjustments: School; gender; age; baseline energy intake; parents’ education; weight status; Physical Activity Index; underreporting (ratio of ratio energy intake:basal metabolic rate); baseline measures of the dependent variable; Funding source(s): NR
Individual studies (alphabetized by author)
Abdel Gawwad, 2006 ^50^; Saudi Arabia, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 129; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: Incomplete questionnaire; Grade level: Elementary school; Age: NR; Female: 100%; Race/ethnicity: NR; SES: Maternal education: Illiterate: 11.6%, Primary-intermediate: 22.5%, Secondary: 27.9%, University: 38.0% | Int1: Nutrition education delivered by physicians and dietitians (N=63; Cluster N=2); Comp: Delayed intervention (N=66; Cluster N=2); Theory/framework: SCT; Intervention duration: 120 min; Outcome measurement: Usual intake habits assessed with 31 item questionnaire (higher scores = better dietary practices) completed by children in class immediately following education session | Usual intake habits, Mean (SD); [underlined: 5th grade children]: Int (N=32): 84.84 (9.59), Comp (N=34): 88.29 (5.97); [underlined: 6th grade children]: Int (N=31): 81.32 (8.07), Comp (N=32): 80.94 (6.06) p<0.001 ↓; Model adjustments: None; Funding source(s): NR
Arrizabalaga-López, 2020,^51^ PROFRUVE; Spain, RCT-Cluster; Total Baseline N: 185; Total Analytic N: 136; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Did not complete the 7-d food record, extreme values; Grade level: Elementary school; Age (Mean (SD)): 8.45 (0.776) y; Female: 44%; Race/ethnicity: NR; SES: Low or middle–low: ~39%; High or middle– high: ~50%; NR: ~11% | Int: 14 session nutrition education intervention focused on fruit and vegetables and delivered by a nutritionist (N=62; Cluster N=4); Comp: Two sessions with general fruit and vegetable information delivered by a nutritionist (N=74; Cluster N=4); Theory/framework: TPB; Intervention duration: 1 academic y; Outcome measurement: Fruit and vegetable consumption (excluding potatoes and legumes) evaluated using a self-administered validated 7-d food record completed by parents or guardians at pre- and post-intervention | Intake at pre- and post-intervention (svg/d), Mean (SD), and Mean change (95% CI); [underlined: Fruit and vegetable intake]; Int: Pre: 2.27 (1.01), Post: 2.72 (1.15), Change: 0.45 (0.17, 0.74); Comp: Pre: 2.35 (0.95), Post: 2.36 (1.04), Change: 0.01 (−0.20, 0.22); Int vs Comp: Post: p=0.070, Change: p=0.001 ↑ (Note: similar results when examined in linear mixed model controlling for baseline intake, age, sex, and SES); [underlined: Fruit intake]; Int: Pre: 1.49 (0.78), Post: 1.80 (0.83), Change: 0.31 (0.13, 0.50); Comp: Pre: 1.55 (0.77), Post: 1.57 (0.74), Change: 0.02 (−0.13, 0.16); Int vs Comp: Post: p=0.183, Change: p=0.001 ↑; [underlined: Vegetable intake]; Int: Pre: 0.78 (0.40), Post: 0.92 (0.53), Change: 0.14 (−0.01, 0.28); Comp: Pre: 0.80 (0.40), Post: 0.79 (0.48), Change: −0.01 (−0.11, 0.10); Int vs Comp: Post: p=0.56, Change: p=0.046 ↑; [underlined: Fresh fruit intake]; Int: Pre: 1.16 (0.65), Post: 1.36 (0.70), Change: 0.20 (0.04, 0.37); Comp: Pre: 1.07 (0.56)), Post: 1.10 (0.59), Change: 0.04 (−0.07, 0.14); Int vs Comp: Post: p=0.021, Change: p=0.035 ↑; [underlined: Fruit juice intake]; Int: Pre: 0.33 (0.32), Post: 0.44 (0.37), Change: 0.11 (0.03, 0.19); Comp: Pre: 0.48 (0.44), Post: 0.46 (0.40), Change: −0.02 (−0.12, 0.08); Int vs Comp: Post: p=0.519, Change: p=0.020 ↑; [underlined: Raw vegetable intake]; Int: Pre: 0.33 (0.28), Post: 0.48 (0.38), Change: 0.15 (0.05, 0.25); Comp: Pre: 0.34 (0.30), Post: 0.39 (0.33), Change: 0.05 (−0.02, 0.11); Int vs Comp: Post: p=0.093, Change: p=0.175; [underlined: Cooked vegetable intake]; Int: Pre: 0.45 (0.26), Post: 0.44 (0.31), Change: −0.01 (−0.09, 0.07); Comp: Pre: 0.46 (0.29), Post: 0.41 (0.27), Change: −0.05 (−0.12, 0.02); Int vs Comp: Post: p=0.801, Change: p=0.350; Model adjustments: None; Funding source(s): Government of the Basque Country; CIBERobn; City Council of Vitoria-Gasteiz; University of the Basque Country
Bannon, 2006 ^52^; United States (Connecticut), RCT-Cluster; Total Baseline N: 53; Total Analytic N: 50; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Sent to nurse, refused snack, allergies; Grade level: Elementary school; Age (Mean (SD)): 5.0 (0.04) y; Female: 46%; Race/ethnicity: White: 92%; Black: 4%; Hispanic: 4%; SES: Connecticut Economic Reference Group of School (“A” - most affluent to “I” - least affluent): “F” | Int1: Sixty second “gain-framed” video that emphasizes the benefits of eating apples (N=14; Cluster N=1); Int2: Sixty second “loss-framed” video that emphasizes the negative consequences of not eating apples (N=18; Cluster N=1); Comp: Sixty second video unrelated to nutrition (rainy day activity) (N=18; Cluster N=1); Theory/framework: Prospect theory; Intervention duration: 1 min; Outcome measurement: Snack choice assessed during 10-15 min play break following viewing of video; children offered choice of animal crackers or an apple and selection was observed by experimenter | Choice of apple or animal crackers for snack, % of children; Int: Apples: 57.1%, Animal crackers: 42.9%; Int2: Apples: 55.6%, Animal crackers: 44.4%; Comp: Apples: 33.3%, Animal crackers: 66.77%; Int vs Comp: p=0.059; Int2 vs Comp: p<0.05 ↑; Int and Int2 combined vs Comp: p<0.01 ↑; Model adjustments: None; Funding source(s): NR
Baranowski, 2000 ^54^; United States (Southeast), RCT-Cluster; Total Baseline N: 1,732; Total Analytic N: 1,172; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Did not complete all assessments, race other than Black or White; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: White: 84.7%; Black: 15.3%; SES: NR | Int: Gimme 5 curriculum targeting fruit, juice, and vegetable intake (N=NR; Cluster N=8); Comp: No intervention (N=NR; Cluster N=8); Theory/framework: SCT; Intervention duration: ~1 y (two 6 wk intervention periods 1 y apart); Outcome measurement: Diet assessed by 7-d food record completed by children and coded by trained dietitians at baseline (1 y pre-intervention), mid-intervention (immediately following first 6 wk intervention period), and post-intervention (immediately following second 6 wk intervention period) | Intake at pre-, mid-, and post-intervention (svg), Mean (SE); [underlined: Fruit, juice, and vegetables]; Pre: Int: 2.3 (0.1), Comp: 2.4 (0.1); Mid: Int: 2.3 (0.1), Comp: 2.1 (0.1); Post: Int: 2.3 (2.1), Comp: 2.1 (0.1); Group by time interaction: p=0.038 ↑; [underlined: Vegetables]; Pre: Int: 1.1 (0.1), Comp: 1.2 (0.1); Mid: Int: 1.2 (0.1), Comp: 1.0; Post: Int: 1.1 (0.1), Comp: 1.1 (0.1); Group by time interaction: p=0.004 ↑; [underlined: Fruit and juices]; Pre: Int: 1.2 (0.1), Comp: 1.2 (0.1); Mid: Int: 1.1 (0.1), Comp: 1.1 (0.1); Post: Int: 1.1 (0.1), Comp: 1.0 (0.1); Group by time interaction: p>0.10; [underlined: Fruit, juice, and vegetables at weekday lunches]; Pre: Int: 0.9 (0.1), Comp: 1.0 (0.1); Mid: Int: 1.0 (0.1), Comp: 0.8 (0.1); Post: Int: 0.9 (0.1), Comp: 0.8 (0.1); Group by time interaction: p=0.074; Difference in change from mid- to post-intervention: p=0.06; [underlined: Fruit, juice, and vegetables at all other times]; Pre: Int: 1.6 (0.1), Comp: 1.7 (0.1); Mid: Int: 1.6 (0.1), Comp: 1.5 (0.1); Post: Int: 1.6 (0.1), Comp: 1.5 (0.1); Group by time interaction: p>0.10; Model adjustments: Race; sex; random effects for school nested in treatment group and individual nested in school; Funding source(s): NR
Bashirian, 2008 ^55^; Iran, RCT-Cluster; Total Baseline N: 218; Total Analytic N: 185; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Did not complete post-intervention questionnaire; Grade level: Elementary school; Age (Mean): 11 y; Female: ~49% Race/ethnicity: NR; SES: NR | Int: Fruit and vegetable educational program (5 lessons) including preparing and taste testing of fruits and vegetables at each session (N=84; Cluster N=4); Comp: No intervention (N=101; Cluster N=4); Theory/framework: NR; Intervention duration: 2 mo; Outcome measurement: Assessed with 1-wk fruit and vegetable recall, read aloud by project worker, administered pre-intervention and post-intervention. | Intake at post-intervention, %; [underlined: Citrus]: Never: Int: 2.4%, Comp: 16%; 1-2x/wk: Int: 45.2%, Comp: 30%; 3-4x/wk: Int: 14.3%, Comp: 28%; Daily: Int: 38.1%, Comp: 26%; p=0.032 ↑; [underlined: Banana]: Never: Int: 7.1%, Comp: 24%; 1-2x/wk: Int: 42.9%, Comp: 32%; 3-4x/wk: Int: 28.4%, Comp: 34%; Daily: Int: 21.4%, Comp: 10%; p=0.082; [underlined: Vegetables]: Never: Int: 11.9%, Comp: 10%; 1-2x/wk: Int: 38.1%, Comp: 22%; 3-4x/wk: Int: 26.2%, Comp: 30%; Daily: Int: 23.8%, Comp: 16%; p=0.023 ↑; [underlined: Cucumber]: Never: Int: 7.1%, Comp: 22%; 1-2x/wk: Int: 33.3%, Comp: 46%; 3-4w/wk: Int: 40.5%, Comp: 28%; Daily: Int: 19%, Comp: 4%; p=0.002 ↑; [underlined: Tomato]: Never: Int: 11.9%, Comp: 26%; 1-2x/wk: Int: 45.2%, Comp: 50%; 3-4x/wk: Int: 23.8%, Comp: 16%; Daily: Int: 19%, Comp: 8%; p=0.023 ↑; [underlined: Carrot]: Never: Int: 23.8%, Comp: 46%; 1-2x/wk: Int: 33.3%, Comp: 34%; 3-4x/wk: Int: 16.7%, Comp: 10%; Daily: Int: 26.2%, Comp: 10%; p=0.061; [underlined: Lettuce]: Never: Int: 7.1%, Comp: 26%; 1-2x/wk: Int: 35.7%, Comp: 44%; 3-4x/wk: Int: 26.2%, Comp: 20%; Daily: Int: 31%, Comp: 10%; p=0.007 ↑; [underlined: Cabbage]: Never: Int: 31%, Comp: 44%; 1-2x/wk: Int: 28.6%, Comp: 26%; 3-4x/wk: Int: 16.7%, Comp: 24%; Daily: Int: 23.8%, Comp: 6%; p=0.066; Note: According to text, with Bonferroni correction no comparisons were statistically significant; Model adjustments: None; Funding source(s): Hamadan University of Medical Sciences
Battjes-Fries, 2017 ^56^; The Netherlands, RCT-Cluster; Total Baseline N: 1,010; Total Analytic N: 877; Total Baseline Cluster N: 34; Total Analytic Cluster N: 34; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 10.3 y; Female: 51%; Race/ethnicity: Dutch: ~91%; Non-Dutch: ~9%; SES: Maternal education level: Low: ~14%, Middle: ~52%, High: ~34% | Int1: Taste Lessons nutrition education program (5 sessions) (N=236; Cluster N=11); Int2: Taste Lessons nutrition education program (5 sessions) plus hands-on activities related to vegetables and cooking (N=364; Cluster N=11); Comp: No intervention (N=277; Cluster N=12); Theory/framework: NR; Intervention duration: 3 mo; Outcome measurement: Vegetable intake reported by children using 3 questions: how many days (per wk) do you eat vegetables, what quantity of vegetables do you eat at supper (svg spoons), and how many days they ate vegetables besides at supper | Change in intake from baseline to post-intervention, Mean (SD) and Mean difference (95% CI); [underlined: Vegetables consumed at supper (d/wk)]:; Int: 0.0 (1.2), Int2: 0.1 (1.2), Comp: 0.1 (1.3); Int vs Comp (ref): −0.1 (−0.2, 0.1),p=NS; Int2 vs Comp (ref): 0.0 (−0.2, 0.2), p=NS; Int (ref) vs Int2: 0.1 (−0.2, 0.3), p=NS; [underlined: Vegetables at supper (svg spoon)]:; Int: 0.0 (0.6), Int2: −0.1 (0.6), Comp: −0.1 (0.6); Int vs Comp (ref): 0.1 (−0.1, 0.3), p=NS, Int2 vs Comp (ref): −0.1 (−0.2, 0.1), p=NS, Int (ref) vs Int2: −0.1 (−0.3, 0.1), p=NS; [underlined: Vegetables consumed as snack (d/wk)]:; Int: 0.1 (0.9), Int2: 0.1 (0.9), Comp: 0.2 (0.9); Int vs Comp (ref): −0.1 (−0.3, 0.1), p=NS, Int2 vs Comp (ref): −0.1 (−0.3, 0.1), p=NS, Int (ref) vs Int2: 0.0 (−0.2, 0.2), p=NS; Model adjustments: Age; sex; Funding source(s): Platform for Food Education, Netherlands Organisation for Health Research and Development ZonMw
Christian, 2014 ^57^; United Kingdom, RCT-Cluster; Total Baseline N: 1,256; Total Analytic N: 641; Total Baseline Cluster N: 23; Total Analytic Cluster N: 21; Criteria for exclusion from analysis: School withdrew, lost data, absent on data collection, incomplete diet diaries, left school; Grade level: Elementary school; Age (Mean): ~8.1 y; Female: ~49%; Race/ethnicity: White: ~33%; Black: ~15%; Asian: ~17%; Chinese or Other: ~2%; Mixed: ~7%; Prefer not to say: ~26%; SES: Free school meal eligibility: ~28% | Int: Royal Horticultural Society (RHS) led school gardening intervention (N=312; Cluster N=10); Comp: Teacher-led school gardening intervention (N=329; Cluster N=11); Theory/framework: SCT; Intervention duration: 18 mo; Outcome measurement: Assessed with modified version of validated 115 item Child and Diet Evaluation Tool (CADET) questionnaire with pre-allocated food portion sizes based on age and sex at baseline and post-intervention. The school portion of the CADET was completed by trained fieldworkers who observed students at mealtime; the home portion was completed by parents. | Change in intake from baseline to post-intervention (g/d), Int vs Comp (Ref), Mean (SE) and Mean difference (95% CI); [underlined: Fruit]: Int: −8 (30.8), Comp: −20 (29), Difference: −28 (−60, 3), p=0.08; [underlined: Vegetables]: Int: 16 (19.6), Comp: 29 (18.2), Difference: −13 (39, 11), p=0.2; [underlined: Combined fruit and vegetables]: Int: 1 (39.4), Comp: 41 (36.7), Difference: −40 (−88, 1), p=0.06; [underlined: Fruit at schoo]l: Int: −25 (10.1), Comp: −12 (14.2), Difference: −13 (−41, 14), p=0.3; [underlined: Fruit at home]: Int: −32 (15.8), Comp: −13 (14.1), Difference: −19 (−50, 40), p=0.2; [underlined: Vegetables at schoo]l: Int: −8 (9.6), Comp: −1 (5.9), Difference: −7 (−26, 12), p=0.4; [underlined: Vegetables at home]: Int: 12 (11.2), Comp: 23 (11.0), Difference: −11 (−29, 7), p=0.2; [underlined: Combined fruit and vegetables at schoo]l: Int: −25 (10.8), Comp: −4 (16.0), Difference: −21 (−54, 11), p=0.2; [underlined: Combined fruit and vegetables at home]: Int: −19 (20.8), Comp: 9 (20.4), Difference: −28 (−71, 14), p=0.2; Intake at post-intervention, Int vs Comp (Ref), Mean (SE) and Mean difference (95% CI); [underlined: Sodium (mg/d)]: Int: 2272 (286), Comp: 2257 (267.7), Difference: 16 (−357, 388), p=0.9; [underlined: Total sugars (g/d)]: Int: 90 (10.5), Comp: 99 (10.0), Difference: −8 (−18, 2), p=0.1; [underlined: Fiber (g/d)]: Int: 10 (1.3), Comp: 11 (1.3), Difference: −1 (−3, 1), p=0.1; Model adjustments: Age; sex; ethnicity; Index of Multiple Deprivation Score; School (random effect); Funding source(s): National Institute for Health Research Public Health Research Programme
Cotter, 2013 ^58^; Portugal, RCT-Cluster; Total Baseline N: 139; Total Analytic N: 127; Total Baseline Cluster N: 9; Total Analytic Cluster N: 9; Criteria for exclusion from analysis: Incomplete urinary collection (determined using creatinine levels as compliance check); Grade level: Elementary school; Age (Mean (SD)): 10.9 (0.7) y; Range: 10-12 y; Female: 55%; Race/ethnicity: NR; SES: NR | Int1: Salt intake education (N=43; Cluster N=3); Int2: Salt intake education with school gardening project (N=53; Cluster N=3); Comp: Standard curriculum (N=31; Cluster N=3); Theory/framework: NR; Intervention duration: 6 mo; Outcome measurement: Salt intake estimated with 24h urine collection that occurred at baseline and post-intervention. Sodium excretion level determined using flame photometry and salt intake derived as 1 mEq/24-h sodium = 0.058 g per day of salt | Change in estimated salt intake baseline to post-intervention (g/d), Mean (SD); Int1: −0.60 (3.24); Int2: −1.08 (2.47); Comp: −0.35 (2.42); Within-group comparisons: Int 2: p<0.05 ↑; Int 1 & Comp: p>0.05; Between-group comparisons: all p>0.05; Categories of estimated change in salt intake baseline to post-intervention, %; Increased ≥1 g/d: Int1: 37.2%, Int2: 18.9%, Comp: 25.8%; Between 0.99 g/d reduction and 0.99 g/d increase: Int1: 14.0%, Int2: 30.2%, Comp: 41.9%; Reduced ≥1 g/d: Int1: 48.8%, Int2: 50.9%, Comp: 32.3%; p=0.041 ↑; Model adjustments: None; Funding source(s): NR
Cunha, 2013,^60^ Parents, students, and teachers for healthy eating (PAPPAS); Brazil, RCT-Cluster; Total Baseline N: 478; Total Analytic N: 559 (larger number due to participants entering the study after baseline); Total Baseline Cluster N: 20; Total Analytic Cluster N: 20; Grade level: Elementary school; Age (Mean): 11.2 y; Female: 48%; Race/ethnicity: White: 25.6%; Brown: 45.2%; Black: 29.2% (as reported by paper); SES: NR | Int: Nine monthly nutrition education sessions aimed to promote healthy eating habits in adolescents delivered by trained nutritionists and involving families and teachers (N=277; Cluster N=10); Comp: No intervention (N=282; Cluster N=10); Theory/framework: Pedagogy of the Oppressed approach; Intervention duration: 9 mo; Outcome measurement: Intake assessed with validated FFQ at baseline, mid-year school (mo 6), and post-intervention (end of term). At baseline and at the end of the study, intake also assessed with 24-h recall administered by nutritionists using the multiple pass method. | Variation in daily frequency of consumption (units NR), Mean (95% CI) and β coefficient; [underlined: Cookies]; Int: −1.35 (−0.20, −0.75) vs Comp: 0.02 (−0.04, 0.09); Group by time interaction β coefficient: 0.13, p<0.001 ↑; [underlined: Sodas]; Int: −0.20 (−0.30, −0.11) vs Comp: −0.08 (−0.18, 0.02); Group by time interaction β coefficient: 0.13, p=0.02 ↑; [underlined: Juices]; Int: −0.16 (−0.28, −0.04) vs Comp: 0.01 (−0.12, 0.14); Group by time interaction β coefficient: 0.03, p=0.66; [underlined: Beans]; Int: 0.01 (−0.02, 0.05) vs Comp: 0.00 (−0.35, 0.04); Group by time interaction β coefficient: −0.01, p=0.54; [underlined: Fruits]; Int: 0.17 (0.01, 0.34) vs Comp: 0.10 (−0.05, 0.26); Group by time interaction β coefficient: −0.16, p=0.04 ↑; *Note: 24-h recall data NR, but verified results of FFQ; Model adjustments: None; Funding source(s): Foundation of Support of Research of the State of Rio de Janeiro; National Counsel of Technological and Scientific Development; Pan American Health and Education Foundation
de Droog, 2014 ^102^; The Netherlands, RCT-Parallel; Total Baseline N: 160; Total Analytic N: 160; Grade level: Elementary school; Age (Range): 4-6 y; Female: 49%; Race/ethnicity: NR; SES: NR | Int1: Picture book promoting carrot intake with character congruent with carrots and read in interactive style (N=26); Int2: Picture book promoting carrot intake with character incongruent with carrots and read in interactive style (N=26); Int3: Picture book promoting carrot intake with character congruent with carrots and read in passive style (N=26); Int4: Picture book promoting carrot intake with character incongruent with carrots and read in passive style (N=26); Comp: No intervention (N=56); Theory/framework: NR; Intervention duration: 5 d; Outcome measurement: Intake of 4 foods (carrot, cucumber, salty sticks, cheese) was measured after the final reading session (d 5) for all participants; proportional intake was measured by dividing the number of pieces of each food eaten by the total number of food pieces eaten | Intake at post-intervention, Mean (SD); [underlined: Carrots]: Experimental (all 4 groups): 0.14 (0.14) vs Comp: 0.08 (0.17), p<0.01 ↑; Reading style (active/passive): Int 1 & Int 2: 0.17 (0.16) vs. Int 3 & Int 4: 0.12 (0.11), p<0.05 ↑; Character congruence (congruent/incongruent): Int1 & Int3 vs Int2 & Int4: p=NS; [underlined: Cucumbers]: Experimental: 0.19 (0.02) vs Comp: 0.24 (0.02), p<0.05 ↓; [underlined: Cheese]: Experimental: 0.24 (0.02) vs Comp: 0.32 (0.03), p<0.05 ↑; [underlined: Salty snacks]: Experimental: 0.39 (0.19) vs Comp: 0.38 (0.18), p=NS; Mean (SD) intake of each food for each of the 4 experimental groups provided in paper; Model adjustments: Hunger (only correlated and adjusted for with cucumber and cheese); time of day when snacks were offered (ranged from 9am-3pm; only correlated and adjusted for with cucumber and cheese); BMI (tested but did not correlate with intake; was not adjusted for in final analyses); Funding source(s): The Netherlands Organisation for Scientific Research (NWO)
Drapeau, 2016,^61^ Team Nutriathlon; Canada, RCT-Cluster; Total Baseline N: 404; Total Analytic N: 404; Total Baseline Cluster N: 23; Total Analytic Cluster N: 23; Criteria for exclusion from analysis: Data points >15 svg/d of fruit and vegetables and >10 svg/d of dairy products; Grade level: Elementary school; Age (Range): ~10-12 y; Female: 49%; Race/ethnicity: NR; SES: Low-medium SES school: 52% | Int: Individual- and team-level goal-setting intervention (Team Nutriathlon) with the aim of increased fruit, vegetable, and dairy product intake (N=242; Cluster N=13); Comp: No goal setting intervention with instructions to maintain usual eating habits (N=162; Cluster N=10); Theory/framework: None; Intervention duration: 8 wk; Outcome measurement: Daily intake record sheets were completed on weekdays at 4 time points for 1 wk: baseline, 5 or 6 wk after baseline (‘‘during’’), final (8 wk after baseline), and follow-up (10 wk after final) | Intake over time (svg/d); [underlined: Fruit / Vegetable]: Group by time interaction: p<0.0001 ↑; Int > Comp at all outcome time points (during, final, follow-up), p<0.0001 ↑; [underlined: Dairy products]: Group by time interaction: p<0.0001 ↑; Int > Comp at all outcome time points (during, final, follow-up), p<0.0001 ↑; Intake values also reported in paper by gender, baseline intake, and school SES (moderation analyses). Interactions between group, time, and gender/baseline intake/school SES were all NS.; Proportion of intake across different meals; [underlined: Fruit / Vegetable]:; Follow-up: Int vs Comp for snacks: 0.27 vs 0.22, p=0.03 (breakfast [0.17 vs 0.18], lunch [0.31 vs 0.32], supper [0.25 vs 0.27]: all p=NS); During and Final: Int vs Comp for snacks, breakfast, lunch, supper: all data NR and p=NS; [underlined: Dairy Products]:; During, Final, and Follow-up: Int vs Comp for snacks, breakfast, lunch, supper: all data NR and p=NS; Model adjustments: Baseline consumption, school SES, gender all tested as potential moderators (all NS); Funding source(s): Fonds Québécois sur la recherche et la culture
Gatto, 2017,^62^ LA Sprouts; United States (Los Angeles, California), RCT-Cluster; Total Baseline N: 375; Total Analytic N: 319; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: Change in reported intake ≤ the 1st, or ≥ the 99th percentile, changed schools or withdrew from after-school program, absent on all data collection days; Grade level: Elementary school; Age (Mean (SD)): 9.3 (0.9) y; Female: 52%; Race/ethnicity: Hispanic/Latino: 89%; SES: Eligible free/reduced price: 90% | Int: LA Sprouts curriculum consisting of weekly lessons in cooking/nutrition and gardening at after-school program (N=172; Cluster N=2); Comp: Delayed intervention control (usual after-school program during study) (N=147; Cluster N=2); Theory/framework: Bandura’s “self-efficacy”; Intervention duration: 12 wk; Outcome measurement: The 41-item Block Kids Food Screener was used to assess intake during the previous week pre- and post-intervention (7-14 d after final class) | Change in intake, pre- to post-intervention, Absolute change; [underlined: Meat (oz eq/d)]: Int: −0.1, Comp: −0.6, p=0.17; [underlined: Dairy (c eq/d)]: Int: −0.1, Comp: −0.1, p=0.56; [underlined: Whole grains (oz eq/d)]: Int: 0.04, Comp: −0.08, p=0.10; [underlined: Vegetables (c eq/d)]: Int: −0.03, Comp: −0.2, p=0.04 ↑; [underlined: Fruit, fruit juice (c eq/d)]: Int: −0.04, Comp: −0.1, p=0.56; [underlined: Apples, bananas, oranges (c eq/d)]: Int: 0.02, Comp: −0.08, p=0.12; [underlined: Lettuce salad (c eq/d)]: Int: 0.0, Comp: −0.04, p=0.28; [underlined: Green beans, peas (c eq/d)]: Int: 0.01, Comp: −0.01, p=0.08; [underlined: Tomatoes (c eq/d)]: Int: −0.01, Comp: −0.02, p=0.21; Change in intake, pre- to post-intervention, Absolute change; [underlined: Added sugars (tsp/d)]: Int: 0.8, Comp: −0.7, p=0.11; [underlined: Dietary fiber (g/d)]: Int: 0.4, Comp: −2.0, p=0.04 ↑; Model adjustments: Age; sex; ethnicity (Hispanic/Latino vs not); English spoken at home; school; energy (kcal); Funding source(s): NIH; Keck Foundation
Gold, 2017 ^63^; United States (North Dakota), RCT-Cluster; Total Baseline N: 662; Total Analytic N: 535; Total Baseline Cluster N: 26; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Did not complete baseline or post-intervention surveys; Grade level: Elementary school; Age (Range): ~8-9 y; Female: ~52%; Race/ethnicity: White: ~78%; SES: Percent eligible for free or reduced-priced meals within schools (Mean (SD)): 47.7 (18.7) | Int1: Multicomponent nutrition education classroom curriculum (Go Wild With Fruits and Veggies! [GWWFV]) delivered by extension educators including taste-testing, classroom activities, take home challenges, and parent newsletters to increase fruit and vegetable intake (N=NR; Cluster N=NR); Int2: GWWFV curriculum with no taste testing offered (N=NR; Cluster N=NR); Comp: No intervention (N=NR; Cluster N=12); Theory/framework: SCT; Intervention duration: 7 wk; Outcome measurement: Assessed with self-report 13-item fruit and vegetable FFQ from a revised version of the validated School Physical Activity and Nutrition questionnaire, distributed to children on the first day of the intervention and immediately following the intervention | Intake at post-intervention, Mean; [underlined: Fruit (x/d)]; Int1: 3.7, Int2: 2.7, Comp: 2.0; Int1 vs Comp: p<0.05 ↑, Int2 vs Comp: p=NS; [underlined: Vegetables (x/d)]; Int1: 3.9, Int2: 3.7, Comp: 2.9; Int1 vs Comp: p=NS, Int2 vs Comp: p=NS; Model adjustments: Baseline intake; Funding source(s): NR
Gonçalves, 2018 ^103^; Portugal, RCT-Parallel; Total Baseline N: 142; Total Analytic N: 142; Grade level: Elementary school; Age (Mean (SD)): 6.44 (1.21) y; Female: 51%; Race/ethnicity: Portuguese nationality: 98%; SES: NR | Int: Nutri Ventures cartoon with healthy eating content (N=69); Comp: Cartoon without content on eating/food (N=73); Theory/framework: NR; Intervention duration: 20 min; Outcome measurement: Expressed food choice measured by allowing child to eat ad libitum from 4 bowls of healthy and less healthy foods (grapes, baby carrots, chips, and chocolates) on an individual basis with 4 researchers in the room; exact number of food items eaten were recorded | Food choice and consumption (# of items eaten) at post-intervention, Mean (SD) and Adjusted mean difference (SE); [underlined: Less healthy foods]: Int: 6.9 (7.10), Comp: 6.3 (5.65); Int (ref) vs Comp: −0.101 (0.18), p=0.57; [underlined: Healthy foods]: Int: 4.7 (4.41), Comp: 2.6 (3.81); Int (ref) vs Comp: −0.600 (0.19), p=0.002 ↑; Model adjustments: Age; BMI; Funding source(s): Fundação para a Ciência e Tecnologia; Portuguese Foundation for Science and Technology; FEDER; Portuguese Ministry of Science, Technology, and Higher Education
Griffin, 2015 ^64^; United Kingdom, RCT-Cluster; Total Baseline N: 268; Total Analytic N: 79; Total Baseline Cluster N: 14; Total Analytic Cluster N: 14; Criteria for exclusion from analysis: Did not return FFQ at baseline, 10 wk post-intervention, and/or 34 wk post-intervention; Grade level: Elementary school; Age (Median): ~11.08 y; Female: ~58%; Race/ethnicity: NR; SES: Scottish Index of Multiple Deprivation: “More deprived” (1-3): ~35%, “Less deprived” (4-5): ~65 % | Int: Nutrition education focused on sugar content of food and beverages delivered during two 45-minute sessions (N=48; Cluster N=8); Comp: Delayed intervention (N=31; Cluster N=6); Theory/framework: None; Intervention duration: 7-10 d (educational poster displayed in classroom during 34-wk follow-up); Outcome measurement: Intake during the past 2-3 mo assessed with validated Scottish Collaborative Group 140-item FFQ completed by parent/guardian with input from child at baseline, 10-wk follow-up, and 34-wk follow-up | Non-milk extrinsic sugar intake (%E/d) and change in intake at baseline, 10-wk follow-up, and 34-wk follow-up, Intake - Median (IQR), Change - Mean (SD), Difference in change - Mean (95% CI); [underlined: Baseline]: Int: 17.0 (13.5 - 21.0), Comp: 15.6 (12.2 - 19.5); 10-wk follow-up: Int: 18.0 (15.3 - 21.7), Comp: 16.2 (13.0 - 20.1); 34-wk follow-up: Int: 15.3 (13.5 - 19.3), Comp: 15.4 (12.5 - 18.8); [underlined: Change: Baseline to 10-wk follow-up]; Int: 1.4 (5.9), Comp: 0.4 (4.3), Int vs Comp (ref): 0.09 (−1.5, 3.4), p=0.44; [underlined: Change: Baseline to 34-wk follow-up]; Int: −1.2 (5.5), Comp: 0.8 (7.0), Int vs Comp (ref): −0.2 (−4.9, 0.8), p=0.15; Note: Results for change from baseline to 10-wk follow-up were similar when all participants with data for baseline and 10-wk follow-up, but not 34-wk follow-up (Int: N=95, Comp: N=60), were included; Model adjustments: Deprivation indicator; Funding source(s): Scottish Government Rural and Environment Research and Analysis Services
He, 2015,^65^ School-EduSalt Study; China, RCT-Cluster; Total Baseline N: 279; Total Analytic N: 274; Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: Incomplete urinary collection (defined as volume <500 mL/24-h or implausible creatinine levels). Sensitivity analyses were conducted including these individuals.; Grade level: Elementary school; Age (Mean (SD)): 10.1 (0.5) y; Female: 52%; Race/ethnicity: NR; SES: Parental education: ≤ 6y: 20%, 6-9 y: 49%, >9 y: 31% | Int: Salt reduction education with at home component (N=139; Cluster N=14); Comp: Usual health education with no content on salt (N=135; Cluster N=14); Theory/framework: NR; Intervention duration: 3.5 mo; Outcome measurement: Intake estimated with two consecutive 24-h urine samples were collected at baseline and post-intervention, and an ion selective electrode method was used for sodium analysis. For each time point, the average of the 2 measurements was used in analyses. | Change in salt intake from baseline to post-intervention (g/d), Mean (95% CI); Int: −0.7 (−1.2, −.02), Comp: 1.2 (0.7, 1.7); Difference in change, Int vs Comp (ref): −1.9 (−2.6, −1.3), p<0.001 ↑; Model adjustments: School location; class size; age (child and adults), sex; BMI; indoor/outdoor temperature; participants nested within family and family nested within school (random effects); Funding source(s): UK Medical Research Council
Hermans, 2018 ^104^; The Netherlands, RCT-Parallel; Total Baseline N: 118; Total Analytic N: 108; Criteria for exclusion from analysis: Absent, did not complete knowledge test, technical issues; Grade level: Elementary school; Age (Mean): ~11.4 y; Female: ~46%; Race/ethnicity: NR; SES: NR | Int: Virtual reality videogame (Alien Health Game) designed to increase children’s nutritional knowledge (N=58); Comp: Web-based nutrition game (Super Shopper) not explicitly designed to teach children about nutrition and healthy food choices (N=50); Theory/framework: Situated and embodied cognition; Intervention duration: 2 d; Outcome measurement: Under the pretext of a taste test, all children were given the opportunity to eat from an assortment of foods, either energy dense or nutrient dense; the energy-dense foods were salted potato crisps and chocolate candies; the nutrient-dense foods were green grapes and cucumber slices; the food was weighed before and after each test, conducted immediately after the second play session and at 2-wk follow-up | Intake at post-intervention and 2-wk follow-up, effect size*; [underlined: Nutrient-dense food]; Int vs Comp: 0.004, p=0.999; Group by time interaction: 0.002, p=0.999; [underlined: Energy-dense food]; Int vs Comp: 0.011, p=0.999.; Group by time interaction: <0.001, p=0.999; *All other results presented graphically; Model adjustments: None; Funding source(s): Grant of the Province of Limburg, The Netherlands
Jamelske, 2018 ^66^; United States (Wisconsin), RCT-Cluster; Total Baseline N: 218; Total Analytic N: 218; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean (SD)): 7.2 (1.2) y; Female: 45.9%; Race/ethnicity: White: 97.2% ; Black: 2.3% ; Asian/Pacific Islander: 0.5%; SES: Eligible for free/reduced price lunch: 28.9% | Int1: Moderate teacher encouragement to eat vegetable snack (N=73; Cluster N=4); Int2: High teacher encouragement to eat vegetable snack (N=72; Cluster N=4); Comp: No teacher encouragement (N=73; Cluster N=4); Theory/framework: NR; Intervention duration: 8 wk; Outcome measurement: Proportion consumed calculated as (pre – post weight)/(pre – cup weight) yielding an intake measure ranging from 0.00 to 1.00 for each student for each day; data analyzed for the first serving and the seventh and eighth serving (post-intervention) | Proportion of grape tomato consumed, Mean; [underlined: First svg]: Int1: 0.407, Int2: 0.563, Comp: 0.265; Int1 vs Comp: p=0.05 ↑; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.05 ↑; [underlined: 7th svg]: Int1: 0.306, Int2: 0.502, Comp: 0.173; Int1 vs Comp: p=0.06; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.01 ↑; [underlined: 8th svg]: Int1: 0.291, Int2: 0.506, Comp: 0.184; Int1 vs Comp: p=0.12; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p<0.01 ↑; Proportion of baby carrots consumed, Mean; [underlined: First svg]: Int1: 0.725, Int2: 0.845, Comp: 0.618; Int1 vs Comp: p=0.12; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.05 ↑; [underlined: 7th svg]: Int1: 0.569, Int2: 0.787, Comp: 0.543; Int1 vs Comp: p=0.73; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p<0.01 ↑; [underlined: 8th svg]: Int1: 0.556, Int2: 0.800, Comp: 0.590; Int1 vs Comp: p=0.67; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p<0.01 ↑; Proportion of green pepper strip consumed, Mean; [underlined: First svg]: Int1: 0.490, Int2: 0.507, Comp: 0.274; Int1 vs Comp: p<0.01 ↑; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.83; [underlined: 7th svg]: Int1: 0.386, Int2: 0.514, Comp: 0.305; Int1 vs Comp: p=0.28; Int2 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.11; [underlined: 8th svg]: Int1: 0.401, Int2: 0.443, Comp: 0.288; Int1 vs Comp: p=0.14; Int2 vs Comp: p=0.05 ↑; Int1 vs Int2:p=0.61; Model adjustments: None; Funding source(s): University of Wisconsin-Eau Claire
James, 2004,^67^ Christchurch Obesity Prevention Project in Schools (CHOPPS); United Kingdom, RCT-Cluster; Total Baseline N: 644; Total Analytic N: 235; Total Baseline Cluster N: 29; Total Analytic Cluster N: 29; Criteria for exclusion from analysis: Absent, refused, moved school, did not return diet diary; Grade level: Elementary school; Age (Mean (SD)): 8.7 (0.9) y; Female: ~50%; Race/ethnicity: NR; SES: NR | Int: Nutrition education program focused on reduction of “fizzy” drinks (sweetened and unsweetened) and encouragement of balanced diet delivered by study staff over 4 sessions with assistance from teachers (N=NR; Cluster N=15); Comp: No intervention (N=NR; Cluster N=14); Theory/framework: NR; Intervention duration: 1 academic y; Outcome measurement: Beverage intake measured with diet diaries (2 weekdays, 1 weekend day) completed by the child at baseline and post-intervention | Intake at baseline and post-intervention and change in intake (glasses/3d), Mean (SD), Mean change (95% CI), and Difference in change (95% CI); [underlined: Total carbonated drinks]; Int: Baseline: 1.9 (0.5), Post-intervention: 1.3 (0.6), Change: −0.6 (−1.0, −0.1); Comp: Baseline: 1.6 (0.6), Post-intervention: 1.8 (0.6), Change: 0.2 (−0.2, 0.5); Difference in change, Int (ref) vs Comp: 0.7 (0.1, 1.3), p=NR ↑; [underlined: Carbonated drinks with sugar]; Int: Baseline: 1.2 (0.3), Post-intervention: 0.9 (0.6), Change: −0.3 (−0.6, 0.1); Comp: Baseline: 1.1 (0.6), Post-intervention: 1.2 (0.5), Change: 0.0 (−0.3, 0.4); Difference in change, Int (ref) vs Comp: 0.1 (−0.4, 0.5), p=NR; [underlined: Diet carbonated drinks]; Int: Baseline: 0.7 (0.3), Post-intervention: 0.4 (0.2), Change: −0.3 (−0.6, −0.1); Comp: Baseline: 0.4 (0.3), Post-intervention: 0.6 (0.3), Change: 0.1 (−0.1, 0.4); Difference in change, Int (ref) vs Comp: 0.6 (0.2, 1.1), p=NR ↑; [underlined: Carbonated drinks with caffeine]; Int: Baseline: 0.8 (0.3), Post-intervention: 0.6 (0.3), Change: −0.2 (−0.4, 0.1); Comp: Baseline: 0.7 (0.4), Post-intervention: 0.6 (0.5), Change: −0.1 (−0.3, 0.1); Difference in change, Int (ref) vs Comp: −0.0 (−0.4, 0.3), p=NR; Note: Analyses conducted on mean values within clusters; Model adjustments: Intracluster correlation; cluster size; Funding source(s): GlaxoSmithKline, Aventis, Pfizer, Bournemouth Diabetes and Endocrine Centre
Katz, 2011 ^68^; United States (Independence, Missouri), RCT-Cluster; Total Baseline N: 778; Total Analytic N: 305; Total Baseline Cluster N: 5; Total Analytic Cluster N: 5; Criteria for exclusion from analysis: Student non-compliance; Grade level: Elementary school; Age: ~26% 7y, ~32% 8y, ~42% 9y; Female: ~51%; Race/ethnicity: NR; SES: NR | Int: Nutrition Detectives nutrition education program focused on selection of healthful foods provided over four 20-minute sessions; a booster session was provided 3 months after initial program (N=136; Cluster N=3); Comp: No intervention (N=169; Cluster N=2); Theory/framework: NR; Intervention duration: 1 mo; Outcome measurement: Intake assessed with Youth and Adolescent Questionnaire filled out at home with assistance from parents/guardians at baseline and post-booster | Change in intake from baseline to post-booster, Mean (SD); [underlined: Saturated fat (g)]: Int: −0.6 (9.4), Comp: −0.9 (9.0), p=0.25; [underlined: Fiber (g)]: Int: 0.2 (5.9), Comp: 0.7 (5.8), p=0.43; [underlined: Sodium (mg)]: Int: −92.8 (765.2), Comp: −17.3 (891.9), p=0.44; Model adjustments: None; Funding source(s): NR
Kaufman-Shriqui, 2016 ^69^; Israel, RCT-Cluster; Total Baseline N: 238; Total Analytic N: 231; Total Baseline Cluster N: 11; Total Analytic Cluster N: 11; Criteria for exclusion from analysis: Did not complete questionnaires, moved, inability to arrange a meeting; Grade level: Elementary school; Age (Mean (SD)): 5.3 (0.5) y; Female: 52.5%; Race/ethnicity: NR; SES: Below poverty line: 32.2% | Int: Nutrition education intervention (Ten weekly 45 minute sessions) emphasizing healthy affordable nutrition using traditional and ethnically accepted diverse nutritional recommendations delivered by a dietitian, weekly newsletters, and 3 nutrition focused meetings for parents, and standard physical activity classes (N=165; Cluster N=7); Comp: Standard physical activity classes with no nutrition intervention (N=66; Cluster N=4); Theory/framework: Ecological model; Intervention duration: 3 mo; Outcome measurement: Intake assessed with questions selected from an FFQ completed by mothers at baseline, post-intervention, and 3-mo follow-up. Quality of packed lunch assessed by study personnel every two weeks on random, non-intervention days following the Choices Food Profiling criteria (scores 0-5). | Nutritional Habit, Percent and Percent Change*; [underlined: Eating a variety of foods]; Baseline: Int: 54.1% vs Comp: 48.5%, p=0.45; Post-intervention: Int: 80.6%, Comp: 56.1%; Percent change from baseline to post-intervention: Int: 48.9% vs Comp: 15.6%, p<0.001 ↑; 3-mo follow-up: Int: 79.4%, Comp: 56.6%; Percent change from baseline to 3-mo follow-up: Int: 46.7% vs Comp: 16.8%, p<0.001 ↑; [underlined: Daily fruit and vegetable consumption]; Baseline: Int: 56.5% vs Comp: 52.9%, p=0.41; Post-intervention: Int: 81.2%, Comp: 62.1%; Percent change from baseline to post-intervention: Int: 43.7% vs Comp: 17.4%, p=0.001 ↑; 3-mo follow-up: Int: 78.8%, Comp: 61.7%; Percent change from baseline to 3-mo follow-up: Int: 39.4% vs Comp: 16.5%, p=0.001 ↑; [underlined: Daily sweets and candy consumption]; Baseline: Int: 53.5% vs Comp: 48.5%, p=0.23; Post-intervention: Int: 35.8%, Comp: 30.3%; Percent change from baseline to post-intervention: Int: −33.2% vs Comp: −37.5%, p=0.08; 3-mo follow-up: Int: 30.6%, Comp: 33.3%; Percent change from baseline to 3-mo follow-up: Int: −42.8% vs Comp: −31.3%, p=0.13; [underlined: Daily sugar-sweetened beverage consumption]; Baseline: Int: 46.5% vs Comp: 50.0%, p=0.70; Post-intervention: Int: 27.3%, Comp: 36.4%; Percent change from baseline to post-intervention: Int: −41.3% vs Comp: −27.2%, p=0.02 ↑; 3-mo follow-up: Int: 31.2%, Comp: 41.7%; Percent change from baseline to 3-mo follow-up: Int: −32.8% vs Comp: −16.6%, p<0.05 ↑; *Percent change in percent of students; Change in quality of packed lunch over time, Mean change (SD) and percent change; Int: 1.16 (0.16), 120% vs Comp: 0.41 (0.18), 42%; p<0.0001 ↑; Model adjustments: School cluster (analyses of quality of packed lunch only); Funding source(s): S&P Foundation; The S. Daniel Abraham International Center for Health and Nutrition; The Israel National Institute for Health Policy Research
LaChausse, 2017 ^70^; United States (San Bernadino County, California), RCT-Cluster; Total Baseline N: 406; Total Analytic N: 275; Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: Did not complete post-test survey, other reasons NR; Grade level: Elementary school; Age (Mean): ~9.8 y; Female: ~54%; Race/ethnicity: White: ~19%; Black: ~13%; Asian: ~2%; Hispanic: ~56%; Native American: ~3%; Multi-racial: ~7%; Other: 13%; SES: Low-income school (based on % eligible free/reduced price lunch): 100% | Int: Harvest of the Month nutrition education program delivered during an after-school program (N=127; Cluster N=14); Comp: No intervention (N=148; Cluster N=14); Theory/framework: None; Intervention duration: 4 mo; Outcome measurement: Previous day intake assessed with self-administered Youth Network Survey, based on the School and Physical Activity Nutrition Survey, with data collector assistance at 2-wk pre-intervention and 3-mo follow-up. | Previous day intake (number of times consumed) assessed at 3-mo follow-up, Mean (SD); [underlined: Fruit]: Int: 1.9 (1.5), Comp: 1.7 (1.6), p=0.38; [underlined: Vegetables]: Int: 1.5 (1.5), Comp: 1.5 (1.5), p=0.47; [underlined: Cheese]: Int: 0.65 (0.77), Comp: 0.72 (0.83), p=0.95; [underlined: Milk]: Int: 1.5 (0.96), Comp: 1.2 (0.98), p=0.10; [underlined: Yogurt]: Int: 0.48 (0.75), Comp: 0.38 (0.64), p=0.33; [underlined: Cerea]l: Int: 0.77 (0.82), Comp: 0.72 (0.86), p=0.74; [underlined: French Fries]: Int: 0.88 (0.93), Comp: 0.79 (0.85), p=0.25; [underlined: Sports Drinks]: Int: 1.2 (1.0), Comp: 1.1 (0.92), p=0.82; [underlined: Fruit Juice]: Int: 1.4 (1.3), Comp: 1.1 (1.2), p=0.19; [underlined: Soda]: Int: 0.67 (0.83), Comp: 0.53 (0.83), p=0.19; [underlined: Sweets]: 0.74 (0.98), Comp: 0.71 (0.93), p=0.72; Model adjustments: Pre-intervention intake; ethnicity (Hispanic/non-Hispanic); Funding source(s): USDA Supplemental Nutrition Assistance Program Education through California Department of Public Health, Network for a Healthy California
Larsen, 2015 ^71^; United States (California), RCT-Cluster; Total Baseline N: 1,713; Total Analytic N: 921 at post-intervention, 931 at follow-up; Total Baseline Cluster N: 47; Total Analytic Cluster N: 47; Criteria for exclusion from analysis: Did not complete pre-intervention assessment, did not complete post-intervention and/or follow-up assessment; Grade level: Elementary school; Age (Mean (SD)): 9.00 (0.43) y; Female: 48%; Race/ethnicity: White: 32%; Black: 8%; Asian: 15%; Hispanic: 38%; SES: Enrolled in free/reduced price lunch program: 47% | Int: Nutrition Pathfinders 7 lesson nutrition education program delivered by classroom teachers (N=543 at post-intervention, N=532 at follow-up; Cluster N=27); Comp: No intervention (N=378 at post-intervention, N=399 at follow-up; Cluster N=20); Theory/framework: HBM; SCT; Intervention duration: 10 wk; Outcome measurement: Previous day’s intake assessed with modified version of the elementary-level, 22-item School Physical Activity and Nutrition Questionnaire (SPAN) completed by the child at pre-intervention, post-intervention, and 3-mo follow-up | Pre-intervention intake (Mean (SD)) and change to post-intervention and 3-mo follow-up, Mean change (SD) and adjusted difference in change (Comp (ref)); [underlined: Low-nutrient/high-density foods]:; Pre: Int: 3.48 (2.95), Comp: 3.78 (3.45); Change to Post: Int: −0.40 (2.76), Comp: −0.08 (2.63); Difference: −0.338, p<0.05 ↑; Change to Follow-up: Int: −0.33 (3.01), Comp: −0.25 (3.07); Difference: −0.245, p=NS; [underlined: Sugar-sweetened beverages]:; Pre: Int: 1.35 (1.43), Comp: 1.45 (1.57); Change to Post: Int: −0.31 (1.36), Comp: −0.13 (1.35); Difference: −0.164, p<0.05 ↑; Change to Follow-up: Int: −0.21 (1.52), Comp: −0.18 (1.47); Difference: −0.054, p=NS; [underlined: Protein foods (meats, eggs, peanut butter, fish, beans)]:; Pre: Int: 2.59 (1.87), Comp: 2.83 (2.17); Change to Post: Int: 0.28 (2.14), Comp: −0.15 (2.07); Difference: 0.299, p<0.10; Change to Follow-up: Int: −1.55 (2.03) (Note: potential error in reporting), Comp: −0.25 (2.39); Difference: 0.322, p<0.05 ↑; [underlined: Dairy]:; Pre: Int: 4.44 (1.91), Comp: 4.31 (1.94); Change to Post: Int: 0.07 (2.33), Comp: 0.02 (1.97); Difference: 0.028, p=NS; Change to Follow-up: Int: −1.55 (2.03), Comp: −1.32 (2.01); Difference: −0.112, p=NS; [underlined: Grains (cereal, pasta, white bread, dark bread)]:; Pre: Int: 2.75 (1.81), Comp: 2.69 (1.93); Change to Post: Int: 0.15 (2.13), Comp: −0.10 (2.11); Difference: 0.238, p=NS; Change to Follow-up: Int: 0.07 (2.16), Comp: −0.29 (1.98); Difference: 0.401, p<0.01 ↑; [underlined: White Bread]:; Pre: Int: 0.93 (0.88), Comp: 0.88 (0.92); Change to Post: Int: 0.15 (1.14), Comp: 0.01 (1.12); Difference: 0.130, p<0.10; Change to Follow-up: Int: 0.17 (1.18), Comp: −0.05 (1.14); Difference: 0.206, p<0.01 ↓; [underlined: Dark Bread]:; Pre: Int: 0.57 (0.78), Comp: 0.56 (0.75); Change to Post: Int: 0.05 (0.98), Comp: 0.02 (0.99); Difference: 0.014, p=NS; Change to Follow-up: Int: 0.05 (1.03), Comp: −0.02 (0.93); Difference: 0.091, p<0.10; [underlined: Vegetables]:; Pre: Int: 1.20 (1.05), Comp: 1.53 (1.07); Change to Post: Int: 0.01 (1.12), Comp: −0.01 (1.08); Difference: 0.046, p=NS; Change to Follow-up: Int: −0.04 (1.21), Comp: −0.10 (1.19); Difference: 0.101, p=NS; [underlined: Fruit/Fruit Juice]:; Pre: Int: 2.36 (1.66), Comp: 2.53 (1.71); Change to Post: Int: −0.01 (1.60), Comp: −0.20 (1.67); Difference: 0.154, p=NS; Change to Follow-up: Int: −0.05 (1.74), Comp: −0.35 (1.79); Difference: 0.243, p<0.10; [underlined: Healthy Foods (milk, vegetables, fruit, 100% fruit juice)]:; Change to Post: Difference: 0.137, p=NS; Change to Follow-up: difference: 0.229, p<0.10; Model adjustments: Sex; pre-intervention intake; school-level SES; clustering of students within classrooms; Funding source(s): Dairy Council of California, American Cancer Society
Lehto, 2014,^72^ PRO GREENS Project; Finland, RCT-Cluster; Total Baseline N: 934; Total Analytic N: 727; Total Baseline Cluster N: 19; Total Analytic Cluster N: 19; Criteria for exclusion from analysis: Class did not return implementation questionnaire; Grade level: Elementary school; Age (Mean): ~11.4 y; Female: ~49%; Race/ethnicity: NR; SES: NR | Int1: High degree of implementation of a nutrition education intervention, including taste tests (N=173; Cluster N=NR); Int2: Low degree of implementation of a nutrition education intervention, including taste tests (N=130; Cluster N=NR); Comp: No intervention (N=424; Cluster N=10); Theory/framework: Intervention mapping method; Intervention duration: 8 mo; Outcome measurement: Fruit and vegetable intake measured using validated FFQ at baseline and 1 y after baseline | Change in intake (x/wk), Mean Difference (95% CI); [underlined: Fruit]:; Int1 vs Comp (ref): 1.89 (0.26, 3.52), p<0.05 ↑; Int2 vs Comp (ref): 0.64 (−0.43, 1.71), p=NS; [underlined: Vegetables]:; Int1 vs Comp (ref): −0.07 (−2.03, 1.90), p=NS; Int2 vs Comp (ref): 0.65 (−0.87, 2.17), p=NS; Model adjustments: Age; sex; baseline fruit and vegetable intake; Funding source(s): European Commission’s Programme of Community Action in the Field of Public Health 2003–8, Juho Vainio Foundation
Leung, 2014 ^105^; United States (Brooklyn [Crown Heights and East New York], New York), RCT-Parallel; Total Baseline N: 59; Total Analytic N: 59; Grade level: Elementary and Middle/Junior high school; Age (Mean (Range)): ~11 y (8.3-15.5 y); Female: 54%; Race/ethnicity: White: ~2%; Black: ~74%; Hispanic: 17%; Other/Mixed: ~7%; SES: Eligible for free lunch (school level data): ~88% | Int: Manga comic promoting the intake and benefits of fruit read by child at an after-school program (N=31); Comp: Attention-control (non-health related newsletter and word search) (N=28); Theory/framework: SCT; Transportation-Imagery Model; Intervention duration: 60 min; Outcome measurement: Snack selection assessed by direct observation of student choice of 1 of 8 items (4 pre-portioned fresh fruit options, 4 energy-dense snacks in original packaging) immediately following reading of comic/attention-control materials | Selection of fruit as snack, % and OR (95% CI); Int: 61%, Comp (ref): 35%; OR: 3.63 (1.09, 12.1), p=0.04 ↑; Model adjustments: Age; sex; previous week fruit and vegetable consumption; Funding source(s): Professional Staff Congress-City University of New York Award
Llauradó, 2014,^73^ Educació en Alimentació (EdAl-2); Spain, RCT-Cluster; Total Baseline N: 916; Total Analytic N: 690; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Missing height/weight measurement for 1st or 3rd year of study, no parental consent; Grade level: Elementary school; Age (Mean): ~8 y; Female: ~48%; Race/ethnicity: Western European: ~78%; Eastern European: ~9%; Latin American: ~7%; North African Arab: ~6%; SES: NR | Int: Educació en Alimentació (EdAl) nutrition education program, consisting of classroom practice, teaching practice, and parental activity components, delivered by university student health promoter agents in twelve 1-h sessions over 22 months. (N=320; Cluster N=1); Comp: No intervention (N=370; Cluster N=1); Theory/framework: NR; Intervention duration: 22 mo (3 academic y); Outcome measurement: Intake habits assessed with Krece Plus Questionnaire and Avall Questionnaire completed by parents at baseline and post-intervention. | Intake at post-intervention (Krece Plus Questionnaire), %; [underlined: Dairy product at breakfast]: Int: 93.5%, Comp: 91.1%, p=0.574; [underlined: Cereals at breakfast]: Int: 58.2%, Comp: 57.1%, p=0.225; Girls: Int: 49.6%, Comp: 60.0%, p=0.031 ↓; Boys: Int: 66.4%, Comp: 54.6%, p=0.706; [underlined: Pastry at breakfast]: Int: 19.6%, Comp: 12.3%, p=0.002; Girls: Int: 15.5%, Comp: 12.4%, p=0.260; Boys: Int: 23.5%, Comp: 12.3%, p=0.002 ↓; [underlined: Daily fruit or natural juice]: Int: 73.1%, Comp: 74.8%, p=0.472; [underlined: Fruit, second/d]: Int: 44.3%, Comp: 36.5%, p<0.001 ↑; Girls: Int: 47.5%, Comp: 39.0%, p<0.001 ↑; Boys: Int: 41.2%, Comp: 34.1%, p=0.141; [underlined: Dairy product, second/d]: Int: 79.2%, Comp: 72.3%, p=0.384; [underlined: Vegetables, daily]: Int: 75.9%, Comp: 67.3%, p=0.028 ↑; Girls: Int: 77.5%, Comp: 63.3%, p=0.017 ↑; Boys: Int: 74.4%, Comp: 70.8%, p=0.473; [underlined: Vegetables, >1/d]: Int: 31.8%, Comp: 21.8%, p=0.001 ↑; Girls: Int: 34.5%, Comp: 23.1%, p=0.149; Boys: Int: 29.1%, Comp: 20.7%, p=0.001 ↑; [underlined: Fish, regularly]: Int: 74.1%, Comp: 70.6%, p=0.312; [underlined: Fast food, >1/wk]: Int: 8.8%, Comp: 3.9%, p=0.003 ↓; Girls: Int: 10.1%, Comp: 2.8%, p=0.013 ↓; Boys: Int: 7.4%, Comp: 4.9%, p=0.106; [underlined: Legumes, >1/wk]: Int: 72.2%, Comp: 70.7%, p=0.027 ↑; Girls: Int: 73.3%, Comp: 76.2%, p=0.013 ↓; Boys: Int: 71.1%, Comp: 65.9%, p=0.555; [underlined: Candy, >1/wk]: Int: 12.3%, Comp: 14.9%, p=0.479; [underlined: Pasta or rice daily]: Int: 66.1%, Comp: 68.6%, p=1; Intake at post-intervention (AVall Questionnaire), %; Before leaving home; [underlined: Dairy products]: Int: 87.6%, Comp: 81.1%, p=0.836; [underlined: Pastry]: Int: 2%, Comp: 0.7%, p=0.606; [underlined: Cereals]: Int: 31.6%, Comp: 30.9%, p=0.409; [underlined: Fresh fruit or natural juice]: Int: 24.6%, Comp: 22.3%, p=0.256; [underlined: Sandwich]: Int: 18.7%, Comp: 19.8%, p=0.889; [underlined: Juice package/soft drinks]: Int: 6.2%, Comp: 8.9%, p=0.483; Break (midmorning); [underlined: Dairy products]: Int: 15%, Comp: 11.6%, p=0.488; [underlined: Pastry]: Int: 0.9%, Comp: 2.2%, p=1; [underlined: Cereals]: Int: 4.7%, Comp: 5.9%, p=0.659; [underlined: Fresh fruit or natural juice]: Int: 13.4%, Comp: 17.2%, p=0.721; [underlined: Sandwich]: Int: 35.7%, Comp: 41.4%, p=0.299; [underlined: Juice package/soft drinks]: Int: 7.7%, Comp: 12.9%, p=0.543; Similar results seen when girls and boys analyzed separately unless otherwise noted.; Model adjustments: None; Funding source(s): Diputació de Tarragona 2011, Ajuntament d’Amposta provided foods to develop activities in school
Mangunkusumo, 2007 ^74^; The Netherlands, RCT-Cluster; Total Baseline N: 495; Total Analytic N: 486; Total Baseline Cluster N: 30; Total Analytic Cluster N: 30; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 10.3 y; Female: ~53%; Race/ethnicity: ~86% Dutch background (both parents born in the Netherlands); SES: NR | Int: Combination of Internet-tailored nutrition advice for the children followed by Internet-supported 5-min dietary counselling by the nurse in the presence of at least 1 parent. (N=263; Cluster N=16); Comp: No intervention (N=223; Cluster N=14); Theory/framework: Behavioral change theory; Intervention duration: 2 wk; Outcome measurement: Fruit intake during the previous week assessed with questions adapted from a validated FFQ. Vegetable intake during the previous assessed with pre-coded 24-h recall. Usual daily intake of fruit and vegetables assessed with two questions. Assessment conducted at baseline and 3-mo follow-up | Intake at 3-mo follow-up, β or OR (95% CI); [underlined: Fruit intake (svg/d), Mean (SD)]:; Int: 1.1 (0.7) vs Comp (ref): 1.2 (0.7); β: −0.05 (–0.16, 0.06); [underlined: Usual daily fruit intake (%)]:; Int: 32.0% vs Comp (ref): 34.7%; OR: 0.82 (0.45, 1.49); [underlined: Vegetable intake (g), Mean (SD)]:; Int: 76.9 (68.7) vs Comp (ref): 74.9 (69.7); β: 3.55 (–7.90, 15.00); [underlined: Usual daily vegetable intake (%)]:; Int: 28.1% vs Comp (ref): 28.7%; OR: 0.81 (0.44, 1.47); Model adjustments: Region; gender; age; baseline measure; random intercept for nurse and class level; Funding source(s): The Netherlands Organization for Health Research and Development
Panunzio, 2007,^75^ Porta la frutta a scuola (“Bring some fruit to school”); Italy, RCT-Cluster; Total Baseline N: 521; Total Analytic N: 471; Total Baseline Cluster N: 20; Total Analytic Cluster N: 20; Criteria for exclusion from analysis: Did not “complete study”; Grade level: Elementary school; Age (Mean): ~9.6 y; Female: ~53%; Race/ethnicity: NR; SES: NR | Int: Nutrition education delivered by nutritionists in the classroom for first 24 wk (2h/wk), including 12 wk with interactive activities; no meetings during the last 12 wk (N=243; Cluster N=10); Comp: Nutrition education (last 12 wk), integrated into all subjects and including interactive activities, delivered by teachers who received training (2h/wk for first 24 wk) by nutritionists (N=228; Cluster N=10); Theory/framework: NR; Intervention duration: 36 wk; Outcome measurement: Intake assessed with daily dietary diary collected daily in the classroom for 36 wk. Food group frequencies calculated for each 12-wk period (period 1, 2, and 3) | Difference in change in % of participants with intake >1 portion/d (>1 portion/wk for legumes) between study periods 1, 2, and 3 (Int vs Comp [Ref]), Difference (95% CI) and OR (95% CI); [underlined: Period 2 vs Period 1]; Fruit: Difference: 1.6 (1.1, 2.7); OR: 1.1 (0.4, 2.1), p=NS; Vegetables: Difference: 1.8 (1.7, 3.2); OR: 1.2 (0.6, 1.9), p=NS; Legumes: Difference: 1.6 (1.1, 4.1); OR: 1.9 (0.7, 2.6), p=NS; Chips: Difference: −2.5 (−3.8, −0.8); OR: 0.8 (0.6, 1.8), p=NS; Sugar-sweetened drink: Difference: −1.9 (−2.7, −0.5); OR: 0.7 (0.6, 3.1), p=NS; [underlined: Period 3 vs Period 1]; Fruit: Difference: 3.9 (0.3, 5.8); OR: 1.9 (0.9, 2.6), p=NS; Vegetables: Difference: 2.1 (0.5, 4.7); OR: 1.3 (0.7, 2.3), p=NS; Legumes: Difference: 7.1 (1.1, 14.9); OR: 1.2 (0.8, 1.9), p=NS; Chips: Difference: −5.2 (−15.5, −0.8); OR: 0.7 (0.5, 2.7), p=NS; Sugar-sweetened drink: Difference: 1.1 (0.1, 4.7); OR: 1.2 (0.6, 2.5), p=NS; [underlined: Period 3 vs Period 2]; Fruit: Difference: −19.7 (−28.8, −11.5); OR: 0.4 (0.2, 0.7), p<0.0001 ↔; Vegetables: Difference: −37.9 (−49.1, −28.6); OR: 0.7 (0.3, 0.8),p<0.0001 ↔; Legumes: Difference: −33.0 (−41.7, −19.9); OR: 0.6 (0.4, 0.8), p<0.0001 ↔; Chips: Difference: 25.5 (19.3, 42.1); OR: 2.5 (1.6, 3.3), p<0.0001 ↔; Sugar-sweetened drink: Difference: 29.4 (16.6, 35.8); OR: 2.2 (1.8, 3.5), p<0.0001 ↔; Model adjustments: None; Funding source(s): NR
Panunzio, 2011 ^76^; Italy, RCT-Cluster; Total Baseline N: 813; Total Analytic N: 804; Total Baseline Cluster N: 32; Total Analytic Cluster N: 32; Criteria for exclusion from analysis: Did not “complete study”; Grade level: Elementary school; Age (Mean (SD)): 9.0 (0.5) y; Female: ~53%; Race/ethnicity: NR; SES: Maternal education: Middle school or below: ~51%, High school: ~39%, University: ~10% | Int: Nutrition education integrated into multiple subjects, including interactive activities, and delivered by teachers who received training from nutritionists. Parents also received education and were asked to meet with children to discuss topics. (N=409; Cluster N=16); Comp: Nutrition education integrated into multiple subjects, including interactive activities, and delivered by teachers who did self-training. Parents also received education from teachers and were asked to meet with children to discuss topics. (N=395; Cluster N=16); Theory/framework: NR; Intervention duration: 15 wk; Outcome measurement: Intake assessed with daily dietary diary completed for 15 wk by children in the classroom on weekdays under teacher supervision, and at home on weekends with parental help. Food group frequencies calculated for each 5-wk period (period 1, 2, and 3). | Difference in change in % of participants with intake ≥2 portion/d between study periods 1, 2, and 3 (Int vs Comp [Ref]), Difference (95% CI) and OR (95% CI); [underlined: Period 2 vs Period 1]; Fruit: Difference: 11.3 (9.2, 16.1); OR: 1.6 (0.3, 8.9), p=NS; Vegetables: Difference: 14.3 (10.6, 20.2); OR: 1.8 (0.4, 7.2), p=NS; [underlined: Period 3 vs Period 1]; Fruit: Difference: 24.2 (16.7, 32.9); OR: 2.0 (1.7, 5.4), p<0.0001 ↑; Vegetables: Difference: 19.1 (9.1, 26.6); OR: 1.9 (1.8, 3.0), p<0.0001 ↑; [underlined: Period 3 vs Period 2]; Fruit: Difference: 11.3 (9.4, 24.5); OR: 1.2 (1.1, 6.2), p<0.0001 ↑; Vegetables: Difference: 8.3 (15.3, 19.7); OR: 1.1 (1.1, 2.6), p<0.0001 ↑; Number of participants by grade with intake ≥2 portion/d during study periods 2 and 3, Mean (SD); [underlined: 2nd grade] (Int: N=88, Comp: N=94); Period 2, Fruit: Int: 35.0 (10.1), Comp: 21.3 (9.5), p<0.0001 ↑; Period 2, Vegetables: Int: 15.9 (7.2), Comp: 11.9 (9.9), p<0.0001 ↑; Period 3, Fruit: Int: 42.9 (12.5), Comp: 38.4 (19), p=0.053; Period 3, Vegetables: Int: 18.5 (4.9), Comp: 13.8 (2.8), p<0.0001 ↑; [underlined: 3rd grade] (Int: N=104, Comp: N=94); Period 2, Fruit: Int: 39.4 (2.1), Comp: 17.7 (4.7), p<0.0001 ↑; Period 2, Vegetables: Int: 30.6 (4.9), Comp: 11.5 (2.8), p<0.0001 ↑; Period 3, Fruit: 47.7 (16.4), Comp: 42.9 (18.8), p=0.056; Period 3, Vegetables: Int: 33.8 (8.7), Comp: 16.5 (9.1), p<0.0001 ↑; [underlined: 4th grade] (Int: N=104, Comp: N=102); Period 2, Fruit: Int: 41.1 (10.8), Comp: 20.5 (8.1), p<0.0001 ↑; Period 2, Vegetables: Int: 26.3 (9.5), Comp: 18.3 (10.4), p<0.0001 ↑; Period 3, Fruit: Int: 50.9 (10.2), Comp: 24.7 (9.5), p<0.0001 ↑; Period 3, Vegetables: Int: 30.4 (7.2), Comp: 21.8 (12.1), p<0.0001 ↑; [underlined: 5th grade] (Int: N=113, Comp: N=105); Period 2, Fruit: 50.7 (14.8), Comp: 20.5 (9.9), p<0.0001 ↑; Period 2, Vegetables: 37.9 (10.7), Comp: 13.9 (8.1), p<0.0001 ↑; Period 3, Fruit: 59.3 (12.7), Comp: 22.6 (8.5), p<0.0001 ↑; Period 3, Vegetables: 40.9 (10.6), Comp: 17.7 (9.8), p<0.0001 ↑; Model adjustments: None; Funding source(s): NR
Perikkou, 2013 ^77^; Cyprus, RCT-Cluster; Total Baseline N: 218; Total Analytic N: 184; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Available nutrition data not provided; Grade level: Elementary school; Age (Mean): ~9 y; Female: 54%; Race/ethnicity: Cypriot: 100%; SES: Parental years of schooling: ~13y | Int1: Nutrition education, 15 min lessons once/week for one school year (N=59; Cluster N=2); Int2: Exposure to teacher role modeling healthy eating at least 3x/wk for one school year (N=67; Cluster N=2); Comp: No intervention (N=58; Cluster N=2); Theory/framework: SCT; Intervention duration: 1 academic y; Outcome measurement: Intake assessed using 2d food record completed by parents on 2 consecutive weekdays at baseline, immediately post-intervention, and 1-y follow-up | Fruit intake at post-intervention (svg/d); Int1 > Comp, p<0.001 ↑; Int2 > Comp, p<0.001 ↑; Int1 vs Int2, p=NS; Fruit intake at 1-y follow-up (svg/d); Int1 > Comp, p<0.08; Int2 > Comp, p<0.001 ↑; Int2 > Int1, p<0.001 ↑; Group: p<0.001; Group by Time interaction: p<0.001 ↑; Model adjustments: Child BMI; maternal and paternal education; Funding source(s): Harokopio University - Department of Nutrition and Dietetics Graduate Program
Perry, 2002 ^78^; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: NR; Total Analytic N: 1,927; Total Baseline Cluster N: 20; Total Analytic Cluster N: 20; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 9.6 y; Female: ~50%; Race/ethnicity: White: 47%; Black: 18%; Asian: 14%; Native American: 5%; Hispanic: 5%; Other: 11%; SES: NR | Int: “All’s Well That Eats Well” educational theater production with follow-up classroom and home activities related to fruit and vegetable consumption (N=NR; Cluster N=10); Comp: Delayed intervention (N=NR; Cluster N=10); Theory/framework: SCT; Intervention duration: 45 min (play); duration of follow-up activities NR; Outcome measurement: Previous day’s intake assessed with 14 item food recall survey focused on fruits and vegetables, administered to students pre-intervention and 3-wk follow-up | Intake at 3-wk follow-up (Int) vs pre-intervention (Comp), Mean and Mean difference (SE; 95% CI); [underlined: Food Recall Scale]: Int: 5.57, Comp: 5.08; Mean difference: 0.50 (0.26; −0.03, 1.02), p=0.061; Model adjustments: School (random effect); Funding source(s): National Theatre for Children, Health Partners, NIH
Ribeiro-Silva, 2014 ^79^; Brazil, RCT-Cluster; Total Baseline N: 531; Total Analytic N: 202; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: No blood collection at baseline or follow-up; Grade level: Elementary and Middle/Junior high school; Age (Mean (Range)): ~8.2 y (7-14 y); Female: ~52%; Race/ethnicity: NR; SES: Maternal education ≤4th grade: ~23% | Int: Nutrition education, food preparation workshops for teachers and food service staff, and nutrition education workshops for families. (N=142; Cluster N=1); Comp: No intervention (N=60; Cluster N=1); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake assessed via FFQ at baseline and post-intervention | Fruit and vegetable intake frequency, %; [underlined: Baseline]; <75th percentile: Int: 73.1%, Comp: 75.9%; ≥75th percentile: Int: 26.9%, Comp: 24.1%; Int vs Comp: p=0.635; [underlined: Post-intervention]; <75th percentile: Int: 67.9%, Comp: 88.7%; ≥75th percentile: Int: 32.0%, Comp: 11.3%; Int vs Comp: p=0.001 ↑; Model adjustments: None; Funding source(s): Fundação de Amparo à Pesquisa do Estado da Bahia, Programa de Educação para o Trabalho - Projeto Parceria: Educação e Trabalho (PROPET), Ministério da Saúde
Serebrennikov, 2020 ^84^; United States (Midwestern state), RCT-Cluster; Total Baseline N: 135; Total Analytic N: 98; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Missing demographic information, brought lunches from home, absent on data collection days; Grade level: Elementary school; Age (Mean (SE)): 7.9 (0.8) y; Female: ~42.5%; Race/ethnicity: White: ~91%; SES: Parental education ≥ Bachelor’s degree: ~47% | Int: Bi-weekly 15-20 min nutrition education program focused on fruits and vegetables delivered by trained teachers (N=62; Cluster N=5); Comp: No intervention (N=36; Cluster N=5); Theory/framework: HBM; Intervention duration: 6 wk; Outcome measurement: Amount of fruits and vegetables selected, wasted, and consumed at lunch assessed by digital photographs of lunch plates before the start of lunch and at the end of lunch, graded by 3 independent, trained study personnel using the quarter-based method; weights determined based on reference weights of food items; measurements were made bi-weekly and one week was dropped from analysis due to school closure for part of week | Post-intervention selection (g), Mean Difference (SE), Int vs Comp (ref); [underlined: Fruits and vegetables]: 25.678 (30.766), p=NS; Group by time interaction: all p=NS; [underlined: Fruits]: 17.109 (12.212), p=NS; [underlined: Vegetables]: 26.609 (14.985) p<0.10; Post-intervention intake (g), Mean Difference (SE), Int vs Comp (ref); [underlined: Fruits and vegetables]: −0.344 (15.344), p=NS; [underlined: Fruits]: 10.339 (7.539), p=NS; [underlined: Vegetables]: −10.744 (12.176), p=NS; Post-intervention waste (g), Mean Difference (SE), Int vs Comp (ref); [underlined: Fruits and vegetables]: 27.729 (32.881), p=NS; Group by time interaction: all p=NS; [underlined: Fruits]: −16.188 (12.145), p=NS; [underlined: Vegetables]: 24.516 (9.947), p<0.10; Model adjustments: Age; race; gender; parent’s marital status; parent’s education; day; classroom cluster; Funding source(s): Indiana State Department of Health
Sgambato, 2019,^85^ Parents, students, community health agents, and teachers for healthy eating (PAAPPAS); Brazil, RCT-Cluster; Total Baseline N: 2,447; Total Analytic N: 2,276; Total Baseline Cluster N: 18; Total Analytic Cluster N: 18; Criteria for exclusion from analysis: Absent, refusal, left school, pregnant; Grade level: Elementary school; Age (Mean): 11.5 y; Female: 48%; Race/ethnicity: White: ~25%; Black: ~24%; Mixed: ~51%; SES: NR | Int: School- and home-based obesity prevention program encouraging a variety of healthy eating behaviors and physical activity (N=1,164; Cluster N=9); Comp: No intervention (N=1,112; Cluster N=9); Theory/framework: Paulo Freire’s theory; Intervention duration: 6 mo; Outcome measurement: Intake assessed with validated 23-item FFQ at baseline and post-intervention. In a random subsample of 30% of participants, one 24-h food recall was collected at baseline and post-intervention. | Frequency of intake at baseline and post-intervention, Mean and Mean Difference in Change (SD); [underlined: Milk (200 mL svg/d)]: Baseline: Int: 0.47, Comp: 0.48, Post-intervention: Int: 0.51, Comp: 0.50; Int vs Comp (ref): −0.009 (0.53), p=NS; [underlined: Beans (100 g svg/d)]: Baseline: Int: 0.91, Comp: 0.92, Post-intervention: Int: 0.98, Comp: 0.98, Int vs Comp (ref): −0.025 (0.02), p=NS; [underlined: Fruits (100 g svg/d)]: Baseline: Int: 0.82, Comp: 0.84, Post-intervention: Int: 0.84, Comp: 0.87, Int vs Comp (ref): 0.016 (0.02), p=NS; [underlined: Vegetables (75 g svg/d)]: Baseline: Int: 0.49, Comp: 0.49, Post-intervention: Int: 0.51, Comp: 0.51, Int vs Comp (ref): 0.006 (0.01), p=NS; [underlined: Cookies (85 g svg/d)]: Baseline: Int: 0.57, Comp: 0.59, Post-intervention: Int: 0.62, Comp: 0.59, Int vs Comp (ref): 0.007 (0.01), p=NS; [underlined: Sodas (200 mL svg/d)]: Baseline: Int: 0.68, Comp: 0.70, Post-intervention: Int: 0.69, Comp: 0.67, Int vs Comp (ref): −0.025 (0.02), p=NS; [underlined: Processed meat (15 g svg/d)]: Baseline: Int: 0.62, Comp: 0.64, Post-intervention: Int: 0.66, Comp: 0.63, Int vs Comp (ref): −0.011 (0.01), p=NS; [underlined: Sugar-sweetened fruit-based drinks (200 mL svg/d)]: Baseline: Int: 0.80, Comp: 0.84, Post-intervention: Int: 0.82, Comp: 0.78, Int vs Comp (ref): 0.023 (0.02), p=NS; Note: Results were similar when the intervention group was limited to children who participated in at least 3 activities; Change in daily frequency of intake score (sum of healthier items: milk, beans, water, fruits, vegetables) – (sum of less healthy items: cookies, sodas, processed meat, sugar-sweetened fruit-based drinks) from baseline to post-intervention, Mean (SD); [underlined: Males]: Int: −0.55 (7.08) vs Comp (ref): 0.51 (6.64), p=0.13; [underlined: Females]: Int: 0.29 (7.89) vs Comp (ref): 0.11 (7.19), p=0.04 ↑; Change in intake from baseline to post-intervention (24-h recall) (g), Mean Difference (SD); [underlined: Fruit juice]: Int vs Comp (ref): −0·42 (0·18), p<0.05 ↑; [underlined: Other foods]: Data NR; Model adjustments: Age; sex; cluster effects; Funding source(s): Conselho Nacional de Desenvolvimento Científico e Tecnol´ogico, Fundação de Amparo à Pesquisa do Estado do Rio de Janeiro
Sharma, 2015 ^86^; United States (Dallas & Houston, Texas), RCT-Cluster; Total Baseline N: 107; Total Analytic N: 94; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Did not complete baseline or follow-up survey or dietary recall; Grade level: Elementary school; Age (%): 9y: 52%, 10y: 40%, 11y: 8%; Female: 43%; Race/ethnicity: White: 26.6%; Black: 10.5%; Hispanic: 48.6%; SES: Eligible free/reduced price (Range): 20-85% | Int: Web-based computer game (Quest to Lava Mountain) exposure used to increase knowledge of the health-optimizing role of food, nutrition, and physical activity (N=44; Cluster N=3); Comp: No intervention (Usual curriculum) (N=50; Cluster N=3); Theory/framework: SCT; Theory of Reasoned Action; Intervention duration: 6 wk; Outcome measurement: Two, random CATCH 24-h dietary recall interviews conducted either in person or via telephone at baseline and end of 6-wk intervention on 2 nonconsecutive weekdays by trained research staff | Change in intake from pre- to post-intervention (svg/1000 kcal), Int vs Comp (ref), Beta coefficient (95% CI); [underlined: Fruit]: −0.27 (−0.57, 0.03), p=0.08; [underlined: Vegetables]: 0.17 (−0.05, 0.39), p=0.13; Change in intake from pre- to post-intervention (g/1000 kcal), Int vs Comp (ref), Beta coefficient (95% CI); [underlined: Dietary fiber]: 0.88 (−0.52, 2.28, p=0.22; [underlined: Sugars]: −9.73, (−18.00, −1.47), p=0.02 ↑; Model adjustments: Age; ethnicity; BMI; school; Funding source(s): The Cooper Institute; The Safeway Foundation; the Michael & Susan Dell Foundation through the Michael & Susan Dell Center for Healthy Living at the University of Texas School of Public Health
Smith, 2016 ^87^; United States (Whatcom and Skagit Counties, Washington), RCT-Cluster; Total Baseline N: 142; Total Analytic N: 139; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Missing data; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: NR; SES: NR | Int: “Pulse on Health” curriculum (hands-on multidisciplinary garden lessons) (N=120; Cluster N=6); Comp: No intervention (N=19; Cluster N=1); Theory/framework: NR; Intervention duration: 3 wk; Outcome measurement: Students completed a pre- and post-intervention with one question asking how frequently they eat beans using a 5 point Likert scale: 1 (never) to 5 (once a day). | Frequency of bean intake, difference-in-difference estimated coefficient (SE); [underlined: Pre-intervention difference, Int vs Comp (ref)]: −0.133 (0.111), p=NS; [underlined: Post-intervention difference, Int vs Comp (ref)]: 0.047 (0.082), p=NS; Treatment effect, Int vs Comp (ref): 0.180 (0.138), p=NS; Model adjustments: None; Funding source(s): American Pulse Association, Washington State University, the Northwest Agriculture Research Foundation, USDA National Institute of Food and Agriculture
Struempler, 2014 ^88^; United States (Alabama), RCT-Cluster; Total Baseline N: NR; Total Analytic N: 2,477; Total Baseline Cluster N: 60; Total Analytic Cluster N: 60; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age: NR; Female: ~49%; Race/ethnicity: Black: ~46%; Non-Black (predominantly White): ~54%; SES: Free/reduced price lunch participation: Schools with 75-100% students participating: 46%, Schools with 50-75% students participating: 54% | Int: Body Quest nutrition education program consisting of 17 weekly, 45 minute classes focused on fruit and vegetable consumption (N=1,674; Cluster N=NR); Comp: No intervention (N=803; Cluster N=NR); Theory/framework: Experiential Learning Theory; Intervention duration: 17 wk; Outcome measurement: Intake of school lunch assessed with the What’s for Lunch checklist completed by the child with assistance from teachers at 2 wk pre-intervention and 2 wk post-intervention | Intake at pre- and post-intervention (svg/wk), Data NR; [underlined: Fruit]; Group by time interaction: p<0.001 ↑; Post-intervention: Int > Comp, p<0.001 ↑; [underlined: Vegetables]; Group by time interaction: p<0.001 ↑; Post-intervention: Int > Comp, p<0.001 ↑; Model adjustments: Pre-intervention intake; Sex; Race; School free/reduced price lunch participation; School Fresh Fruit and Vegetable Program participation; Funding source(s): Alabama Cooperative Extension System, USDA Supplemental Nutrition Assistance Program
Taghdisi, 2016 ^89^; Iran, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 184; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age: NR; Female: 0%; Race/ethnicity: NR; SES: NR | Int: Nutrition education sessions (four 45 minute sessions) for students and one 60 minute training session for teachers and parents to improve fruit and vegetable consumption in children (N=94; Cluster N=1); Comp: No intervention (N=90; Cluster N=1); Theory/framework: TPB; Intervention duration: NR; Outcome measurement: 24-h fruit and vegetable recall questionnaire for 3 consecutive days (including two workdays) pre-intervention and 3-mo follow-up; after a full explanation of how to answer the questions was given, the recall was completed by the students with parental supervision | Intake at pre-intervention and 3-mo follow-up (svg/d), Mean (SD); [underlined: Fruit]; Int: Pre-intervention: 0.43 (0.27) vs 3-mo follow-up: 1.03 (0.60), p=0.001 ↑; Comp: Pre-intervention: 0.44 (0.25) vs 3-mo follow-up: 0.48 (0.25), p=0.230; Int vs Comp (3-mo follow-up): p=0.001 ↑; [underlined: Vegetables]; Int: Pre-intervention: 0.48 (0.27) vs 3-mo follow-up: 0.85 (0.23), p=0.001 ↑; Comp: Pre-intervention: 0.46 (0.26) vs 3-mo follow-up: 0.45 (0.24), p=0.650; Int vs Comp (After): p=0.001 ↑; [underlined: Fruit and Vegetables]; Int: Pre-intervention: 0.46 (0.23) vs 3-mo follow-up: 0.95 (0.3), p=0.001 ↑; Comp: Pre-intervention: 0.44 (0.22) vs 3-mo follow-up: 0.47 (0.16), p=0.094; Int vs Comp (After): p=0.001 ↑; Model adjustments: None; Funding source(s): NR
Tarro, 2019,^90^ European Youth Tackling Obesity (EYTO)-Kids project; Spain, RCT-Cluster; Total Baseline N: 702; Total Analytic N: 544; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Did not complete post-intervention survey; Grade level: Elementary school; Age (Mean (SD)): 9.22 (0.57) y; Female: 49%; Race/ethnicity: West Europe: 64%; East Mediterranean: 24%; East-Central Europe: 3%; American Regions: 7%; African Regions: 1%; SES: NR | Int: Social marketing nutrition education delivered by adolescents (N=296; Cluster N=8); Comp: No intervention (N=248; Cluster N=8); Theory/framework: NR; Intervention duration: 10 mo; Outcome measurement: Diet intake assessed using EnKid Questionnaire and the HABITS Questionnaire (sugary drinks) completed by parents at baseline and post-intervention | Intake at baseline and post-intervention, % or Mean (SD); [underlined: ≥1 Fruit/d (%)]:; Baseline: Int: 45.4% vs Comp: 41.5%; Post-intervention: Int: 53.4% vs Comp: 45.2% Difference in change: p=0.476; [underlined: Fruit portions/d]:; Baseline: Int: 1.18 (0.74) vs Comp: 1.15 (0.71); Post-intervention: Int: 1.3 (0.71) vs Comp: 1.16 (0.74); Difference in change: p=0.371; [underlined: ≥1 Vegetable/d (%)]:; Baseline: Int: 37.0% vs Comp: 27.5%; Post-intervention: Int: 35.3% vs Comp: 35.5% Difference in change: p=0.143; [underlined: ≥1 Sugary drink every d (%)]:; Baseline: Int: 36.2% vs Comp: 36.4%; Post-intervention: Int: 37.8% vs Comp: 33.3% Difference in change: p=0.386; [underlined: No gummy or sweets during wk (%)]:; Baseline: Int: 79.6% vs Comp: 89.8%; Post-intervention: Int: 87.1% vs Comp: 89.7% Difference in change: p=0.004 ↑; [underlined: No fast food during wk (%)]:; Baseline: Int: 80.1% vs Comp: 87.9%; Post-intervention: Int: 81.8% vs Comp: 86.2% Difference in change: p=0.047 ↑; Similar results seen when sugary drinks analyzed separately (commercial juice, soft drinks, and carbonated drinks); similar results seen when girls and boys analyzed separately except for fast food, sweets, and soft drinks (significant effects only in girls); Model adjustments: None; Funding source(s): Obra Social La Caixa
Turnin, 2001 ^93^; France, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 1,576; Total Baseline Cluster N: 16; Total Analytic Cluster N: 15; Criteria for exclusion from analysis: Did not complete post-intervention questionnaire; Grade level: Elementary school; Age (Mean): ~9 y; Female: ~52.5%; Race/ethnicity: NR; SES: NR | Int: Nutrition education delivered by teachers with 2 h/wk to play nutritional learning games on computers for 5 wk (N=827; Cluster N=NR); Comp: Nutrition education delivered by teachers for 5 wk (N=749; Cluster N=NR); Theory/framework: NR; Intervention duration: 5 wk; Outcome measurement: Intake assessed with 3-d diet record on consecutive days (2 weekdays, 1 weekend day) post-intervention; eating habits assessed with 9 item questionnaire post-intervention; measures completed by children, who were trained by dietitians, with help from parents | Intake at post-intervention (g/d x 1000/kcal per d), Data NR; [underlined: Plain dairy products]: Int > Comp, p<0.05 ↑; [underlined: Starchy food]: Int > Comp, p<0.001 ↓; [underlined: Meat]: Int < Comp, p<0.005 ↑; [underlined: Delicatessen food]: Int < Comp, p<0.01 ↑; [underlined: Sweetened dairy dessert]: Int < Comp, p<0.0001 ↑; [underlined: Green vegetables]: Int < Comp, p<0.0001 ↓; [underlined: Fruit]: Int > Comp, p<0.0001 ↑; Eating habits at post-intervention, % (Int N=846, Comp N=720); [underlined: Eat fruits and vegetables daily]: Int: 80.4%, Comp: 76.1%, p=0.05; Intake at post-intervention, Mean (SE); [underlined: Saccharose (% kcal)]: Int: 11.5 (0.1), Comp: 12.2 (0.2), p<0.001 ↑; [underlined: Fiber (g)]: Int: 12.6 (0.1), Comp: 12.1 (0.1), p<0.05 ↑; Model adjustments: None; Funding source(s): French Ministry of Health (Clinical Research Hospital Program)
van den Berg, 2020,^95^ Texas, Grow! Eat! Go! (TGEG) study; United States (South and Central Texas), RCT-Cluster; Total Baseline N: 1,326; Total Analytic N: NR; Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (%): <8 y: 70.6%; >9 y: 29.4%; Female: 50.8%; Race/ethnicity: White: 19.9%; Black: 18%; Hispanic: 42%; Other: 19.7%; SES: Eligible for free/reduced price lunch: 78% | Int1: School garden intervention Learn!Grow!Eat!Go! (LGEG) delivered by trained teachers (N=NR; Cluster N=7); Int2: Physical activity intervention Walk Across Texas delivered by trained teachers (N=NR; Cluster N=7); Int3: Garden and physical activity intervention (Combined) (N=NR; Cluster N=7); Comp: No intervention (N=NR; Cluster N=7); Theory/framework: SCT; Intervention duration: 6 mo; Outcome measurement: Previous day vegetable consumption was assessed using a student survey administered orally during the school day at baseline and post-intervention; 3 vegetable consumption questions (possible total values 0-9) adapted from the validated School PA and Nutrition (SPAN) Survey | Previous day vegetable consumption, Pre - Post change, Mean (SD) and Mean difference (SD); Int1+Int3 (groups with LGEG): −0.26 (0.12), Int2+Comp (groups without LGEG): −0.3 (0.12); Int1+Int3 vs Int2+Comp (ref): 0.04 (0.17), p=0.825; Previous day vegetable consumption, Pre - Post intake and change, Mean (SD) and Mean difference (SD); Pre: Int1: 2.66 (0.16), Comp: 2.71 (0.17); Post: Int1: 2.34 (0.16), Comp: 2.3 (0.17); Change: Int1: −0.32 (0.16), Comp: −0.41 (0.18); Difference in change: Int1 vs Comp (ref): 0.09 (0.24), p=0.712; Model adjustments: Cohort of data collection; sex; ethnicity; cluster (random effect); Funding source(s): National Institute of Food and Agriculture USDA, Michael & Susan Dell Foundation through the Michael & Susan Dell Center for Healthy Living UTHealth
Vardanjani, 2015 ^94^; Iran, RCT-Cluster; Total Baseline N: 72; Total Analytic N: 72; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Elementary school; Age: NR; Female: 100%; Race/ethnicity: NR; SES: Father’s education, diploma: ~56% | Int: Junk food reduction education program (N=36; Cluster N=1); Comp: Normal coursework (N=36; Cluster N=1); Theory/framework: NR; Intervention duration: 1 wk; Outcome measurement: Consumption frequency of 12 unhealthy snacks and beverages was measured using validated questionnaire (specific type NR) at baseline and 2-month follow up | Intake at baseline and 2-mo follow-up (units NR), Mean (SD); [underlined: Unhealthy snacks and beverages]; Int: Baseline: 39.86 (9.85), 2-mo follow-up: 50.00 (6.11), p<0.001 ↑; Comp: Baseline: 37.57 (10.82), 2-mo follow-up: 36.07 (9.92), p=0.32; Int vs Comp at 2-mo: p<0.001 ↑; Note: Higher scores indicate more favorable consumption pattern; Model adjustments: None; Funding source(s): Research committee of Shahid Beheshti University of Medical Sciences
Viggiano, 2018 ^96^; Italy, RCT-Cluster; Total Baseline N: 1,313; Total Analytic N: 611 at post-intervention 379 at 10-mo follow-up; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Missing post-intervention assessment; Grade level: Elementary school; Age (Range): 7-11 y; Female: ~48%; Race/ethnicity: NR; SES: NR | Int: Kalèdo game promoting nutrition knowledge and healthy lifestyle (weekly for 20 wk) (N=380 at post-intervention; N=207 at 10-mo follow-up; Cluster N=5); Comp: No intervention (N=231 at post-intervention; N=172 at 10-mo follow-up; Cluster N=5); Theory/framework: NR; Intervention duration: 20 wk; Outcome measurement: Intake assessed with a 7-d food diary in graphical form, listing a variety of food items including “junk food” (i.e., candies, chocolate, chewy gum, chips, crackers, fruit juice beverage, snacks, and sugary drinks) and “healthy food” (i.e., fruit, fresh-squeezed orange juice, vegetable, and yogurt); assessment was completed by children with teacher assistance at baseline, post-intervention, and 10-mo follow-up. | Intake at baseline, post-intervention, and 10-mo follow-up (x/wk in school), Mean (95% CI) and Difference; [underlined: Junk food]; Baseline: Int: 13.45 (12.35, 14.54), Comp: 12.21 (10.70, 13.72); Post-intervention: Int: 12.14 (10.73, 13.55) vs Comp: 13.17 (11.95, 14.38), p=0.149; 10-mo: Int: 10.88 (9.63, 12.14) vs Comp: 15.41 (13.59, 17.22), p<0.01 ↑; [underlined: Healthy food]; Baseline: Int: 4.72 (4.12, 5.32), Comp: 3.31 (2.55, 4.07); Post-intervention: Int: 4.87 (4.27, 5.47) vs Comp: 1.66 (1.29, 2.03), p<0.01 ↑; 10-mo: Int: 7.66 (6.92, 8.40) vs Comp: 2.34 (1.63, 3.05), p<0.01 ↑; Note: N varied by time point; at post-intervention: Int N=380, Comp N=231; at 10 mo: Int N=207, Comp: N=172; Model adjustments: Baseline dietary intake; Funding source(s): Second University of Naples, Associazione Culturale Kaledo, Regione Campania, Provincia di Napoli, and Provincia di Salerno
Warren, 2003 ^106^; United Kingdom, RCT-Parallel; Total Baseline N: 218; Total Analytic N: 86; Criteria for exclusion from analysis: Did not complete/return postal questionnaire at baseline or at study end; Grade level: Elementary school; Age (Mean (SD)): 6.1 (0.6) y; Female: 49%; Race/ethnicity: White: 89%; SES: Parental education (degree or post-graduate qualification): 39% | Int1: Nutrition education program delivered by study staff during weekly/bi-weekly 25-minute lunchtime clubs for 4 school terms. (N=20); Int2: Physical activity education program (did not meet inclusion/exclusion criteria) (N=23); Int3: Combined nutrition and physical activity education program (did not meet inclusion/exclusion criteria) (N=21); Comp: Food education program that did not provide nutrition information delivered by study staff during weekly/bi-weekly 25-minute lunchtime clubs for 4 school terms. (N=22); Theory/framework: Social Learning Theory; Intervention duration: ~14 mo; Outcome measurement: Intake assessed with 24-h recall and 42 item FFQ completed by parent at baseline and 1-mo follow-up | Intake at 1-mo follow-up; Fiber score (based on intake of vegetarian alternatives, wholemeal bread and breakfast cereals, potatoes, vegetables, salads, fresh fruit and other fruits): Data NR, p=NS; Model adjustments: None; Funding source(s): United Kingdom Food Standards Agency
Williams, 2016 ^97^; United States (New York City, New York), RCT-Cluster; Total Baseline N: 271; Total Analytic N: 240; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Did not make purchase post-intervention; Grade level: Elementary school; Age (Range): 8-11 y; Female: NR; Race/ethnicity: NR; SES: Peer Index (Mean): ~50 (high-need schools) | Int: Hip Hop HEALS (Healthy Eating and Living in Schools) nutrition education program consisting of three 1-hour sessions and homework assignments focused on menu label literacy (N=149; Cluster N=2); Comp: No intervention (N=91; Cluster N=1); Theory/framework: Theory of Reasoned Action; SCT; Intervention duration: 3 d; Outcome measurement: Purchases assessed by sales at small kiosks set up in high student traffic locations by researchers at baseline and immediately following the intervention; children were given $0.50 to make purchases and all foods, with labels, were priced at $0.50 | Purchases at post-intervention, %; [underlined: “Go” foods]: Int: 36% vs Comp: 24%, p>0.05; Apples: Int: 8% vs Comp: 3%, p>0.05; Grapes: Int: 20% vs Comp: 10%, p<0.05 ↑; Fruit Cup: Int: 8% vs Comp: 11%, p>0.05; [underlined: “Slow” foods]: Int: 28% vs Comp: 31%, p>0.05; Granola Bar: Int: 8% vs Comp: 15%, p>0.05; Rice Krispies Treat: Int: 13% vs Comp: 7%, p>0.05; Goldfish Crackers: Int: 7% vs Comp: 9%, p>0.05; [underlined: “Whoa” foods]: Int: 36% vs Comp: 45%, p>0.05; Cheez-Its: Int: 7% vs Comp: 14%, p>0.05; Chocolate Chip Cookies: Int: 9% vs Comp: 14%, p<0.01 ↑; Devils Food Cake: Int: 20% vs Comp: 17%, p>0.05; Model adjustments: None; Funding source(s): New York City Council Office of Inez Dickens, Columbia University
Zota, 2016,^98^ DIATROFI Program; Greece, RCT-Cluster; Total Baseline N: 14,869; Total Analytic N: 3,627; Total Baseline Cluster N: 146; Total Analytic Cluster N: 146; Criteria for exclusion from analysis: Missing a pre-or post-intervention questionnaire, missing information required to link pre- and post-intervention surveys; Grade level: Elementary school and Middle/Junior high school and High school; Age (Range): 4-18 y; Female: ~53%; Race/ethnicity: NR; SES: Maternal education: Low: ~26%, Medium: ~54%, High: ~20%; Family affluence scale: Low: ~29%, Medium: ~54%, High: ~17%; Food insecurity: 51% | Int: Nutrition education with one free, healthy meal daily (N=1,609; Cluster N=73); Comp: One free, healthy meal per day at school without nutrition education (N=2,018; Cluster N=73); Theory/framework: NR; Intervention duration: 1 academic y; Outcome measurement: Intake assessed using a modified version of a semi-quantitative FFQ, completed by a parent at pre- and post-intervention | Increased weekly consumption of food groups provided by the program from pre- to post-intervention, OR (95% CI); [underlined: Children (4-11 y, Int: N=1187, Comp: N=1369)]; [underlined: Milk or yogurt:] 1.25 (1.03, 1.51), p<0.05 ↑; [underlined: Vegetables:] 1.09 (0.93, 1.28), p=NS; [underlined: Fruits:] 1.22 (1.02, 1.46), p<0.05 ↑; [underlined: Whole grains:] 1.18 (0.96, 1.45), p=NS; [underlined: Adolescents (12-18 y, Int: N=422, Comp: N=649)]; [underlined: Milk or yogurt:] 0.82 (0.64, 1.06), p=NS; [underlined: Vegetables:] 1.40 (1.09, 1.80), p<0.05 ↑; [underlined: Fruits:] 1.03 (0.78, 1.36), p=NS; [underlined: Whole grains:] 0.83 (0.62, 1.12), p=NS; Model adjustments: Sex; region; maternal, paternal, and child country of birth; maternal and paternal education; sports outside school; type of household, weight status; Family Affluence Scale; food insecurity; school near Roma establishments; number of children in the family (all considered in stepwise model); Funding source(s): Stavros Niarchos Foundation

a Abbreviations: β: beta; BMI: body mass index; c: cup; CI: confidence interval; Comp: comparator; d: day; eq: equivalent; FFQ: food frequency questionnaire; g: gram; h: hour; HBM: Health Belief Model; HPM: Health Promotion Model; Int: intervention; K: kindergarten; kcal: kilocalorie; mEq: milliequivalent; min: minute; mL: milliliter; mo: month; N: sample size; NIH: National Institutes of Health; NR: not reported; NS: non-significant; OR: odds ratio; oz: ounce; p: p-value; RCT: randomized controlled trial; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; TPB: Theory of Planned Behavior; tsp: teaspoon; USDA: United States Department of Agriculture; vs: versus; wk: week; x: times; y: year

b Color and symbol coding: Bolded, green with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator; Bolded, blue text with ↔: statistically significant effects (as reported in the article) in which the interpretation of results is unclear

Table 4 Risk of bias for randomized controlled trials examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in elementary school children^a^,^b^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Abdel Gawwad, 2006^50^ | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS
Arrizabalaga-López, 2020^51^ | LOW | LOW | LOW | LOW | LOW | LOW
Bannon, 2006^52^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Baranowski, 2000^54^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Baranowski, 2003^53^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Bashirian, 2008^55^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Battjes-Fries, 2017^56^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Christian, 2014^57^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW
Cotter, 2013^58^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Cullen, 2005^59^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Cunha, 2013^60^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW
de Droog, 2014,^102^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Drapeau, 2016^61^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Gatto, 2017^62^ | LOW | LOW | LOW | LOW | LOW | LOW
Gold, 2017^63^ | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS
Gonçalves, 2018,^103^ Parallel | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Griffin, 2015^64^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
He, 2015^65^ | LOW | LOW | LOW | LOW | LOW | LOW
Hermans, 2018,^104^ Parallel | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Jamelske, 2018^66^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
James, 2004^67^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Katz, 2011^68^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
Kaufman-Shriqui, 2016^69^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
LaChausse, 2017^70^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Larsen, 2015^71^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Lehto, 2014^72^ | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS
Leung, 2014,^105^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Llauradó, 2014^73^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Mangunkusumo, 2007^74^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Panunzio, 2007^75^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Panunzio, 2011^76^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Perikkou, 2013^77^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Perry, 2002^78^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Reinaerts, 2007^41^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Reinaerts, 2008^40^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Ribeiro-Silva, 2014^79^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
Rosário, 2012^80^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Rosário, 2013^81^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Rosário, 2016^82^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Rosário, 2017^83^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Serebrennikov, 2020^84^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
Sgambato, 2019^85^ | LOW | LOW | LOW | LOW | LOW | LOW
Sharma, 2015^86^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Smith, 2016^87^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS
Struempler, 2014^88^ | HIGH | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Taghdisi, 2016^89^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Tarro, 2014^91^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | SOME CONCERNS
Tarro, 2014^92^ | SOME CONCERNS | HIGH | LOW | LOW | LOW | SOME CONCERNS
Tarro, 2019^90^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW
Turnin, 2001^93^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS
van den Berg, 2020^95^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Vardanjani, 2015^94^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Viggiano, 2018^96^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Warren, 2003,^106^ Parallel | SOME CONCERNS | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Williams, 2016^97^ | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS
Zota, 2016^98^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version) for cluster-RCTs ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601 .) and the [underlined: “Cochrane Risk-of-bias 2.0” (RoB 2.0)] (2019 version) for parallel-RCTs ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi: 10.1136/bmj.l4898.31462531 )

b All studies cluster-RCTs except when otherwise noted

Table 5 Evidence examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in elementary school children^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
5-A-Day Cafeteria Power Plus
Perry, 2004,^38^ 5-A-Day Cafeteria Power Plus; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: 1,668; Total Analytic N: 1,168; Total Baseline Cluster N: 26; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Parent/student refusal, absent, moved, changed to a school with a different intervention condition; Grade level: Elementary school; Age: NR; Female: 49%; Race/ethnicity: White: ~90%; SES: Free/reduced price meals served: ~21% | Int: Changes to environmental factors to increase opportunities to eat fruits and vegetables, provide role models who eat fruits and vegetables, and institute social support to eat fruits and vegetables (N=NR; Cluster N=13); Comp: No intervention (N=NR; Cluster N=13); Theory/framework: SCT; health behavior planning model; Intervention duration: 2 y; Outcome measurement: Intake assessed by trained observers in the cafeteria who recorded all items eaten at lunch and portion sizes for target children at baseline and post-intervention | Post-intervention intake (svg), Mean and Mean difference (SE); [underlined: Fruits and vegetables]: Int: 1.30, Comp: 1.21; Difference: 0.09 (0.09), p=0.33; [underlined: Fruits and vegetables, excluding potatoes]: Int: 1.06, Comp: 0.92; Difference: 0.14 (0.06), p=0.03 ↑; [underlined: Fruits and vegetables, excluding potatoes and juice]: Int: 0.64, Comp: 0.50; Difference: 0.15 (0.05), p=0.02 ↑; [underlined: Fruits]: Int: 0.79, Comp: 0.63; Difference: 0.16 (0.05), p=0.01 ↑; [underlined: Fruits, no juice]: Int: 0.37, Comp: 0.21; Difference: 0.17 (0.04), p=0.00 ↑; [underlined: Fruit juice]: Int: 0.42, Comp: 0.42; Difference: −0.01 (0.03), p=0.77; [underlined: Vegetables]: Int: 0.52, Comp: 0.58; Difference: −0.06 (0.06), p=0.32; [underlined: Vegetables, no potatoes]: Int: 0.27, Comp: 0.29; Difference: −0.02 (0.04), p=0.55; Results similar when analyzed as svg/1000 kcal; Model adjustments: Baseline value; grade; sex; school (random effect); Funding source(s): National Cancer Institute
Gray, 2007,^30^ 5-A-Day Cafeteria Power Plus United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: 1,668; Total Analytic N: 1,168; Total Baseline Cluster N: 26; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Range): ~6-10 y; Female: 49%; Race/ethnicity: White: ~90%; SES: Free/reduced price meals served: ~21% | Int: Changes to environmental factors to increase opportunities to eat fruits and vegetables, provide role models who eat fruits and vegetables, and institute social support to eat fruits and vegetables (N=NR; Cluster N=13); Comp: No intervention (N=NR; Cluster N=13); Theory/framework: SCT; health behavior planning model; Intervention duration: 2 y; Outcome measurement: Selection assessed by trained observers in the cafeteria who recorded all items taken at lunch and portion sizes for target children at baseline and post-intervention | Post-intervention selection (svg), Mean and Mean difference; [underlined: Fruit and vegetables]: Int 1.66, Comp: 1.56, Int vs Comp (ref): 0.10, p=0.32; [underlined: Fruit, total]: Int: 0.98, Comp: 0.76, Int vs Comp (ref): 0.23, p<0.001 ↑; [underlined: Fruit, excluding juice]: Int: 0.50, Comp: 0.27, Int vs Comp (ref): 0.23, p<0.001 ↑; [underlined: Fruit juice]: Int: 0.48, Comp: 0.48, Int vs Comp (ref): 0.00, p=0.92; [underlined: Vegetables]: Int: 0.68, Comp: 0.81, Int vs Comp (ref): −0.12, p=0.09; Model adjustments: Baseline value; grade; sex; school (random effect); Funding source(s): National Cancer Institute
Unnamed study – the Netherlands
Reinaerts, 2007 ^41^; The Netherlands, RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): ~9 y; Female: ~52%; Race/ethnicity: Dutch native (both parents born in The Netherlands): ~69%; SES: NR | Int1: Free fruit and vegetable snack distributed each school day (N=NR; Cluster N=3); Int2: Age-appropriate classroom curriculum and parental involvement (N=NR; Cluster N=3); Theory/framework: Intervention mapping; Intervention duration: 1 academic y; Outcome measurement: Fruit, juice, and vegetable intake assessed via pre-structured 24-h food recall completed by parents at baseline and post-intervention. Other intakes assessed via FFQ completed by parents at baseline and post-intervention. | Intake at post-intervention, Mean (SD) and Mean difference; [underlined: Fruit (portions/d)]: Int (n=270): 1.5 (0.9), Int2 (n=206): 1.5 (0.8); Int (ref) v Int2: 0.01, p=NS; [underlined: Vegetables (g/d), by grade group or Dutch origin]:; Pre-K: Int (n=52): 53 (23), Int2: NR; Int (ref) v Int2: −0.10, p=NS; 1st-3rd: Int (n=108): 63 (30), Int2: NR; Int (ref) v Int2: −0.13, p=NS; 4th-6th: Int (n=94): 78 (38), Int2: NR; Int (ref) v Int2: −10.34, p<0.001 ↑; Native: Int (n=125): 61 (28), Int2: NR; Int (ref) v Int2: −0.26, p=NS; Non-native: Int (n=117): 71 (37), Int2: NR; Int (ref) v Int2: −10.41, p<0.01 ↑; [underlined: Vegetable snack (between meals; x/d), by grade group or sex]:; Pre-K: Int (n=53): 0.3 (0.3), Int2 (n=53): 0.3 (0.3); Int (ref) v Int2: 0.01, p=NS; 1st-3rd: Int (n=108): 0.3 (0.3), Int2 (n=84): 0.3 (0.3); Int (ref) v Int2: 0.04, p=NS; 4th-6th: Int (n=97): 0.4 (0.3), Int2 (n=64): 0.3 (0.3); Int (ref) v Int2: −0.08, p<0.05 ↑; Boys: Int: NR, Int2 (n=91): 0.2 (0.3); Int (ref) v Int2: −0.06, p<0.05 ↑; Girls: Int: NR, Int2 (n=110): 0.3 (0.3); Int (ref) v Int2: 0.04, p=NS; [underlined: 24-h fruit, juice, and vegetables (x/d), by grade group or Dutch origin]: Pre-K: Int (n=41): 3.1 (1.4), Int2: NR; Int (ref) v Int2: −0.33, p=NS; 1st-3rd: Int (n=92): 3.3 (1.3), Int2: NR; Int (ref) v Int2: 0.06, p=NS; 4th-6th: Int (n=85): 4.0 (1.7), Int2: NR; Int (ref) v Int2: −0.22, p=NS; Native: Int: NR, Int2 (n=160): 3.0 (1.2); Int (ref) v Int2: −0.14, p=NS; Non-native: Int: NR, Int2 (n=19): 3.8 (1.4); Int (ref) v Int2: 0.49, p=NS; Model adjustments: Baseline consumption; sex, grade group; ethnicity (Dutch native or non-native); nesting child within class within school; interactions between intervention and sex, ethnicity, and grade group; Funding source(s): The Netherlands Organization for Health Research and Development
Reinaerts, 2008 ^40^; The Netherlands, RCT-Cluster; Total Baseline N: 952; Total Analytic N: 209; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Missing data; Grade level: Elementary school; Age (Mean (SD)): ~8 y; Female: ~53%; Race/ethnicity: Dutch native (both parents born in The Netherlands): ~69%; SES: NR | Int1: Free fruit and vegetable snack distributed each school day (N=85; Cluster N=3); Int2: Age-appropriate classroom curriculum promoting fruit and vegetable consumption and parental involvement (N=124; Cluster N=3); Theory/framework: Intervention mapping; Intervention duration: 1 academic y; Outcome measurement: Fruit, juice, and vegetable intake assessed via pre-structured 24-h food recall completed by parents at baseline, post-intervention, and 1-y follow-up. Other intakes assessed via FFQ completed by parents at baseline, post-intervention, and 1-y follow-up. | Intake at post-intervention and 1-y follow-up, Mean (SD); [underlined: Fruit (portions/d)]: Int: 1.41 (0.83) at post-intervention, 1.25 (0.76) at 1 y follow-up, Int2: 1.27 (0.70) at post-intervention, 1.18 (0.75) at 1 y follow-up, p=NS; [underlined: Vegetable (g/d)]: Int: 49.0 (26.5) at post-intervention, 49.6 (25.6) at 1 y follow-up, Int2: 43.6 (24.7) at post-intervention, 48.4 (24.0) at 1 y follow-up, p<0.05 ↑; [underlined: Vegetable snack (between meals; x/d)]: Int: 0.38 (0.28) at post-intervention, 0.40 (0.30) at 1 y follow-up, Int2: 0.31 (0.29) at post-intervention, 0.26 (0.24) at 1 y follow-up, p<0.05 ↑; [underlined: 24-h fruit, juice, and vegetables (x/d)]: Int: 3.38 (1.18) at post-intervention, 3.22 (1.13) at 1 y follow-up, Int2: 3.10 (1.12) at post-intervention, 3.02 (1.29) at 1 y follow-up, p=NS; Model adjustments: Baseline consumption; age; ethnicity (Dutch native or non-native); time; child nested in school; Funding source(s): The Netherlands Organization for Health Research and Development
Individual studies (alphabetized by author)
Ashfield-Watt, 2009 ^21^; New Zealand, RCT-Cluster; Total Baseline N: 2,032; Total Analytic N: 1,173; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Illegible/missing questionnaires; Grade level: Elementary school; Age (Mean): ~8.8 y; Female: ~50%; Race/ethnicity: European: ~5%; Asian: ~2%; New Zealand Maori: ~23%; Pacific People: ~58%; Mixed/Other: ~12%; SES: Attending decile 1 school (schools with greatest proportion of students from low SES backgrounds): 100% | Int: Provision of free, seasonal fruits to schools (N=687 at wk 10, N=623 at 6-wk follow-up; Cluster N=5); Comp: No intervention (N=486 at wk 10, N=550 at 6-wk follow-up; Cluster N=5); Theory/framework: NR; Intervention duration: 10 wk; Outcome measurement: Previous day’s fruit intake self-reported by children and assessed via Day in the Life Questionnaire, which was administered in class by teachers at baseline, wk 10 of the intervention, and 6-wk follow-up | Wk 10 intervention intake, Mean (SE); [underlined: Fruit - total (pieces/school d)]: Int: 1.22 (0.03), Comp: 0.92 (0.04), p<0.01 ↑; [underlined: Fruit - school (pieces/school d)]: Int: 0.93 (0.02), Comp: 0.50 (0.03), p<0.01 ↑; Change in fruit intake at school from baseline to wk 10, %; [underlined: 0 pieces/school d at baseline]:; Wk 10: 0 pieces/school d - Int: 36%, Comp: 68%; 1 piece/school d - Int: 41%, Comp: 22%; ≥2 pieces/school d - Int: 23%, Comp: 9%; Int vs Comp: p<0.001 ↑; [underlined: 1 piece/school d at baseline]:; Wk 10: 0 pieces/school d - Int: 19%, Comp: 42%; 1 piece/school d - Int: 43%, Comp: 36%; ≥2 pieces/school d - Int: 38%, Comp: 22%; Int vs Comp: p=0.001 ↑; [underlined: ≥2 pieces/school d at baseline]:; Wk 10: 0 pieces/school d - Int: 15%, Comp: 31%; 1 piece/school d - Int: 40%, Comp: 38%; ≥2 pieces/school d - Int: 45%, Comp: 31%; Int vs Comp: p=0.001 ↑; 6-wk follow-up intake, Mean (SE); [underlined: Fruit - total (pieces/school d)]: Int: 0.61 (0.03), Comp: 0.96 (0.04), p<0.01 ↓; [underlined: Fruit - school (pieces/school d)]: Int: 0.37 (0.02), Comp: 0.52 (0.03), p<0.01 ↓; Change in fruit intake at school from wk 10 to 6-wk follow-up, %; [underlined: 0 pieces/school d at wk 10]:; 6 wk follow-up: 0 pieces/school d - Int: 74%, Comp: 67%; 1 piece/school d - Int: 17%, Comp: 21%; ≥2 pieces/school d - Int: 9%, Comp: 12%; Int vs Comp: p=0.20; [underlined: 1 piece/school d at wk 10]:; 6 wk follow-up: 0 pieces/school d - Int: 62%, Comp: 45%; 1 piece/school d - Int: 24%, Comp: 33%; ≥2 pieces/school d - Int: 14%, Comp: 22%; Int vs Comp: p=0.001 ↓; [underlined: ≥2 pieces/school d at wk 10]:; 6 wk follow-up: 0 pieces/school d - Int: 56%, Comp: 31%; 1 piece/school d - Int: 27%, Comp: 25%; ≥2 pieces/school d - Int: 17%, Comp: 44%; Int vs Comp: p<0.001 ↓; Note: N for total fruit intake was less than for fruit at school for both wk 10 (Total N=944) and 6-wk follow-up (Total N=979); Model adjustments: Sex; baseline intake; school randomization pair; Funding source(s): New Zealand Ministry of Health
Belot, 2016 ^22^; United Kingdom, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 638; Total Baseline Cluster N: 31; Total Analytic Cluster N: 31 immediately post-intervention; 21 at 6-mo follow-up; Criteria for exclusion from analysis: No parental consent; Grade level: Elementary school; Age (Ranges): 6-7 y; 9-10 y; Female: ~51%; Race/ethnicity: White British: ~87%; SES: Free school meal: ~18% | Int1: Individual incentive for choosing or bringing a fruit or vegetable at lunch (N=NR; Cluster N=NR); Int2: Competition incentive for choosing or bringing a fruit or vegetable at lunch (N=NR; Cluster N=NR); Comp: No intervention (N=NR; Cluster N=NR); Theory/framework: Behavioral economics; Intervention duration: 4 wk; Outcome measurement: Food choice and intake were recorded by lunch monitors, who assessed when students chose or brought a fruit or vegetable with a packed lunch, and whether the student ate more than half of the fruit or vegetable served; choice and intake were measured during intervention (weeks 2-5), immediately post-intervention (week 6), and at 6-mo follow-up | Choice of at least one fruit or vegetable, Point estimate (SE); [underlined: During intervention (wk 2-5)]; Int1 vs Comp+Int2 (ref): 0.024 (0.050), p=0.659; Int2 vs Comp+Int1 (ref): 0.045 (0.031), p=0.180; Int1 vs Int2: p=0.711; [underlined: Post-intervention (wk 6)]; Int1 vs Comp+Int2 (ref): −0.045 (0.059), p=0.567; Int2 vs Comp+Int1 (ref): 0.001 (0.034), p=0.955; Int1 vs Int2: p=0.396; [underlined: 6-mo follow-up (N=392)]; Int1 vs Comp+Int2 (ref): −0.016 (0.070), p=0.853; Int2 vs Comp+Int1 (ref): −0.058 (0.057), p=0.358; Int1 vs Int2: p=0.496; Choice of at least one fruit or vegetable among children who did not select a fruit or vegetable every day at baseline (N=215), Point estimate (SE); [underlined: During intervention (wk 2-5)]; Int1 vs Comp+Int2 (ref): 0.096 (0.080), p=0.340; Int2 vs Comp+Int1 (ref): 0.175 (0.060), p=0.018 ↑; Int1 vs Int2: p=0.428; [underlined: Post-intervention (wk 6)]; Int1 vs Comp+Int2 (ref): −0.035 (0.094), p=0.687; Int2 vs Comp+Int1 (ref): 0.096 (0.043), p=0.048 ↑; Int1 vs Int2: p=0.204; [underlined: 6-mo follow-up (N=168)]; Int1 vs Comp+Int2 (ref): 0.017 (0.066), p=0.853; Int2 vs Comp+Int1 (ref): 0.055 (0.104), p=0.629; Int1 vs Int2: p=0.753; Intake of more than half of fruit or vegetable, Point estimate (SE); [underlined: During intervention (wk 2-5)]; Int1 vs Comp+Int2 (ref): 0.054 (0.060), p=0.464; Int2 vs Comp+Int1 (ref): 0.114 (0.063), p=0.194; Int1 vs Int2: p=0.488; [underlined: Post-intervention (wk 6)]; Int1 vs Comp+Int2 (ref): 0.008 (0.075), p=0.893; Int2 vs Comp+Int1 (ref): 0.082 (0.073), p=0.354; Int1 vs Int2: p=0.446; [underlined: 6-mo follow-up]: data NR; Intake of more than half of fruit or vegetable among children who did not select a fruit or vegetable every day at baseline (N=215), Point estimate (SE); [underlined: During intervention (wk 2-5)]; Int1 vs Comp+Int2 (ref): 0.078 (0.068), p=0.318; Int2 vs Comp+Int1 (ref): 0.190 (0.076), p=0.024 ↑; Int1 vs Int2: p=0.220; [underlined: Post-intervention (wk 6)]; Int1 vs Comp+Int2 (ref): −0.006 (0.096), p=0.979; Int2 vs Comp+Int1 (ref): 0.117 (0.066), p=0.126; Int1 vs Int2: p=0.210; [underlined: 6-mo follow-up]: data NR; *Results varied by age: detrimental effect of the individual incentive on choice in young children during and post-intervention, null effect (or detrimental effect in subsample with <100% choice at baseline) on intake in young children during and post-intervention; no effect (or beneficial effects in the subsample with <100% choice at baseline) of the individual incentive on choice in older children, beneficial effect on intake during the intervention (see paper for more details). Similar results to main analyses were found when analyses conducted by sex and SES.; Model adjustments: None; Funding source(s): Esme Fairbairn Foundation
Brauchla, 2013 ^23^; United States (Rural Indiana), RCT-Cluster; Total Baseline N: 81; Total Analytic N: 67; Total Baseline Cluster N: 11; Total Analytic Cluster N: 11; Criteria for exclusion from analysis: Dietary recalls deemed unreliable or not representative of usual intake, child chose not eat snack on at least 50% of eating occasions; Grade level: Elementary school; Age (%): 7-8y: 15%, 9-11y: 85%; Female: 47%; Race/ethnicity: White: 63%; Black: 4%; Asian: 4%; Hispanic: 11%; Other: 5%; SES: NR | Int: High-fiber snacks with skim milk (N=32; Cluster N=NR); Comp: No intervention (N=35; Cluster N=NR); Theory/framework: NR; Intervention duration: 8 wk; Outcome measurement: Diet: two 24-hr recalls via telephone completed by children at baseline, mid-intervention, and post-intervention. Parental assistance encouraged for younger children. | Mid-intervention intake, Mean (SD); [underlined: Fruits (svg)]: Int: 0.97 (1.03) vs Comp: 0.95 (1.02), p=NS; [underlined: Vegetables (svg)]: Int: 1.05 (0.60) vs Comp: 1.18 (1.14), p=NS; [underlined: Grains (svg)]: Int: 6.86 (1.77) vs Comp: 5.08 (1.95), p<0.05 ↑; [underlined: Whole grains (svg)]: Int: 2.08 (1.39) vs Comp: 0.59 (0.81), p<0.05 ↑; [underlined: Dairy (svg)]: Int: 2.22 (1.21) vs Comp: 2.13 (0.97), p=NS; [underlined: Sweets (svg)]: Int: 0.55 (0.68) vs Comp: 0.50 (0.55), p=NS; [underlined: Beverages (svg)]: Int: 1.22 (0.79) vs Comp: 1.23 (0.96), p=NS; [underlined: Saturated fatty acids (g)]: Int: 19.23 (9.15) vs Comp: 17.93 (6.39), p=NS; [underlined: Total dietary fiber (g)]: Int: 14.58 (5.06) vs Comp: 9.99 (4.02), p<0.05 ↑; [underlined: Soluble dietary fiber (g)]: Int: 4.88 (2.16) vs Comp: 3.23 (1.19), p<0.05 ↑; [underlined: Insoluble dietary fiber (g)]: Int: 9.63 (3.21) vs Comp: 6.70 (3.11), p<0.05 ↑; [underlined: Fiber density (g/1000 kcal)]: Int: 9.49 (2.80) vs Comp: 7.11 (2.18), p<0.05 ↑; [underlined: Added sugars (g)]: Int: 61.40 (37.90) vs Comp: 57.27 (34.80), p=NS; Post-intervention intake, Mean (SD); [underlined: Fruits (svg)]: Int: 0.98 (1.15) vs Comp: 1.01 (1.02), p=NS; [underlined: Vegetables (svg)]: Int: 1.06 (0.82) vs Comp: 1.25 (0.90), p=NS; [underlined: Grains (svg)]: Int: 6.30 (2.28) vs Comp: 5.45 (1.58), p<0.05 ↑; [underlined: Whole grains (svg)]: Int: 0.77 (1.00) vs Comp: 0.56 (0.76), p=NS; [underlined: Dairy (svg)]: Int: 2.25 (1.18) vs Comp: 1.99 (1.40), p=NS; [underlined: Sweets (svg)]: Int: 0.55 (0.64) vs Comp: 0.33 (0.37), p<0.05 ↓; [underlined: Beverages (svg)]: Int: 1.47 (1.20) vs Comp: 1.32 (1.03), p=NS; [underlined: Saturated fatty acids (g)]: Int: 20.15 (6.86) vs Comp: 18.20 (8.24), p=NS; [underlined: Total dietary fiber (g)]: Int: 11.06 (4.73) vs Comp: 10.00 (11.06), p=NS; [underlined: Soluble dietary fiber (g)]: Int: 4.13 (2.22) vs Comp: 3.62 (1.75), p=NS; [underlined: Insoluble dietary fiber (g)]: Int: 6.87 (3.26) vs Comp: 6.29 (2.86), p=NS; [underlined: Fiber density (g/1000 kcal)]: Int: 7.32 (2.96) vs Comp: 7.19 (2.55), p=NS; [underlined: Added sugars (g)]: Int: 53.48 (30.55) vs Comp: 50.59 (28.62), p=NS; Model adjustments: None; Funding source(s): NR
Cohen, 2015,^24^ Modifying Eating and Lifestyles at School Study (MEALS Study); United States (Massachusetts), RCT-Cluster; Total Baseline N: 2,638; Total Analytic N: 2,638 (968 with complete data used to calculate estimates); Total Baseline Cluster N: 14; Total Analytic Cluster N: 14; Grade level: Elementary and Middle/Junior high school; Age (Mean): 11.5 y (Range: 8-16); Female: 53%; Race/ethnicity: White: ~6%; Black: ~4%; Asian: ~3%; Hispanic: ~86%; SES: Eligible free/reduced price: ~91% | Int1: Chef intervention/training only (N=379; Cluster N=2); Int2: Smart Café cafeteria-based intervention only (N=651; Cluster N=4); Int3: Chef intervention/training followed by a Smart Café cafeteria-based intervention (N=672; Cluster N=2); Comp: Control (delayed intervention) (N=936; Cluster N=6); Theory/framework: Choice architecture strategies; Intervention duration: Chef intervention: 7 mo; Smart Café: 4 mo; Outcome measurement: Lunch selection and consumption measured on 2 randomly selected, nonconsecutive days at baseline and during the 2 intervention data collection periods by direct observation and weighing of remaining food after lunch by study staff | Selection after 3 mo of intervention, Mean % of students selecting, OR (95% CI); (Note: Before Smart Cafe intervention initiated); [underlined: Fruit]: Comp + Int2 (ref): 60.1, Int1 + Int3: 66.9; 1.46 (0.67, 3.21), p>0.05; [underlined: Vegetables]: Comp + Int2 (ref): 46.6, Int1 + Int3: 57.8, 1.75 (1.36, 2.24), p<0.05 ↑; Intake after 3 mo of intervention, Mean (SE), Difference (95% CI); (Note: Before Smart Cafe intervention initiated); [underlined: Entree (%)]: Comp + Int2 (ref): 73.9 (4.0), Int1 + Int3: 71.7 (5.1), −2.2 (−11.3, 6.9), p>0.05; [underlined: Fruit (%)]: Comp + Int2 (ref): 72.1 (7.9), Int1 + Int3: 73.2 (9.4), 1.1 (−15.1, 17.2), p>0.05; [underlined: Fruit (cups)]: Comp + Int2 (ref): 0.42 (0.05), Int1 + Int3: 0.42 (0.06), 0.00 (−0.10, 0.11), p>0.05; [underlined: Vegetables (%)]: Comp + Int2 (ref): 48.2 (8.9), Int1 + Int3: 40.5 (9.8), −7.8 (−31.5, 16.0), p>0.05; [underlined: Vegetables (cups)]: Comp + Int2 (ref): 0.24 (0.04), Int1 + Int3: 0.20 (0.05), −0.04 (−0.16, 0.08), p>0.05; Selection after 7 mo of intervention, Mean % of students selecting, OR (95% CI); [underlined: Fruit]: Comp (ref): 51.1; Int1: 71.6, 3.08 (2.23, 4.25); Int2: 54.3, 1.45 (1.13, 1.87); Int3: 78.1, 3.10 (2.26, 4.25), all p<0.05 ↑; [underlined: Vegetables]: Comp (ref): 33.7; Int1: 64.2, 2.54 (1.83, 3.54); Int2: 50.6, 1.91 (1.46, 2.50); Int3: 76.4, 7.38 (5.26, 10.35), all p<0.05 ↑; Intake after 7 mo of intervention, Mean (SE), Difference (95% CI); [underlined: Entree (%)]: Comp (ref): 80.7 (4.8); Int1: 68.1 (6.9), −12.6 (−26.2, 1.1); Int2: 81.6 (5.6), 0.9 (−9.9, 12.0); Int3: 84.6 (7.1), 3.9 (−10.0, 17.8); all p>0.05; [underlined: Fruit (%)]: Comp (ref): 67.4 (6.7); Int1: 88.1 (9.9), 20.7 (−1.3, 42.7); Int2: 63.0 (8.6), −4.4 (−23.8, 15.0); Int3: 58.6 (8.9), −8.8 (−28.7, 11.1); all p>0.05; [underlined: Fruit (cups)]: Comp (ref): 0.34 (0.05); Int1: 0.51 (0.07), 0.17 (0.03, 0.30), p<0.05 ↑; Int2: 0.34 (0.07), −0.00 (−0.13, 0.11), p>0.05; Int 3: 0.30 (0.07), −0.04 (−0.17, 0.08), p>0.05; [underlined: Vegetables (%)]: Comp (ref): 28.9 (5.8); Int1: 59.7 (6.1), 30.8 (17.7, 43.8), p<0.05 ↑; Int2: 18.2 (6.3), −10.7 (−23.8, 2.4), p>0.05; Int3: 53.4 (7.1), 24.5 (10.0, 39.0), p<0.05 ↑; [underlined: Vegetables (cups)]: Comp (ref): 0.14 (0.03); Int1: 0.30 (0.03), 0.16 (0.09, 0.22), p<0.05 ↑; Int2: 0.09 (0.03), −0.05 (−0.12, 0.01), p>0.05; Int3: 0.27 (0.04), 0.13 (0.05, 0.19), p<0.05 ↑; Note: Data on milk intake in the Smart Cafe schools presented in the paper, but intervention implementation was inconsistent, and some data were collapsed, limiting usefulness; Model adjustments: Age; sex; race/ethnicity; baseline selection or consumption (depending on outcome); school (random effect); Funding source(s): Arbella Insurance; Nutritional Epidemiology of Cancer Education and Career Development Program
Coleman, 2012,^25^ The Healthy Options for; Nutrition Environments in Schools (Healthy ONES); United States (San Diego County, California), RCT-Cluster; Total Baseline N: 4,033; Total Analytic N: NR; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: NR; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: Non-Hispanic White: 21%; Black: 26%; Hispanic/Latino: 42%; Other/Mixed: 11%; SES: Eligible for free/reduced price lunch: 100% | Int: Implementation of school nutrition policy and environmental changes to eliminate unhealthy foods/beverages at school, develop nutrition services as source of healthy eating, and have staff model healthy eating (N=NR; Cluster N=4); Comp: No intervention (N=NR; Cluster N=4); Theory/framework: Evidence-based public health rapid improvement process model; Intervention duration: 2 y; Outcome measurement: Food brought from home directly observed in the cafeteria and recess/playground environments, and via observation of school trash for food in the classroom and at school-wide events. Observations were made ~1 x/mo during school year in addition to holidays for both intervention years. | Outside food and beverages at baseline and intervention year 1 and 2, Mean (variability)*; [underlined: Outside unhealthy foods (items/child/wk)]:; Baseline: Int: 0.47 (0.22), Comp: 0.67 (0.31); Year 1: Int: 0.71 (0.24), Comp: 1.03 (0.38); Year 2: Int: 0.32 (0.30), Comp: 0.89 (055); Group by time interaction: p=0.01 ↑; Group by time by environment (recess/classroom/lunch) interaction: p=0.02 ↑ (significant differences between groups for recess - decrease in outside unhealthy foods for intervention and increase for control, no significant differences between groups for classroom/lunch); [underlined: Outside unhealthy beverages (items/child/wk)]:; Baseline: Int: 0.26 (0.11), Comp: 0.32 (0.12); Year 1: Int: 0.23 (0.10), Comp: 0.35 (0.10); Year 2: Int: 0.09 (0.05), Comp: 0.28 ± (0.15); Group by time interaction: p=0.01 ↑; Group by time by environment interaction: p=NS; [underlined: Outside healthy foods (items/child/wk)]:; Baseline: Int: 0.20 (0.11), Comp: 0.26 (0.09); Year 1: Int: 0.24 (0.11), Comp: 0.35 (0.16); Year 2: Int: 0.17 (0.11), Comp: 0.37 (0.28); Group by time interaction: p=0.01 ↑; Group by time by environment interaction: p=0.002 ↑ (significant difference between groups for recess - decrease in outside healthy food for intervention and no change for control, significant difference between groups for lunch - increase in outside healthy food for intervention and decrease for control, no significant difference between groups for classroom); [underlined: Outside healthy beverages (items/child/wk)]:; Baseline: Int: 0.10 (0.08), Comp: 0.12 (0.05); Year 1: 0.14 (0.07), Comp: 0.19 (0.06); Year 2: 0.09 (0.07), Comp: 0.16 (0.08); Group by time interaction: p=NS; Group by time by environment interaction: p=NS; *Did not report whether SD or SE; Note: Schools were unit of analysis; Model adjustments: None; Funding source(s): USDA National Research Initiative
Cullen, 2015 ^26^; United States (Houston, Texas), RCT-Cluster; Total Baseline N: NR; Total Analytic N: 1,149; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: White: 59%; Black: 10%; Asian: 10%; Hispanic: 21% (across entire school district); SES: Eligibility for free or reduced price meals (across entire school district): 26% | Int: New NSLP guidelines for fruits and vegetables (3 servings) (N=535; Cluster N=4); Comp: Current USDA meal pattern for fruits and vegetables (2 servings) (N=614; Cluster N=4); Theory/framework: NR; Intervention duration: 1 semester; Outcome measurement: Students’ food selection and intake was recorded via direct observation in the cafeteria during lunch by trained research staff assigned to specific schools; school visits occurred 1 d/wk during the semester | Food selection at lunch, % selecting or Mean (SE); [underlined: Fruit (%)]: Int: 56%, Comp: 51%, p=NS; [underlined: Fruit (cups)]: Int: 0.29 (0.01), Comp: 0.26 (0.01), p=NS; [underlined: Juice (%)]: Int: 50%, Comp: 61%, p<0.001 ↓; [underlined: Juice (cups)]: Int: 0.26 (0.01), Comp: 0.32 (0.01), p<0.001 ↓; [underlined: Fruit and juice (%)]: Int: 82%, Comp: 87%, p<0.05 ↓; [underlined: Fruit and juice (cups)]: Int: 0.54 (0.01), Comp: 0.59 (0.01), p<0.05 ↓; [underlined: Total vegetables (%)]: Int: 63%, Comp: 52%, p<0.001 ↑; [underlined: Total vegetables (cups)]: Int: 0.32 (0.01), Comp: 0.22 (0.01), p<0.001 ↑; [underlined: Dark green vegetables (%)]: Int: 10%, Comp: 8%, p=NS; [underlined: Dark green vegetables (cups)]: Int: 0.06 (0.01), Comp: 0.03 (0.01), p<0.01 ↑; [underlined: Red orange vegetables (%)]: Int: 19%, Comp: 17%, p=NS; [underlined: Red orange vegetables (cups)]: Int: 0.07 (0.01), Comp: 0.06 (0.01), p=NS; [underlined: Starchy vegetables (%)]: Int: 47%, Comp: 36%, p<0.001 ↑; [underlined: Starchy vegetables (cups)]: Int: 0.15 (0.01), Comp: 0.10 (0.01), p<0.001 ↑; [underlined: Other vegetables (%)]: Int: 13%, Comp: 11%, p=NS; [underlined: Other vegetables (cups)]: Int: 0.02 (0.00), Comp: 0.02 (0.00), p=NS; [underlined: Legumes (%)]: Int: 4%, Comp: 2%, p=NS; [underlined: Legumes (cups)]: Int: 0.02 (0.00), Comp: 0.01 (0.00), p=NS; [underlined: Grains (%)]: Int: 100%, Comp: 100%, p=NS; [underlined: Grains (oz eq)]: Int: 2.21 (0.04), Comp: 2.21 (0.04), p=NS; [underlined: Whole grains (%)]: Int: 40%, Comp: 48%, p<0.05 ↓; [underlined: Whole grains (oz eq)]: Int: 0.48 (0.03), Comp: 0.59 (0.03), p<0.01 ↓; [underlined: Protein foods (%)]: Int: 100%, Comp: 100%, p=NS; [underlined: Protein foods (oz eq)]: Int: 2.00 (0.04), Comp: 2.27 (0.04), p<0.001 ↓; [underlined: Milk (%)]: Int: 90%, Comp: 91%, p=NS; Milk (oz): Int: 7.11 (0.11), Comp: 7.28 (0.10), p=NS; Food consumed at lunch, Mean (SE); [underlined: Fruit (cups)]: Int: 0.20 (0.01), Comp: 0.18 (0.01), p=NS; [underlined: Fruit (%)]: Int: 67% (2), Comp: 64% (2), p=NS; [underlined: Juice (cups)]: Int: 0.18 (0.01), Comp: 0.23 (0.01), p<0.001 ↓; [underlined: Juice (%)]: Int: 70% (2), Comp: 70% (2), p=NS; [underlined: Fruit and juice (cups)]: Int: 0.38 (0.01), Comp: 0.41 (0.01), p=NS; [underlined: Fruit and juice (%)]: Int: 69% (2), Comp: 67% (2), p=NS; [underlined: Total vegetables (cups)]: Int: 0.14 (0.01), Comp: 0.10 (0.01), p<0.01 ↑; [underlined: Total vegetables (%)]: Int: 40% (17), Comp: 63% (18), p=NS; [underlined: Dark green vegetables (cups)]: Int: 0.01 (0.00), Comp: 0.00 (0.00), p=NS; [underlined: Dark green vegetables (%)]: Int: 13% (4), Comp: 23% (5), p=NS; [underlined: Red orange vegetables (cups)]: Int: 0.03 (0.00), Comp: 0.03 (0.00), p=NS; [underlined: Red orange vegetables (%)]: Int: 38% (4), Comp: 43% (4), p=NS; [underlined: Starchy vegetables (cups)]: Int: 0.10 (0.01), Comp: 0.06 (0.01), p<0.01 ↑; [underlined: Starchy vegetables (%)]: Int: 39% (3), Comp: 37% (3), p=NS; [underlined: Other vegetables (cups)]: Int: 0.01 (0.00), Comp: 0.00 (0.00), p<0.05 ↑; [underlined: Other vegetables (%)]: Int: 28% (4), Comp: 15% (5), p<0.05 ↑; [underlined: Legumes (cups)]: Int: 0.01 (0.00), Comp: 0.00 (0.00), p=NS; [underlined: Legumes (%)]: Int: 46% (9), Comp: 40% (11), p=NS; [underlined: Grains (oz eq)]: Int: 1.62 (0.04), Comp: 1.65 (0.04), p=NS; [underlined: Grains (%)]: Int: 73% (2), Comp: 73% (1), p=NS; [underlined: Whole grains (oz eq)]: Int: 0.30 (0.02), Comp: 0.39 (0.02), p<0.05 ↓; [underlined: Whole grains (%)]: Int: 64% (3), Comp: 65% (3), p=NS; [underlined: Protein foods (oz eq)]: Int: 1.43 (0.05), Comp: 1.77 (0.04), p<0.001 ↓; [underlined: Protein foods (%)]: Int: 72% (2), Comp: 79% (1), p<0.01 ↓; [underlined: Milk (oz)]: Int: 5.38 (0.15), Comp: 5.19 (0.14), p=NS; [underlined: Milk (%)]: Int: 81% (5), Comp: 75% (5), p=NS; Model adjustments: Sex; school SES; grade; Funding source(s): NIH, USDA/Agricultural Research Service
Delaney, 2017 ^27^; Australia, RCT-Cluster; Total Baseline N: 2,714; Total Analytic N: 2,714; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: No lunch order during follow-up (complete case analyses); Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: NR; SES: School in least advantaged SES region using the Socio-Economic Index for Area (SEIFA 2011): 50% | Int: Redesign of canteen (cafeteria) online ordering system based on consumer-behavior strategies by modifying availability, labeling, placement, and prompting (N=1,144; Cluster N=5); Comp: No intervention (N=1,570; Cluster N=5); Theory/framework: Consumer-behavioral strategies; Intervention duration: 2 mo; Outcome measurement: Purchases assessed via report from online ordering system during 2 mo baseline period and 2 mo intervention period. Nutritional content determined by food label and food database | Nutrient content of lunch purchases during intervention, Mean (SD) and Mean difference (95% CI); [underlined: Saturated fat (g)]: Int: 2.87 (1.73), Comp: 4.84 (2.71), Int vs Comp (ref): −2.37 (−3.08, −1.67), p<0.001 ↑; [underlined: Saturated fat (% energy)]: Int: 9.32 (4.72), Comp: 10.69 (4.16), Int vs Comp (ref): - 1.77 (−2.73, −0.82), p<0.001 ↑; [underlined: Sugar (g)]: Int: 18.19 (10.44), Comp: 16.42 (12.63), Int vs Comp (ref): 1.16 (−0.50, 2.83), p=0.17; [underlined: Sugar (% energy)]: Int: 37.82 (24.89), Comp: 18.38 (12.49), Int vs Comp (ref): 19.82 (13.92, 25.71), p<0.001 ↓; [underlined: Sodium (mg)]: Int: 399.89 (307.86), Comp: 526.54 (295.79), Int vs Comp (ref): −227.56 (−334.93, −120.19), p<0.001 ↑; Nutritional quality of lunch purchases during intervention, Mean (SD) and Mean difference (95% CI); [underlined: High nutritional value items in lunch orders (%)]: Int: 51.21 (36.94), Comp: 37.93 (27.06), Int vs Comp (ref): 21.47 (13.83, 29.11), p<0.001 ↑; [underlined: Low nutritional value items in lunch orders (%)]: Int: 1.21 (8.02), Comp: 11.11 (16.48), Int vs Comp (ref): −7.52 (−11.33, −3.71), p<0.001 ↑; Effects of intervention on nutrient content of purchases did not vary by student grade (K-2 vs 3-6); intention to treat analyses with multiple imputation (above) were similar to complete case analyses (Int N: 936, Comp N: 1435); Model adjustments: Baseline values; clustering at school level; Funding source(s): Hunter New England Population Health, University of Newcastle Australia, National Health and Medical Research Council, National Heart Foundation, Hunter Medical Research Institute
Folta, 2006,^28^ Shape Up Somerville: Audio Adventures; United States (Somerville, Massachusetts), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 8; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Could not implement bean dishes in school; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: ~48%; Race/ethnicity: White: ~48%; Black: ~18%; Asian: ~7%; Native American: ~0.5%; Hispanic: ~26%; SES: Free/reduced price lunch: ~65% | Int: Introduction of variety of bean/legume dishes in school meals with a series of audio messages promoting bean/legume consumption (N=487 [81] students enrolled per school; Cluster N=3); Comp: Introduction of variety of bean/legume dishes in school meals (N=393 [91] students enrolled per school; Cluster N=3); Theory/framework: SCT; Theory of Reasoned Action; Intervention duration: ~3 mo; Outcome measurement: Choice of bean main dish (compared to standard main dish - hot dog) measured by direct observation by trained data collectors at the end of the cafeteria line on each day bean dishes were served | Choice of bean dish during intervention, OR (95% CI); [underlined: Choice of beans (all dishes)], Int vs Comp (ref): 0.93 (0.81, 1.07), p=0.31; [underlined: Choice of bean taco], Int vs Comp (ref): 0.96 (0.80, 1.14), p=0.61; [underlined: Choice of bean chili] , Int vs Comp (ref): 1.50 (1.12, 2.04), p=0.01 ↑; Note: Effects on bean dish selection varied by intervention dose delivered, with the intervention school with highest dose having greater odds of selection and intervention school with lowest dose having lower odds of selection (see paper for more detail); Model adjustments: Grade; sex; Funding source(s): General Mills’ Champions Youth Nutrition and Fitness Grant
Goto, 2013 ^29^; United States (Northern CA), RCT-Cluster; Total Baseline N: NR; Total Analytic N: 677; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: Majority non-white; SES: NSLP eligibility rate of school >50%: 100% | Int1: Acquiring chocolate milk at lunch was made more difficult (N=247; Cluster N=1); Int2: Perceived availability and prominence of chocolate milk at lunch was reduced (N=153; Cluster N=1); Comp: No intervention (N=277; Cluster N=1); Theory/framework: Theory of Behavioral Economics; Intervention duration: 5 d; Outcome measurement: Selection of milk observed by trained research assistants during lunch at point of sale for 5 d pre-intervention and 5 d during the intervention | Percentage of students selecting white milk at least once during week, % and OR (95% CI); [underlined: Pre-intervention]: Int1: 30%, Int2: 33%, Comp: 23%; [underlined: During intervention]: Int1: 48%, Int2: 35%, Comp: 24%; Int1 vs Comp (ref): 3.92 (2.06, 7.47), p<0.001 ↑; Int2 vs Comp (ref): 1.58 (0.88, 2.82), p=0.125; Proportion of total milk selected that was white milk during week, Mean (SD) and IRR (95% CI); [underlined: Pre-intervention]: Int1: 0.24 (0.40), Int2: 0.24 (0.39), Comp: 0.17 (0.34); [underlined: During intervention]: Int1: 0.33 (0.41), Int2: 0.26 (0.40), Comp: 0.17 (0.34); Int1 vs Comp (ref): 2.14 (1.57, 2.92), p<0.001 ↑; Int2 vs Comp (ref): 1.32 (0.98, 1.77), p=0.064; Model adjustments: Grade in school; pre-intervention selection; number of observations (IRR); Funding source(s): USDA Supplemental Nutrition Assistance Program
Hendy, 2005 ^31^; United States (Rural county in eastern Pennsylvania), RCT-Cluster; Total Baseline N: 313; Total Analytic N: 188; Total Baseline Cluster N: 14; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Half the school classrooms were randomized, only 4 classrooms from each grade were selected and to be included, children had to be observed at least 4 times at baseline and 12 of 18 times under token reinforcement; Grade level: Elementary school; Age (Mean (SD)): 8.2 (1.3) y; Female: 51%; Race/ethnicity: White: 95%; SES: NR | Int: “Kids Choice” school lunch program targeting fruit reinforcement: Peers encouraged participation, one additional fresh fruit and fresh vegetable were added to all lunch trays to provide children a choice, and small, delayed reinforcement was provided for consumption of 1/8 cup of fruit during the lunch meal. (N=96; Cluster N=6); Comp: “Kids Choice” school lunch program targeting vegetable reinforcement: Peers encouraged participation, one additional fresh fruit and fresh vegetable were added to all lunch trays to provide children a choice, and small, delayed reinforcement was provided for consumption of 1/8 cup of vegetable during the lunch meal. (N=92; Cluster N=6); Theory/framework: Self Determination Theory; SCT; Group Socialization Theory; Intervention duration: ~6 wk; Outcome measurement: Trained observers recorded when children consumed at least 1/8 cup of fruit or vegetable during a school lunch period for 3 d/wk for 2 wk baseline and 6 wk during intervention (split into three 4 meal blocks). | Number of meals in which at least 1/8 cup fruit was consumed; [underlined: 1st grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; [underlined: 2nd grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; [underlined: 4th grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; Post-hoc comparisons found only children reinforced for eating fruit showed a significant, lasting increase in fruit consumption from baseline through three periods of reinforcement; Number of meals in which at least 1/8 cup vegetables was consumed; [underlined: 1st grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; [underlined: 2nd grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; [underlined: 4th grade]: Group: p<0.001; Group by Study Phase interaction: p<0.001 ↑; Post-hoc comparisons found only children reinforced for eating vegetables showed a significant, lasting increase in vegetable consumption from baseline through three periods of reinforcement; N by grade and group: 1st grade: Int: n=29, Comp: n=31; 2nd grade: Int: n=33, Comp: n=28; 4th grade: Int n=34, Comp: n=33; Model adjustments: None; Funding source(s): Penn State University
Lai, 2020 ^32^; United States (Chicago Heights, Illinois), RCT-Cluster; Total Baseline N: 17,346 observations; Total Analytic N: 14,130 observations (Children contributed multiple observations); Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: Experimenter or teacher error, data recording error, child not following directions; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: 51%; Race/ethnicity: White: 4%; Black: 39%; Hispanic: 57%; Multiracial: 1%; SES: Eligible for free or reduced-price school lunch: ~95% | Int1: Verbal prompt in cafeteria line (N=548 children, 2,882 observations; Cluster N=NR); Int2: Health prompt in cafeteria line (N=582 children, 3,034 observations; Cluster N=NR); Int3: Taste prompt in cafeteria line (N=515 children, 2,866 observations; Cluster N=NR); Int4: Incentives attached to white milk cartons in cafeteria line with no prompt (N=539 children, 2,494 observations; Cluster N=NR); Comp: No intervention (N=466 children, 2,854 observations; Cluster N=NR); Theory/framework: Rational Choice Theory; Intervention duration: 5 d; Outcome measurement: Food selection and consumption during lunch recorded by researchers; milk intake calculated by weight and food consumption by visual inspection | Difference in selection of white milk over chocolate milk, Coefficient (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: 2.22 (0.59), p<0.01 ↑; Int2 vs Comp: 2.16 (0.65), p<0.01 ↑; Int3 vs Comp: 1.52 (0.69), p<0.01 ↑; Int4 vs Comp: 2.52 (0.37), p<0.01 ↑; Int1, Int2, and Int3 vs Comp: p<0.01 ↑; Int4 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.94; Int1 vs Int3, p=0.41; Int2 vs Int3, p=0.44; Int1 vs Int4, Int2 vs Int4, Int3 vs Int4: all p>0.10; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: 1.39 (0.39); p<0.01 ↑; Int2 vs Comp: 1.31 (0.48); p<0.01 ↑; Int3 vs Comp: 0.80 (0.49); p=0.11; Int4 vs Comp: 1.45 (0.45); p<0.01 ↑; Difference in milk intake (mL), β (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: −7.20 (7.17), p=NS; Int2 vs Comp: −5.57 (11.31), p=NS; Int3 vs Comp: −4.56 (7.00), p=NS; Int4 vs Comp: −20.16 (6.58), p<0.01 ↓; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: 3.88 (5.81), p=NS; Int2 vs Comp: −4.67 (11.66), p=NS; Int3 vs Comp: −13.24 (11.31), p=NS; Int4 vs Comp: −24.76 (10.03), p<0.05 ↓; Difference in added sugars intake (g), β (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: −0.52 (0.25), p<0.05 ↑; Int2 vs Comp: −0.66 (0.27), p<0.05 ↑; Int3 vs Comp: −0.63 (0.28), p<0.05 ↑; Int4 vs Comp: −1.56 (0.53), p<0.01 ↑; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: −0.05 (0.18), p=NS; Int2 vs Comp: −0.34 (0.38), p=NS; Int3 vs Comp: −0.61 (0.32), p<0.1 ↑; Int4 vs Comp: −0.98 (0.44), p<0.05 ↑; Model adjustments: Baseline white milk intake; Funding source(s): Cornell Center for Behavioral Economics and Child Nutrition Programs
Loewenstein, 2016 ^33^; United States (Utah), RCT-Cluster; Total Baseline N: ~8,000; Total Analytic N: NR; Total Baseline Cluster N: 40; Total Analytic Cluster N: 40; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age: NR; Female: ~49%; Race/ethnicity: White: ~77%; Hispanic: ~17%; Other: ~6%; SES: Free or reduced price lunch: ~43% | Int1: Incentives given for eating a serving a fruit or vegetables at lunch for 3 wk (N=663 [190]/school; Cluster N=22); Int2: Incentives given for eating a serving a fruit or vegetables at lunch for 5 wk (N=629 [150]/school; Cluster N=18); Theory/framework: NR; Intervention duration: 3 or 5 wk; Outcome measurement: Researchers recorded the number of servings children took and ate of fruit and vegetables during lunch at baseline, during the intervention, 1-mo follow-up, and 2-mo follow-up | Intake during final intervention wk (3 or 5 wk); [underlined: Ate at least 1 svg/d of fruits and vegetables (%)]: Int: 75.4 vs Int2: 79.7, p>0.10; [underlined: Amount eaten of fruit and vegetables (svg/d)]: Int: 0.906 vs Int2: 0.927, p>0.10; Intake at 1-mo follow-up; [underlined: Ate at least 1 svg/d of fruits and vegetables (%)]: Int: 49.6 vs Int2: 58.5, p>0.10; [underlined: Amount eaten of fruit and vegetables (svg/d)]: Int: 0.658 vs Int2: 0.762, p>0.10; Intake at 2-mo follow-up; [underlined: Ate at least 1 svg/d of fruit and vegetables (%)]: Int: 48.1 vs Int2: 54.0, p>0.10; [underlined: Amount eaten of fruit and vegetables (svg/d)]: Int: 0.648 vs Int2: 0.716, p>0.10; Model adjustments: Grade; gender; day of week; school; Funding source(s): USDA Economic Research Service
Marchiori, 2012 ^101^; Belgium, RCT-Parallel; Total Baseline N: 85; Total Analytic N: 77; Criteria for exclusion from analysis: Presence of food allergies, overweight, weight problems, dieting behavior, food intake control in order to gain or lose weight, lack of hunger; Grade level: Elementary school; Age (Mean (SD)): 9.2 (2.5) y; Female: 55%; Race/ethnicity: Belgian nationality: 86%; SES: NR | Int: Half-sized cookies for school snack (N=40); Comp: Normal-sized cookies for school snack (N=37); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Amount and number of cookies consumed were assessed by subtracting number of cookies left from the initial count | Intake, Mean (SD) or Mean; [underlined: Cookies consumed (#)]: Int: 14.6 (5.8) , Comp: 9.2 (3.5), p<0.001 ↓; [underlined: Amount of cookies consumed (g)]: Int: 51, Comp: 64, p<0.05 ↑; [underlined: Amount of cookies consumed (kcal)]: Int: 274, Comp: 342, p<0.05 ↑; Model adjustments: Age; BMI; height; weight; exercise; hunger; Funding source(s): National Research Fund Luxembourg
Mazzeo, 2017 ^34^; United States (Mid-Atlantic), RCT-Cluster; Total Baseline N: 606; Total Analytic N: 606; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: No participation in school breakfast and/or lunch program; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: White: ~16%; Black: ~50%; Hispanic/Latino: ~29%; Biracial: ~4%; SES: Recipient of free/reduced price breakfast and lunch: ~63% | Int: Encouragement to try fruits or vegetables in the cafeteria with verbal praise and sticker if food was tasted (N=300; Cluster N=1); Comp: No intervention (N=306; Cluster N=1); Theory/framework: NR; Intervention duration: 8 wk; Outcome measurement: Plate waste assessed by trained research assistants in 20% increments from no food left to all food left at baseline, immediate post-intervention, and 6-wk follow-up | Plate waste at post-intervention and 6-wk follow-up, %; [underlined: Fruit and vegetables combined (excluding juice)]: Group by time interaction: p<0.0001 ↑; Follow-up: Int: 39.23%, Comp: 52.06%, p<0.05 ↑; [underlined: Fruit and vegetables combined (including juice)]: Group by time interaction: p=0.0006 ↑; Follow-up: Int: 35.08%, Comp: 46.16%, p<0.05 ↑; [underlined: Vegetables]: Group by time interaction: p=0.0001 ↑; Follow-up: Int: 34.52%, Comp: 57.26%, p<0.05 ↑; [underlined: Fruits (excluding juice)]: Group by time interaction: p=0.6309; Group: NR, p=NS; [underlined: Fruits (including juice)]: Group by time interaction: p=0.2384; Group: Int: 35.96%, Comp: 39.01%, p=0.0470 ↑; Model adjustments: None; Funding source(s): NIH
Miller, 2016 ^100^; United States (Alachua County, Florida), RCT-Parallel; Total Baseline N: NR; Total Analytic N: 71; Criteria for exclusion from analysis: Students who never pre-ordered their school lunch; Grade level: Elementary school; Age: NR; Female: 43%; Race/ethnicity: White: 71%; Black: 18%; Other: 11%; SES: NSLP Eligibility Status: Free lunch: 53.3%; Reduced-price : 8.3%; Full-price: 38.5% | Int1: Children pre-ordered lunch each morning using a web-based program (N=35); Int2: Children pre-ordered lunch each morning using a web-based program which provided behavioral nudges based on MyPlate recommendations (N=36); Comp: No intervention (Group did not meet I/E criteria) (N=98); Theory/framework: NR; Intervention duration: 2 wk; Outcome measurement: Percent pre-ordered meals containing vegetable, fruit and low-fat milk as recorded by the computer. | Food component preordered during intervention, %; [underlined: Meals containing vegetable]: Int1: 75.2% vs Int2: 89.8%, p=0.000 ↑; Int1 vs Int2: p=0.056; Int1 vs Int2 during wk 1: p=0.333; Int vs Int2 during wk 2: p=0.023 ↑; [underlined: Meals containing fruit]: Int1: 85.5% vs Int2: 93.4%, p=0.018 ↑; Int1 vs Int2: p=0.011 ↑; Int1 vs Int2 during wk 1: p=0.034 ↑; Int vs Int2 during wk 2: p=0.077; [underlined: Meals containing low-fat milk]: Int1: 76.4% vs Int2: 89.2%, p=0.002 ↑; Int1 vs Int2: p=0.014 ↑; Int1 vs Int2 during wk 1: p=0.019 ↑; Int1 vs Int2 during wk 2: p=0.114; Note: Meals were the unit of analysis (Int: n=229 at baseline and n=165 during intervention; Int2: n=241 at baseline and n=167 during intervention); Model adjustments: Race/ethnicity; sex; NSLP participation; Funding source(s): University of Florida
Moore, 2008 ^35^; United Kingdom, RCT-Cluster; Total Baseline N: 1,632; Total Follow-up N: 1,612; (Repeated cross-sections within schools, some participants assessed at both time points); Total Baseline Cluster N: 43; Total Analytic Cluster N: 43; Criteria for exclusion from analysis: Incomplete data, reported eating >8 portions of fruit; Grade level: Elementary school; Age (Range): 9-11 y; Female: ~51%; Race/ethnicity: NR; SES: Localities with free school meal entitlement higher than national average (>17%): 100% | Int: New fruit tuck shop at school (N=918 at baseline wave, N=921 at follow-up wave; Cluster N=23); Comp: No intervention (N=714 at baseline wave, N=691 at follow-up wave; Cluster N=20); Theory/framework: NR; Intervention duration: ~1 y; Outcome measurement: Intake assessed via single, computerized, validated 24 h recall completed by children at baseline and post-intervention. | Intake at post-intervention, Raw mean (median) and Adjusted mean difference (95% CI); [underlined: Fruit (svg/d)]: Int: 2.54 (2), Comp: 2.51 (2); Int vs Comp (ref): 0.089 (−0.199, 0.377), p=NS; Interaction with school policy: p=NS; [underlined: Fruit (svg/d at school)]: Int: 0.74 (0), Comp: 0.69 (0); Int vs Comp (ref): 0.057 (−0.100, 0.213), p=NS; Interaction with school policy: p<0.02; “Fruit only” snack policy, Int vs Comp (ref): 0.37 0.11, 0.64); “No food” snack policy, Int vs Comp (ref): 0.14 (−0.30, 0.58); No restrictions, Int vs Comp (ref): −0.13 (−0.33, 0.07); [underlined: Sweets/chocolates/biscuits (svg/d)]: Int: 3.95 (3), Comp: 3.81 (3); Int vs Comp (ref): −0.137 (−0.527, 0.255), p=NS; Interaction with school policy: p=NS; [underlined: Sweets/chocolates/biscuits (svg/d at school)]: Int: 1.12 (1), Comp: 1.01 (1); Int vs Comp (ref): −0.116 (−0.289, 0.056), p=NS; Interaction with school policy: p=NS; [underlined: Chips (svg/d)]: Int: 1.60 (1), Comp: 1.45 (1); Int vs Comp (ref): −0.036 (−0.249, 0.177), p=NS; Interaction with school policy: p=NS; [underlined: Chips (svg/d at school)]: Int: 0.80 (1), Comp: 0.68 (1); Int vs Comp (ref): −0.047 (−0.153, 0.060), p=NS; Interaction with school policy: p=NS; Model adjustments: Baseline intake; school size; country (England or Wales); snack policy; preference for intervention; Funding source(s): Food Standards Agency Food Choice Programme
Morizet, 2012 ^36^; France, RCT-Cluster; Total Baseline N: 362; Total Analytic N: 362; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Grade level: Elementary school; Age (Range): 8-11 y; Female: NR; Race/ethnicity: NR; SES: NR | Int1: Labeling new vegetable dishes with basic information (N=44 carrot; N=72 broccoli; Cluster N=2); Int2: Labeling new vegetable dishes with basic information and an attractive name (N=41 carrot, N=90 broccoli; Cluster N=2); Comp: No intervention (N=60 carrot, N=65 broccoli; Cluster N=2); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Choice of vegetable dish assessed in cafeteria by video recording during lunch | Choice of new vegetable dish over familiar vegetable dish, %; [underlined: Carrot]: Data NR (figure only); Int1 > Comp, p=0.012; Int2 > Comp, p=0.002 ↑; Int1 vs Int2 NS, p=0.585; [underlined: Broccol]i: Data NR (figure only); Int1 vs Comp NS, p=0.08; Int2 vs Comp NS, p=0.053; Int1 vs Int2 NS, p=0.916; Model adjustments: None; Funding source(s): Bonduelle
Olsen, 2012 ^37^; Denmark, RCT-Cluster; Total Baseline N: 220; Total Analytic N: NR; Total Baseline Cluster N: NR; Total Analytic Cluster N: NR; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): ~10.5 y; Female: ~43%; Race/ethnicity: Primarily Caucasian; SES: Primarily middle class | Int1: Exposure to a mixture of a neutrally liked and a liked vegetable for a pre-lunch snack for 6 d, followed by exposure to a mixture of a neutrally liked, a liked, and a disliked vegetable for a pre-lunch snack for 6 d (N=NR; Cluster N=NR); Int2: Exposure to a neutrally liked vegetable for a pre-lunch snack for 6 d, followed by exposure to a mixture of a neutrally liked, a liked, and a disliked vegetable for a pre-lunch snack for 6 d (N=NR; Cluster N=NR); Int3: Exposure to a mixture of a neutrally liked and a disliked vegetable for a pre-lunch snack for 6 d, followed by exposure to a mixture of a neutrally liked, a liked, and a disliked vegetable for a pre-lunch snack for 6 d (N=NR; Cluster N=NR); Theory/framework: Evaluative conditioning; Intervention duration: ~2 wk; Outcome measurement: Intake assessed during each 6-d period by subtracting the weight of leftover vegetables from the portion offered during pre-lunch snack. | Total vegetable intake across both periods, Mean (SE); Int1: 539.3 (35.2), Int2: 332.3 (34.5), Int3: 347.4 (32.1); Group by day by vegetable interaction: p<0.0001 ↑; [underlined: Cauliflower (neutrally liked; g)]: Int1: 241.7 (22.0), Int2: 220.8 (28.1), Int3: 171.0 (19.8); Int1 vs Int2: p=0.005; Int1 vs Int3: p=0.0005 ↑; [underlined: Sugar snap peas (liked; g)]: Int1: 266.1 (14.8), Int2: 86.7 (5.8), Int3: 82.2 (4.9); Int1 vs Int2 vs Int3: all p=NS; [underlined: Celery (disliked)]: Int1: 31.9 (5.8), Int2: 24.7 (5.0), Int3: 94.2 (14.6); Int1 vs Int2 vs In3: all p=NS; Note: Because only some groups received celery or sugar snap peas during the first period, the total intake for these vegetables appear much higher despite lack of statistical significance; Model adjustments: Vegetable liking; pickiness; child and class specific random effects; other explanatory variables describing attitudes and background of the children were tested but NS; Funding source(s): Danish Strategic Research Council for Food and Health, vegetables provided by Agrova Food
Raju, 2010 ^39^; United States, RCT-Cluster; Total Baseline N: ~31,000; Total Analytic N: NR (646 of 1,659 homerooms with complete data); Total Baseline Cluster N: 55; Total Analytic Cluster N: 55; Criteria for exclusion from analysis: Missing data; Grade level: Elementary and Middle/Junior high school; Age (Range): 5-14 y; Female: NR; Race/ethnicity: NR; SES: NR | Int1: Personal pledge and incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=NR); Int2: Competition and incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=); Comp: Only incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=NR); Theory/framework: Behavior modification theories; Intervention duration: 6 wk; Outcome measurement: Fruit and vegetable choice: trained cafeteria staff kept record of whether students chose ≥2 fruit and vegetables during lunch at 1-wk follow-up) and 10-wk follow-up; unit of analysis was the proportion of students at the homeroom level | Selection of ≥2 fruit and/or vegetables at lunch, Change in proportion from baseline to 10-wk follow-up*; [underlined: Younger children (Grades 1-2)]:; Int1: 0.08, Int2: 0.24, Comp: 0.09; Int1 vs Comp, Pr=NS; Int2 > Comp, Pr>0.95 ↑; Int1 < Int2, Pr>0.95 ↑; [underlined: Older children (Grades 3-8)]:; Int1: 0.07, Int2: 0.11, Comp: 0.03; Int1 > Comp, Pr>0.95 ↑; Int2 > Comp, Pr>0.90 ↑; Int1 < Int2, Pr>0.95 ↑; *Pr = posterior probability (Pr>0.95 analogous to p<0.05); Model adjustments: Baseline proportion of students choosing fruits and vegetables; homeroom; school; Funding source(s): NR
Samek, 2019 ^42^; United States (Chicago Heights, Illinois), RCT-Cluster; Total Baseline N: 1,469; Total Follow-Up N: 1,483; (Note: Data analyzed at classroom level, allowing N at follow-up to be greater than baseline); Total Baseline Cluster N: 90; Total Analytic Cluster N: 90; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: Black: ~38%; Hispanic: ~24%; SES: Eligible free/reduced price: >90% | Int1: Brief educational message about milk with sticker prior to lunch (N=498 on day 1; N=524 on day 2; Cluster N=30); Int2: Brief educational message about milk with encouragement to make goal to drink white milk prior to lunch (N=502 on day 1, N=530 on day 2; Cluster N=33); Comp: Brief educational message about milk prior to lunch only (N=469 on day 1, N=429 on day 2; Cluster N=27); Theory/framework: Behavioral theories (theory of reciprocity, theories of self-control); Intervention duration: 1 d; Outcome measurement: For each classroom, the proportion of children choosing white milk relative to total milk (white + chocolate milks) was measured by research assistants observing milk selection in the cafeteria on 2 consecutive days | Baseline (day 1) vs Intervention (day 2) milk selection, %; Int 1: 14.9% vs 65.5%; Int 2: 9.8% vs 54.8%; Comp: 8.3% vs 47.8%, all p<0.05 ↑; Day 2 selection: Int1 vs Comp: p<0.01 ↑; Int 2 vs Comp: p=0.03 ↑; Int 1 vs Int 2: p<0.01 ↑; Difference in proportion selecting white milk on day 2, Mean proportion (SE); Int1: 0.142 (0.0462), p<0.05 ↑; K-3rd grade: 0.176 (0.06888), p<0.05 ↑; 4-6th grade: 0.0796 (0.0815), p=NS; Int2: 0.101 (0.0571), p=NS; K-3rd grade: 0.180 (0.0697), p<0.05 ↑; 4-6th grade: 0.0497 (0.0910), p=NS; Model adjustments: None (primary analysis); grade (secondary analysis); baseline selection (secondary analysis); Funding source(s): USDA Research Innovation and Development Grants in Economics Program; USDA Cooperative Agreement
Schwartz, 2007 ^43^; United States (New England), RCT-Cluster; Total Baseline N: ~324; Total Analytic N: ~324; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: Caucasian: ~90%; SES: Eligible for free/reduced price lunch: <10% | Int: Verbal prompt by cafeteria workers asking whether children would like fruit or juice during lunch (N=~155; Cluster N=1); Comp: No verbal prompt given (N=~169; Cluster N=1); Theory/framework: NR; Intervention duration: ~7 mo; Outcome measurement: Selection and consumption of fruit or juice assessed by parent volunteers, who observed children in the cafeteria for 2 days (after ~5 mo and ~7 mo of intervention) | Selection of fruit or juice, % and OR (95% CI); [underlined: After ~5 mo]:; Fruit: Int: 76%, Comp: 45%, 3.96 (2.2, 7.0), p=NR ↑; Juice: Int: 21%, Comp: 20%, 1.0 (0.5, 2.0), p=NR; [underlined: After ~7 mo]:; Fruit: Int: 48%, Comp: 32%, 1.9 (1.1, 3.3), p=NR ↑; Juice: Int: 38%, Comp: 23%, 2.1 (1.2, 3.8), p=NR ↑; Consumed fruit or juice selected, % and OR (95% CI); [underlined: After ~5 mo]:; Fruit: Int: 70%, Comp: 69%, 3.50 (2.0, 6.2), p=NR ↑; Juice: Int: 64%, Comp: 58%, 1.1 (0.6, 2.5), p=NR; [underlined: After ~7 mo]:; Fruit: Int: 87%, Comp: 65%, 2.3 (1.3, 4.2), p=NR ↑; Juice: Int: 88%, Comp: 62%, 2.9 (1.5, 5.5), p=NR ↑; Model adjustments: None; Funding source(s): NR
Shemilt, 2004 ^44^; United Kingdom, RCT-Cluster; Total Baseline N: 6,076; Total Analytic N: 3,008 at 3 mo, 3,007 at 12 mo; Total Baseline Cluster N: 41; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Missing data, children originally in grade 6 and 11 no longer attending intervention or control schools; Grade level: Elementary and Middle/Junior high school; Age (Mean): ~10 y; Female: ~50%; Race/ethnicity: White: ~93%; Black: ~1%; Asian: ~6%; SES: Eligible for free school meals (%): ~34% | Int: Funding to start school breakfast club (N=1,504 at 3 mo, N=1,676 at 12 mo; Cluster N=15); Comp: No intervention (N=1,504 at 3 mo, N=1,331 at 12 mo; Cluster N=11); Theory/framework: NR; Intervention duration: 1 y; Outcome measurement: Intake assessed with questionnaire developed by researchers and based on the WHO Health Behaviour in School-Aged Children Questionnaire and the European Network of Health Promoting Schools Questionnaire; administered by school staff at baseline, after 3 mo, and after 12 mo | Has fresh fruit for breakfast after 3 mo and after 12 mo, % and OR CI; [underlined: After 3 mo]: Int: 13%, Comp: 17%; Int vs Comp (ref): 0.74 (0.53, 1.02); [underlined: After 12 mo]: Int: 12%, Comp: 13%; Int vs Comp (ref): 0.97 (0.68, 1.38); Model adjustments: School type; baseline intake; sex; eligibility for free school meals; Funding source(s): United Kingdom Department of Health National Health Service Executive
Vale, 2014 ^99^; United States (Central Illinois), RCT-Parallel; Total Baseline N: 839; Total Analytic N: 820; Criteria for exclusion from analysis: Contamination with other food or beverage, unknown sex or grade of participant; Grade level: Elementary school; Age: NR; Female: 47%; Race/ethnicity: NR; SES: Eligible for free/reduced price lunch (across whole school): ~41% | Int1: Increased vegetable content of meat sauce at lunch to 0.4 c (N=272); Int2: Increased vegetable content of meat sauce at lunch to 0.45 c (N=291); Comp: Meat sauce with regular vegetable content (0.25 c) at lunch (N=257); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Intake assessed by measuring weight of entrée (spaghetti with meat sauce) at the end of lunch and subtracting that from the weight of the entrée prior to serving | Vegetable intake, Mean difference; Int 1 vs Comp (ref): 0.16 c (57% higher); Int 2 vs Comp (ref): 0.19 c (71% higher); Group effect: p=0.00 ↑; Group by grade interaction: p=0.225; Note: Similar results found when boys and girls were analyzed separately; Model adjustments: Grade by intervention group interaction; Funding source(s): NR
van Kleef, 2014 ^46^; The Netherlands, RCT-Cluster; Total Baseline N: 47 classes; Total Analytic N: 46 classes; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Leftover bread rolls accidentally mixed up with already counted leftover bread rolls; Grade level: Elementary school; Age (Mean (SD)): 9.7 (1.2) y; Female: ~50%; Race/ethnicity: NR; SES: NR | Int1: Regular shaped whole wheat bread and regular shaped white bread (N=12 classes; Cluster N=3); Int2: Regular shaped whole wheat bread and fun-shaped white bread (N=12 classes; Cluster N=3); Int3: Fun-shaped whole wheat bread and regular shaped white bread (N=11 classes; Cluster N=3); Comp: Fun-shaped whole wheat bread and fun-shaped white bread (N=11 classes; Cluster N=3); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Observed consumption measured at class level by subtracting number of leftover bread rolls from total number of rolls available before breakfast; children’s self-reported consumption measured via survey after breakfast | Observed intake (number of rolls), Mean (SD); [underlined: Total bread rolls]:; Int1: 3.0 (0.7), Int2: 2.6 (0.8), Int3: 3.3 (0.9), Comp: 2.8 (0.4); Whole wheat – fun shape (Int3 and Comp): p=0.20, White bread – fun shape (Int2 and Comp): p=0.06, Interaction: p=0.64; [underlined: Whole wheat bread rolls]:; Int1: 0.6 (0.5), Int2: 0.3 (0.3), Int3: 1.4 (0.6), Comp: 0.5 (0.2); Whole wheat – fun shape (Int3 and Comp): p=0.001 ↑, White bread – fun shape (Int2 and Comp): p<0.001 ↓, Interaction: p=0.02; [underlined: White bread rolls]:; Int1: 2.3 (0.4), Int2: 2.3 (0.6), Int3: 2.0 (0.7), Comp: 2.4 (0.3); Whole wheat – fun shape: p=0.26, White bread – fun shape: p=19, Interaction: p=0.18; *Similar results when analyzed as g/wk; Self-reported intake (number of rolls; N=904), Mean (SD); [underlined: Total bread rolls]:; Int1: 3.6 (2.0), Int2: 3.3 (2.5), Int3: 3.8 (2.6), Comp: 3.3 (1.9); Whole wheat – fun shape (Int3 and Comp): p=0.81, White bread – fun shape (Int2 and Comp): p=0.045 ↔, Interaction: p=0.65; [underlined: Whole wheat bread rolls]:; Int1: 1.0 (1.7), Int2: 0.4 (0.9), Int3: 1.5 (2.0), Comp: 0.7 (1.4); Whole wheat – fun shape (Int3 and Comp): p<0.001 ↑, White bread – fun shape (Int2 and Comp): p<0.001 ↓, Interaction: p=0.28; [underlined: White bread rolls]:; Int1: 2.3 (2.0), Int2: 2.9 (2.4), Int3: 2.0 (2.1), Comp: 2.4 (1.7); Whole wheat – fun shape (Int3 and Comp): p<0.01 ↑, White bread – fun shape (Int2 and Comp): p<0.001 ↓, Interaction: p=0.53; Model adjustments: None (observed intake); age (self-report intake); ate breakfast before school (self-report intake); Funding source(s): Dutch Bakery Center, Ministry of Economic Affairs
van Kleef, 2015 ^45^; The Netherlands, RCT-Cluster; Total Baseline N: 254; Total Analytic N: 254; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Grade level: Elementary school; Age (Mean (SD) & Range): 10.1 (1.3) y, 8-13 y; Female: 56%; Race/ethnicity: NR; SES: NR | Int1: Cucumber with large portion size and in one piece (N=63; Cluster N=3); Int2: Cucumber with large portion size and pre-sliced (N=64; Cluster N=3); Int3: Cucumber with small portion size and in one piece (N=64; Cluster N=3); Comp: Cucumber with small portion size and pre-sliced (N=63; Cluster N=3); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: The cucumber was weighed before and after intake period by trained study staff | Cucumber intake (g), Mean (SD); Main effect, portion size (large vs small): Large: 139.4 (95.3), Small: 90.4 (47.1), p<0.001 ↑; Main effect, unit size (one piece vs pre-sliced): Data NR, p=0.58; Interaction effect, portion by unit size: Data NR, p=0.87; Excluding children who consumed the whole portion or who did not eat any of the portion from analyses did not change effects; Model adjustments: Age; appetite; Funding source(s): None
Vandeweghe, 2018 ^47^; Belgium, RCT-Cluster; Total Baseline N: 154; Total Analytic N: NR; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean (SD)): 5.08 (0.61) y; Female: 53.2%; Race/ethnicity: NR; SES: NR | Int1: Repeated neutral exposure to a generally disliked vegetable (N=NR; Cluster N=2); Int2: Repeated exposure with verbal encouragement for tasting a generally disliked vegetable (N=NR; Cluster N=2); Int3: Repeat exposure with token reward for tasting a generally disliked vegetable (N=NR; Cluster N=2); Comp: No intervention (N=NR; Cluster N=2); Theory/framework: Reinforcement Sensitivity Theory; Intervention duration: 8 wk; Outcome measurement: Vegetable consumption was determined by the difference in weight between the initial amount of chicory (60 g) and the amount of chicory after the test. Children were served 60 g steamed chicory and in a neutral tone instructed to eat as much as they liked at pre-intervention, post-intervention, and 8-wk follow-up; the test was 8 min in duration. | Pre-intervention, post-intervention, and 8-wk follow up consumption, Mean (g); Group by time interaction: p<0.001 ↑; [underlined: Pre-intervention]:; Group: p=0.747; [underlined: Post-intervention and 8-wk follow-up]:; Int1, Int 2, and Int 3 all greater than Comp: All p<0.028 ↑; Int1 vs Int2 vs Int3: All p>0.24; Note: Child reward sensitivity (based on parent completion of the 13-item Behavioral Inhibition System/Behavioral Activation System scales) had no moderating effect on consumption; Model adjustments: School; Funding source(s): Agency for Innovation by Science and Technology (IWT) of Flanders
Wolfenden, 2017 ^48^; Australia, RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 70; Total Analytic Cluster N: 57; Criteria for exclusion from analysis: Canteen no longer operational, school declined participation in follow-up data collection; Grade level: Elementary school; Age (Range): ~5-12 y; Female: NR; Race/ethnicity: NR; SES: School in least advantaged SES region using the Socio-Economic Index for Area (2006): ~44% | Int: Support for implementation of a healthy canteen (cafeteria) policy (N=2,492 purchases, 256 [147] students per school; Cluster N=27); Comp: No intervention to support implementation (N=2,310 purchases, 253 [173] students per school; Cluster N=30); Theory/framework: Theoretical Domains Framework; Intervention duration: 12-14 mo; Outcome measurement: Purchases assessed via direct observation by research staff on one school day and nutritional content calculated based on product labels and nutrient databases following the intervention. | Sodium content (mg) of purchased food, Mean (95% CI); Int: 261 (248, 274); Comp: 308 (293, 322); Difference, Int vs Comp (ref): −46.81 (−96.97, 3.35), p=0.07; Model adjustments: Clustering effects; Funding source(s): Australian Research Council, Hunter New England Population Health, Hunter Medical Research Institute
Wyse, 2019 ^49^; Australia, RCT-Cluster; Total Baseline N: 1,938; Total Analytic N: 1,727; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Did not place a lunch order during the follow-up period; Grade level: Elementary school; Age: NR; Female: NR; Race/ethnicity: NR; SES: School in least advantaged SES area: 83% | Int: Redesigned online food ordering system to list fruit and vegetable snack items first and last in the online menu (N=1,096; Cluster N=3); Comp: No changes to online ordering system menu (N=631; Cluster N=3); Theory/framework: NR; Intervention duration: 4 wk; Outcome measurement: Selection of fruit and vegetable snack items assessed via automatic records from online ordering system assessed 4 wk pre-intervention and during 4 wk intervention | Selection of fruit and vegetable snack items pre-intervention and during intervention, % and OR (95% CI); [underlined: Lunch orders containing fruit and/or vegetable snack]:; Int: 9.24% (pre-intervention), 10.63% (during intervention); Comp: 4.48% (pre-intervention), 5.23% (during intervention); Time by group interaction: 1.136 (0.791, 1.632), p=0.490; [underlined: Lunch order items that are fruit and/or vegetable snack]:; Int: 5.17% (pre-intervention), 6.01% (during intervention); Comp: 2.27% (pre-intervention), 2.64% (during intervention); Time by group interaction: 1.051 (0.653, 1.618), p=0.991; Note: Analyses based on number of orders (Pre: Int - 5334, Comp - 2476; Post: Int - 5739, Comp - 2560); Model adjustments: Clustering at school and student level; Funding source(s): Hunter New England Population Health, University of Newcastle Australia, National Health and Medical Research Council, The Heart Foundation, Australian Research Council

a Abbreviations: BMI: body mass index; CI: confidence interval; Comp: comparator; d: day; eq: equivalent; g: gram; h: hour; kcal: kilocalorie; Int: intervention; IRR: incidence rate ratio; K: kindergarten; mg: milligram; mL: milliliter; min: minute; mo: month; N: sample size; NIH: National Institute of Health; NR: not reported; NS: non-significant; OR: odds ratio; oz; ounce; p: p-value; RCT: randomized controlled trial; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; USDA: United States Department of Agriculture; vs: versus; wk: week; x: time(s); y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator; Bolded, blue text with ↔: statistically significant effects (as reported in article) in which the interpretation of results is unclear

Table 6 Risk of bias for randomized controlled trials examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in elementary school children^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Ashfield-Watt, 2009^21^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Belot, 2016^22^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Brauchla, 2013^23^ | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Cohen, 2015^24^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Coleman, 2012^25^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Cullen, 2015^26^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Delaney, 2017^27^ | LOW | LOW | LOW | LOW | LOW | LOW
Folta, 2006^28^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Goto, 2013^29^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Gray, 2007^30^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Hendy, 2005^31^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Lai, 2020^32^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Loewenstein, 2016^33^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Marchiori, 2012,^101^ Parallel | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Mazzeo, 2017^34^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Miller, 2016,^100^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Moore, 2008^35^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Morizet, 2012^36^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Olsen, 2012^37^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Perry, 2004^38^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Raju, 2010^39^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Reinaerts, 2007^41^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Reinaerts, 2008^40^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Samek, 2019^42^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Schwartz, 2007^43^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Shemilt, 2004^44^ | LOW | LOW | HIGH | LOW | LOW | SOME CONCERNS
Vale, 2014,^99^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
van Kleef, 2014^46^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
van Kleef, 2015^45^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Vandeweghe, 2018^47^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Wolfenden, 2017^48^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW
Wyse, 2019^49^ | LOW | LOW | LOW | LOW | LOW | LOW

a All studies cluster-RCTs except when otherwise noted

Table 7 Evidence examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in elementary school children^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Pro Children Study
te Velde, 2008,^20^ Pro Children Study; Norway, the Netherlands, Spain, RCT-Cluster; Total Baseline N: 1,801; Total Analytic N: 1,472; Total Baseline Cluster N: 62; Total Analytic Cluster N: 61; Criteria for exclusion from analysis: Moved, sick, invalid questionnaire; Grade level: Elementary school; Age (Mean): ~10.8 y; Female: ~53%; Race/ethnicity: NR; SES: Family education: >12 y: ~42%, 10-12 y: ~28%, 7-9 y: ~22%, <7 y: ~8% | Int: (i) Nutrition education, (ii) free fruit and vegetable provision, (iii) encouragement of parents to support fruit and vegetable intake, and (iv) raising community awareness (N=798; Cluster N=31); Comp: No intervention (N=674; Cluster N=30); Theory/framework: Intervention mapping; Intervention duration: 2 y; Outcome measurement: Intake assessed via pre-coded 24 h recall instrument completed by children for the previous day’s fruit and vegetable intake (excluding potatoes and dried fruit) at baseline, mid-intervention, and at post-intervention | Intake at mid-intervention, Mean (SD) and Adjusted mean difference (95% CI); [underlined: Fruit and vegetable intake (g/d)]: Int: 277 (241), Comp: 224 (222); Int vs Comp (ref): 56.9 (28.0, 85.9), p<0.05 ↑; [underlined: Vegetable intake (g/d)]: Int: 89 (123), Comp: 70 (101); Int vs Comp (ref): 23.6 (7.80, 39.3), p<0.05 ↑; [underlined: Fruit intake (g/d)]: Int: 188 (162), Comp: 154 (162); Int vs Comp (ref): 34.1 (14.3, 54.0), p<0.05 ↑; *Effects were primarily due to higher intake outside school hours (see paper for more details); Intake at post-intervention, Mean (SD) and Adjusted mean difference (95% CI); [underlined: Fruit and vegetable intake (g/d)]: Group by country interaction: p<0.015 ↑; Norway: Int: 332 (262), Comp: 241 (228); Int vs Comp (ref): 91.5 (49.8, 133.2), p=NR; Group by time interaction: p=0.044 ↑; Spain: Int: 192 (132), Comp: 171 (132); Int vs Comp (ref): 12.3 (−40.8, 65.3), p=NR; Group by time interaction: p=0.090; The Netherlands: Int: 270 (226), Comp: 243 (206); Int vs Comp (ref): 28.7 (−12.8, 70.1), p=NR; Group by time interaction: p=0.072; [underlined: Vegetable intake (g/d)]: Int: 73 (98), Comp: 63 (89); Int vs Comp (ref): 9.23 (−2.76, 21.2), p=NR; [underlined: Fruit intake (g/d)]: Group by country interaction: p<0.015 ↑; Norway: Int: 258 (205), Comp: 172 (180); Int vs Comp (ref): 87.8 (53.7, 121.9), p=NR; Group by time interaction: p=0.002 ↑; Spain: Int: 141 (117), Comp: 136 (116); Int vs Comp (ref): 0.01 (−46.5, 46.5), p=NR; Group by time interaction: p=0.032 ↓; The Netherlands: Int: 176 (155), Comp: 158 (157); Int vs Comp (ref): 17.3 (−10.8, 45.4), p=NR; Group by time interaction: p=0.175; *Effects for Norway seen during and outside of school hours (see paper for more details); Model adjustments: Age; sex; baseline value; country; nesting of student within school; Funding source(s): Commission of the European Communities
Lien, 2014,^13^ Pro Children Study; Norway, the Netherlands, Spain, RCT-Cluster; Total Baseline N: 1,801; Total Analytic N: 1,245; Total Baseline Cluster N: 62; Total Analytic Cluster N: 61; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): ~10.8 y; Female: NR; Race/ethnicity: NR; SES: Parental education: >12 y: 41%, ≤12 y: 59% | Int: (i) Nutrition education, (ii) free fruit and vegetable provision, (iii) encouragement of parents to support fruit and vegetable intake, and (iv) raising community awareness (N=NR; Cluster N=31); Comp: No intervention (N=NR; Cluster N=30); Theory/framework: Intervention mapping; Intervention duration: 2 y; Outcome measurement: Intake assessed via pre-coded 24 h recall instrument for fruit and vegetable intake (excluding potatoes and dried fruit) at baseline, mid-intervention, and post-intervention | Intake at mid-intervention by parental education, Mean difference (95% CI), Int vs Comp (ref); [underlined: Fruit and vegetables (g/d)]:; Parental education ≤12 y: 39.9 (6.7, 73.2), p=0.022 ↑; Parental education >12 y: 56.1 (8.7, 103.4), p=0.024 ↑; [underlined: Vegetables (g/d)]:; Parental education ≤12 y: 16.8 (0.4, 33.2), p=0.049 ↑; Parental education >12 y: 19.3 (−4.1, 42.7). p=0.111; [underlined: Fruit (g/d)]:; Parental education ≤12 y: 23.6 (−0.8, 48.0), p=0.062; Parental education >12 y: 37.8 (5.5, 70.0), p=0.025 ↑; Intake at post-intervention by parental education and country, Mean difference (95% CI), Int vs Comp (ref); [underlined: Fruit and vegetables (g/d)]:; Norway - Parental education ≤12 y: 112.0 (55.4, 168.7), p=0.001 ↑; Parental education >12 y: 80.7 (16.5, 144.9), p=0.025 ↑; Spain - Parental education ≤12 y: 9.3 (−51.4, 69.9), p=0.768; Parental education >12 y: 38.7 (−34.7, 112.2), p=0.319; The Netherlands - Parental education ≤12 y: 51.6 (−20.9, 124.2), p=0.699; Parental education >12 y: −10.2 (−61.2, 40.8), p=0.176; [underlined: Vegetables (g/d)]:; Norway - Parental education ≤12 y: 11.2 (−12.2, 34.7), p=0.362; Parental education >12 y: 3.0 (−26.5, 32.5), p=0.842; Spain - Parental education ≤12 y: 11.9 (−9.19, 33.0), p=0.284; Parental education >12y: 13.3 (−12.9, 39.4), p=0.337; The Netherlands - Parental education ≤12 y: 13.9 (−18.8, 46.6), p=0.501; Parental education >12 y: −10.2 (−39.4, 19.0), p=0.412; [underlined: Fruit (g/d)]:; Norway - Parental education ≤12 y: 100.2 (54.72, 145.7), p<0.001 ↑; Parental education >12 y: 79.5 (24.1, 134.9), p=0.012 ↑; Spain - Parental education ≤12 y: −3.4 (−55.4, 48.6), p=0.900; Parental education >12 y: 21.8 (−38.2, 81.7), p=0.488; The Netherlands - Parental education ≤12 y: 37.4 (−21.1, 95.9), p=1.00; Parental education >12 y: 0.0 (−36.5, 36.5), p=0.223; Model adjustments: Baseline intake; sex; age; Funding source(s): Commission of the European Communities, European Union Public Health Programme
Unnamed study – United States
Blom-Hoffman,^4^ 2008; United States (Boston, Massachusetts), RCT-Cluster; Total Baseline N: 297; Total Analytic N: 80; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 6.2 y; Female: 49%; Race/ethnicity: Black: ~33%; Asian: ~12%; Hispanic: ~46%; White: ~4%; Other: ~5%; SES: Students receiving free or reduced price lunch: 91% | Int: Fruit and Vegetable Promotion Program, including morning announcements, fruit and vegetable posters, educational computer games in the classroom, take-home activity books, and verbal praise and a sticker for eating fruits and vegetables at school (N=37; Cluster N=2); Comp: No nutrition intervention (N=43; Cluster N=2); Theory/framework: SLT; Intervention duration: ~1.5 school y; Outcome measurement: Intake assessed by single question from structured questionnaire administered over the phone to parents in their native language at pre-intervention (summer 2005), after intervention year 1 (summer 2006), and after intervention year 2 (summer 2007) | Fruit and vegetable consumption (svg/d), Mean (SD); [underlined: Baseline]: Int: 2.46 (0.99), Comp: 2.44 (1.1); [underlined: After intervention year 1]: Int: 2.89 (0.97), Comp: 2.35 (1.2); [underlined: After intervention year 2]: Int: 2.76 (0.9), Comp: 2.40 (1.1); [underlined: Group by time interaction]: p=NS; Model adjustments: None; Funding source(s): National Institute of Child Health and Human Development
Hoffman, 2010 ^10^; United States (Northeast), RCT-Cluster; Total Baseline N: 297; Total Analytic N: 210; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 6.2 y; Female: 49%; Race/ethnicity: White: 3%; Black: 33%; Asian: 12%; Latino: 46%; Other: 6%; SES: Eligible for free/reduced price lunch: 91% | Int: Fruit and Vegetable Promotion Program, including morning announcements, fruit and vegetable posters, educational computer games in the classroom, take-home activity books, and verbal praise and a sticker for eating fruits and vegetables at school (N=127 at y 1, N=113 at y 2; Cluster N=2); Comp: No intervention (N=123 at year 1, N=97 at year 2; Cluster N=2); Theory/framework: SLT; Intervention duration: ~1.5 school y; Outcome measurement: Intake measured via trained research assistants during lunch by observing foods on trays and measuring/weighing fruit and vegetables not consumed and subtracting from the size of portion served three times at pre-intervention (winter 2006), after intervention year 1 (spring 2006), and after intervention year 2 (spring 2007) | Intake after intervention year 1, Mean (95% CI); [underlined: Fruit (g/lunch)]: Int: 45 (40, 51), Comp: 26 (21, 31), p<0.001 ↑; [underlined: Vegetable (g/lunch)]: Int (n=128): 18 (15, 20), Comp: 8 (6, 10), p<0.01 ↑; Intake after intervention year 2, Mean (95% CI); [underlined: Fruit (g/lunch)]: Int: 34 (30, 39), Comp (n=97): 23 (18, 28), p<0.001 ↑; [underlined: Vegetable (g/lunch)]: Int: 15 (12, 17), Comp: 9 (7, 11), p=NS; Model adjustments: Pre-intervention fruit and vegetable intake; sex; race/ethnicity; BMI z-score; fruit and vegetable preference; school; Funding source(s): National Institute of Child Health and Human Development
Hoffman, 2011 ^11^; United States (Northeast), RCT-Cluster; Total Baseline N: 297; Total Analytic N: 177 at year 3, 166 at 1 y post-intervention; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: Moved to another school; Grade level: Elementary school; Age (Mean): 6.2 y; Female: 49%; Race/ethnicity: White: 3%; Black: 33%; Asian: 12%; Latino: 46%; Other: 6%; SES: Eligible for free/reduced price lunch: 91% | Int: Fruit and Vegetable Promotion Program, including morning announcements, fruit and vegetable posters, educational computer games in the classroom, take-home activity books, and verbal praise and a sticker for eating fruits and vegetables at school (N=91 at y 3, N=85 at 1 y post-intervention; Cluster N=2); Comp: No intervention (N=86 at y 3, N=81 at 1 y post-intervention; Cluster N=2); Theory/framework: SLT; Intervention duration: ~2.5 school y; Outcome measurement: Intake measured via trained research assistants during lunch by observing foods on trays and measuring fruit and vegetables not consumed and subtracting from the size of portion served three times at pre-intervention (winter 2006), after intervention year 1 (spring 2006), after intervention year 2 (spring 2007), after intervention year 3 (spring 2008), and 1-y follow-up (spring 2009) | Intake after intervention year 3, Mean (95% CI); [underlined: Fruit (g/lunch)]: Int: 33 (29, 38), Comp: 32 (28, 37), p=NS; [underlined: Vegetable (g/lunch)]: Int: 16 (13, 19), Comp: 11 (8, 13), p<0.10; Intake at 1-y follow-up intake, Mean (95% CI); [underlined: Fruit (g/lunch)]: Int: 30 (26, 34), Comp: 34 (29, 39), p=NS; [underlined: Vegetable (g/lunch)]: Int: 14 (11, 16), Comp: 12 (9, 14), p=NS; Model adjustments: Pre-intervention fruit and vegetable intake; sex; race/ethnicity; BMI z-score; fruit and vegetable preference; school; Funding source(s): National Institute of Child Health and Human Development
Individual studies (alphabetized by author)
Anderson, 2005 ^1^; United Kingdom, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 129; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Ranges): 6-7 y and 10-11 y; Female: ~54%; Race/ethnicity: NR; SES: Postal code in most deprived areas (4-6) based on Depcat score: 83% | Int: Increased provision of fruit and vegetables in school through tuck shops and lunches, opportunities to taste fruits and vegetables, promotion of fruits and vegetables in school, newsletters, and nutrition curriculum. (N=64; Cluster N=2); Comp: No intervention (N=65; Cluster N=2); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake assessed via 3 d food diary with interview by trained assistants at baseline and post-intervention. Younger children (6-7 y) were interviewed all 3 d, older children (10-11 y) were interviewed once at end of 3 d. | Intake at baseline and post-intervention, Mean (SE); [underlined: Fruit and vegetables (g)]:; Baseline: Int: 202 (101.9), Comp: 170 (109.6); Post-intervention: Int: 235 (151.2), Comp: 163 (109.6); Group difference in change: p=0.617; [underlined: Fruit (g)]:; Baseline: 133 (11.9), Comp: 100 (11.7); Post-intervention: Int: 183 (17.0), Comp: 107 (14.2); Group difference in change: p=0.042 ↑; [underlined: Vegetables (g)]:; Baseline: Int: 69 (41.1), Comp: 70 (58.1); Post-intervention: Int: 52 (48.6), Comp: 55 (42.3); Group difference in change: p=0.823; *When girls and boys were analyzed separately, significant intervention effects on fruit only seen in girls.; Intake at baseline and post-intervention, Mean (SE); [underlined: Sucrose (g)]:; Baseline: Int: 55.1 (17.5), Comp: 56.7 (20.0); Post-intervention: Int: 54.6 (19.4), Comp: 52.7 (22.7); Group difference in change: p=0.578; Model adjustments: Fruits and Vegetables: None; Sucrose: Age; Sex; Funding source(s): The Food Standards Agency (United Kingdom)
Bauer, 2020,^2^ One Healthy Breakfast initiative; United States (Philadelphia, Pennsylvania), RCT-Cluster; Total Baseline N: 1,362; Total Analytic N: 977 at midpoint, 793 at post-intervention; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean (SD)): 10.8 (1.0) y; Female: 51%; Race/ethnicity: White: 7%; Black: 67%; Asian: 6%; Hispanic: 17%; Multirace/other: 3%; SES: Eligible for free/reduced-price meals: 79% | Int: Breakfast offered in the classroom with nutrition education, social marketing at school, marketing at corner stores near school, and parent outreach (One Healthy Breakfast initiative) (N=NR; Cluster N=8); Comp: No intervention (universal breakfast offered in cafeteria) (N=NR; Cluster N=8); Theory/framework: NR; Intervention duration: 2.5 y; Outcome measurement: Food and drink consumption the morning of data collection measured via Breakfast Patterns Survey, which was completed by child on a tablet computer in their classroom after breakfast at baseline, midpoint (1.5 y) and post-intervention | Intervention mid-point intake the morning of data collection, OR (95% CI); Int vs Comp (ref); [underlined: Milk]: 1.69 (1.26, 2.28) ↑; [underlined: 100% Juice]: 1.62 (1.14, 2.32) ↑; [underlined: SSBs]: 0.75 (0.47, 1.21); [underlined: Fruit]: 1.51 (1.04, 2.19); [underlined: Grain products]: 1.31 (1.02, 1.68) ↑; [underlined: Meat/meat alternatives]: 1.44 (1.03, 2.00) ↑; [underlined: Foods high in saturated fat and added sugars]: 0.75 (0.59, 0.97) ↑; [underlined: Pattern meeting SBP meal component requirements]: 3.43 (2.03, 5.80) ↑; Post-intervention intake the morning of data collection, OR (95% CI); Int vs Comp (ref); [underlined: Milk]: 1.16 (0.86, 1.56); [underlined: 100% Juice]: 1.86 (1.25, 2.77) ↑; [underlined: SSBs]: 0.56 (0.33, 0.97) ↑; [underlined: Fruit]: 1.18 (0.79, 1.76); [underlined: Grain products]: 0.95 (0.77, 1.16); [underlined: Meat/meat alternatives]: 1.20 (0.88, 1.65); [underlined: Foods high in saturated fat and added sugars]: 0.63 (0.46, 0.87) ↑; [underlined: Pattern meeting SBP meal component requirements]: 3.09 (1.82, 5.25) ↑; Model adjustments: Cluster; Funding source(s): USDA
Blom-Hoffman, 2004 ^3^; United States (Urban city in northeastern state), RCT-Cluster; Total Baseline N: 91; Total Analytic N: NR; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Students brought lunch from home; Grade level: Elementary school; Age: NR; Female: 55%; Race/ethnicity: Black: 100%; SES: Eligible for free/reduced price lunch: ~95% | Int: Fruit and vegetable curriculum, family newsletter and cookbook development, and positive verbal and token reinforcement for eating fruit and vegetables at lunch (N=NR; Cluster N=3); Comp: Waitlist control (N=NR; Cluster N=3); Theory/framework: SLT; Intervention duration: 5 wk; Outcome measurement: Visual estimates of the amount of vegetables remaining on school lunch trays assessed by trained research assistants using a 6-point modified version of the Comstock Scale; lower ratings on the Comstock scale indicate more vegetables were eaten; three days were assessed at pre- and post-intervention. | Difference in vegetables consumption (Comstock Scale rating), Mean (SD); [underlined: Pre-intervention]: Int: 3.46 (1.72) vs Comp: 2.98 (1.77), p=NS; [underlined: Post-intervention]: Int: 3.21 (1.88) vs Comp: 3.27 (1.87), p=NS; Model adjustments: None; Funding source(s): Maternal and Child Health Bureau, Department of Health and Human Services
Evans, 2013,^5^ Project Tomato; United Kingdom, RCT-Cluster; Total Baseline N: 1,031; Total Analytic N: 658; Total Baseline Cluster N: 54; Total Analytic Cluster N: 50; Criteria for exclusion from analysis: Poor completion of dietary assessment, absent on the day of the survey, move from the school, withdrawal of schools; Grade level: Elementary school; Age (Mean): 7 y; Female: ~50%; Race/ethnicity: Non-white: ~18%; SES: Index of multiple deprivation (Median): ~17 | Int: Multi-component school-based intervention to increase children’s fruit and vegetable intake (N=311; Cluster N=24); Comp: Control group (N=347; Cluster N=26); Theory/framework: Health maintenance behavior theories; Intervention duration: 10 mo; Outcome measurement: Diet intake measured with validated 24h dietary assessment tool (CADET) completed by parents at home and trained field workers at school | Post-intervention intake, Mean (95% CI) and Mean difference (95% CI); [underlined: Fruit (g)]: Int: 133 (119, 148), Comp: 134 (118, 149), Int vs Comp: 0 (−20, 20), p=1.0; [underlined: Fruit (portions)]: Int: 1.7 (1.5, 1.9), Comp: 1.7 (1.5, 1.9), Int vs Comp: 0.0 (−0.3, 0.3), p=1.0; [underlined: Vegetables (g)]: Int: 122 (109, 135), Comp: 119 (107, 132), Int vs Comp: 2 (−15, 19), p=0.8; [underlined: Vegetables (portions)]: Int: 1.5 (1.3, 1.7), Comp: 1.5 (1.3, 1.7), Int vs Comp: 0.0 (−0.2, 0.3), p=0.08; [underlined: Fruit & vegetables (g)]: Int: 253 (234, 273), Comp: 255 (237, 273), Int vs Comp: 2 (−23, 26), p=0.9; [underlined: Fruit & vegetables (portions)]: Int: 3.2 (2.9, 3.4), Comp: 3.2 (2.9, 3.4), Int vs Comp: 0.0 (−0.3, 0.3), p=0.9; Post-intervention intake, Mean (95% CI) and Mean difference (95% CI); [underlined: Saturated fat (g)]: Int: 22.4 (21.1, 23.6), Comp: 22.4 (21.2, 23.6), Int vs Comp: 0.0 (−1.5, 1.5), p=1.00; [underlined: Total sugar (g)]: Int: 111.5 (105.8, 117.2), Comp: 110.4 (104.8, 116), Int vs Comp: 1.1 (−5.5, 7.6), p=0.75; [underlined: NSP (dietary fiber) (g)]: Int: 12.4 (11.7, 13.1), Comp: 12.3 (11.6, 13.0), Int vs Comp: 0.1 (−0.7, 0.9), p=0.79; [underlined: Sodium (mg)]: Int: 2460 (2329, 2591), Comp: 2334 (2207, 2461), Int vs Comp: 126 (−36, 287), p=0.13; Model adjustments: Age; gender; baseline results; Funding source(s): National Prevention Research Initiative of the United Kingdom Medical Research Council
Foster, 2008 ^6^; United States (Philadelphia, Pennsylvania), RCT-Cluster; Total Baseline N: 1,349; Total Analytic N: 844; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Transferred schools, absent; Grade level: Elementary school; Age (Mean (SD)): 11.2 (1.0) y; Female: ~54%; Race/ethnicity: White: ~12%; Black: ~45%; Asian: ~22%; Hispanic: ~15%; Other: ~6%; SES: School with ≥50% children eligible for free/reduced price meals: 100% | Int: School nutrition policy initiative targeting school self-assessment, staff training, nutrition education, nutrition standards for foods sold in school, social marketing, and family outreach (N=479; Cluster N=5); Comp: No intervention (N=365; Cluster N=5); Theory/framework: NR; Intervention duration: 2 y; Outcome measurement: Intake assessed via self-administered, validated 152-item FFQ (Youth/Adolescent Questionnaire) at baseline and post-intervention | Change in intake from baseline to post-intervention, Mean and Mean difference (95% CI); [underlined: Fruits and vegetables (number/d)]:; Baseline: Int: 5.26, Comp: 5.33; Post-intervention: Int: 4.17, Comp: 4.28; Change: Int: −1.09, Comp: −1.05, Int vs Comp (ref): −0.04 (−0.37, 0.30), p=0.82; Model adjustments: Race/ethnicity; sex; age; randomization pair; baseline weight; baseline intake; Funding source(s): CDC, USDA/Food and Nutrition Service Food Stamp Nutrition Education Program
Franken, 2018 ^7^; The Netherlands (Aruba), RCT-Cluster; Total Baseline N: 453; Total Analytic N: 377; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Absent; Grade level: Elementary school; Age (Mean (SD)): 11.4 (0.98) y; Female: 54%; Race/ethnicity: NR; SES: NR | Int: Promotion of water consumption by trained peer influencers (“Share H2O” intervention) (N=192; Cluster N=2); Comp: No intervention (N=185; Cluster N=4); Theory/framework: NR; Intervention duration: 8 wk; Outcome measurement: SSB consumption (including juice, soft drinks, energy drinks, and sports drinks) measured via six questions completed by children on weekday and weekend intake, assessed at pre- and post-intervention | Post-intervention intake, Mean and Mean difference (95% CI); [underlined: SSBs (glasses)]: Int: 4.80, Comp: 4.94; Mean difference: −0.12 (−0.24, 0.00), p=0.04 ↑; Model adjustments: Sex; age; thirst; baseline SSB intake; perceived descriptive and injunctive norms related to SSBs; Funding source(s): University of Aruba
Habib-Mourad, 2014,^9^ Intervention to promote; Healthy Eating and Physical; Activity in Lebanese School children (Health-E-PALS); Lebanon, RCT-Cluster; Total Baseline N: 374; Total Analytic N: 363; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Absent; Grade level: Elementary school; Age (Mean): ~10.2 y; Female: 45%; Race/ethnicity: NR; SES: NR | Int: School-based multicomponent obesity-prevention program, with education, a food service intervention, and parental involvement (N=188; Cluster N=4); Comp: No intervention (N=175; Cluster N=4); Theory/framework: SCT; Intervention duration: 3 mo; Outcome measurement: Intake and dietary habits measured via 13-item questionnaire completed by students in the classroom pre- and post-intervention. | Post-intervention snack consumption, OR (95% CI); Int vs Comp (ref); [underlined: Chips]: 0.14 (0.11, 0.19), p<0.05 ↑; [underlined: Chocolate]: 0.54 (0.25, 1.15), p=NS; [underlined: Soft drinks]: 0.31 (0.18, 0.51), p<0.05 ↑; [underlined: Sweetened drinks]: 0.47 (0.16, 1.40), p=NS; [underlined: Fruit]: 1.65 (0.87, 3.10), p=NS; [underlined: Sandwich]: 1.50 (0.78, 2.90), p=NS; [underlined: Number of snacks/d]: 0.62 (0.34, 1.15), p=NS; Post-intervention snack purchases from school shop, OR (95% CI); Int vs Comp (ref); [underlined: Chips]: 0.16 (0.04, 0.61), p<0.05 ↑; [underlined: Chocolate]: 0.29 (0.12, 0.66), p<0.05 ↑; [underlined: Soft drinks]: 0.12 (0.04,0.29), p<0.05 ↑; [underlined: Sweetened drinks]: 0.40 (0.15, 1.07), p=NS; [underlined: Fruit]: 0.80 (0.40, 1.50), p=NS; [underlined: Sandwich]: 0.64 (0.34, 1.12), p=NS; Model adjustments: Baseline measures; Funding source(s): Eastern Mediterranean Regional Office Special Grant for Research in Priority Areas of Public Health (EMRO/WHO)
Habib-Mourad, 2020,^8^ Ajyal Salima–Healthy Kids; Lebanon, RCT-Cluster; Total Baseline N: 1,239; Total Analytic N: 974 at post-intervention, 806 at 1-y follow-up; Total Baseline Cluster N: 36; Total Analytic Cluster N: NR; Criteria for exclusion from analysis: School drop or school change; Grade level: Elementary school; Age (Mean (SD)): 9.95 (1.13) y; Female: 53.7%; Race/ethnicity: NR; SES: Public school (low SES): 55% | Int: Obesity-prevention program with nutrition education, a food service intervention, and parental involvement (N=527 at post-intervention, N=457 at post washout; Cluster N=NR); Comp: No intervention (wait list control) (N=447 at post-intervention, N=349 post washout; Cluster N=NR); Theory/framework: SCT; Intervention duration: 2 y; Outcome measurement: Dietary habits assessed via questionnaire completed by children in presence of research team and absence of school personnel | Post-intervention intake of at least once/d, OR (95% CI); Int vs Comp (ref); [underlined: Fruit]: 1.56 (1.18, 2.08), p=0.002 ↑; [underlined: Raw veggies]: 1.79 (1.32, 2.43), p=0.000 ↑; [underlined: Chips]: 0.52 (0.32, 0.84), p=0.008 ↑; [underlined: Soft drinks]: 0.64 (0.42, 0.95), p=0.027 ↑; [underlined: Sweet drinks]: 0.62 (0.40, 0.96), p=0.32; *When private and public schools were analyzed separately, significant intervention effects were seen for fruit and raw veggies in private schools and chips in public schools; all other comparisons were NS; 1-y follow-up intake of at least once/d, OR (95% CI); Int vs Comp (ref); [underlined: Fruit]: 1.28 (0.99, 1.65), p=0.054; [underlined: Raw veggies]: 1.66 (1.25, 2.19), p=0.000 ↑; [underlined: Chips]: 0.86 (0.58, 1.26), p=0.493; [underlined: Soft drinks]: 0.68 (0.48, 0.97), p=0.031 ↑; [underlined: Sweet drinks]: 0.71 (0.47, 1.07), p=0.104; *When private and public schools were analyzed separately, no significant intervention effects were seen in private schools and significant intervention effects were seen for fruit, raw veggies, and sweet drinks in public schools; all other comparisons were NS; Model adjustments: Age; gender; cluster; baseline dietary behaviors; Funding source(s): Nestlé for Healthier Kids Initiative–Nestlé Middle East
Horne, 2009 ^12^; Ireland, RCT-Cluster; Total Baseline N: 435; Total Analytic N: NR; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Range): 4-11 y; Female: NR; Race/ethnicity: NR; SES: Medium School deprivation level | Int: Food Dudes educational videos and reward program (16 d), including free fruit and vegetable during intervention period, with lower intensity, 12-mo maintenance phase (N=NR; Cluster N=1); Comp: Free fruit and vegetable provision during intervention without Food Dude program or maintenance phase (N=NR; Cluster N=1); Theory/framework: NR; Intervention duration: 1 y; Outcome measurement: Provision and consumption of food brought from home assessed by researchers who recorded the contents of lunchboxes before and after lunch for 3 d at baseline and 3 d at post-intervention; consumption of food provided by school assessed by researchers who weighed fruit and vegetables before and after consumption for 4 d at baseline and during the final 4 d of the program (before the maintenance phase) | Intake of school-provided foods, Mean; Group by phase interaction: p<0.001 ↑; Group by phase by food type interaction: p<0.001 ↑; [underlined: Fruit (g)]; Baseline: Int: 36, Comp: 29, p=0.31; During program: Int: 47, Comp: 25, p<0.001 ↑; [underlined: Vegetables (g)]; Baseline: Int: 7, Comp: 7, p=0.80; During program: Int: 20, Comp: 5, p<0.001 ↑; Provision and intake of food in lunchboxes, Mean; [underlined: Fruit, juice, and vegetables provided (g)]; Group by phase interaction: p<0.001 ↑; Baseline: Int: 61, Comp: 74, p=0.158; Post-intervention: Int: 103, Comp: 71, p<0.001 ↑; [underlined: Fruit, juice, and vegetables consumed (g)]; Group by phase interaction: p<0.001 ↑; Baseline: Int: 41, Comp: 42, p=0.88; Post-intervention: Int: 71, Comp: 47, p<0.001 ↑; Model adjustments: Age; Funding source(s): Bord Bia (Irish Food Board); Fyffes plc provided fruit and vegetables
Liz Martins, 2016 ^14^; Portugal, RCT-Cluster; Total Baseline N: 151; Total Analytic N: 144; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Children that did not have lunch at school at least one day at 1 wk or 3 mo follow-up; Grade level: Elementary school; Age (Mean): ~9.3 y; Female: 47%; Race/ethnicity: NR; SES: Free school lunch: 35% | Int1: Nutrition education (6 h) for children, posters related to food waste reduction made by children and posted in the canteen, and stickers for not wasting food at lunch on “no plate waste day” (N=28; Cluster N=1); Int2: Food waste education for teachers, who were then asked to play active role in encouraging children to eat their lunch (N=53; Cluster N=1); Comp: No intervention (N=63; Cluster N=1); Theory/framework: NR; Intervention duration: 3 d; Outcome measurement: Plate waste measured by trained researchers by physical weighing of individual meals and leftovers using a digital scale for 5 d at baseline, 1-wk follow-up, and 3-mo follow-up; percent plate waste calculated as ratio of edible food discarded per edible food served. | Change in plate waste between baseline and 1-wk follow-up (% points), Mean (SE) and Adjusted Mean Difference (95% CI); [underlined: Soup]: Int1: −11.9 (2.8), Int2: −6.8 (1.6), Comp: 5.1 (2.0); Int1 vs Comp (ref): −16.1 (−23.7, −8.5), p<0.001 ↑; Int2 vs Comp (ref): −14.0 (−24.1, −3.8), p=0.007 ↑; [underlined: Main dish]: Int1: −13.0 (3.0), Int2: 3.0 (1.6), Comp: 10.5 (2.2); Int1 vs Comp (ref): −28.2 (−41.1, 15.3), p<0.001 ↑; Int2 vs Comp (ref): −15.1 (−35.3, 5.2), p=0.145; [underlined: Identical main dish]: Int1: −33.9 (4.8), Int2: 3.7 (2.6), Comp: 5.0 (2.4); Int1 vs Comp (ref): −39.2 (−55.3, −23.0), p<0.001 ↑; Int2 vs Comp (ref): −7.2 (−37.1, 22.7), p=0.639; Change in plate waste between baseline and 3-mo follow-up (% points), Mean (SE) and Adjusted Mean Difference (95% CI); [underlined: Soup]: Int1: −5.8 (4.4), Int2: −5.5 (1.9), Comp: 1.6 (2.4); Int1 vs Comp (ref): −5.0 (−14.0, 4.1), p=0.281; Int2 vs Comp (ref): −17.7 (−36.3, 1.0), p=0.063; [underlined: Main dish]: Int1: 0.6 (2.7), Int2: −2.2 (1.8), Comp: 13.1 (2.5); Int1 vs Comp (ref): −0.9 (−17.2, 15.3), p=0.912; Int2 vs Comp (ref): 3.8 (−20.8, 28.5), p=0.762; [underlined: Identical main dish]: Int1: −13.7 (3.2), Int2: −5.4 (2.4), Comp: 8.8 (3.2); Int1 vs Comp (ref): −40.6 (−66.6, −14.6), p=0.002 ↑; Int2 vs Comp (ref): −40.8 (−79.0, −2.6), p=0.036 ↑; Model adjustments: Children’s social support group, mean initials servings at baseline, and mean initial servings at 1-wk or 3-mo follow-up; Funding source(s): Fundação para a Ciência e Tecnologia
Morrill, 2016 ^15^; United States (Northern Utah), RCT-Cluster; Total Baseline N: 2,292; Total Analytic N: 2,257; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: School transfers, missing observations; Grade level: Elementary school; Age (%): Grade 1-2: 44%, Grade 3-5: 56%; Female: 46%; Race/ethnicity: Study sample NR; School District: White: 91%; Hispanic/Latino: 8%; Native American 8%; Black: 1%; Asian: 1%; SES: Qualified for free or reduced lunch: 44% | Int1: Food Dudes educational videos with prize reward for fruit and vegetable consumption (16 d, phase 1), and continued, lower intensity prize rewards (~3.5 mo, phase 2) (N=852; Cluster N=2); Int2: Food Dudes educational videos with praise reward for fruit and vegetable consumption (16 d, phase 1), and continued, lower intensity praise rewards (~3.5 mo, phase 2) (N=635; Cluster N=2); Comp: No intervention (N=770; Cluster N=2); Theory/framework: NR; Intervention duration: ~4 mo; Outcome measurement: Fruit and vegetable consumption assessed by digital imaging of pre- and post- lunch trays coded by trained observers assessed at baseline, phase 1, phase 2, and 6-mo follow-up. | Intake (cups) after Phase 1, Adjusted mean difference (95% CI); [underlined: Fruits]: Int1 vs Comp (ref): 0.12 (0.09, 0.14), p<0.05 ↑; Int2 vs Comp (ref): 0.07 (0.04, 0.09), p<0.05 ↑; Int1 vs Int2 (ref): 0.05 (0.02, 0.08), p<0.05 ↑; [underlined: Vegetables]: Int1 vs Comp (ref): 0.20 (0.18, 0.22), p<0.05 ↑; Int2 vs Comp (ref): 0.14 (0.12, 0.17), p<0.05 ↑; Int1 vs Int2 (ref): 0.05 (0.04, 0.08), p<0.05 ↑; [underlined: Combined fruits and vegetables]: Int1 vs Comp (ref): 0.32 (0.28, 0.35), p<0.05 ↑; Int2 vs Comp (ref): 0.21 (0.17, 0.25), p<0.05 ↑; Int1 vs Int2 (ref): 0.11 (0.07, 0.15), p<0.05 ↑; Intake (cups) after Phase 2, Adjusted mean difference (95% CI); [underlined: Fruits]: Int1 vs Comp (ref): 0.07 (0.04, 0.10), p<0.05 ↑; Int2 vs Comp (ref): −0.01 (−0.05, 0.09), p=NS; Int1 vs Int2 (ref): 0.05 (0.02, 0.08), p<0.05 ↑; [underlined: Vegetables]: Int1 vs Comp (ref): 0.06 (0.03, 0.09), p<0.05 ↑; Int2 vs Comp (ref): 0.06 (0.03, 0.10), p<0.05 ↑; Int1 vs Int2 (ref): 0.01 (−0.03, 0.03), p=NS; [underlined: Combined fruits and vegetables]: Int1 vs Comp (ref): 0.13 (0.09, 0.17), p<0.05 ↑; Int2 vs Comp (ref): 0.08 (0.03, 0.12), p<0.05 ↑; Int1 vs Int2 (ref): 0.01 (0.01, 0.10), p=NS; Intake (cups) at 6-mo follow-up, Adjusted mean difference (95% CI); [underlined: Fruits]: Int1 vs Comp (ref): 0.06 (0.02, 0.10), p<0.05 ↑; Int2 vs Comp (ref): 0.02 (−0.06, 0.03), p=NS; Int1 vs Int2 (ref): 0.05 (0.01, 0.09), p<0.05 ↑; [underlined: Vegetables]: Int1 vs Comp (ref): 0.05 (0.03, 0.07), p<0.05 ↑; Int2 vs Comp (ref): - 0.01 (−0.01, 0.03), p=NS; Int1 vs Int2 (ref): 0.07 (0.05, 0.09), p<0.05 ↑; [underlined: Combined fruits and vegetables]: Int1 vs Comp (ref): 0.12 (0.07, 0.17), p<0.05 ↑; Int2 vs Comp (ref): −0.01 (−0.05, 0.06), p=NS; Int1 vs Int2 (ref): 0.13 (0.07, 0.18), p<0.05 ↑; Model adjustments: Baseline fruit and vegetable consumption; grade level; sex; classroom (random effect); Funding source(s): USDA
Qian, 2019 ^16^; China, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 4,482; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Range): ~8-9 y; Female: 46%; Race/ethnicity: NR; SES: From Qinghai Province - low SES region: 36.5% | Int: Comprehensive nutrition program including nutrition education, information for teachers and parents, social media messages and promotion in school of healthy eating. (N=2,086; Cluster N=6); Comp: No intervention (N=2,396; Cluster N=6); Theory/framework: WHO’s Health Promoting Schools model; SLT; Intervention duration: 1 school y; Outcome measurement: Child reported number of times they did 9 key eating behaviors measured at pre- and post-intervention | Post-intervention intake (Shandong Province - higher SES region), %; [underlined: Eat more vegetables than meat/eggs at lunch and dinner]: Int: 40.3%, Comp: 20.6%, p<0.001 ↑; [underlined: Vegetables, 3 or more portions/d]: Int: 61.3%, Comp: 34.2%, p<0.001 ↑; [underlined: Fruit, 2 or more portions/d]: Int: 67.4%, Comp: 42.6%, p<0.001 ↑; [underlined: Dairy, daily]: Int: 54.2%, Comp: 32.7%, p<0.001 ↑; [underlined: Fried foods, less than 1 x/wk]: Int: 70.8%, Comp: 48.1%, p<0.001 ↑; [underlined: Fast foods, less than 1 x/mo]: Int: 89.4%, Comp: 77.9%, p<0.001 ↑; Post-intervention intake (Qinghai Province - lower SES region), %; [underlined: Eat more vegetables than meat/eggs at lunch and dinner]: Int: 19.6%, Comp: 18.1%, p=NS; [underlined: Vegetables, 3 or more portions/d]: Int: 27.6%, Comp: 23.0%, p<0.05 ↑; [underlined: Fruit, 2 or more portions/d]: Int: 35.2%, Comp: 33.0%, p=NS; [underlined: Dairy, daily]: Int: 25.6%, Comp: 25.4%, p=NS; [underlined: Fried foods, less than 1 x/wk]: Int: 46.5%, Comp: 45.8%, p=NS; [underlined: Fast foods, less than 1 x/mo]: Int: 72.7%, Comp: 69.9%, p=NS; Model adjustments: None; Funding source(s): Ferrero Trading (Shanghai) Company Limited
Reynolds, 2000,^17^ High 5 Project; United States (Alabama), RCT-Cluster; Total Baseline N: 1,698; Total Analytic N: 1,426; Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 8.7 y; Female: 50%; Race/ethnicity: White: 83%; Black: 16%; Other: 1%; SES: Household income (Median): $40,000-$50,000 | Int: Multi-component intervention (High 5) including 14-lesson nutrition curriculum, involvement of parents in completing curriculum homework, and training for food service personnel to improve purchasing, preparation, and promotion of fruit and vegetables (N=NR; Cluster N=14); Comp: No intervention (N=NR; Cluster N=14); Theory/framework: SCT; Intervention duration: ~1 y; Outcome measurement: Intake assessed via single 24 h recall completed by children at baseline, post-intervention, and 1-y follow-up; intake at lunch assessed for random subset of children by observation of child lunch trays before and after consumption | Intake (svg) at post-intervention, Mean (95% CI); [underlined: Fruit]: Int: 1.71 (1.45, 1.99), Comp: 0.83 (0.63, 1.04), p<0.0001 ↑; [underlined: Fruit meeting 5 a Day guidelines]: Int: 1.53 (1.29, 1.79), Comp: 0.76 (0.58, 0.97), p<0.0001 ↑; [underlined: Vegetables]: Int: 1.84 (1.61, 2.09), Comp: 1.15 (0.95, 1.35), p<0.0001 ↑; [underlined: Vegetables meeting 5 a Day guidelines]: Int: 0.85 (0.69, 1.03), Comp: 0.35 (0.23, 0.48), p<0.0001 ↑; [underlined: Fruit and vegetables]: Int: 3.96 (3.51, 4.44), Comp: 2.28 (1.92, 2.66), p<0.0001 ↑; [underlined: Fruit and vegetables meeting 5 a Day guidelines (svg)]: Int: 2.81 (2.43, 3.21), Comp: 1.35 (1.07, 1.66), p<0.0001 ↑; Intake (svg) in cafeteria at post-intervention (N=425), Mean (95% CI); [underlined: Fruit]: Int: 0.16 (0.09, 0.25), Comp: 0.11 (0.04, 0.19), p<0.33; [underlined: Vegetables]: Int: 0.11 (0.05, 0.19), Comp: 0.14 (0.07, 0.24), p<0.56; [underlined: Fruit and vegetables]: Int: 0.38 (0.26, 0.52), Comp: 0.38 (0.25, 0.52), p<0.99; Nutrient intake at post-intervention, Mean (95% CI); [underlined: Saturated fat (% kcal)]: Int: 11.07 (10.60, 11.54), Comp: 12.00 (11.51, 12.49), p<0.009 ↑; [underlined: Fiber (g)]: Int: 11.32 (10.66, 12.02), Comp: 9.69 (9.10, 10.31), p<0.0010 ↑; Intake (svg) at 1-y follow-up, Mean (95% CI); [underlined: Fruit]: Int: 1.21 (1.01, 1.41), Comp: 0.65 (0.50, 0.82), p<0.0001 ↑; [underlined: Fruit meeting 5 a Day guidelines]: Int: 1.08 (0.90, 1.27), Comp: 0.58 (0.43, 0.73), p<0.0002 ↑; [underlined: Vegetables]: Int: 1.60 (1.42, 1.79), Comp: 1.25 (1.08, 1.43), p<0.009 ↑; [underlined: Vegetables meeting 5 a Day guidelines]: Int: 0.61 (0.51, 0.71), Comp: 0.38 (0.30, 0.48), p<0.0021 ↑; [underlined: Fruit and vegetables]: Int: 3.20 (2.89, 3.52), Comp: 2.21 (1.94, 2.49), p<0.0001 ↑; [underlined: Fruit and vegetables meeting 5 a Day guidelines] : Int: 2.05 (1.81, 2.31), Comp: 1.20 (1.00, 1.41), p<0.0001 ↑; Intake (svg) in cafeteria at 1-y follow-up (N=425), Mean (95% CI); [underlined: Fruit]: Int: 0.09 (0.04, 0.16), Comp: 0.11 (0.05, 0.18), p<0.66; [underlined: Vegetables]: Int: 0.12 (0.05, 0.21), Comp: 0.15 (0.07, 0.25), p<0.63; [underlined: Fruit and vegetables]: Int: 0.29 (0.18, 0.41), Comp: 0.38 (0.25, 0.52), p<0.30; Nutrient intake at 1-y follow-up, Mean (95% CI); [underlined: Saturated fat (% kcal)]: Int: 11.49 (11.04, 11.94), Comp: 12.24 (11.77, 12.71), p<0.0249 ↑; [underlined: Fiber (g)]: Int: 10.68 (9.89, 11.54), Comp: 9.23 (8.52, 10.00), p<0.0119 ↑; *Nutrient analyses considered significant at p<0.0025 due to Bonferroni correction; Model adjustments: Baseline intake; nesting of student within classroom; Funding source(s): National Cancer Institute
Scherr, 2017,^18^ Shaping Healthy Choices Program (SHCP); United States (Northern and Central Valley, California), RCT-Cluster; Total Baseline N: 493; Total Analytic N: 195; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: Moved from the area, did not complete the pre and post FFQ assessment; Grade level: Elementary school; Age (Mean): ~9.6 y; Female: ~50%; Race/ethnicity: White:~25%; Black: ~4%; Asian: ~28%; Hispanic: ~16%; Other: ~9%; Multiple: 18%; SES: Household income: <$40,000: ~19%, $40,000-59,999: ~14%, $60,000-79,999: ~15%, $80,000-$99,999: ~10%; ≥$100,000: ~42% | Int: Garden-enhanced education, including family and community partnerships (N=109; Cluster N=2); Comp: No intervention (N=86; Cluster N=2); Theory/framework: SCT; Social Ecological Model; Intervention duration: ~ 1 school y; Outcome measurement: Fruit and vegetable intake measured via validated Block FFQ completed by children at pre-intervention and post-intervention | Change in intake between pre- and post-intervention, Mean (SD); [underlined: Fruit (MyPlate svg)]: Int: −0.15 (1.47), Comp: −0.08 (1.39), p=0.72; [underlined: Vegetable (MyPlate svg)]: Int: −0.11 (0.80); Comp: 0.01 (0.60); p=0.26; Results were similar for the sub-analyses by school district: all NS; Model adjustments: Race/ethnicity; household income; baseline nutrition knowledge score; Test of Basic Science Process Skills score; physical activity; parental pressure to eat; Funding source(s): University of California Agriculture and Natural Resources Grant, USDA, University of California Supplemental Nutrition Assistance Program Education
Sichieri, 2009 ^19^; Brazil, RCT-Cluster; Total Baseline N: 1,134; Total Analytic N: 927; Total Baseline Cluster N: 22; Total Analytic Cluster N: 22; Criteria for exclusion from analysis: NR; Grade level: Elementary school; Age (Mean): 10.9 y; Female: ~53%; Race/ethnicity: White: 42%; Black: 30%; Mulatto: 28%; SES: NR (All students from public school - Authors note that most students in public schools are of low SES level) | Int: Lifestyle education program (ten 1-h sessions) focused on reduction of SSB with promotion of water consumption through banners and branded water bottles (N=434; Cluster N=11); Comp: Lower intensity general health education (N=493; Cluster N=11); Theory/framework: NR; Intervention duration: 7 mo; Outcome measurement: Beverage intake measured using one 24-h recall administered by nutritionists and self-reported by children at baseline and post-intervention; mean beverage intake of classes was used as the unit of analysis for change in intake (not individual intake) | Baseline to post-intervention change in intake, Mean (95% CI) and Mean difference (95% CI); [underlined: Carbonated beverages (mL/d/class):] Int: −69.0 (−114.0, −24.0), Comp: −13.0 (−56.0, 31.0); Int vs Comp (ref): −56.0 (−119.0, −7.0) ↑; Post-intervention intake, Mean; [underlined: Carbonated beverages (mL/d)]: Int: 228 vs Comp: 280, p=0.03 ↑; [underlined: Juices (mL/d)]: Int: 151 vs Comp: 115, p=0.08; Model adjustments: None; Funding source(s): Brazilian National Research Council

a Abbreviations: BMI: body mass index; CI: confidence interval; Comp: comparator; d: day; g: gram; h: hour; kcal: kilocalorie; Int: intervention; mg: milligram; mL: milliliter; mo: month; N: sample size; NR: not reported; NS: non-significant; OR: odds ratio; p: p-value; RCT: randomized controlled trial; ref: reference group; SBP: School Breakfast Program; SCT: Social Cognitive Theory; SLT: Social Learning Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; SSB: sugar-sweetened beverage; svg: serving; USDA: United States Department of Agriculture; vs: versus; wk: week; x: time(s); y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator

Table 8 Risk of bias for randomized controlled trials examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in elementary school children^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Anderson, 2005^1^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Bauer, 2020^2^ | LOW | LOW | LOW | LOW | LOW | LOW
Blom-Hoffman, 2004^3^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Blom-Hoffman, 2008^4^ | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Evans, 2013^5^ | LOW | LOW | SOME CONCERNS | LOW | LOW | LOW
Foster, 2008^6^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Franken, 2018^7^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Habib-Mourad, 2014^9^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Habib-Mourad, 2020^8^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Hoffman, 2010^10^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Hoffman, 2011^11^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Horne, 2009^12^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Lien, 2014^13^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Liz Martins, 2016^14^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Morrill, 2016^15^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Qian, 2019^16^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Reynolds, 2000^17^ | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Scherr, 2017^18^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW
Sichieri, 2009^19^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Te Velde, 2008^20^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a All studies cluster-RCTs

## Middle and junior high school

### Conclusion statements and grades

#### Teaching and educational interventions

Moderate evidence from this rapid review indicates that curriculum-based nutrition education improves dietary intake (particularly overall dietary quality and vegetable intake) in middle and junior high school adolescents. Common components of successful curricula include parental involvement or use of internet- or computer-based technology. (Grade: Moderate)

Insufficient evidence from this rapid review is available to determine the relationship between non-curriculum-based teaching and educational interventions (such as games and reading materials) and dietary intake in middle and junior high school adolescents. (Grade: Grade not assignable)

#### Behavioral and environmental interventions

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions beneficially affect in-school food and beverage selection among middle and junior high school adolescents. (Grade: Moderate)

Limited evidence from this rapid review suggests that some school-based behavioral and environmental interventions, particularly those targeting food palatability or presentation, may improve in-school intake of fruit and vegetables among middle and junior high school adolescents. (Grade: Limited)

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

Moderate evidence from this rapid review indicates school-based interventions that combine educational and environmental strategies targeting promotion and increased availability of nutrient dense foods and beverages improve middle and junior high school adolescent food purchasing behaviors and dietary intake, particularly for fruit, vegetables and foods and beverages of lower nutritional quality. (Grade: Moderate)

Limited evidence from this rapid review suggests school-based interventions that combine educational and environmental strategies promoting and increasing availability of nutrient dense foods, may have a greater beneficial effect on middle and junior high school adolescent dietary intake, particularly fruit and vegetable intake, than interventions that use either strategy alone. (Grade: Limited)

### Summary of the evidence

#### Teaching and educational interventions

- Thirty RCTs (32 articles) examined teaching and educational interventions in middle and junior high school adolescents
  ○ Twenty-one RCTs examined curriculum-based nutrition education, although there was large variation in the content, delivery, and dose of the interventions
    ■ Seventeen RCTs found that curriculum-based nutrition education significantly improved dietary intake
    ■ Successful curricula tended to include parental involvement or a component with internet- or computer-based technology
    ■ Overall diet quality and vegetable intake were commonly studied outcomes that tended to be beneficially impacted by the interventions
    ■ Intake of fruit, milk/dairy, food and beverages of lower nutritional quality, and fiber were other commonly studied outcomes, but results were less consistent
    ■ Bean and legume intake also showed improvement, but were measured in too few studies to draw conclusions
  ○ Nine RCTs examined non-curriculum-based nutrition education, including three RCTs each for game-based interventions, reading materials, or other types of teaching and educational interventions; however, the evidence was too heterogeneous to draw conclusions
    ■ Interventions with potential include game-based learning, using individual- and team-based consumption goals to build autonomy over food choices, as well as targeting personal determinant prototype perception using theory-based evidence; however, additional research is needed
  ○ The body of evidence is limited by:
    ■ Risk of bias related to concerns of selective reporting;
    ■ Heterogeneity in the content, delivery, and dose of curriculum-based interventions;
    ■ Minimal evidence to determine the impact on diet beyond the immediate post-intervention period; and
    ■ Small number of studies on non-curriculum-based teaching and educational interventions.

#### Behavioral and environmental interventions

- Fourteen RCTs (14 articles) examined behavioral and environmental interventions in middle and junior high school adolescents
  ○ Ten RCTs examined the effects of behavioral and environmental interventions on food and beverage selection, all assessed in school
    ■ All but one study reported beneficial effects on at least one aspect of in-school food and beverage selection targeted by the intervention; fruit and vegetables were the most commonly assessed outcomes, but other food items or categories, such as white milk and favorable or unfavorable snack foods and beverages, were also assessed
    ■ A variety of behavioral and environmental interventions were tested and were successful at improving food and beverage selection at school
    ■ Most studies also included elementary or high school children or adolescents, but did not report separate analyses by age or grade level
  ○ Ten RCTs examined the effect of behavioral and environmental interventions on food and beverage intake, most of which assessed in-school intake
    ■ Results across the body of evidence were inconsistent
      - Fruit and vegetable intake were the most commonly assessed outcomes, and approximately half the interventions detected beneficial effects
      - Of the four interventions that did not detect a significant effect on fruit or vegetable intake, one reported notable contamination between the intervention and control groups and one was focused more broadly on low-fat á la carte options
      - Other food items were examined in few studies, were not the primary target of the intervention, or had inconsistent results
    ■ Interventions that targeted the palatability or presentation of food were the most common strategies that positively impacted fruit or vegetable intake; however, this still represented a small number of studies
  ○ The bodies of evidence for both selection and intake were limited by the:
    ■ Risk of bias due to selection of reported result and missing outcome data;
    ■ Heterogeneity in the types of behavioral and environmental interventions tested (including within more specific subsets of strategies);
    ■ Short duration and lack of longer-term follow-up post-intervention for many studies; and
    ■ Small number of studies targeting any single type of behavioral or environmental intervention.

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

- Ten cluster-RCTs (14 articles) examined the effect of educational interventions combined with behavioral and/or environmental interventions on diet and diet-related behaviors in middle school or junior high school adolescents.
  ○ The majority of studies were relatively large, theory-based, 6 months or longer in duration, had good fidelity, and designed to answer the research question.
  ○ All studies included nutrition education combined with an environmental or behavioral strategy.
    ■ Eight RCTs included an environmental strategy that promoted and enhanced availability of nutrient dense foods; five also enhanced food palatability, and two strengthened nutrition-related school policy.
    ■ One environmental strategy promoted healthy foods without increasing availability.
    ■ One RCT examined a behavioral intervention targeting goal setting.
  ○ Eight RCTs assessed dietary intake and two assessed student food and beverage purchases
  ○ Studies with strong fidelity to the intervention reported that combined strategies (particularly those that promoted and increased availability of nutrient dense foods) improved adolescent food purchasing behaviors and dietary intake of fruit and vegetables, fish, bread, and a warm lunch meal, and decreased intake of sugar sweetened beverages, fast foods, sucrose, and “unhealthy” foods.
  ○ Four cluster-RCTs with lower overall generalizability and precision reported that school-based interventions that combined nutrition education with increased availability and promotion of healthy foods tended to have a greater positive effect on middle and junior high school student dietary intake than single component interventions focused on education or environmental strategies alone.
  ○ The body of evidence was limited by:
    ■ Risk of bias due to selection of reported result and missing outcome data; and
    ■ Lack of studies that assessed sustainment of intervention effects beyond the immediate post-intervention period.

### Synthesis of the evidence

The body of evidence on middle and junior high school adolescents includes 57 articles from 52 cluster-RCTs^24–26,28,32,39,44,79,90,98,107–151^ and 2 parallel RCTs.^105,152^ Half of the studies utilized teaching and educational strategies, and about a quarter utilized behavioral and/or environmental strategies; fewer studies assessed combined teaching and educational strategies with behavioral and environmental strategies.

#### Teaching and educational interventions

##### Description of the evidence

Thirty-two articles examined the effect of school-based teaching and educational interventions on diet and diet-related behaviors in middle and junior high school adolescents.^79,90,98,105,107–133,152^ Most studies were cluster-randomized, while two studies were parallel, randomizing participants at the individual level.^105,152^ The majority of studies were conducted exclusively in middle and junior high schools; two were conducted in conjunction with elementary schools,^79,105^ four were conducted in conjunction with high schools,^110,124,130,152^ and one was conducted across all grade levels.^98^ The studies were conducted in a variety of high and very high HDI countries, including Brazil,^79,110,111,129^ Canada,^112^ China,^131,132^ France,^125^ Germany,^116^ Greece,^98^ Hong Kong Special Administrative Region (China),^113^ Hungary,^128^ Iran,^114,115,118,119,127^ Italy,^107,130^ Japan,^133^ the Netherlands,^109,121^ Norway,^108,123^ Spain,^90,122^ Turkey,^126^ the United Kingdom,^124,152^ and the United States.^105,117,120^ Of the 20 studies that provided data on SES, more than half were conducted in populations, areas, or schools with a large proportion of low SES or parental education,^79,98,105,108,110,114,118–120,123,124,126,129,132^ while 7 were conducted in populations with a greater range of SES or parental/caregiver education.^109,111,112,115,122,125,127^ Most studies did not report the race or ethnicity of participants.^79,98,108,110–112,114–116,118–123,125–130,133,152^ Among studies providing race/ethnicity data, six were conducted in schools with participants that were predominantly one race or ethnicity; participants in these studies were predominantly Black,^105^ White,^107^ Asian,^113,131,132^ of Western European origin,^90^ Chinese,^113^ or Dutch ethnicity.^109^ Two studies enrolled a more diverse student population.^117,124^ Although most studies enrolled both male and female participants, six studies exclusively enrolled female students.^114,115,118,124,127,133^ Analytic sample size of the cluster-RCTs ranged from 71^120^ to 3,627^98^ participants, with most studies including between 100 and 1,000 participants; 1 cluster-RCT did not provide the total analytic participant sample size.^109^ The number of clusters analyzed in these studies ranged from 2^79,111,114,115,126,127,131^ to 146,^98^ with most analyzing between 5 and 20 clusters. The analytic sample sizes of the 2 parallel RCTs were 59^105^ and 198^152^ individual participants.

Most of the teaching and educational interventions utilized a new or existing nutrition curriculum involving a combination of strategies (e.g., cooking, internet- or computer-based technology). Other interventions focused on game-based learning, educational reading materials, or other singular strategies, as described below. Twenty-one articles reported the theories or frameworks that informed the design of the intervention^105,108,109,111,113–121,123–125,127,129,131,132,152^; the most commonly cited theories included Theory of Planned Behavior (TPB)^109,118,120,124,152^ and SCT.^105,108,123,127^. Most interventions were compared to a usual care or non-intervention control,^79,90,105,107,109–112,114–119,121,122,124–133^ but some were compared to a different intervention not related to nutrition,^120,152^ a different intervention related to nutrition,^118,132,152^ or an identical intervention without the component of interest.^98,108,113,123^ Outcomes were primarily assessed by self-report of overall food and beverage intake^79,90,107–121,123–133,152^ (one study^98^ used parent-report), but some were determined by visual observation of students’ food and beverage choices or consumption at school.^105,116,122^ Evidence from these studies and participant characteristics are described in Table 9; the risk of bias assessments are described in Table 10. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Curriculum-based nutrition education

Twenty-one cluster-RCTs (23 articles) examined the effect of curriculum-based interventions involving a combination of teaching and educational strategies on dietary intake in middle and junior high school adolescents,^79,90,98,108–111,113–115,117–121,123,125–128,131–133,152^ with primarily beneficial effects on at least 1 targeted outcome. About half of the interventions were implemented over an academic year or longer^79,90,98,108,110,111,119,123,125,128^; a third were between ^8^ weeks and ^6^ months duration^,109,113,117,121,126,127,131–133^ and a handful were less than 6 weeks.^114,115,118,120^ Interventions were delivered by a variety of educators, including teachers,^108,109,119,121,123,131–133^ external educators (e.g., nutritionists, dietitians, health professionals, researchers),^79,90,98,110,111,113–115,118,120,125–128^ and older students.^117^

Nine RCTs were implemented over an academic year or longer.^79,90,98,108,110,111,119,123,125,128^

Brito Beck da Silva et al^111^ assessed the effect of the StayingFit Brazil online nutrition education program, which consisted of sixteen 30-minute sessions supervised by a nutritionist once per week over 12 months. The online content included educational text, learning questions, feedback, food and activity logs, hunger and satiety scales, a goals log, and discussion forums. Printed materials of the online content were also made available to parents. Intake during the previous week was assessed with a self-administered FFQ. At post-intervention, students who received the StayingFit Brazil program had higher odds of more frequent bean consumption and lower odds of more frequent soft drink consumption compared to the control group. No significant differences were detected in the intake of other dietary components that were measured, including at least one type of vegetable, raw salad, cooked vegetables or legumes, fruit, milk, fried snacks, ultra-processed meats, crackers, cookies, snacks, and candies.

Takacs et al^128^ assessed the impact of a 9-month multi-component intervention in Hungary that focused on general nutrition. The intervention consisted of 27 weekly nutrition education classes (25-45 minutes each) delivered by a trained dietitian, 5 after-school cooking classes, online educational materials, games, tasting, and food preparation. The after-school cooking classes focused on fruit and vegetables, reducing dietary risk factors, the importance of breakfast, and reducing added sugars and were attended by children, parents, and grandparents. Dietary behavior was assessed by self-report with the assistance of a trained field worker and measured a variety of factors including the frequency of breakfast skipping, number of meals, daily fluid intake, and the frequency of dairy product, fruit, vegetable, sweets, fast food, energy drink, and sugary drink intake. The intervention resulted in more favorable changes in total dietary behavior immediately following the intervention compared to children who received no intervention; however, significant differences between groups were no longer detected by the end of summer break. In addition, the statistically significant improvement in dietary behavior was a 0.2 score increase on a scale of 0-10 and may not be practically significant.

A study conducted in Norway assessed the effect of the Fruits and Vegetables Make the Marks educational SCT-based intervention administered over 1 academic year.^108,123^ Seven 135-minute sessions delivered monthly during sixth grade home economics classes by the regular teacher focused on the health benefits of eating fruit and vegetables, recommended fruit and vegetable intake, food preparation, and taste testing activities. Six newsletters were also distributed to the parents to increase communication about fruit and vegetables and to encourage availability and accessibility of fruit and vegetables at home. Both the intervention and control groups had access to the national fruit and vegetable subscription program, which provided paying students with a piece of fruit or a carrot each school day, usually at lunch. Combined fruit and vegetable intake was assessed with a 24-hour recall administered by a project worker at post-intervention and 1-year follow-up; fruit and vegetable intake was also assessed by a 17-item FFQ at post-intervention and 1-, 3-, 7-, and 14-year follow-ups. Compared to students in the control group, the fruit and vegetable focused education did not have an effect on children’s daily fruit and vegetable consumption immediately post-intervention or 1-year follow-up.^108^ Long-term follow-up showed that there was still no effect of the educational intervention on fruit and vegetable consumption 3-, 7-, or 14-years follow-up.^123^ However, there was low implementation of the classroom education component and the dropout rate for the long-term follow-up was 50 percent. The results from this trial are in contrast to a similar Norwegian study,^142^ which found that offering a free fruit and vegetable subscription program with the educational intervention increased adolescent fruit and vegetable intake, compared to access to the paid fruit and vegetable subscription program (see Combined interventions for more detailed information).

Brito Beck da Silva et al^110^ conducted a study in Brazil assessing the effect of nutrition education delivered by a nutritionist. The intervention consisted of eight 50-minute nutrition education sessions delivered over 9 months to middle and high school-aged students, with additional workshops to reinforce concepts from the educational sessions. Children were also given educational materials to bring home to their families that encouraged maintenance of a healthy lifestyle. Intake during the previous week was assessed with a self-administered FFQ. Participants in the intervention group had significantly higher odds of more frequent legume and vegetable consumption post-intervention compared to the control group. No significant differences between groups were detected for other measured dietary components including beans, rice, fruit, milk, candies, snacks, processed meats, and soft drinks.

Another study in Brazil involved a 9-month multi-component intervention with elementary and middle school-aged students.^79^ The intervention involved six 50-minute nutrition education classes to promote healthy eating and physical activity; three1-hour food preparation workshops for teachers and food service staff; and two 1-hour nutrition education workshops for families covering food groups, their nutrients, and their respective functions in the body, as well as steps for promoting a healthy diet at school. All education was delivered by a dietitian. Combined fruit and vegetable intake was assessed with an FFQ. Compared to the control group, children who received the intervention consumed fruit and vegetables more frequently at post-intervention. Results were not separated by age group. Notably, the study had a very high attrition rate (62 percent) and the control group had much higher attrition (77 percent) than the intervention group (48 percent).

A study in Greece examined the effect of adding a nutrition education program to the daily free, healthy meal received by a large sample of elementary, middle, and high school students over the course of 1 academic year (see Elementary school for results in children).^98^ The educational program included informational school posters, age-appropriate workbooks and games, interactive events, and leaflets for parents and school staff. Interactive informational and cooking events were conducted by nutrition experts, athletes, and volunteer chefs. The control group received the free, healthy meal but no nutrition education program. Parents reported adolescent intake on a semi-quantitative FFQ at baseline and post-intervention. Adolescents (aged 12-18 years) who received the intervention had a significantly greater weekly consumption of vegetables post-intervention compared to the control group. There were no significant differences between groups in intake of milk/yogurt, fruit, or whole grains. Notably, loss to follow-up was high (76 percent) due to missing questionnaires or information required to link participant information pre-and post-intervention.

Keshani et al^119^ conducted a study in Iran involving four 90-minute teacher-facilitated interactive learning sessions delivered over 1 academic year, as well as a briefing session for parents and school health instructors. Content was based on the 2015-2020 Dietary Guidelines for Americans and collaborative learning techniques were used, such as group discussions, reciprocal teaching, and problem-based learning. The control group received the standard school curriculum. Dietary intake during the previous month was measured with an FFQ and diet quality was then assessed using the Revised Children’s Diet Quality Index. Overall diet quality, as well as intake of added sugars, fruit, vegetables, and dairy, improved between baseline and 1-month follow-up in the intervention group compared to the control group. Total and whole grain intake did not differ between groups at post-intervention. Although statistically significant effects were detected, the practical significance of the results is unclear due to the small magnitude of effect.

The European Youth Tackling Obesity-Kids project in Spain investigated a 10-month social marketing training intervention delivered by health professionals.^90^ Middle school adolescents (aged 12-14 years) received a 2-hour training from health professionals on nutrition topics, healthy lifestyles, social marketing principles, and tools to communicate healthy messages. After the training, the adolescents then designed and delivered nutrition education to children aged 9-11 years (see Elementary school for results in children). Dietary intake was self-reported using select questions from two questionnaires. Among the adolescents, the intervention had no effect on intake of fruit, vegetables, fast food, or sugary drinks compared to the no intervention control group.

Finally, the study conducted in France consisted of two 50-minute sessions delivered by a trained researcher.^125^ The classroom sessions were delivered 1 year apart and focused on healthy eating attitudes, balanced meal planning, and how to overcome barriers to having a balanced diet. Intervention activities included role-play, visualization, group work, and discussion. Adherence to balanced diet was assessed by self-report of the previous day’s intake and its relationship to the Programme National Nutrition Santé Guideline Score tool. Students exposed to these two nutrition education sessions maintained their level of adherence to a balanced diet between 6-months pre-intervention and 3-months post-intervention compared to students in the no intervention control group, whose adherence to a balanced diet decreased.

Eight RCTs were between 8 weeks and 6 months duration.^109,113,117,121,126,127,131–133^

Yamaoka et al^133^ randomized all-female classes in Japan into two groups: an intervention group that received 6 months of nutrition education and a control group that received standard health science education. The nutrition education intervention included 12 group dietary education/counseling sessions delivered biweekly by a teacher who was also a dietitian. The goal of the intervention was to improve nutrition knowledge and motivate changes in behavior. Tailored advice was given to the students based on an initial FFQ and some individual feedback was provided after group sessions. Children were also asked to talk about what they learned from the sessions with their mother/guardian. Fiber and salt intake during the previous month were assessed with an FFQ. Change in fiber and salt intake from baseline to post-intervention did not differ between the intervention group and the control group.

A study conducted in China randomized schools to two intervention groups and a no intervention control group.^131,132^ One intervention group implemented education only and included 26 weekly 15-minute nutrition sessions delivered by trained teachers and 6 monthly 30-minute peer support activities. Intervention information focused on health promotion and included a balanced diet, nutrient functions and deficiencies, supplements, good hygiene, and food safety. The second intervention group implemented changes to the school environment targeting health promotion, in addition to education (see Combined interventions) for more detailed information). Eating behavior, which measured weekly consumption of fresh fruit, vegetables, dairy products, breakfast, dessert, fried food, and soft drinks, was assessed after 3-months of the intervention.^132^ Change in eating behavior score varied significantly across the groups, with larger increases observed in the education group and the education plus environmental changes group compared to the control group. However, because comparisons between individual groups were not reported, it is unclear which between group comparisons drove the overall significant effect. At post-intervention, intake was assessed with an FFQ and a significantly higher percentage of students in the education only group reported consuming vegetables daily and consuming no fried food during the previous week compared to children who received no intervention.^131^ No differences between groups were detected for soft drink, dessert, fresh fruit, or milk intake.

The study conducted in Turkey assessed the effect of nutrition education focused on the Mediterranean diet; topics included adequate and balanced nutrition, the importance of nutrition during adolescence, World Health Organization nutrition guidelines, and the characteristics and health effects of the Mediterranean diet.^126^ The 1-hour sessions were delivered twice weekly by a researcher for 8 weeks, with a 2-hour booster session provided 1 month after the main program. The sessions utilized multiple strategies, including audio-visual materials; banners, leaflets, and posters made by children; and organized activities such as plays, poems, and songs. Adherence to a Mediterranean diet pattern was assessed with the Mediterranean Diet Quality Index (KIDMED) after the booster session was completed. Students exposed to this Mediterranean diet focused nutrition education program reported higher adherence to the Mediterranean diet post-intervention compared to children who did not receive the intervention.

Forneris and colleagues^117^ conducted a peer-led Goals for Health intervention in rural areas of the United States that included 12 weekly sessions of health and nutrition education delivered by trained high school students to a large sample of sixth grade students. The intervention focused on life-skills surrounding healthy eating, and included goal-setting activities, skits, videos, and healthy snacks. There was a focus on fiber and fat knowledge and intake. Fruit and vegetable intake and fiber intake were assessed with a brief, self-administered FFQ at post-intervention, 1-year follow-up, and 2-years follow-up. Intake of fruit and vegetables (combined) and fiber decreased over time in both the intervention and control groups, but there were no significant differences between the intervention and control group. The study authors noted that these measures had relatively low internal consistency and may not have been a strong measure of the intervention’s effect on these foods. Additionally, this study had 53 percent attrition due to participants moving from the area or absences, but differences in attrition between groups could not be determined because only total sample size was reported.

An educational intervention tested in Hong Kong SAR involved six health educator-administered lessons over 12 weeks, with content on food choices, benefits of common nutrients, diet and diseases, healthy diets, and the relationship between diet and exercise.^113^ Nutrition education via e-learning was then used to capture student’s food records and provide dietary analysis, including educational information on nutrient composition of the foods consumed and personalized feedback on how well their diets meet dietary guidelines. The control group was also exposed to health educator-administered lessons and nutrition education via e-learning, but they did not receive personalized feedback on their diets. Intake was assessed through self-reported daily food intake through the e-learning online system. Students in the intervention group decreased their daily intake of sugar and saturated fat, as well as increased their daily intake of dietary fiber and sodium compared to the control group. It was not clarified whether measured sugar intake included only added sugars or added sugars in addition to naturally occurring sugar.

An Iranian study assessed the effect SCT-based nutrition education sessions in female middle school-aged students.^127^ The intervention was delivered by a researcher and consisted of eight weekly 60-minute sessions on dietary behaviors and behavioral determinants, including weekly consumption of breakfast, fruit and vegetables, unhealthy snacks, and fast food, as well as daily fruit and vegetable serving sizes. Parents attended two 2-hour workshop sessions and received a newsletter and 10 text and video reminder messages to boost their knowledge and encouragement of healthy dietary behaviors in their children. The control group received routine nutrition education consisting of two 30-minute sessions. Dietary intake was assessed via questionnaire. The theory-based nutrition education intervention increased fruit and vegetable intake (both frequency and servings) and decreased unhealthy snack and fast food intake frequency between baseline and both 3- and 6-months follow-up, compared to the control group. Between group differences increased for fruit, vegetable, and unhealthy snack intake frequency between the 3- and 6-month follow-up but decreased for fast food intake frequency; group by time interactions were not significant for fruit and vegetable intake servings between the two follow-ups.

Two Dutch studies examined the Krachtvoer program, an educational program that aims to increase fruit and fruit juice intake, decrease high-fat snack intake, and increase breakfast frequency and quality through experiential learning and cognition driven activities delivered by teachers.^109,121^ Experiential learning activities included taste testing and food preparation, while cognition driven activities included actions such as comparing personal dietary intake to Dutch recommendations. A take-home bag with healthy products and a newsletter for parents was also provided. The program was administered over eight 50-minute school lessons. In the first study, results from an FFQ showed the Krachtvoer educational intervention significantly increased fruit intake compared to usual nutrition education curriculum, but did not have a significant impact on intake of fruit juice or sweet and savory snacks.^121^ Results from a 24-hour recall supported the FFQ findings and also showed that there was no effect on intake of sugar from breakfast or saturated fat from snacks or breakfast. Notably, of the 25 original clusters, 8 dropped out after randomization but before baseline data collection. In addition, the statistically significant increase of 0.2 servings/day of fruit may not be practically significant. In a second Dutch study assessing the 8-week Krachtvoer program, a positive effect of the educational intervention was detected for fruit, fruit juice and a variety of snacks, assessed through self-report with investigator developed and FFQ-derived questions, immediately post-intervention compared to the control group.^109^ At 6-months follow-up, beneficial effects on fruit intake frequency were retained and sweets consumption had improved significantly compared to the control group; differences between groups were no longer significant for fruit juice and all other snacks.

Four RCTs were 6 weeks or less in duration.^114,115,118,120^

Lane et al^120^ implemented the Kids SIPsmartER intervention in a small sample of US students. The intervention combined the TPB with health and media literacy to reduce consumption of SSBs. Trained researchers delivered six weekly 45-minute lessons, which included teach-back worksheets, a short didactic portion, an interactive application activity, and an at-home assignment. Brief phone calls were also delivered to parents to reinforce the lesson content at home. Intake of SSBs was assessed with a beverage intake questionnaire. Although SSB intake in students who received the intervention decreased from baseline to post-intervention and 3-months follow-up, these changes were not significantly different compared to a matched-contact control group who received a physical activity intervention of the same duration.

One intervention randomized classes from girls schools in Iran into one of two TPB-based intervention groups or a control group, which did not receive an intervention.^118^ The education provided to both intervention groups focused on improving snacking behavior and was delivered weekly or biweekly over three 90-minute sessions. Strategies utilized during the sessions included informational lectures, group discussions, booklets, and handouts. One intervention group included goal/intention setting for healthy behaviors, while the other intervention group did not. Intake of snacks during the previous week was assessed with a self-administered FFQ. Nutrition education with goal/intention setting reduced unhealthy snack intake at 10-days and 3-months follow-up, but also reduced healthy snack intake at 10-days follow-up, compared to no intervention. Nutrition education without goal/intention setting reduced unhealthy snack intake at 10-days follow-up (but not 3-months follow-up) compared to no intervention; no effect on healthy snack intake was detected for either time point. No significant differences between the two intervention groups were detected.

A second study in Iran assessed nutrition education based on Pender’s Health Promotion Model (HPM) that focused on improving breakfast consumption.^114^ The intervention was delivered by researchers to middle school girls over four weekly 45- to 60-minute sessions, in addition to usual classroom nutrition education. Sessions included small group activities and content focused on the importance of breakfast, what constitutes a healthy and balanced breakfast, and strategies to overcome barriers and improve self-efficacy around eating breakfast. Training sessions were also held for teachers, focusing on the role of breakfast in improving students’ cognition, and for mothers, teaching them how to prepare breakfast with improved nutritional quality. Fiber intake at breakfast was assessed with 3-day breakfast records at baseline and 1 month following the intervention. Nutrition education based on Pender’s HPM increased fiber intake at breakfast compared to those who did not receive the intervention.

Another study in Iran utilized Pender’s HPM, but focused on increasing dairy consumption in middle school girls.^115^ The intervention was delivered over four weekly 40- to 45-minute sessions, which included small group activities and focused on the benefits of dairy foods (primarily low-fat dairy) and strategies to overcome barriers and improve self-efficacy around dairy consumption. Posters about the benefits of dairy consumption were also hung around the school. Lastly, a nutrition expert conducted a training session with parents and teachers regarding how dairy can improve the health of adolescents and how they can support increased dairy consumption in the students. Dietary intake was assessed with 3-day diet records at baseline and post-intervention. This nutrition education program based on Pender’s HPM increased dairy food intake compared to those who received no intervention. However, the intervention had no effect on saturated fat or fiber intake. Although the 0.3 servings/day increase in dairy intake was statistically significant, this magnitude of effect may not be practically significant.

##### Game-based learning

Three cluster-RCTs examined educational games in relation to food intake and dietary intake-related behaviors^107,122,130^; all studies had a beneficial effect on at least one targeted outcome.

Two studies in Italy assessed the effect of the educational board game, Kalèdo, which was designed to improve knowledge of the Mediterranean diet and promote a healthy lifestyle, particularly dietary behavior.^107,130^ In the first study, middle school-aged children played Kalèdo for 15-30 minutes every week for 24 weeks.^107^ Intake was assessed with a questionnaire. Compared to no intervention, the children who played Kalèdo consumed significantly more vegetables post-intervention; the impact of the intervention on consumption of other food items was not reported. The second study of Kalèdo^130^ was conducted with both middle school and high school students.^130^ Dietary habits were assessed with the Adolescent Food Habits Checklist and a second dietary questionnaire at post-intervention and 12-month follow-up. After 20 weekly 15- to 30-minute play sessions, middle school students showed significantly improved eating behavior and food habits at post-intervention compared to a control group that didn’t receive an intervention. By the 12-month follow-up, changes in both middle school students were no longer significant compared to the control group.

The final game-based learning intervention was conducted in Spain and was implemented on a single day.^122^ Teams of adolescents participated in a 50-minute game-based nutrition workshop led by three trained nutritionists. Students competed over their nutritional knowledge and were quizzed on the following topics: hydration, lunches and snacks based on the Mediterranean diet; prioritizing fresh fruit juices over sugar-sweetened beverages, homemade lunches and snacks, daily meal distribution, knowledge of which foods are unhealthy, the benefits of fiber-rich foods, and the relation between excessive fat and sugar intake and health problems. Expressed food preference was assessed by the student’s choice of midmorning snack (one food and one drink). Three types of food and drink vouchers were randomly assigned to the students before choosing: standard, 2-for-1 of unhealthy foods with standard drink choices, and 2-for-1 unhealthy drinks with standard food choices. Among seventh grade students, the game-based nutrition workshop decreased the probability of choosing an unhealthy food and drink for a midmorning snack over a healthy food and drink, compared to a control group that didn’t receive an intervention. However, there was no effect on choosing unhealthy drinks among children who received a voucher promoting unhealthy drinks; in contrast, the voucher promoting unhealthy foods did not nullify the effects of the intervention on unhealthy food selection Because study personnel were not inside the classroom when the snacks were being selected, it is possible that some students switched snacks before selection could be recorded. Consumption and long-term behavior changes were not measured.

##### Educational reading materials

Two cluster-RCTs^124,129^ and one parallel RCT^105^ investigated the effects of educational reading materials on diet and diet-related behaviors, with mixed results.

Toral et al^129^ implemented a stage-based intervention in seventh and eighth grade students over 6 months in Brazil. Educational magazines promoting healthy eating were given out every month at school and focused on overcoming barriers against healthy eating, breakfast and meal distribution, the link between nutrition status and exercise, the role of nutrients, nutrient labeling, and diet-related diseases. The student’s stage of change was identified at the beginning of the study and newsletters promoting fruit and vegetable consumption tailored to that stage of change (pre-contemplation, contemplation/preparation, or action/maintenance) were also mailed home monthly. Combined fruit and vegetable intake was assessed through self-report. Compared to the control group that received no intervention, seventh and eighth grade students who received printed nutrition education materials did not have significantly different fruit and vegetable intake post-intervention.

Leung and colleagues^105^ investigated the effect of Manga (Japanese comic art) promoting fruit intake and its benefits on elementary and middle school-aged children at an after-school program in the United States. Thirty pages of the comic were narrative and one page was non-narrative in order to reinforce the health messages. After the exposure, children were offered a choice of snack from eight items (four fruits and four energy-dense items). Students who read the comic advocating for fruit consumption had greater selection of fruit as a snack compared to children who were randomized to read a non-health related newsletter and word search. There was no further assessment to determine the long-term effect of reading the comic on fruit consumption and results were not broken out by age group.

A study conducted in the United Kingdom assessed the effect of providing a tailored leaflet to middle and high school-aged female students based on their baseline dietary intake.^124^ The leaflets included dietary guidance on brown bread, whole-grain cereal, fruit, and vegetables. Control participants received a generic leaflet based on national guidelines. Intake was assessed through three 24-hour dietary recalls sheets provided at baseline and at 3-month follow-up. Although brown bread intake increased in both groups between baseline and the 3-month follow-up, the tailored intervention leaflet significantly increased brown bread intake compared with the control leaflet. Fruit intake did decrease in both the intervention and control group, but the difference was not significant between groups. Whole-grain cereal and vegetable intake did not vary significantly across time or between groups. Although there was a statistically significant increase in brown bread intake, the change may not be practically significant (0.12 servings/day). Results were not separated by age group.

##### Other strategies

Two cluster-RCTs^112,116^ and one parallel RCT^152^ utilized other educational strategies that did not fit cleanly into curriculum-based interventions, game-based learning, or educational reading materials. All studies had a beneficial effect on at least one targeted outcome.

One study implemented a 6-week, web-based version of the Team Nutriathlon intervention using key behavior change techniques related to self-determination models to increase consumption of fruit and vegetables, as well as milk and milk alternatives in Canadian seventh and eighth grade students.^112^ Individually, students were challenged to reach an average daily consumption of six servings of fruit and vegetables and three servings of milk and milk alternatives based on Canada’s Food Guide. As teams of three to five students, success depended on both the quantity and variety of foods consumed. Follow-ups were planned every 2 weeks during the intervention to develop autonomy regarding food choices. During the last follow-up, final consumption results were determined, and students were awarded with symbolic prizes. The control group was exposed to the usual school curriculum, which didn’t include a specific nutrition program. Dietary intake was self-reported through a web-based platform. The web-based Team Nutriathlon program increased consumption of vegetables and fruit, as well as milk and milk alternatives during and shortly after the intervention, compared to the control. Differences between groups were no longer present 10-weeks post-intervention.

A study conducted in the United Kingdom randomized participants to one of two intervention groups or a control group.^152^ The 1-week interventions aimed to increase fruit and vegetable consumption and enrolled students in both middle school and high school. The first intervention was volition-based and students wrote down how, where, and when they would eat five portions of fruit and vegetables every day for the following week, and then were asked to implement those plans. The second intervention was motivation-based and rooted in TPB; it included raising awareness of the health benefits of fruit and vegetables through reading, as well as documenting personal beliefs about the benefits of consuming fruit and vegetable, barriers to consuming them, and means of overcoming those barriers. The control group also received a volition-based intervention, but it instead focused on homework. Both the volition-based and motivation-based interventions increased fruit and vegetable intake from baseline to post-intervention. However, only the volition-based intervention increased intake relative to the control group and there was no difference in change between the two intervention groups. Notably, the study had a high rate of attrition (56 percent) and was underpowered for both the motivation-based intervention group and the control group.

Dohnke et al^116^ assessed a theory-based intervention conducted during one regular classroom session targeting prototype perception (i.e., social image of a typical peer engaging in a certain behavior). Within the intervention group, middle school-aged participants were divided into two sub-groups, receiving social media profiles of either a “healthy” or “unhealthy” eater that matched the sex of the student. Although students were split during the session, the total intervention group was compared to a control group that didn’t receive an intervention. Adolescents who received a profile of a “healthy” eater were asked to describe up to seven similarities between themselves and the “healthy” eater. Adolescents who received a profile of an “unhealthy” eater were asked to describe up to seven differences between them and the “unhealthy” eater. Students were then grouped with others who had the same sex and “type” of eater profile and created and presented profile summaries. At post-intervention, the intervention group consumed a higher proportion of fruit than sweets compared to the control group, as well as a greater amount of fruit overall, when offered unlimited access to a bowl of both foods. At 4-weeks follow-up, sweets consumption was lower in the intervention group compared to the control group based on both a 24-hour recall and in-person consumption when presented with unlimited access to fruit and sweets, but no differences were detected for proportion of fruit or overall fruit intake.

##### Summary

Studies on teaching and educational interventions provided the largest contribution to the body of evidence in middle and junior high school adolescents. Most studies implemented curriculum-based interventions, which primarily had beneficial effects on dietary intake. Although curricula were heterogeneous in their methods and components, several patterns emerged. Common strategies among successful curricula include parental involvement and an internet- or computer-based technology component. Fruit and vegetable intake were the most studied outcomes; studies found a mix of beneficial and null effects for fruit, whereas vegetables tended to be beneficial impacted by the interventions. Overall diet quality (e.g., adherence to balanced or Mediterranean diet) was another commonly studied outcome; of the eight studies that assessed overall diet quality, five found that the intervention had a beneficial effect compared to the control. Dairy, food and beverages of lower nutritional quality, and fiber were other commonly studied outcomes, but the results were not consistent enough to draw conclusions. Fewer studies measured whole grains, protein foods, added sugars, sodium, and saturated fat. Curricula tended to have positive results when delivered by a researcher, but additional research is needed to confirm. No clear pattern of effect emerged for intervention duration.

Some studies used non-curriculum-based interventions to target the acceptance of healthier foods and dietary patterns. Game-based learning generally had a beneficial effect on at least one measure of food intake or eating behavior. Three studies utilized reading materials to educate participants found mixed results, including beneficial, unfavorable, and no effect on various diet outcomes. Other types of interventions were administered in single studies and showed beneficial outcomes, including a theory-based intervention targeting social perception of healthy and unhealthy foods, volition-based and motivation-based interventions to increase fruit and vegetable intake, and an intervention focusing on individual- and team-based consumption goals to build autonomy over food choices. However, it is difficult to make meaningful conclusions about the various non-curriculum-based interventions since they were assessed in too few of studies. In addition, several studies were conducted in populations that were not exclusively middle and junior high school adolescents. More research is needed on non-curriculum-based teaching and educational strategies.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates that curriculum-based nutrition education improves dietary intake (particularly overall dietary quality and vegetable intake) in middle and junior high school adolescents. Common components of successful curricula include parental involvement or use of internet- or computer-based technology. This conclusion statement received a grade of Moderate. There was insufficient evidence examining the effects of non-curriculum-based teaching and educational interventions (e.g., games, reading materials); therefore, conclusions were not drawn, and the body evidence was not graded. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: The main area of potential risk of bias in this body of evidence was related to concerns of selective reporting; only one study had information on an a priori analysis plan.^90^ About half of the studies had concerns related to missing outcome data and three studies did not provide adequate information on the randomization process. All studies had low risk of bias related to deviations from intended interventions, and one study had concerns related to outcome measurement.^117^
- Consistency: Curriculum-based interventions in this body of evidence utilized diverse teaching and educational strategies. Additionally, there was large variation in the content, delivery, and dose of the interventions. Although this heterogeneity limits the ability to assess consistency across studies, some areas of consistency are worth noting. Most studies detected beneficial effects of curriculum-based interventions on at least one measure of dietary intake. Overall diet quality and vegetable intake were commonly studied outcomes that tended to be beneficially impacted by the interventions. Less consistent results were observed for intake of fruit, milk/dairy, food and beverages of lower nutritional quality, and fiber. Other dietary components, including bean and legume intake, were examined in too few of studies to assess consistency. Interventions that were delivered by researchers and those with parental involvement or an internet- or computer-based technology component tended to have beneficial outcomes. Among the four studies that measured dietary intake and found primarily null results, one noted low internal consistency of the outcome measure,^117^ another reported low implementation of the intervention,^108,123^ one was focused more narrowly on nutrients in female students,^133^ and one was not on the primary target audience of the intervention.^90^
- Directness: Studies in this body of evidence directly assessed the research question in terms of the population, intervention, comparators, and outcomes.
- Precision: Sample and cluster sizes varied across the body of evidence, ranging from 71 to 3627 participants and 2 to 146 clusters. Most studies in this body of evidence did not report power calculations. Of the seven studies that reported power calculations, one did not meet their pre-specified sample size goal^90^ and two were completed for an outcome unrelated to diet.^110,111^ For some statistically significant results, practical significance may be limited given the small increases in dietary intake.
- Generalizability: There are limits to the generalizability of this body of evidence to middle and junior high school adolescents in the United States. Although studies were conducted in a wide variety of high or very high HDI countries, only two studies were conducted in the United States and neither studied overall dietary quality or vegetable intake. Several studies did not report information on SES and race/ethnicity; when reported, studies tended to enroll participants from a range of SES and racial/ethnic backgrounds. Most studies were conducted exclusively in middle and junior high school, but three studies were conducted in conjunction with elementary school and/or high school.

#### Behavioral and environmental interventions

##### Description of the evidence

Fourteen cluster-RCTs examined the effect of school-based behavioral and environmental interventions on diet and diet-related behaviors in middle or junior high school-aged adolescents.^24–26,28,32,39,44,134–140^ Of these, six were conducted exclusively in middle or junior high schools,^135,136,138–140^ six were conducted in conjunction with elementary schools,^24–26,28,32,39,44^ and two were conducted in conjunction with high schools.^134,137^ Most studies were conducted in the United States^24–26,28,32,39,134–136,138^; other studies were conducted in Canada,^140^ the Netherlands,^137^ Sweden,^139^ and the United Kingdom.^44^ Sample size, in regards to both clusters randomized and individual participants assessed, varied greatly, ranging from relatively small studies (2 clusters, less than 100 individual participants)^136^ to large studies (55 clusters, several thousand individual participants)^39^; most studies included several hundred or more individual participants and half of the studies included over 10 clusters.^24,32,39,44,134,137,140^ Several studies were specifically conducted in schools with high proportions of students eligible for free or reduced price meals through the NSLP or other forms of economic assistance,^24,25,28,32,135,136^ whereas some studies enrolled schools with a range of SES.^26,134,138^ In general, studies were conducted in schools with diverse student populations; several were conducted in schools that enrolled a high proportion of Black and/or Hispanic students,^24,25,28,32,136^ while others reported being conducted in schools that enrolled a predominantly White student body.^44,134,135,138^ A variety of strategies were examined across the studies, including using rewards, incentives, nudges, or prompts; modifying food palatability, presentation, and promotion; changing food availability and school food policies; and implementing a combination of behavioral and environmental strategies, as described below. Eight studies reported the theory, model, or framework used to inform the intervention.^24,25,28,32,39,135,138,139^ Most interventions were compared to usual care or no intervention,^24–26,32,44,134,135,137–140^ although some were compared to different interventions or identical interventions without the component of interest.^24,28,32,39,136,140^ Outcomes were primarily assessed by study personnel via direct observation or weighing of food selected and consumed at school,^24,26,28,32,39,135,136,138,139^ although some studies used sales records^134,137^ or measures of self-reported intake.^44,134,140^ Ten studies examined food and beverage selection,^24–26,28,32,39,134,135,137,138^ while 10 studies examined food and beverage intake.^24,26,32,44,134–136,138–140^ Most studies assessed in-school selection and/or intake,^24–26,28,32,39,134–140^ but a few assessed overall selection or intake.^44,134,140^ Evidence from these studies and participant characteristics are described in Table 11; the risk of bias assessments are described in Table 12. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Rewards, incentives, prompts, and nudges

Two cluster-RCTs, both conducted in the United States, assessed the effects of using rewards, incentives, nudges, or prompts to influence adolescent food choices,^32,39^ generally detecting beneficial effects.

Raju and colleagues^39^ examined the effect of a 6-week intervention that combined incentives for selecting fruit and vegetables at lunch with personal pledges or with a group competition in elementary and middle school students.^39^ In the first intervention group, students were asked to make a personal pledge to eat more fruit and vegetables and were incentivized to select two or more fruits and/or vegetables through small incentives that could be earned daily and the opportunity to win a larger prize through a random drawing if they selected at least two fruits and/or vegetables each day of the week. Students in the second intervention group were told they were in a healthy eating competition with other schools and were offered the same incentives. Students in the comparison group only received the incentives. Trained cafeteria staff recorded student selection of fruit and vegetables. Both intervention groups, the competition with incentives and the personal pledges with incentives, increased the proportion of children and adolescents selecting two or more fruits or vegetables at lunch 10 weeks after the intervention concluded compared to incentives alone. Due to the lack of a true control group, the effectiveness of the incentives compared to no incentives cannot be discerned. Analyses with middle school students alone were not conducted.

The second study separately assessed the effects of four different nudge or incentive strategies in the cafeteria line over 5 days to influence elementary and middle school students’ milk choice: a verbal prompt to try white milk, a verbal prompt to try white milk because it is healthy, a verbal prompt to try white milk because it tastes good, or a small incentive attached to the white milk carton.^32^ No prompt or incentive was provided in the control group. Researchers assessed selection and consumption during lunch through observation and weighing. During the intervention, all four intervention groups increased in the proportion of students choosing white milk over chocolate milk compared to the control group. There were no differences between the three verbal prompt groups, or between the incentive group and any of the prompt groups. Furthermore, all verbal prompt groups consumed less added sugars than the control group without decreasing the amount of milk consumed; the incentive group consumed less added sugars than the control group but also decreased the amount of milk consumed. Similar, but less consistent, results were obtained during 2 days of follow-up, when prompts and incentives were discontinued.

##### Food palatability, presentation, and promotion

Six cluster-RCTs, all but one conducted in the United States, examined strategies targeting the palatability, presentation, and promotion of foods at school,^24,28,135,136,138,139^ with beneficial effects generally observed for fruit and vegetables.

Two studies implemented interventions that were primarily focused on improving the palatability of certain foods.^136,139^

First, Prell et al^139^ implemented changes in the cafeteria to encourage fish consumption by students in Swedish schools. Fish consumption was encouraged in the intervention group by providing multiple choices and preparations of fish, improving sauces and side dishes that accompanied the fish, and using fish-related decorations in the cafeteria. Fish consumption was measured by structured observations in the cafeteria. After 1 academic year, although fish consumption tended to increase in the intervention group, this effect was not statistically significant compared to a no-intervention control group. However, the magnitude of effect was intermediate to that of a third group that received nutrition education in addition to the environmental intervention, which did detect significant, beneficial effects relative to the control group (see Combined interventions for more detailed information).

Second, Johnston et al^136^ assessed the impact of pairing a weekly vegetable snack with peanut butter for 4 months.^136^ Intake was assessed by visual inspection and weighing of vegetables following the snack. Adolescents who were provided a vegetable snack with peanut butter increased the amount and variety of vegetables consumed relative to adolescents who were provided vegetables alone. Results were similar when limited to students categorized as being “vegetable resistant” at baseline.

Two studies implemented interventions that were primarily focused on modifying how fruit is presented in the cafeteria.^135,138^

Greene et al^135^ conducted a study focused primarily on food presentation that assessed the effect of fruit promoting strategies in the school lunchroom for 6 weeks.^135^ Changes in the cafeteria included offering several varieties of fruit at multiple locations in the lunch line, displaying cut and whole fruit labeled with creative names in attractive cups and bowls, and displaying facts about fruit in the lunch room. Selection and intake were assessed by trained field researchers through observation. Compared to adolescents who attended control schools that made no changes, adolescents exposed to the fruit promoting lunchroom changes had greater increases in selection and consumption of fruit from pre- to post-intervention; there was no difference in change for vegetables or white milk. The results of a third group, which implemented similar strategies in the school lunchroom to promote vegetable consumption, were not described or reported.

The second study more narrowly focused on food presentation, assessing the effect of offering pre-sliced apples (compared to the usual offering of whole apples) for 1 week on apple purchases, consumption, and waste.^138^ Outcomes were assessed through observation by trained field researchers. Although there was no difference in apple purchases between groups, the percentage of adolescents who consumed more than half of their purchased apple was greater in the group offered pre-sliced apples compared to the group offered whole apples.

One study, Shape Up Somerville: Audio Adventures, focused exclusively on food promotion, assessing the effect of daily bean-promoting audio messages played over the public address system for approximately 3 months.^28^ In both the intervention and control schools two new bean dishes were incorporated into the school lunch menu one to two times per month. Choice of meals was measured through direct observation by trained data collectors. The odds of choosing a bean dish did not differ between the intervention and control group during the study. When the two types of dishes were analyzed separately, there was no effect of study group on selection of the bean taco dish, but the odds of choosing the bean chili dish were greater in the intervention group compared to the control group. The level of implementation, and its effect on choosing bean dishes, varied greatly across schools. Specifically, the school with the lowest level of implementation had lower odds of choosing bean dishes and the school with the highest level of implementation had higher odds of choosing bean dishes, suggesting that greater implementation of this intervention may be important to its efficacy. The study was conducted with both elementary and middle school-aged students but analyses by school level were not reported.

Finally, one cluster-RCT, the Modifying Eating and Lifestyles at School study, targeted food palatability and presentation, assessing the effect of a 7-month chef training intervention and a 4-month “smart café” intervention, alone or combined, on the selection and consumption of fruit and vegetables.^24^ In the chef training intervention, a professional chef collaborated with school cafeteria staff 2-3 days per week to create recipes improving the palatability of foods while incorporating whole grains, produce, healthy fats, and seasonings without added salt or sugar. In the smart café intervention, a variety of choice architecture strategies were implemented to improve the presentation of foods (e.g., offering vegetables at the beginning of the lunch line, placing fruit in attractive containers by the register, promoting fruit and vegetables with prominent signage). Selection and intake of food was assessed by observation and weighing by study staff. Following 3 months of the chef training intervention alone, children and adolescents had higher odds of selecting vegetables at lunch than those at control schools, but there were no significant effects on vegetable consumption or fruit selection and consumption. Following 7 months of the chef training intervention alone, children and adolescents had higher odds of selecting and consuming fruit and vegetables compared to those at control schools. The smart café intervention alone resulted in greater odds of selecting fruit and vegetables compared to no intervention; however, there were no effects on fruit or vegetable consumption. Effects of both interventions combined were similar to those of the chef training intervention alone. White milk was also targeted by the smart café intervention (i.e., placing white milk in front of sugar-sweetened milk), but no effect of this intervention on white milk selection or intake was detected. Some schools opted to only provide white milk on certain days instead of adhering to the intervention and were removed from analyses. Remaining results were then collapsed across the two study groups that received the smart café intervention, limiting their usefulness. The study was conducted with both elementary and middle school-aged children, but analyses by grade level were not reported.

##### Food availability and school policies

Four cluster-RCTs assessed the effect of interventions targeting the availability of certain foods in the school environment and school policies related to food,^26,44,137,140^ with mixed results.

Shemilt et al^44^ assessed the effect of funding to start school breakfast clubs in primary and secondary schools in the United Kingdom. The intervention had no effect on the odds of self-reported consumption of fruit for breakfast after 3 and 12 months of the intervention, compared to the control group; separate analyses by school level were not conducted. However, there was a high level of contamination between the intervention and control groups by the 12-month follow-up, with 77 percent of students in the control arm attending a school with a breakfast club compared to 72 percent of students in the intervention arm. Therefore, it is unlikely this study provides a strong test of the effect of establishing school breakfast clubs on diet and the results should be interpreted with caution.

The Canadian Northern Fruit and Vegetable Pilot Programme assessed the effect of providing free fruit and vegetable snacks to students three times per week for 21 weeks.^140^ Intake was assessed with a validated pre-coded 24-hour fruit and vegetable recall questionnaire. The program did not result in significantly greater fruit and vegetable intake at home or at school post-intervention compared to no-intervention controls.^140^ However, the direction and magnitude of results were similar to that of a second intervention group that combined the free fruit and vegetable program with nutrition education, and did detect statistically significant increases in fruit and vegetable intake compared to the control group (see Combined interventions for more detailed information).

A Dutch study, conducted with middle and high school-aged adolescents, assessed the effect of an intervention targeting vending machines that implemented a series of cumulative changes in three 6-week phases: increasing the availability of lower-calorie products; labeling products as favorable (<100 kilocalories [kcal]), moderately unfavorable (100-170 kcal), or unfavorable (>170 kcal) with flyers and posters distributed to support the labeling; and reducing the price of lower-calorie products.^137^ Compared to schools that made no changes to school vending machines, moderately unfavorable foods were a greater proportion and unfavorable foods were a smaller proportion of total vending machine food sales across the duration of the intervention. Similarly, favorable beverages were a greater proportion and unfavorable beverages were a smaller proportion of total vending machine beverage sales by the third phase in intervention schools, compared to control schools. The effect of the intervention on favorable food sales varied by whether the school allowed students to leave the school area or not. Although favorable foods represented a small proportion of total vending machine sales in both intervention and control schools, among schools that did not allow students to leave school during the day, sales of favorable foods were greater in the intervention group than the control group during the first 2 study phases (but not the third study phase); no effect of the intervention was detected in schools that allowed students to leave school grounds during the day. The total sales volumes of the intervention and control schools did not differ significantly during the study.

Finally, a US study assessed the effect of implementing NSLP guidelines for 1 semester, specifically comparing the ability to select one fruit and two vegetable servings per reimbursable meal to the control group (i.e., previous pattern of two fruit and vegetable servings total).^26^ Both groups were served the same school menu. Selection and consumption of foods were directly observed in the cafeteria by trained research staff. Compared to the control group, a greater proportion of adolescents in the intervention group selected fruit, total fruit and juice, total vegetables, starchy vegetables, legumes, and protein foods. Results were similar when assessed as the amount selected, with intervention group adolescents selecting greater amounts of fruit, juice, total fruit and juice, total vegetables, starchy vegetables, and legumes compared to control group adolescents; the amount of whole grain foods selected was lower in the intervention group compared to the control group. Significant effects on consumption were also detected, with the intervention group consuming more fruit, total fruit and juice, total vegetables, starchy vegetables, and legumes, and less grains and whole grains than the control group. When consumption was assessed as a percent of the food item selected, adolescents in the intervention group consumed a smaller proportion of grains, whole grains, and protein foods that they selected compared to the control group. This intervention was also implemented in elementary schools, the results of which are reported in the Elementary school section.

##### Combination of strategies

Two cluster-RCTs, both conducted in the United States, assessed the effect of combining multiple behavioral and environmental strategies, both utilizing sustained, longer-term interventions.^25,134^

The Trying Alternative Cafeteria Options in Schools study targeted the availability and promotion of lower-fat à la carte options in the cafeterias of secondary schools, increasing the availability of lower-fat options by 30 percent from baseline to the end of the 2-year intervention and implementing peer promotion activities (e.g., taste tests, posters) to highlight lower-fat options.^134^ Self-reported intake of fruit and vegetables and low-fat/high-fat food choices did not differ between adolescents in the intervention and control schools throughout the study period. However, the mean rate of increase in lower-fat à la carte sales during the first intervention year and the mean percent of à la carte sales that were lower-fat foods during the second intervention year were greater in the intervention schools compared to the control schools, without significantly impacting food service revenue.

The Healthy Options for Nutrition Environments in Schools study assessed the effect of a broad set of changes to school nutrition policies in elementary and middle schools for 2 years.^25^ The intervention aimed to eliminate unhealthy foods and beverages at school, develop nutrition services as the primary source for healthful eating, and to have school staff model healthful eating; a variety of changes at the school were implemented to support these goals including, but not limited to, having teachers discourage students from bringing unhealthy snacks from home, implementing a daily fruit at recess program, advertising healthy snacks and beverages only, and having staff encourage students to try fruit and vegetables. Food brought from home was assessed by direct observation or observation of waste, depending on the location in school. Over the course of the 2-year intervention, the amount of unhealthy food and beverages brought to school by children and adolescents decreased in the intervention schools compared to the control schools. Healthy beverages brought to school did not differ between groups, but healthy foods brought to school differed between groups and varied by context, with the amount of healthy food brought to school for lunch increasing and the amount brought to school for recess decreasing in intervention schools compared to control schools. Analyses by school level were not conducted. Because the study assessed food brought from home, the extent to which this measure represents choices made by students, versus their caregivers, is unclear.

##### Summary

The behavioral and environmental interventions in this body of evidence utilized diverse strategies that targeted a variety of dietary components, approximately half of which focused on fruit and/or vegetables. There were beneficial effects of behavioral nudges and incentives on food and beverage choices in the cafeteria; however, the targeted dietary component and the type of nudges and incentives utilized varied, limiting direct comparisons that may be made between these two studies.^32,39^ Studies that changed how foods were presented and promoted in school were mixed. However, when focused on the three interventions that targeted fruit and/or vegetable presentation and promotion in the cafeteria there was a tendency to observe beneficial effects on selection and, in the case of shorter-term interventions, intake.^24,135,138^ Because most of these studies tested interventions that were relatively brief in duration, there is a need for more research that investigates the long-term effects of changes to cafeteria choice architecture. Although the exact strategy and target of the interventions varied, the two studies that focused on improving the palatability of fruit and/or vegetables served at school had beneficial effects on intake.^24,136^ Studies that targeted food availability or choices at school, including studies that implemented a combination of environmental strategies (which had a large focus on modifying the availability of foods at school), tended to have beneficial effects on food selection at school, such as increasing selection of vegetables or decreasing purchases of unfavorable foods. However, several studies that targeted food availability did not assess intake and most studies that did reported null effects. In sum, behavioral and environmental interventions implemented among middle school adolescents may have a positive impact on the selection and, in some cases, consumption of healthier food items, although more research is needed to confirm these broad trends and to further investigate the effectiveness of specific types of interventions before stronger conclusions can be drawn.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates that school-based behavioral and environmental interventions beneficially affect in-school food and beverage selection among middle and junior high school adolescents. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: None of the studies in this body of evidence had a pre-registered protocol or clinical trial registration with sufficient information to assess analysis intentions, raising potential concerns regarding selective reporting. Approximately a third of the studies were assessed as having some concerns or high risk of bias due to missing outcome data. Most studies provided sufficient information on the randomization process. All studies were assessed as having low risk of bias due to deviations from intended interventions and outcome measurement.
- Consistency: Interventions in this body of evidence utilized diverse strategies that targeted a variety of dietary components. Despite this heterogeneity which somewhat limits the ability to assess consistency across studies, all but one study reported beneficial effects on some aspect of in-school food and beverage selection, most frequently fruit and vegetables.
- Directness: Most studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: Power calculations were not reported in most of the studies included in this body of evidence. In some cases, the power calculation reported was completed for an outcome unrelated to diet or diet-related behaviors. Only one^135^ of the two studies^26,135^ that reported a power calculation specific to food selection or intake outcomes met their pre-specified sample size goal. Sample sizes varied across the body of evidence, ranging from relatively small samples to relatively large samples in terms of both individual participants and clusters. The variability in interventions, study duration, and food items assessed limits the ability to assess precision across these studies.
- Generalizability: This body of evidence is likely generalizable to middle and junior high school adolescents in the United States. All studies were conducted in the United States except for one conducted in the Netherlands. Schools enrolled participants from a range of SES and ethnic backgrounds (when reported). However, most studies were conducted across multiple school levels and did not report separate analyses by age or grade level, making it more difficult to draw conclusions specific to middle and junior high school adolescents.

Limited evidence from this rapid review suggests that some school-based behavioral and environmental interventions, particularly those targeting food palatability or presentation, may improve in-school intake of fruit and vegetables among middle and junior high school adolescents. This conclusion statement received a grade of Limited. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of the evidence.

- Risk of Bias: None of the studies in this body of evidence had a pre-registered protocol or clinical trial registration with sufficient information to assess analysis intentions, raising potential concerns regarding selective reporting. Nearly half of the studies were assessed as having some concerns or high risk of bias due to missing outcome data. Most studies provided sufficient information on the randomization process and most studies were assessed as having low risk of bias due to deviations from intended interventions. All studies were assessed as having low risk of bias in regard to outcome measurement.
- Consistency: Interventions in this body of evidence utilized diverse strategies that targeted a variety of dietary components. This heterogeneity limits the ability to assess consistency across studies, including within more specific types of interventions. However, some areas of consistency did emerge. First, fruit and vegetable intake, the most common outcomes in this subset of the evidence, tended to be positively affected by behavioral and environmental interventions. Among the four interventions that did not detect a significant effect on fruit or vegetable intake, one reported substantial contamination between the intervention and control groups,^44^ while another was focused more broadly on low-fat à la carte options rather than fruit and vegetables specifically.^134^ Other aspects of food choice and diet were examined in few studies, were not the primary target of the intervention, or had inconsistent results. Second, interventions that targeted the palatability or presentation of food were the most common types of strategies that positively impacted fruit or vegetable intake.
- Directness: Most studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: The variability in interventions, study duration, and outcomes assessed limits the assessment of precision across these studies. Power calculations were not reported in most of the studies included in this body of evidence. In some cases, the power calculation reported was completed for an outcome unrelated to diet or diet-related behaviors. Of the three studies^26,135,140^ that reported power calculations specific to food selection or intake outcomes, only one met their pre-specified sample size goal.^135^ Sample sizes varied across the body of evidence, ranging from relatively small samples to relatively large samples in terms of both individual participants and clusters. Additionally, few studies assessed any particular type of behavioral or environmental intervention, limiting the precision of the evidence supporting relationships between specific interventions and outcomes.
- Generalizability: This body of evidence is largely generalizable to middle and junior high school adolescents in the United States. Most studies were conducted in the United States, with the remaining three studies conducted in Canada, Sweden, and the United Kingdom. Schools enrolled participants from a range of SES and ethnic backgrounds (when reported). Approximately half of studies that assessed behavioral and environmental interventions were conducted across multiple school levels and did not report separate analyses by age or grade level, which could make it more difficult to draw conclusions specific to middle and junior high school adolescents.

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

##### Description of the evidence

Fourteen articles (from 10 cluster-RCTs) examined the effect of interventions that combined nutrition educational interventions and behavioral and/or environmental strategies on diet and diet-related behaviors in middle school and junior high school-aged adolescents.^132,139–151^ One study was conducted in both middle school and high schools,^150^ while the remaining studies were conducted exclusively with middle and junior high school students.^132,139–149,151^ The studies were conducted in a variety of countries including Canada,^140^ China,^132,151^ Denmark,^150^ Finland,^141,145^ the Netherlands,^147^ Norway,^142^ Sweden,^139^ and the United States.^143,144,146,148,149^ Analytic sample size ranged from 2 clusters (N=123 students)^151^ to 26 clusters (N=614^147^ and N=1277^140^ students); 3 studies^132,139,144,151^ included less than 10 clusters (N=123 students^151^ to N~15,000 students^144^), 5 studies^141–143,145,146,148,149^ included 10 to 20 clusters (N=517^142^ to N=3,503^143^ students), and 2 studies^140,147^ included 26 clusters. While SES was not reported in all studies, trials conducted in the United States reported that 84 percent,^144^ 70 percent,^146^ and 20 percent^149^ of students qualified for free or reduced price meals through the NSLP. Parents of students enrolled in a trial conducted in rural China had low educational achievement (6 percent completed junior school and 68 percent completed middle school).^132,151^ In a Finnish study, less than 20 percent of student’s parents had a university degree.^141,145^ Three studies conducted in the United States reported information on race and/or ethnicity: one enrolled participants who were predominately Latinx (75 percent),^144^ a second enrolled participants who were primarily Hispanic (47 percent) and Black (35 percent),^146^ and a third study enrolled participants who were predominantly White (72 percent).^143,148,149^ Among studies conducted outside the United States, a study conducted in China reported that most participants were of Han nationality (88 percent),^132,151^ a study conducted in the Netherlands reported that most participants (72 percent) were native Dutch,^147^ and a Swedish study reported 90 percent of participants were native to Sweden.^139^

A variety of interventions were implemented across the studies; however, all included some type of curriculum-based nutrition education or education through multimedia, combined with a behavioral or environmental enhancement focused on food availability, presentation, marketing, food palatability or nutrition-related school policy implementation. The majority of studies described the theory base or framework of the intervention used, including SCT,^141–145,148–150^ TPB,^139,147^ and the World Health Organization (WHO) socio-ecological framework.^132,151^ The most common duration of interventions was 1 academic year^139,141–143,145^; however, intervention durations varied from 5 weeks^144^ to multiple school years.^146,148,149^ Studies primarily compared the effect of the combined educational and behavioral and/or environmental interventions to a no-intervention comparison group; however, some also compared the combined interventions to groups which received a subset of the intervention components.^132,140,146,150^ Outcomes were primarily assessed by student report, using 24-hour or 48-hour dietary recalls,^140–142,145,149^ an FFQ,^150^ or other types of dietary surveys.^132,143,145–147,149,151^ Two studies assessed outcomes using direct observation of food selected at school,^139,148^ and one study used school sales data and cafeteria participation records.^144^ Two cluster-RCTs used multiple dietary assessment methods: the Teens Eating for Energy and Nutrition at Schools (TEENS) study examined outcomes with a modified and validated survey^143,149^ and school sales data^148^; a Finnish study assessed student intake using intake questionnaires, one administered at school and one at home,^141,145^ and a 48-hour recall in a subset of students.^145^ Three articles assessed in-school selection or intake,^139,144,148^ six articles assessed overall intake,^132,143,146,149–151^ and five articles assessed selection or intake in and outside school.^140–142,145,147^ Evidence from these studies and participant characteristics are described in Table 13; the risk of bias assessments are described in Table 14. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Nutrition education with environmental strategies targeting food availability and promotion

Half of the studies (five cluster-RCTs) that assessed combined educational and behavioral and/or environmental strategies focused on increasing the availability and promotion of healthy food and beverages at school.^139–142,144,145,147^ All studies detected some beneficial effects of the tested intervention.

Prell et al^139^ examined the effect of a fish-focused, TPB-based intervention that implemented changes to school meals and home economics curriculum in Swedish schools. The environmental component of the intervention enhanced the palatability and presentation of fish served by increasing the variety of fish choices in the cafeteria, improving sauces and side dishes that accompanied the fish, and using fish-related decorations in the cafeteria. The educational component of the intervention increased the number of home economics classroom cooking experiences related to fish from three to five, introduced classes on fish selection and preparation, and instructed students to complete a short paper on a fish-related topic. Fish intake was measured by structured observations in the school canteen. After 1 academic year, students exposed to the environmental intervention enhanced by nutrition education consumed more fish than students who received no intervention. The magnitude of effect was similar to that of the group that received only the modifications to the cafeteria; however, differences between this group and the control group did not reach statistical significance (see Behavioral/environmental interventions for more detailed information).

The Finnish study assessed the effect of a 1-year intervention, informed by SCT, which combined nutrition curriculum and environmental strategies to improve eating habits and dietary intake among eighth grade students.^141,145^ Teachers were provided lesson plans, posters, brochures, and games to implement in the classroom. Environmental strategies included removal of vending machines with sweets or soda from schools, improvement in the quality of snacks available in schools, and increased availability of fresh bread at lunch. Drama workshops related to eating and school meals were organized for both teachers and pupils to improve commitment to the intervention. Parental involvement was facilitated through a meeting and a magazine on healthy eating. Intake and habits were assessed using a computer-assisted questionnaire and supervised by a dental nurse.^141^ At the end of the academic year, adolescents in the intervention schools reported more frequent consumption of bread and the warm course at lunch and less frequent consumption of juice or “fizzy” drinks at school compared to students in control schools. No differences between groups were detected for salad and raw vegetables at lunch, juice or “fizzy” drinks at home, sweets, or total dietary score.^141^ Analyses at the same time point using structured questionnaires mailed to children’s homes and, for a randomly selected subset, computer-assisted 48-hour diet recalls performed by nutritionists at school, found somewhat similar results.^145^ Compared to the control group, there was a significant increase in rye bread intake frequency and decrease in sweets intake frequency among intervention group girls, but not boys; no effect on fruit or vegetable intake frequency was detected. Furthermore, for school snacks, intake of sweets among girls and sugary soft drinks among boys decreased in the intervention group compared to the control group; no effect on bread or fruit for snacks was detected. In the subset of adolescents who completed the 48-hour recall, sucrose intake decreased significantly in students in the intervention group compared to the control group, while fruit intake increased in the intervention group compared to the control group; no significant differences in change were observed for vegetable or fiber intake.

A 6-month, TPB-based intervention conducted in the Netherlands involved a curriculum-based intervention and modifications to the school vending machines.^147^ The curriculum component included five lessons, delivered over 3 months, focused on healthy food choices and were supported by computer-assisted online lessons, a teacher’s manual, games, and debating exercises. Changes to school vending machines were implemented in three successive and cumulative 6-week phases: increasing the availability of lower calorie foods, followed by food labelling (nutritionally favorable, moderately favorable, unfavorable), and, finally, reducing prices for lower-calorie foods. Compared to children in the control group, the intervention had no effect on self-reported in-school purchases of soft drinks and snacks containing empty calories. No effect was found on the frequency of students bringing snacks containing empty calories from home, but there was a decrease in the frequency of adolescents bringing soft drinks from home; however, this positive outcome may be influenced by parent choice. The study reported that intervention implementation was incomplete, particularly for the educational component. Results were interpreted with caution, due to risk of bias from a large degree of missing data, which varied by proportion, timing, and reason (vending issues versus non-response) across groups, and concern for bias related to randomization and baseline imbalances between groups.

The Students for Nutrition and eXercise study used social-cognitive health behavior change constructs, ecological influences, and input from community stakeholders to develop and pilot test a 5-week obesity prevention intervention among a predominately Latinx population of seventh grade adolescents in the United States.^144^ The intervention targeted behavior change through handouts on nutrition, discussions, and taste tests led by peer advocates (21 percent of the intervention population), cafeteria changes to market and increase access to healthy foods (i.e., increased availability of cut up fruit and vegetables and tap water), improved point-of-sale signage and nutritional information. The intervention also included multimedia components including a project trailer and kick-off film, physical activity posters, and parent-student activities. Cafeteria and school store sales data collected over the intervention semester indicated that in intervention schools, there was an increased proportion of students served fruit, a decreased proportion of students buying snacks at school, and no change in the proportion of students served vegetables during the intervention, as compared to students in control schools that received no intervention. Although the proportion of snacks sold at school remained lower in the intervention schools post-intervention, results were no longer significant for fruit served at school post-intervention.

Two cluster-RCTs implemented free fruit and vegetable programs and found that enhancing these programs with nutrition education significantly increased middle school student fruit and vegetable intake.^140,142^

A Norwegian study assessed the effect of a 1-year, free daily fruit and vegetable snack program, in combination with seven 135-minute SCT-based nutrition classes delivered by trained home economics teachers.^142^ The Fruits and Vegetables Make the Marks intervention focused on benefits and recommendations of fruit and vegetable intake and included preparing and tasting fruit and vegetables in a kitchen setting, and six parent newsletters. A validated 24-hour fruit and vegetable recall, administered by project staff, was used to assess dietary intake. Compared to control students, who had access to the standard paid fruit and vegetable subscription program without nutrition education, students exposed to the multi-component intervention significantly increased in-school and all-day fruit and vegetable intake post-intervention, and all-day intake at 1-year follow-up.

A Canadian study (Northern Fruit and Vegetable Pilot Programme) assessed a 21-week free fruit and vegetable program, comparing the effect of free fruit and vegetable snacks provided three times a week enhanced with a fruit and vegetable nutrition education curriculum (Paint Your Plate! Create a Masterpiece: Vegetables and Fruit Action Guide for Schools), to the free fruit and vegetable program alone and to a no-intervention control group.^140^ A validated pre-coded 24-hour fruit and vegetable recall questionnaire was used to assess dietary intake in fifth through eighth grade students. Adolescents in the combined intervention group that received free fruit and vegetables with nutrition education consumed significantly more fruit and vegetables at school (but not at home) when compared to those in the control group; the group that received only free fruit and vegetables did not differ significantly from the combined intervention group or the control group (see Behavioral and environmental interventions for more detailed information).

##### Nutrition education with environmental strategies targeting school food policy, availability, and promotion: Comprehensive, multi-year programs

Two cluster-RCTs conducted in the United States implemented interventions over multiple school years that implemented nutrition curricula with changes to school food policy and the availability and promotion of healthy foods and beverages,^143,146,148,149^ with mixed results.

Ickovics et al^146^ examined the effectiveness of school-based nutrition and physical activity policies over a 3-year period in sixth grade adolescents. Schools were randomized to four groups: nutrition intervention, physical activity intervention, nutrition and physical activity intervention, and a delayed intervention control group. The nutrition intervention included nutrition education targeting healthy eating, workshops for parents, and newsletters to be shared with students and parents, along with cafeteria-based promotion of healthy food choices, taste testing, and work with a school wellness team. Additionally, school nutrition policies were implemented requiring a variety of fruit and vegetables be offered, providing only low-fat milk (no flavored milk) and whole-grain cereals, and addressing the use of foods for celebrations and rewards. The physical activity intervention promoted active transport to school (e.g., walking or biking) and physical activity in and outside the classroom, provided newsletters for families, and involved a school-wide fitness challenge. Because the interaction between the nutrition and physical activity interventions was not significant, analyses compared both groups who received the nutrition intervention to both groups who did not receive the nutrition intervention. Diet and nutritional habits were assessed using self-reported student surveys based on the Youth Risk Behavior Survey and a School-Based Nutrition Monitoring Questionnaire. Post-intervention student survey data indicated that students who received the nutrition intervention had significantly lower intake of unhealthy food, SSBs, and fast food compared to students who did not receive the nutrition intervention. No significant effects were observed related to intake of healthy foods or healthy drinks.

The 2-year TEENS study, informed by SCT, evaluated the effectiveness of a comprehensive program designed to increase fruit and vegetable intake and decrease fat intake among seventh and eighth grade adolescents.^143,148,149^ The program consisted of 3 primary components: nutrition curriculum that included 10 behaviorally-based sessions per year delivered by trained teachers with the assistance of trained peer leaders; a family component that consisted of 3 newsletters and behavioral coupons linked to prizes; and a school environment intervention that increased availability and promotion of fruit and vegetables (emphasized in seventh grade) and healthy snacks (emphasized in eighth grade) and established school nutrition advisory councils to foster school environments that encouraged healthier food choices. After the first year of the intervention, Birnbaum et. al.^143^ examined the effects of varying levels of exposure to the intervention, comparing the control group (no intervention) to children who received the school environment component only, children who received the nutrition curriculum, family, and environmental components, and children who were selected as peer leaders and received all intervention components. Dietary intake was measured using a modified and validated version of Behavioral Risk Factor Surveillance System (BRFSS) questionnaire. Students who were selected as peer leaders and were exposed to all intervention components reported significantly greater increases in fruit intake, and fruit and vegetable intake (approximately 1 additional serving per day) compared to no intervention. Children who received the curriculum, family, and environmental components showed smaller increases in fruit and vegetable intake (approximately one-half serving per day), but the level of change compared to the control did not reach statistical significance. Fruit and vegetable intake for children who only received the environmental component did not differ from the control group. At post-intervention, analyses between the control and intervention groups as randomized showed no significant differences in self-reported fruit or vegetable intake measured using the modified BRFSS questionnaire and via 24-hour recall administered by trained staff^149^ or school-level sales of foods to promote or limit.^148^ Similar results were obtained when analyses were conducted by level of exposure to the intervention: intake of fruit and vegetables in children who received all intervention components and children who were only exposed to the environmental component did not differ significantly from the control group.^149^ Notably, classroom implementation of the nutrition curriculum during the second study year was incomplete and the peer leader component was not implemented during the second study year.

##### Nutrition education with other behavioral and environmental strategies

Two cluster-RCTs combined nutrition education with a behavioral or environmental strategy that promoted selection of nutrient dense foods, but did not modify the availability of cafeteria or snack foods served in school.^132,150,151^

A small study conducted in rural Chinese schools compared the effects of a 6-month, multi-component health-promoting school intervention based upon a World Health Organization socio-ecological framework to an educational intervention (at 3 months) and a no-intervention control group (at 3 and 6 months).^132,151^ The health-promoting school intervention and the educational intervention both included a nutrition curriculum delivered by trained teachers over 26 weekly 15-minute sessions; topics included a balanced diet, nutrients, good hygiene, and food safety. Adolescents in both intervention groups also participated in monthly 30-minute peer support activities and were distributed publicity resources at the beginning of the intervention. Additional components included only as part of the health-promoting school intervention included: establishment of a school nutrition group that met monthly; a 90-minute school training session and publicity resources for school staff; posters to display in school; and two 60-minute information sessions, brochures, and monthly messages for parents. A questionnaire was used to assess weekly dietary intake of fresh fruit, vegetables, dairy products, breakfast, dessert, fried food, and soft drinks. At study mid-point (3 months), there was a statistically significant effect of study group on a composite eating behavior score, with the greatest improvement in diet observed among students who received the health-promoting school intervention; however, because comparisons between individual groups were not reported, it is unclear which between group comparisons drove the overall significant effect.^132^ At 6 months, students who received the health-promoting school intervention had greater odds of consuming vegetables daily and not consuming soft drinks, desserts, and fried food during a 1-week period compared to the control group. The health-promoting school intervention had no effect on odds of daily intake of milk or fresh fruit.

Pedersen et al^150^ conducted a study with middle and high school students in Denmark that examined a multi-component health promotion program informed by SCT. The study evaluated behavior change strategies alone, including goal setting for fruit and vegetable consumption and receiving text message reminders and merit-based prizes, or in combination with an education component involving a 45-minute lecture on the importance of eating fruit and vegetables and a hands-on weighing activity. An eight-item FFQ was used to measure fruit and vegetable intake. No differences between the age groups (middle and high school) were found and data were therefore combined. Results from both intervention groups were compared to a control group that received a minimal intervention. There was no effect of either intervention on fruit and vegetable intake at 11-week follow-up compared to the control.

##### Summary

These 14 articles, from 10 cluster-RCTs, provide evidence on a heterogeneous group of interventions that combined nutrition education with behavioral and environmental strategies, implemented with middle or junior high school-aged adolescents. The majority of studies reported the theoretical foundation of the intervention (primarily SCT or TPB), were 6 months or longer in duration, and targeted a variety of dietary components including fruit, vegetables, dairy products, fish, and foods of higher and lower nutritional quality. In general, consistent, beneficial results were found among studies that implemented educational interventions in combination with environmental interventions that increased the availability of healthy meal items and snacks foods in schools. Studies with strong fidelity to the intervention found that these combined strategies impacted a variety of food items including increased adolescent selection or intake of fruit,^143–145^ fruit and vegetables combined,^140,142,143^ fish,^139^ bread,^141,145^ and a warm lunch meal^141^ and decreased selection or intake of fast foods,^146^ SSBs,^141,145,146^ sweets (among girls),^145^ sucrose,^145^ snack foods,^144^ and “unhealthy” foods.^146^ However, two exceptions highlight the potential challenges encountered with coordinating and implementing multi-component interventions in adolescent populations. First, the multi-year TEENS study observed significant benefits during the first year of the study only among adolescents who were exposed to all intervention components and were selected as peer leaders^143^; however, no significant effects were detected at the 2-year mark.^148,149^ Second, a 6-month education and vending machine intervention conducted in the Netherlands did not modify adolescent snack purchases; however, missing data and baseline imbalances in group characteristics could have obscured results.^147^ In both of these studies, classroom implementation of the nutrition curriculum was incomplete; furthermore, in the TEENS study, peer leaders were not trained the second year due to resource constraints and shared food service support by intervention and control schools increased the risk for intervention contamination. Only two studies assessed sustainment of effects post-intervention: Bere et al^142^ found that a 1-year free fruit and vegetable snack program augmented with nutrition education sustained adolescent’s increased intake of fruit and vegetables 1-year post-intervention, while a 5-week intervention had minimal sustained impact on adolescent food choices by the end of the semester.^144^

A few studies evaluated the differences in effect between intervention arms with varying intensity or combinations of intervention strategies, primarily finding that the intervention arm with the greatest intensity or combining the greatest number of intervention strategies tended to have the greatest degree of success in modifying adolescent food related behaviors.^132,139,140,143,149,150^ One study found that nutrition education combined with a free fruit and vegetable snack program significantly increased adolescent fruit and vegetable intake compared to no intervention, while the free fruit and vegetable program alone did not.^140^ Another study found that providing fish-related nutrition education in combination with changes to the cafeteria to encourage fish consumption resulted in greater fish intake compared to no intervention; in contrast, modifications to the cafeteria alone did not result in significant changes to fish intake compared to the control.^139^ Although generalizability to the US population is likely poor, a study conducted in China that combined nutrition education with environmental interventions without enhancing availability of healthy foods found positive benefits compared to a no-intervention control group and appeared to have a greater magnitude of effect than an education-only group.^132^ As previously noted, the TEENS study found that adolescents who had the greatest exposure to the intervention increased fruit and vegetable intake while adolescents who had lower exposure to the intervention did not after the first year of the study^143^; however, following the second intervention year, significant effects were not detected for any level of intervention intensity.^149^ Finally, one study assessed a very low intensity intervention, with and without a single nutrition education session, and found that neither impacted student fruit and vegetable intake relative to the control.^150^

Overall, the combined interventions targeting nutrition education and environmental strategies in this body of evidence tended to improve the nutritional quality of adolescent dietary intake. School-based interventions that combined nutrition education with increased availability and promotion of healthy foods, tended to have a greater positive effect on adolescent food choice than single component interventions focused on education or environmental strategies alone. Additional research is needed to explore what dimensions of multi-component interventions are most vital (e.g., duration, intensity, key components), methods to promote a high degree of fidelity to the education or environmental interventions, and sustainment of effects post-intervention.

##### Assessment of the evidence

Moderate evidence from this rapid review indicates school-based interventions that combine educational and environmental strategies targeting promotion and increased availability of nutrient dense foods and beverages improve middle and junior high school adolescent food purchasing behaviors and dietary intake, particularly for fruit, vegetables and foods and beverages of lower nutritional quality. This conclusion statement received a grade of Moderate. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of evidence.

- Risk of Bias: All but 1 of the 10 cluster-RCTs did not have an a priori protocol with sufficient information to assess statistical analysis intentions, raising concern for risk of bias due to selective reporting. Concern for risk of bias due to missing outcome data was present in approximately half the studies; however, one study^147^ was assessed at high risk of bias because the proportion and timing of missing data differed between study groups. Most studies most were assessed as having low risk of bias due to randomization and deviations from intended interventions. All studies were assessed as having low risk of bias for outcome measurement. Four articles^139,143,147,148^ were found to have concern for risk of bias across three or four domains, as described previously; therefore, results from these studies were interpreted with caution and weighed less heavily in the overall conclusion.
- Consistency: Consistent beneficial effects were reported among studies with high fidelity to educational interventions in combination with environmental interventions that promoted and increased availability of nutrient dense meal components and snacks. The majority of studies were theory-based, 6 months or longer in duration, and all studies included nutrition education. In general, studies that promoted and increased the availability of nutrient dense foods in schools had one or more beneficial effects on student food purchasing behaviors or dietary intake, including increased intake of fruit, vegetables, bread, fish, and milk, and decreased purchases or intake of calorie dense foods and SSBs. Two studies had weaker results. First, one study reported a decrease in adolescents bringing soft drinks from home; but no significant change in purchase of soft drinks and calorie dense snacks purchased in school.^147^ Successive versus simultaneous implementation of intervention components may have decreased the intervention intensity, contributing to null findings, and missing data and baseline imbalances between groups may have obscured results. Second, a 2-year study observed an isolated significant increase in fruit and vegetable intake among students exposed to the greatest intensity of intervention components after 1 year,^143^ but observed no effect after 2 years when the intensity of the intervention was lower.^148,149^ Few studies assessed combined interventions that did not target food availability.
- Directness: Studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: Across the body of evidence, sample sizes were generally large in terms of number of clusters and participants, and approximately 75 percent of studies had a duration longer than 6 months, with half the studies 1 or more years in duration. Few articles in this body of evidence reported a power calculation; however, 3 articles reported adequately powered analyses,^144,146,149^ and one reported a sample size calculation and was slightly underpowered.^140^ Two trials had relatively small sample sizes (N=123 to 228 students); therefore, the precision of these results may not be strong.^132,139,151^
- Generalizability: The body of evidence evaluating interventions that combined nutrition education and environmental and behavioral strategies is generalizable to middle school adolescents in the United States. All trials were conducted in high or very high HDI countries, half of which were conducted in Nordic countries and the Netherlands. Two US studies were conducted in ethnically diverse populations with relatively high proportions of students eligible for free or reduced price meals through the NSLP, while the third US study was conducted in a predominately White population with a relatively low proportion of students eligible for free or reduced price meals. Few of the studies conducted outside the United States reported information on SES or race and ethnicity. All trials were conducted exclusively in middle and junior high schools. Most interventions assessed and outcomes measured were relevant to US students.

Limited evidence from this rapid review suggests school-based interventions that combine educational and environmental strategies promoting and increasing availability of nutrient dense foods, may have a greater beneficial effect on middle and junior high school adolescent dietary intake, particularly fruit and vegetable intake, than interventions that use either strategy alone. This conclusion statement received a grade of Limited. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of evidence.

- Risk of Bias: None of the four cluster-RCTs had an a priori protocol with sufficient information to assess statistical analysis intentions, raising concern for risk of bias due to selective reporting. One study was assessed as having multiple risk of bias concerns due to the randomization process, deviations from intended interventions, and missing outcome data.^139^ The remaining three studies were assessed as having low risk of bias due to randomization, deviations from intended interventions, missing outcome data and outcome measurement.
- Consistency: Three cluster-RCTs examined the effect of adding an education component to an environmental intervention that enhanced availability of fruit and vegetables^140,142^ or fish,^139^ and found a beneficial effect with the use of a combined strategy versus an environmental strategy alone. One trial examined the effect of a health promotion curriculum delivered with and without an environmental intervention promoting nutrient dense foods, and found a significant beneficial effect on eating behaviors in students receiving the combined intervention compared to no intervention, while the effect in the group receiving the education curriculum alone was intermediate.^132^
- Directness: Studies in this body of evidence were direct in relationship to the population, intervention, comparators, and outcomes addressed in the review question.
- Precision: One article in this body of evidence reported a power calculation and was slightly underpowered.^140^ Two of the four trials had relatively small sample sizes (N=188 to 228 students)^132,139^; therefore, the precision of these results may not be strong.
- Generalizability: This body of evidence had limited generalizability to middle school students in the US. All studies were conducted outside the United States and little information was provided on race and ethnicity or SES of participants. Cultural differences in rural China and Sweden, where two of the studies were conducted, are likely to impact study results.

Table 9 Evidence examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Fruits and Vegetables Make the Marks (FVMM)
Bere, 2006,^108^ FVMM; Norway, RCT-Cluster; Total Baseline N: 450; Total Analytic N: 369; Total Baseline Cluster N: 19; Total Analytic Cluster N: 19; Criteria for exclusion from analysis: Not able to participate at post-intervention or 1-y follow-up, inconsistent responses; Grade level: Middle/Junior high school; Age (Mean): 11.3 y; Female: ~55%; Race/ethnicity: NR; SES: Parental education (low): ~52% | Int: (i) Classroom education (7 monthly 135-min sessions delivered by teacher), (ii) parental involvement, and (iii) a paid fruit and vegetable subscription program (N=190; Cluster N=9); Comp: Paid fruit and vegetable subscription program (N=179; Cluster N=10); Theory/framework: SCT; Intervention duration: ~8-9 mo; Outcome measurement: Validated 24-h fruit and vegetable recall for a school day read aloud to the pupils by a project worker conducted at baseline, post-intervention, and 1-y follow-up | Intake at post-intervention and 1-y follow-up, Adjusted Mean (95% CI); [underlined: Fruit and vegetables at school (portions/d):]; Post-intervention: Int: 0.37 (0.22, 0.52), Comp: 0.31 (0.17, 0.44); Int vs Comp: p=0.53; 1-y follow-up: Int: 0.22 (0.06, 0.38), Comp: 0.35 (0.20, 0.51); Int vs Comp: p=0.23; [underlined: Fruit and vegetables all day (portions/d):]; Post-intervention: Int: 2.20 (1.80, 2.60), Comp: 2.12 (1.73, 2.51); Int vs Comp: p=0.76; 1-y follow-up: Int: 1.94 (1.58, 2.30), Comp: 2.14 (1.79, 2.50); Int vs Comp: p=0.41; Model adjustments: Baseline scores; gender; school; Funding source(s): Norwegian Research Council, Norwegian Cancer Society.
Øvrebø, 2019,^123^ FVMM; Norway, RCT-Cluster; Total Baseline N: 450; Total Analytic N: 237; Total Baseline Cluster N: 19; Total Analytic Cluster N: 19; Criteria for exclusion from analysis: Did not complete 14-y follow-up; Grade level: Middle/Junior high school; Age (Mean): 11.8 y; Female: ~55%; Race/ethnicity: NR; SES: Parental education (low): ~52% | Int: (i) Classroom education (7 monthly 135-min sessions delivered by teacher), (ii) parental involvement, and (iii) a paid fruit and vegetable subscription program (N=NR; Cluster N=9); Comp: Paid fruit and vegetable subscription program (N=NR; Cluster N=10); Theory/framework: SCT; Intervention duration: ~8-9 mo; Outcome measurement: Validated 24-h fruit and vegetable recall for a school day read aloud to the pupils by a project worker and a validated 17-item FFQ at baseline, post-intervention, and 1-y follow-up. At 3-y follow-up pupils read the recall themselves. At 7-y follow-up, the survey was sent by regular mail to the participant’s homes. At 14-y follow-up the survey was completed electronically by participants. | Intake at post-intervention and 1-y, 3-y, 7-y, and 14-y follow-up, Adjusted Mean (95% CI); [underlined: Fruit (portions/d):]; Post-intervention: Int: 1.4 (1.2, 1.7), Comp: 1.3 (1.1, 1.5), p=0.409; 1-y follow-up: Int: 1.2 (1.0, 1.5), Comp: 1.4 (1.2, 1.6), p=0.377; 3-y follow-up: Int: 1.4 (1.2, 1.6), Comp: 1.3 (1.1, 1.6), p=0.578; 7-y follow-up: Int: 0.9 (0.4, 1.4), Comp: 0.8 (0.2, 1.3), p=0.689; 14-y follow-up: Int: 1.2 (1.0, 1.5), Comp: 1.2 (0.9, 1.5), p=0.976; [underlined: Vegetables (portions/d):]; Post-intervention: Int: 0.7 (0.5, 0.9), Comp: 0.8 (0.6, 1.0), p=0.405; 1-y follow-up: Int: 0.7 (0.5, 0.9), Comp: 0.8 (0.6, 1.0), p=0.428; 3-y follow-up: Int: 1.0 (0.8, 1.2), Comp: 1.0 (0.8, 1.2), p=0.893; 7-y follow-up: Int: 1.1 (0.6, 1.5), Comp: 1.0 (0.5, 1.6), p=0.984; 14-y follow-up: Int: 1.5 (1.3, 1.8), Comp: 1.7 (1.4, 2.0), p=0.492; Model adjustments: Baseline data; gender; parental education level; Funding source(s): Norwegian Research Council, University of Agder, Free fruit made possible by the Norwegian Fruit and Vegetable Marketing Board
Unnamed Study - China
Wang, 2015 ^132^; China, RCT-Cluster; Total Baseline N: 195; Total Analytic N: 188; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Did not complete baseline and/or follow-up questionnaires, did not participate in interventions as required; Grade level: Middle/Junior high school; Age (Mean (SD)): 12.8 (0.45) y; Female: 52%; Race/ethnicity: Han nationality: 88%; Minority nationality: 12%; SES: Parent education: Junior school or lower: 6%; Middle school: 68%; High school: 21%; College/University or higher: 5% | Int1: Health promotion program including weekly curriculum, monthly peer support activities, monthly school nutrition group, posters to publicize healthy eating, informational brochures, and parent involvement (N=62; Cluster N=1); Int2: Health education curriculum only (N=65; Cluster N=1); Comp: No intervention (N=61; Cluster N=1); Theory/framework: WHO socio-ecological framework; Intervention duration: 3 mo; Outcome measurement: Eating behavior score measured using a questionnaire on the weekly consumption of fresh fruit, vegetables, dairy products, breakfast, dessert, fried food, and soft drinks (scale 0-7); assessed at baseline and after 3 mo of intervention | Eating behavior score (food consumption), Mean and Mean change; Baseline: Int1: 3.16, Int2: 2.78, Comp: 2.64; 3 mo: Int1: 4.13, Int2: 3.54, Comp: 3.02; Change: Int1: 0.97, Int2: 0.76, Comp: 0.38; Between group comparisons: p=0.000 ↑; Model adjustments: None; Funding source(s): Griffith University School of Public Health
Wang, 2015 ^131^; China, RCT-Cluster; Total Baseline N: 130; Total Analytic N: 126; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Did not complete both pre- and post-intervention questionnaires; Grade level: Middle/Junior high school; Age (Mean (SD)): 12.8 (0.4) y; Female: 51.6%; Race/ethnicity: Han nationality: 88.1%; Ethnic minority: 11.9%; SES: NR | Int: Nutrition education program including 26 weekly 15-min nutrition curriculum delivered by trained teachers, 6 monthly 30-min peer support activities, and informational brochure distributed twice during the intervention (N=65; Cluster N=1); Comp: No intervention (N=61; Cluster N=1); Theory/framework: WHO socio-ecological framework; Intervention duration: 6 mo; Outcome measurement: Intake during the past week assessed with self-administered FFQ derived from the 2004 China Adolescent Behavioural Risk Factor Survey administered in the classroom pre- and post-intervention | Post-intervention intake, %; [underlined: No soft drinks:] Int: 49.2%, Comp: 41.0%, p=0.353; [underlined: No dessert:] Int: 44.6%, Comp: 34.4%, p=0.243; [underlined: No fried food:] Int: 52.3%, Comp: 29.5%, p=0.009 ↑; [underlined: Fresh fruits every day:] Int: 70.8%, Comp: 62.3%, p=0.313; [underlined: Vegetables every day:] Int: 96.9%, Comp: 80.3%, p=0.003 ↑; [underlined: ≥1 glass of milk/soy milk/yogurt every day:] Int: 44.6%, Comp: 41.0%, p=0.681; Model adjustments: None; Funding source(s): Grant for Higher Research Degree Students in School of Public Health, Griffith University
Individual studies (alphabetized by author)
Amaro, 2006 ^107^; Italy, RCT-Cluster; Total Baseline N: 291; Total Analytic N: 241; Total Baseline Cluster N: 16; Total Analytic Cluster N: 13; Criteria for exclusion from analysis: Missing post-assessment, had metabolic disease or mental deficit; Grade level: Middle/Junior high school; Age (Mean): ~12.4 y; Female: ~45%; Race/ethnicity: White: 100%; SES: NR | Int: Kalèdo game promoting nutrition knowledge and healthy lifestyle (weekly for 24 wk) (N=153; Cluster N=8); Comp: No intervention (N=88; Cluster N=5); Theory/framework: NR; Intervention duration: 24 wk; Outcome measurement: Intake assessed by 34 questions on weekly intake measured using a 4 rank ordinal scale (0; 1-2; 3-7; >7) at baseline and post-intervention | Vegetable intake (svg/wk) at post-intervention, Mean (95% CI); Int: 3.7 (3.5, 4.1), Comp: 2.8 (2.4, 3.3), p<0.01 ↑; Results NR for other food items.; Model adjustments: Baseline dietary intake; school (random effect); Funding source(s): Italian Association Amici di Raoul Follereau, Commune of Naples, Second University of Naples
Bessems, 2012 ^109^; The Netherlands, RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 22; Total Analytic Cluster N: 21; Criteria for exclusion from analysis: Absent when questionnaire completed, incomplete background characteristics; Grade level: Middle/Junior high school; Age (Mean): ~12.9 y; Female: ~48%; Race/ethnicity: Dutch: ~80%; At least one parent born abroad: ~20%; SES: Score for socioeconomic position (Mean): ~ −0.04 (comparable to average Dutch score) | Int: Krachtvoer nutrition education program to increase fruit intake and healthy breakfast consumption, and decrease fat intake through experiential learning and cognition driven activities (N=1,016; Cluster N=13); Comp: Delayed intervention (N=NR; Cluster N=8); Theory/framework: Self Regulation Theory; TPB; Attitude-social influence-self efficacy model; Intervention duration: 8 wk; Outcome measurement: Intake assessed with items derived from FFQs for fruit and vegetable intake and fat consumption and investigator developed question on favorable/unfavorable snack intake completed by the child under supervision of teachers at baseline, post-intervention, and 6-mo follow-up. | Intake at post-intervention and 6-mo follow-up (Data NR); [underlined: Fruit intake frequency (svg/d)]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int > Comp, p<0.05 ↑; [underlined: Previous day’s fruit intake (svg)]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Fruit juice intake frequency (glasses/d)]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Snack frequency (x/d)]; Post-intervention: Int vs Comp, p=NS; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Previous day’s snack intake (number)]; Post-intervention: Int vs Comp, p=NS; 6-mo follow-up: Int vs Comp, p=NS; Odds of favorable consumption (no intake or more frequent intake of favorable products) at post-intervention and 6-mo follow-up (Data NR); [underlined: Sweets consumption]; Post-intervention: Int vs Comp, p=NS; 6-mo follow-up: Int > Comp, p<0.05 ↑; [underlined: Savory snacks consumption]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Ice cream consumption]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Fried snack consumption]; Post-intervention: Int > Comp, p<0.05 ↑; 6-mo follow-up: Int vs Comp, p=NS; [underlined: Cookie consumption]; Post-intervention: Int vs Comp, p=NS; 6-mo follow-up: Int vs Comp, p=NS; Model adjustments: Sex; educational track; year; baseline intake; ethnicity; SES; random effects of student and class; Funding source(s): The Netherlands Organisation for Health Research and Development
Brito Beck da Silva, 2015 ^110^; Brazil, RCT-Cluster; Total Baseline N: 833; Total Analytic N: 630; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Absent for data collection, refusal to participate in second stage of study; Grade level: Middle/Junior high school and High school; Age (Mean): ~13.25 y; Female: 57.6%; Race/ethnicity: NR; SES: Economic status using the Brazilian Economic Classification Criteria (A-highest to E-lowest): Class E: ~58%, Class B-D: ~42 % | Int: Nutrition education delivered by nutritionists consisting of eight 50-minute sessions focusing on a variety of nutrition topics, with additional workshops to reinforce concepts; children were also given educational materials to bring home to the family. (N=265; Cluster N=1); Comp: No intervention (N=365; Cluster N=1); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake during the previous week assessed with self-administered FFQ at baseline and post-intervention and dichotomized as more frequent (≥5 d/wk) or less frequent (≤4 d/wk) consumption | Odds of more frequent consumption at post-intervention, Int vs Comp (ref), OR (95% CI); [underlined: Bean:] 1.09 (0.87, 1.36); [underlined: Rice:] 1.11 (0.89, 1.39); [underlined: Legumes:] 1.18 (1.03, 1.37) ↑; [underlined: Vegetables:] 1.17 (1.01, 1.35) ↑; [underlined: Fruits:] 1.13 (0.93, 1.37); [underlined: Milk:] 1.14 (0.91, 1.44); [underlined: Candies:] 1.15 (0.92, 1.44); [underlined: Snacks:] 0.95 (0.73, 1.23); [underlined: Processed meats:] 1.16 (0.88, 1.52); [underlined: Soft drinks:] 1.10 (0.88, 1.37); No change in regression parameters when pubertal stage was added to the model.; Model adjustments: Sex; age; SES; physical activity; Funding source(s): NR
Brito Beck da Silva, 2019 ^111^; Brazil, RCT-Cluster; Total Baseline N: 895; Total Analytic N: 608; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: School dropout, refusal to participate in second stage of study; Grade level: Middle/Junior high school; Age (Mean (SD)): 14.49 (1.42) y; Female: 48.4%; Race/ethnicity: NR; SES: Caregiver education level: Illiterate/Incomplete primary education: 27.0%, Completed primary education/Incomplete secondary education: 24.2%, Completed secondary education/Incomplete higher education: 42.6%, Completed higher education: 6.1%; SES: Household assets score: Low: 34.6%, Medium: 32.4%, High: 33.0% | Int: StayingFit Brazil online nutrition education program (16 sessions) delivered once per week for 30 min in the computer room supervised by a nutritionist (N=288; Cluster N=4); Comp: No intervention (N=320; Cluster N=8); Theory/framework: CBT; Intervention duration: 12 mo; Outcome measurement: Intake during the previous week assessed with self-administered FFQ at baseline and post-intervention and dichotomized as more frequent (≥5 d/wk) or less frequent (≤4 d/wk) consumption | Odds of more frequent consumption at post-intervention, Int vs Comp (ref), OR (95% CI); [underlined: Beans:] 1.43 (1.10, 1.86) ↑; [underlined: At least one type of vegetable:] 1.26 (0.94, 1.69); [underlined: Raw salad:] 1.08 (0.79, 1.48); [underlined: Cooked vegetables or legumes:] 1.10 (0.77, 1.57); [underlined: Fruits:] 1.00 (0.75, 1.34); [underlined: Milk:] 1.06 (0.83, 1.36); [underlined: Fried snacks:] 0.98 (0.68, 1.42); [underlined: Ultra-processed meats:] 0.83 (0.58, 1.20); [underlined: Cracker:] 1.00 (0.78, 1.30); [underlined: Cookies:] 0.97 (0.74, 1.26); [underlined: Snacks:] 0.80 (0.56, 1.16); [underlined: Candies:] 1.01 (0.78, 1.30); [underlined: Soft drinks:] 0.65 (0.50, 0.84) ↑; Model adjustments: Sex; age; household assets score; caregiver education; physical activity; pubertal development; Funding source(s): National Council for Scientific and Technological Development, Bahia Research Foundation, Coordination of Superior Level Staff Improvement
Chamberland, 2017 ^112^; Canada, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 282; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Results with >15 portions of vegetables and fruit (96% intervention) and/or >10 servings of milk and alternatives (100% intervention); Grade level: Middle/Junior high school; Age (Mean): 13.6 y; Female: 61%; Race/ethnicity: NR; SES: Medium to high socioeconomic level schools: 100% | Int: Web-based Team Nutriathlon intervention promoting the consumption of vegetables and fruit, and milk and alternatives (N=193; Cluster N=6); Comp: No intervention (N=89; Cluster N=4); Theory/framework: None; Intervention duration: 6 wk; Outcome measurement: Intake was automatically calculated by a web-based platform. With the assistance of a study coordinator, teachers explained the concept of servings and how to use the web-based platform. During the 6 wk intervention, students in the intervention group recorded their intake Monday through Friday using the Team Nutriathlon web-based platform, and students in the control group recorded their consumption Monday to Friday during wk 3 and 5 using a plain web-based platform. At baseline and post-intervention, both groups used a plain web-based platform. Data was collected at baseline, intervention wk 3, intervention wk 5, 2-wk follow-up, and 10-wk follow-up. | Intake, Mean*; [underlined: Vegetables and Fruit (svg/d)]; Baseline: Int vs Comp: p=NS; Intervention wk 3: Int > Comp, Int vs Comp: p=0.08; Intervention wk 5: Int > Comp, Int vs Comp: p=0.0002 ↑; 2-wk follow-up: Int: 6.4, Comp: 3.7, Int vs Comp: p=0.002 ↑; 10-wk follow-up: Int vs Comp: p=NS Group by time interaction: p<0.0001 ↑; [underlined: Milk and Alternatives (svg/d)]; Baseline: Int vs Comp: p=NS; Intervention wk 3: Int > Comp, Int vs Comp: p=0.0005 ↑; Intervention wk 5: Int > Comp, Int vs Comp: p<0.0001 ↑; 2-wk follow-up: Int: 3.5, Comp: 1.6, Int vs Comp: p<0.0001 ↑; 10-wk follow-up: Int vs Comp: p=NS; Group by time interaction: p<0.0001 ↑; *When reported in text, otherwise data from figure only; Note: There was no effect of sex on consumption of vegetables and fruit, and milk and alternatives; Model adjustments: Class; Funding source(s): The Danone Institute
Chung, 2018 ^113^; Hong Kong, China (SAR), RCT-Cluster; Total Baseline N: 95; Total Analytic N: 95; Total Baseline Cluster N: 5; Total Analytic Cluster N: 5; Grade level: Middle/Junior high school; Age (Range): ~13-15 y; Female: 63%; Race/ethnicity: Chinese ethnicity: 100%; SES: NR | Int: Classroom nutrition lessons and nutrition education via e-learning with personalized reports/feedback (N=50; Cluster N=NR); Comp: Classroom nutrition lessons and nutrition education via e-learning without personalized report/feedback (N=45; Cluster N=NR); Theory/framework: Theory of behavioral therapy; Intervention duration: 12 wk; Outcome measurement: Participants used the nutrition education via e-learning online system to self-report daily food intake | Pre-intervention and post-intervention intake, Mean (SD); [underlined: Saturated fat (% energy intake):]; Int: Pre: 13.2 (4.43), Post: 10.9 (3.66); Comp: Pre: 15.3 (7.44), Post: 16.5 (5.87); Int vs Comp: p<0.01 ↑; [underlined: Dietary fiber (g/d):]; Int: Pre: 10.7 (4.20), Post: 19.4 (6.77); Comp: Pre: 11.6 (4.11), Post: 11.4 (4.46); Int vs Comp: p<0.01 ↑; [underlined: Sodium (mg/d):]; Int: Pre: 2800 (1286), Post: 2131 (692); Comp: Pre: 2743 (872), Post: 2802 (691); Int vs Comp: p<0.01 ↑; [underlined: Sugar (g/d):]; Int: pre: 51.8 (23.6), post: 35.2 (11.1); Comp: pre: 51.8 (20.6), post: 55.3 (23.2); Int vs Comp: p<0.01 ↑; Model adjustments: None; Funding source(s): The Education University of Hong Kong
Dehdari, 2014 ^114^; Iran, RCT-Cluster; Total Baseline N: 100; Total Analytic N: 100; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Middle/Junior high school; Age (Mean): 13 y; Female: 100%; Race/ethnicity: NR; SES: Maternal education level: Illiterate: 6%, ≤12th grade: 90%, >12th grade: 4% | Int: Nutrition education focused on improving breakfast consumption delivered over 4 weekly 45-60 min sessions, in addition to usual classroom nutrition education. Teachers and mothers also received one training session. (N=50; Cluster N=1); Comp: Usual classroom nutrition education (N=50; Cluster N=1); Theory/framework: Pender’s HPM; Intervention duration: 4 wk; Outcome measurement: Intake at breakfast assessed with a 3 d breakfast record at baseline and 1-mo follow-up | Fiber intake (g) at baseline and 1-mo follow-up, Mean (SD); Baseline: Int: 3.48 (2.73), Comp: 3.02 (2.26); p=NS; Post: Int: 5.56 (4.46), Comp: 3.60 (2.81); p<0.05 ↑; Results were similar when g converted to % of RDA; Model adjustments: None; Funding source(s): Tehran University of Medical Sciences
Dehdari, 2016 ^115^; Iran, RCT-Cluster; Total Baseline N: 142; Total Analytic N: 142; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Middle/Junior high school; Age: NR; Female: 100%; Race/ethnicity: NR; SES: Maternal education level: Illiterate: 2%, ≤12th grade: 35%, >12th grade: 63% | Int: Nutrition education focused on increasing dairy consumption delivered over 4 weekly 40-45 min sessions. Teachers and mothers also received one training session. (N=71; Cluster N=1); Comp: No intervention (N=71; Cluster N=1); Theory/framework: Pender’s HPM; Intervention duration: 4 wk; Outcome measurement: Intake assessed with a 3 d record at baseline and post-intervention | Intake at baseline and post-intervention, Mean (SD); [underlined: Dairy food intake (svg/d)]; Baseline: Int: 1.52 (0.90), Comp: 1.33 (0.92); p=NS; Post-intervention: Int: 1.81 (0.92), Comp: 1.21 (0.79); p<0.05 ↑; [underlined: Saturated fat (g)]; Baseline: Int: 23.03 (7.75), Comp: 19.66 (6.27); p=NS; Post-intervention: Int: 21.10 (8.39), Comp: 19.72 (6.99); p=NS; [underlined: Fiber (g)]; Baseline: Int: 14.08 (2.71), Comp: 13.47 (3.06); p=NS; Post-intervention: Int: 18.47 (7.14), Comp: 17.39 (9.48); p=NS; [underlined: Fiber (% of RDA)]; Baseline: Int: 54.16 (10.46), Comp: 51.83 (11.79); p=NS; Post-intervention: Int: 71.06 (27.49), Comp: 66.92 (36.49); p=NS; Model adjustments: None; Funding source(s): Iran University of Medical Sciences
Dohnke, 2018 ^116^; Germany, RCT-Cluster; Total Baseline N: 179; Total Analytic N: 105; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Any missing data, absent; Grade level: Middle/Junior high school; Age (Mean (SD)): 14.04 (0.64); Female: 38.9%; Race/ethnicity: 22% with migration background; SES: NR | Int: Social perception intervention focused on comparing “healthy” and “unhealthy” eaters (N=69; Cluster N=NR); Comp: No intervention (N=36; Cluster N=NR); Theory/framework: Prototype-willingness model; Intervention mapping; Intervention duration: 1 d; Outcome measurement: 24-h recall and food consumption (ad libitum access to a bowl of healthy (fruit) and unhealthy (sweets) foods) measured at 3 time points (pre-intervention; immediate post-intervention; 4-wk follow-up. Food consumption was assessed by study staff behavioral observation on a 5-point scale (nothing; the amount that fits between a finger and a thumb; half a handful; a handful; more than a handful) | Intake at post-intervention and 4-wk follow-up, Mean (SD); [underlined: In-person consumption:]; Post-intervention; Proportion of fruit: Int: 0.52 (0.14), Comp: 0.49 (0.11), p≤0.05 ↑; Fruit (5-point scale): Int: 2.00 (0.93), Comp: 1.49 (0.58), p<0.01 ↑; Sweets (5-point scale): Int: 1.87 (0.99), Comp: 1.62 (0.86), p>0.05; 4-wk follow-up; Proportion of fruit: Int: 0.50 (0.11), Comp: 0.48 (0.13), p=NS; Fruit (5-point scale): Int: 1.68 (0.74), Comp: 1.74 (0.78), p=NS; Sweets (5-point scale): Int: 1.74 (0.94), Comp: 2.01 (1.09), p≤0.05 ↑; [underlined: Previous 24-h consumption at 4-wk follow-up]; Proportion of fruit: Int: 0.84 (0.21), Comp: 0.79 (0.28), p=NS; Fruit (g): Int: 505.07 (486.58), Comp: 565.38 (545.60), p=NS; Sweets (g): Int: 50.80 (55.67), Comp: 72.51 (83.67), p≤0.05 ↑; Model adjustments: Age; baseline level of outcome being examined; order of food offered (in-person measures only); Funding source(s): NR
Forneris, 2010,^117^ Goals for Health; United States (Rural Virginia and New York), RCT-Cluster; Total Baseline N: 2,120; Total Analytic N: 1,830 at T2, 1,410 at T3, 999 at T4; Total Baseline Cluster N: 24; Total Analytic Cluster N: 23; Criteria for exclusion from analysis: Absent for data collection; Grade level: Middle/Junior high school; Age: NR; Female: ~50%; Race/ethnicity: White: ~52%; SES: NR | Int: Nutrition education focused on dietary fat and fiber intake delivered by trained high school students weekly (N=NR; Cluster N=12); Comp: Wait-list control (N=NR; Cluster N=11); Theory/framework: Life Development Intervention framework; Intervention duration: 12 wk; Outcome measurement: Intake assessed with self-administered, 35-item FFQ completed at school at baseline, immediate post-intervention, 1-y follow-up, 2-y follow-up | Intake (log-transformed FFQ score, range: 1-7 which corresponds to never to ≥3 x/d) at baseline, post-intervention, 1-y follow-up, and 2-y follow-up, Mean (SE); [underlined: Fruit and vegetables]; Baseline: Int: 1.32 (0.02), Comp: 1.33 (0.02);; Post-intervention: Int: 1.30 (0.02), Comp: 1.32 (0.02);; 1-y follow-up: Int: 1.23 (0.02), Comp: 1.21 (0.02);; 2-y follow-up: Int: 1.20 (0.02), Comp: 1.22 (0.03);; All Int vs Comp, p=NS; Group by time interaction: p=0.76; [underlined: Fiber]; Baseline: Int: 2.41 (0.02), Comp: 2.45 (0.02);; Post-intervention: Int: 2.39 (0.02), Comp: 2.44 (0.02);; 1-y follow-up: Int: 2.28 (0.02), Comp: 2.30 (0.02);; 2-y follow-up: Int: 2.26 (0.02), Comp: 2.29 (0.03);; All Int vs Comp, p=NS; Group by time interaction: p=0.89; Model adjustments: Age; sex; group by time interaction; group by race interaction; group by sex interaction; school (random effect); Funding source(s): National Cancer Institute
Ghasab Shirazi, 2019 ^127^; Iran, RCT-Cluster; Total Baseline N: 230; Total Analytic N: 230; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Middle/Junior high school; Age (Mean): 13.5; Female: 100%; Race/ethnicity: NR; SES: Maternal education level: ≤12th grade: 86%, >12th grade: 14%; SES: Economic status: Bad: 27%, Moderate: 58.7%, Good: 14.3% | Int: Nutrition education based on Social Cognitive Theory consisting of 8 weekly 60-min sessions. (N=115; Cluster N=1); Comp: Routine nutrition education consisting of two 30-min sessions (N=115; Cluster N=1); Theory/framework: SCT; Intervention duration: 8 wk; Outcome measurement: Intake assessed with questions derived from the validated Farsi version of WHO Global School-based Student Health Survey and Youth Risk Behavior Survey, and were measured on a Likert scale at baseline, and 3- and 6-mo follow-up. Scores ranged from 1 to 6 (fruit and vegetable servings), 7 (fruit, vegetable, unhealthy snack frequency) and 8 (fast food frequency). No consumption was indicated as “1” for fruits and vegetables, “7” for unhealthy snacks, and “8” for fast food. Corresponding servings and frequencies reported in the paper. | Intake at 3-mo and 6-mo follow-up, Mean (SD); [underlined: Fruit (frequency)]; 3 mo: Int: 5.3 (1.0), Comp: 3.7 (1.2); p<0.001 ↑; 6 mo: Int: 5.2 (0.8), Comp: 3.3 (1.0); p<0.001 ↑; Group by time interaction: p<0.001 ↑; [underlined: Fruit (svg)]; 3 mo: Int: 4.04 (0.9), Comp: 2.6 (0.8); p<0.001 ↑; 6 mo: Int: 3.9 (0.8), Comp: 2.5 (0.7); p<0.001 ↑; Group by time interaction: p=0.77; [underlined: Vegetable (frequency)]; 3 mo: Int: 4.2 (0.9), Comp: 3.1 (1.2); p<0.001 ↑; 6 mo: Int: 4.2 (0.9), Comp: 2.9 (1.0); p<0.001 ↑; Group by time interaction: p<0.001 ↑; [underlined: Vegetable (svg)]; 3 mo: Int: 3.4 (0.8), Comp: 2.3 (0.7); p<0.001 ↑; 6 mo: Int: 3.3 (0.7), Comp: 2.2 (0.6); p<0.001 ↑; Group by time interaction: p=0.24; [underlined: Unhealthy snack (frequency)]; 3 mo: Int: 4.01 (1.0), Comp: 2.8 (1.1); p<0.001 ↑; 6 mo: Int: 3.8 (0.9), Comp: 2.4 (0.8); p<0.001 ↑; Group by time interaction: p=0.002 ↑; [underlined: Fast food (frequency)]; 3 mo: Int: 5.1 (1.1), Comp: 3.3 (1.1); p<0.001 ↑; 6 mo: Int: 4.8 (1.1), Comp: 3.3 (1.1); p<0.001 ↑; Group by time interaction: p<0.001 ↑; Model adjustments: Baseline intake; Funding source(s): Isfahan University of Medical Sciences
Gratton, 2007 ^152^; United Kingdom, RCT-Parallel; Total Baseline N: 450; Total Analytic N: 198; Criteria for exclusion from analysis: Did not complete questionnaires at baseline or post-intervention, questionnaires could not be matched between baseline and post-intervention; Grade level: Middle/Junior high school and High school; Age (Mean (SD)): 13.1 (1.32) y (Range: 11-16); Female: 52%; Race/ethnicity: NR; SES: NR | Int1: Volition-based intervention to increase fruit and vegetable intake (N=103); Int2: Motivational intervention to increase fruit and vegetable intake (N=52); Comp: Volition-based intervention focused on homework completion (N=43); Theory/framework: TPB; Intervention duration: 1 wk; Outcome measurement: Participants completed a 7-d food diary at baseline (1-wk pre-intervention) and 1-wk follow-up where they recorded the type and portion sizes of fruit and vegetables eaten/d | Fruit and vegetable intake at baseline and 1-wk follow up, Mean (SD); Int1: Baseline: 2.24 (0.99), 1-wk follow-up: 2.77 (1.25), p<0.001 ↑; Int2: Baseline: 2.05 (0.97), 1-wk follow-up: 2.36 (1.18), p<0.001 ↑; Comp: Baseline: 1.95 (1.13), 1-wk follow-up: 1.91 (1.13), p=NS; Int1 vs Comp: p<0.001 ↑; Int2 vs Comp: p=NS; Int1 vs Int2: p=NS; Model adjustments: Attitudes; subjective norm; perceived behavioural control; intentions; Funding source(s): NR
Karimi-Shahanjarini, 2013 ^118^; Iran, RCT-Cluster; Total Baseline N: 739; Total Analytic N: 601 at 10-d, 590 at 3-mo; Total Baseline Cluster N: 29; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Administrative error, lack of cooperation, loss to follow-up, “other reasons”; Grade level: Middle/Junior high school; Age (Mean): ~14 y; Female: 100%; Race/ethnicity: NR; SES: Maternal education level: <12 y: ~39%, 12 y: ~42%, >12 y: ~19% | Int1: Nutrition education based on TPB and focused on improving snacking behavior delivered over three 90-min sessions ~weekly or biweekly. (N=184 at 10-d, N=181 at 3-mo; Cluster N=8); Int2: Nutrition education based on TPB with a section on goal setting and focused on improving snacking behavior delivered over three 90-min sessions ~weekly or biweekly. (N=192 at 10-d, N=189 at 3-mo; Cluster N=9); Comp: No intervention (N=225 at 10-d, N=220 at 3-mo; Cluster N=9); Theory/framework: TPB; Intervention duration: ~3-6 wk; Outcome measurement: Snacking intake during the previous week assessed with a self-administered 48-item FFQ modified from a previously validated FFQ at baseline, 10-d follow-up, and 3-mo follow-up | Difference in intake at 10-d and 3-mo follow-up, Adjusted mean difference (SE; 95% CI); [underlined: Unhealthy snack intake (units NR)]; 10-d follow-up: Int1 vs Comp (ref): −2.66 (0.95; −4.52, −0.79), p<0.01 ↑; Int2 vs Comp (ref): −4.00 (0.94; −5.84, −2.16), p<0.001 ↑; Int1 vs Int2: p=NS; 3-mo follow-up: Int1 vs Comp (ref): −1.20 (1.07; −3.29, 0.89), p=NS; Int2 vs Comp (ref): - 2.09 (1.05; −4.14, −0.04), p<0.05 ↑; Int1 vs Int2: Data NR; [underlined: Healthy snack intake (units NR)]; 10-d follow-up: Int1 vs Comp (ref): −1.09 (0.84; −2.73, 0.55), p=NS; Int2 vs Comp (ref): - 2.86 (0.84; −4.50, −1.22), p<0.001 ↓; Int1 vs Int2: p=NS; 3-mo follow-up: Int1 vs Comp (ref): −1.02 (0.92; −2.82, 0.78), p=NS; Int2 vs Comp (ref): 0.01 (0.90; −0.85, 0.87), p=NS; Int1 vs Int2: Data NR; Model adjustments: Grade; social desirability; maternal education level; baseline intake level; class (random effect); Funding source(s): Tehran University of Medical Sciences
Keshani, 2019 ^119^; Iran, RCT-Cluster; Total Baseline N: 336; Total Analytic N: 311; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Being absent >1 intervention session, being absent during post-test, refusing to answer the questions; Grade level: Middle/Junior high school; Age (Mean): 13.9 y (Range: 13-15 y); Female: 50%; Race/ethnicity: NR; SES: Mother’s education: Illiterate: 2%; Primary & secondary: 45%; High school and diploma: 40%; University: 13% | Int: Classroom nutrition education consisting of four 90-min sessions that used collaborative learning techniques (N=163; Cluster N=NR); Comp: No intervention (standard school curriculum) (N=148; Cluster N=NR); Theory/framework: Health Belief Model; Intervention duration: 1 academic y; Outcome measurement: Intake over the previous month measured using 168-item FFQ. Diet quality was measured using the revised children’s diet quality index (RCDQI). Participants consuming within the recommended levels, received full points (2.5-10 points, depending on the component), and reductions were made in proportion to suboptimal intakes or overconsumption based on recommendations. Criteria used to determine score for each component is described in the paper. Both were measured at baseline and 1-mo follow-up | Baseline and 1-mo follow-up RCDQI total and component scores, Mean (SD); [underlined: Overall diet quality (RCDQI-score; max score=90):]; Int: Baseline: 56.59 (4.15), 1-mo follow-up: 57.98 (4.03), p<0.001;; Comp: Baseline: 56.88 (3.87), 1-mo follow-up: 56.48 (4.17), p=0.79; 1-mo follow-up: Int vs Comp: p<0.001 ↑; [underlined: Total grain (max score=5):]; Int: Baseline: 2.19 (1.41), 1-mo follow-up: 2.16 (1.21), p=0.50;; Comp: Baseline: 2.72 (1.12), 1-mo follow-up: 2.79 (1.12), p=0.01; 1-mo follow-up: Int vs Comp: p=0.07; [underlined: Whole grain (max score=5):]; Int: Baseline: 0.01 (0.08), 1-mo follow-up: 0.07 (0.23), p=0.09;; Comp: Baseline: 0.01 (0.08), 1-mo follow-up: 0.01 (0.10), p=0.07; 1-mo follow-up: Int vs Comp: p=0.80; [underlined: Fruit (max score=10):]; Int: Baseline: 9.51 (1.22), 1-mo follow-up: 9.59 (0.47), p<0.001;; Comp: Baseline: 9.60 (1.20), 1-mo follow-up: 9.40 (1.40), p=0.001; 1-mo follow-up: Int vs Comp: p<0.001 ↑; [underlined: Vegetable (max score=10):]; Int: Baseline: 7.82 (2.03), 1-mo follow-up: 8.49 (1.67), p<0.001;; Comp: Baseline: 8.03 (2.18), 1-mo follow-up: 7.63 (2.24), p<0.001; 1-mo follow-up: Int vs Comp: p<0.001 ↑; [underlined: Dairy (max score=10):]; Int: Baseline: 6.03 (2.81), 1-mo follow-up: 6.52 (2.28), p<0.001;; Comp: Baseline: 6.26 (2.68), 1-mo follow-up: 5.95 (2.59), p<0.001; 1-mo follow-up: Int vs Comp: p<0.001 ↑; [underlined: Added sugars (max score=10):]; Int: Baseline: 7.39 (2.89), 1-mo follow-up: 7.97 (2.64), p<0.001;; Comp: Baseline: 7.00 (3.15), 1-mo follow-up: 7.08 (3.14), p=0.34; 1-mo follow-up: Int vs Comp: p<0.001 ↑; Model adjustments: BMI; nutrition knowledge level (both variables adjusted for only in analysis of total RCDQI score); Funding source(s): Vice-chancellor of research at Shiraz University of Medical Sciences
Lane, 2018,^120^ Kids SIPsmartER; United States (Buchanan County, Virginia), RCT-Cluster; Total Baseline N: 77; Total Analytic N: 71; Total Baseline Cluster N: 5; Total Analytic Cluster N: 5; Criteria for exclusion from analysis: Absent at time of baseline measurements, did not attend regular science class, outliers; Grade level: Middle/Junior high school; Age (Mean): 11.7 y; Female: ~59%; Race/ethnicity: NR; SES: Designated medically underserved area | Int: Kids SIPsmartER theory-based intervention delivered by trained researchers over 6 weekly 45-min lessons to reduce consumption of SSBs (N=43; Cluster N=3); Comp: Matched-contact physical activity program (N=28; Cluster N=2); Theory/framework: TPB; Intervention duration: 6 wk; Outcome measurement: Intake assessed using the Beverage Intake Questionnaire-15 at baseline, immediately post-intervention, and 3-mo follow-up. | SSB Intake, Mean (SD) and Mean Change Score (SD); [underlined: Overall (fluid oz)]; Baseline: Int: 35.6 (25.7), Comp: 32.2 (22.9); Post-intervention: Int: 24.6 (22.0), Comp: 28.8 (29.6); 3-mo follow-up: Int: 23.4 (25.1), Comp: 26.8 (30.6); Baseline to post-intervention: Int: −11.0 (26.5), p=0.01 ↑; Comp: −3.4 (20.8), p=NS; Int vs Comp: p=NS; Baseline to 3-mo follow-up: Int: −12.2 (25.5), p=0.003 ↑; Comp: −5.4 (18.8), p=NS; Int vs Comp: p=NS; [underlined: Overall (kcal)]; Baseline: Int: 467.6 (339.1), Comp: 411.9 (302.7); Post-intervention: Int: 323.9 (295.5), Comp: 362.1 (365.1); 3-mo follow-up: Int: 301.2 (327.6), Comp: 338.0 (386.2); Baseline to post-intervention: −143.7 (370.0), p<0.05 ↑; Comp: −49.8 (276.2), p=NS; Int vs Comp: p=NS; Baseline to 3-mo follow-up: −166.4 (335.8), p<0.01 ↑; Comp: −74.0 (256.4), p=NS; Int vs Comp: p=NS; Model adjustments: None; Funding source(s): National Cancer Institute; Virginia Tech Fralin Translational Obesity Research Center
Leung, 2014 ^105^; United States (Brooklyn [Crown Heights and East New York], New York), RCT-Parallel; Total Baseline N: 59; Total Analytic N: 59; Grade level: Elementary and Middle/Junior high school; Age (Mean (range)): ~11 y (8.3-15.5 y); Female: 54%; Race/ethnicity: White: ~2%; Black: ~74%; Hispanic: 17%; Other/Mixed: ~7%; SES: Eligible for free lunch (school level data): ~88% | Int: Manga comic promoting the intake and benefits of fruit (N=31); Comp: Attention-control (non-health related newsletter and word search) (N=28); Theory/framework: Transportation-Imagery Model; SCT; Intervention duration: 60 min; Outcome measurement: Snack selection assessed by direct observation of student choice of 1 of 8 items (4 pre-portioned fresh fruit options, 4 energy-dense snacks in original packaging) immediately following reading of comic/attention-control materials | Selection of fruit as snack, % and OR (95% CI); Int: 61%, Comp (ref): 35%; OR: 3.63 (1.09, 12.1), p=0.04 ↑; Model adjustments: Age; sex; previous week fruit and vegetable consumption; Funding source(s): Professional Staff Congress-City University of New York Award
Martens, 2008 ^121^; The Netherlands, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 1,613; Total Baseline Cluster N: 25; Total Analytic Cluster N: 18; Criteria for exclusion from analysis: Cluster dropout after randomization but before baseline data collection, failure to return baseline data; Grade level: Middle/Junior high school; Age (%): ≤12 y: 32%, 13 y: 53%, ≥14y: 15%; Female: ~50%; Race/ethnicity: 83% both parents born in the Netherlands; SES: NR | Int: Krachtvoer educational program to increase fruit intake and breakfast quality, and decrease high-fat snacks intake (N=879; Cluster N=10); Comp: Normal nutrition education curriculum (N=734; Cluster N=8); Theory/framework: Intervention mapping framework; Intervention duration: 3 mo; Outcome measurement: FFQ and self-administered 24-h recall assessed fruit, sweet and savory snack, and breakfast intake at baseline and immediate post-intervention | Intake at baseline and post-intervention, Mean (SD); [underlined: Fruit (svg/d):]; Baseline: Int: 0.91 (0.81), Comp: 0.89 (0.75);; Post-intervention: Int: 1.10 (0.86), Comp: 0.96 (0.81); Adjusted difference at post-intervention, Int vs Comp (ref): 0.04, p≤0.05 ↑; [underlined: Yesterday’s fruit consumption (svg):]; Baseline: Int: 0.95 (0.96), Comp: 0.96 (0.93);; Post-intervention: Int: 1.20 (1.00), Comp: 1.10 (1.01); Adjusted difference at post-intervention, Int vs Comp (ref): 0.13, p≤0.01 ↑; [underlined: Fruit juice (glasses/d):]; Baseline: Int: 1.02 (0.71), Comp: 0.95 (0.69);; Post-intervention: Int: 0.99 (0.69), Comp: 0.98 (0.70); Adjusted difference at post-intervention, Int vs Comp (ref): −0.04, p=NS; [underlined: Yesterday’s fruit juice consumption (glasses):]; Baseline: Int: 1.04 (0.77), Comp: 0.91 (0.77);; Post-intervention: Int: 1.11 (0.66), Comp: 1.07 (0.71); Adjusted difference at post-intervention, Int vs Comp (ref): −0.03, p=NS; [underlined: Snacking (pieces/d):]; Baseline: Int: 1.80 (1.38), Comp: 1.88 (1.46);; Post-intervention: Int: 1.70 (1.32), Comp: 1.84 (1.44); Adjusted difference at post-intervention, Int vs Comp (ref): −0.02, p=NS; [underlined: Yesterday’s snack consumption (pieces):]; Baseline: Int: 1.96 (1.52), Comp: 2.05 (1.56);; Post-intervention: Int: 1.82 (1.43), Comp: 1.95 (1.54); Adjusted difference at post-intervention, Int vs Comp (ref): −0.08, p=NS; [underlined: Saturated fat in yesterday’s snack consumption (g):]; Baseline: Int: 6.49 (7.83), Comp: 6.32 (6.96);; Post-intervention: Int: 6.29 (7.77), Comp: 6.61 (7.68); Adjusted difference at post-intervention, Int vs Comp (ref): −0.25, p=NS; [underlined: Saturated fat in yesterday’s breakfast consumption (g):]; Baseline: Int: 3.31 (2.86), Comp: 3.63 (4.59);; Post-intervention: Int: 3.18 (2.93), Comp: 3.45 (4.80); Adjusted difference at post-intervention, Int vs Comp (ref): −0.07, p=NS; [underlined: Sugar in yesterday’s breakfast consumption (g):]; Baseline: Int: 17.10 (14.02), Comp: 17.33 (14.76);; Post-intervention: Int: 17.10 (14.45), Comp: 17.34 (15.51); Adjusted difference at post-intervention, Int vs Comp (ref): −0.20, p=NS; Subgroup analyses by baseline intake are available in paper.; Model adjustments: Gender; age; baseline value of outcome; interaction terms with group assignment for all three variables tested and retained if significant; Funding source(s): The Netherlands Organisation for Health and Development; The Netherlands Heart Foundation
Mora, 2018 ^122^; Spain, RCT-Cluster; Total Baseline N: 3,291; Total Analytic N: 3,264; Total Baseline Cluster N: 126; Total Analytic Cluster N: 126; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school; Age (Mean): ~12.8 y; Female: ~52%; Race/ethnicity: NR; SES: At least one parent employed: ~96% | Int: A 50-min game-based nutrition workshop conducted in classrooms (N=NR; Cluster N=62); Comp: No intervention (N=NR; Cluster N=64); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Food preference was assessed by students’ choice of midmorning snack (one food and one drink) free of charge at baseline and 15 days after baseline (nutrition workshop during 2 wk period). Two healthy and two unhealthy food and drink options were available, and three types of food and drink vouchers were randomly assigned: standard, two-for-one of unhealthy food with standard drink choices, and two-for-one unhealthy drinks with standard food choices | Change in probability of being chosen, Percentage Points (SE); [underlined: Unhealthy food]; Overall: Int vs Comp (ref): −0.071 (0.01), p<0.01 ↑; Regular voucher: Int vs Comp (ref): −0.074 (0.01), p<0.01 ↑; Two-for-one unhealthy food voucher: Int vs Comp (ref): −0.064 (0.02), p<0.01 ↑; [underlined: Unhealthy beverage]; Overall: Int vs Comp (ref): −0.044 (0.01), p<0.01 ↑; Regular voucher: Int vs Comp (ref): −0.047 (0.02), p<0.05 ↑; Two-for-one unhealthy drink voucher: Int vs Comp (ref): −0.037 (0.02), p=NS; Model adjustments: Influence of peers; individual, family, school, or neighborhood characteristics; Funding source(s): Chair of Public Finance: Healthcare and Education Policy Assessment; Spanish State Programme of R+D+I
Rees, 2010 ^124^; United Kingdom, RCT-Cluster; Total Baseline N: 823; Total Analytic N: 637; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Completing <2 dietary recalls at either baseline or 3-mo follow up; Grade level: Middle/Junior high school and High school; Age (Range): 12-16 y; Female: 100%; Race/ethnicity: White: 53%; Asian: 19%; Black: 16%; Mixed: 10%; SES: Schools were low income and/or high ethnic diversity (overall sample was “lower than average income”) | Int: Tailored leaflet based on responses to diet questionnaire (N=323; Cluster N=NR); Comp: Generic leaflet (N=314; Cluster N=NR); Theory/framework: TPB; Transtheoretical Model; Intervention duration: 1 d; Outcome measurement: Participants were provided with three 24-h dietary recall sheets over three different days at baseline, and again at 3-mo follow-up, to record food and drink intake from the previous day. | Change in intake (svg/d) from baseline to 3-mo follow-up, Mean; [underlined: Brown bread:] Int: 0.12 ; Comp: 0.07 (between group p<0.05 ↑; within group, both p<0.05 ↑); [underlined: Wholegrain cereal:] Int: 0.00 ; Comp: −0.03 (between & within group, all p=NS); [underlined: Fruit:] Int: −0.15 ; Comp: −0.11 (between group p=NS; within group, both p<0.05 ↓); [underlined: Vegetables:] Int: 0.00 ; Comp: −0.03 (between & within group, all p=NS); Model adjustments: School; location; school year; ethnicity; Funding source(s): The Food Standards Agency
Rennie, 2015,^125^ CaPSCA; France, RCT-Cluster; Total Baseline N: NR; Total Analytic N: 183; Total Baseline Cluster N: 19; Total Analytic Cluster N: 19; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school; Age (Range): ~11-12 y; Female: 51%; Race/ethnicity: NR; SES (scores range from 0-6, 0=low affluence, 6=high affluence) (Mean (SD)): 4.18 (1.32) | Int: Two 50-min intervention sessions delivered 1 y apart by a trained researcher in the classroom focusing on attitudes towards healthy eating, planning balanced meals, and how to overcome barriers to having a balanced diet. (N=637; Cluster N=7); Comp: No intervention (N=1,201; Cluster N=12); Theory/framework: Taxonomy of behavior change techniques; Intervention duration: 1 y; Outcome measurement: Adherence to a healthy balanced diet assessed with report of previous day’s intake by participant and its relationship to the Programme National Nutrition Santé Guideline Score tool, approximately 6-mo pre-intervention and 3-mo follow-up. The adherence score focuses on protein, fruits and vegetables, dairy, carbohydrates, added sugars, added fat, and added salt with a maximum score of 27.5. | Adherence to a balanced diet change from pre-intervention to 3-mo follow-up, Adjusted mean change; Group by time interaction: p=0.047 ↑; Change: Int: 0.19, p=0.66, Comp: −1.25, p=0.014 ↓; Model adjustments: Sex; SES; school (random effect); Funding source(s): La Comité des Hauts-de-Seine de la Ligue Nationale Contre le Cancer
Ribeiro-Silva, 2014 ^79^; Brazil, RCT-Cluster; Total Baseline N: 531; Total Analytic N: 202; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: No blood collection at baseline or follow-up; Grade level: Elementary and Middle/Junior high school; Age (Mean): ~8.2 y; Female: ~52%; Race/ethnicity: NR; SES: Maternal education ≤4th grade: ~23% | Int: Nutrition education (six 50-min sessions), food preparation workshops for teachers and food service staff, and nutrition education workshops for families. (N=142; Cluster N=1); Comp: No intervention (N=60; Cluster N=1); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake assessed via FFQ at baseline and post-intervention | Fruit and vegetable intake frequency, %; [underlined: Baseline]; <75th percentile: Int: 73.1%, Comp: 75.9%; ≥75th percentile: Int: 26.9%, Comp: 24.1%; Int vs Comp: p=0.635; [underlined: Post-intervention]; <75th percentile: Int: 67.9%, Comp: 88.7%; ≥75th percentile: Int: 32.0%, Comp: 11.3%; Int vs Comp: p=0.001 ↑; Model adjustments: None; Funding source(s): Fundação de Amparo à Pesquisa do Estado da Bahia, Programa de Educação para o Trabalho - Projeto Parceria: Educação e Trabalho (PROPET), Ministério da Saúde
Sahingoz, 2019 ^126^; Turkey, RCT-Cluster; Total Baseline N: 160; Total Analytic N: 160; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: Middle/Junior high school; Age (Range): 11-16 y; Female: ~41%; Race/ethnicity: NR; SES: Maternal education level: Illiterate: 7%, Just literate: 8%, Elementary school: 60%, Middle school: 20%, High school: 5% | Int: Nutrition education focused on the Mediterranean diet delivered by a researcher over twice weekly, 1 h sessions for 8 wk with a 2 h booster session 1 mo following the program (N=76; Cluster N=1); Comp: No intervention (N=84; Cluster N=1); Theory/framework: NR; Intervention duration: ~12 wk; Outcome measurement: Adherence to a Mediterranean diet assessed by the 16-item KIDMED, administered pre- and post-intervention (scores range from 0 to 12) | KIDMED scores at pre- and post-intervention, Mean (SD); Pre: Int: 5.20 (2.45), Comp: 6.06 (2.16), p=0.019; Post: Int: 11.84 (0.52), Comp: 5.26 (2.65), p=0.000 ↑; Model adjustments: None; Funding source(s): NR
Takacs, 2020 ^128^; Hungary, RCT-Cluster; Total Baseline N: 229; Total Analytic N: 226 at post-intervention, 203 at post-summer break; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Missing data (not specified); Grade level: Middle/Junior high school; Age (Mean): ~12.5 y; Female: ~55%; Race/ethnicity: NR; SES: NR | Int: Intervention consisting of weekly nutrition education classes during school delivered by a trained dietitian (27 sessions over 9 mo) including tasting and food preparation, 5 after-school cooking classes offered during the second semester attended by children, parents, and grandparents, and educational materials provided on Facebook or over email. (N=116 at post-intervention, N=108 at post-summer break; Cluster N=4); Comp: No intervention (N=110 at post-intervention, N=95 at post-summer break; Cluster N=4); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake assessed by 10 questions completed by the child with assistance of a trained field worker in the classroom at baseline, post-intervention, and post-summer break follow-up. Questions measured a variety of factors including frequency of breakfast skipping, number of meals, daily fluid intake, and the frequency of dairy product, fruit, vegetable, sweets, fast food, energy drink, and sugary drink intake. Answers for questions summed with total score ranging from 0 to 10, with higher scores reflecting more favorable dietary behavior. | Change in intake from baseline to post-intervention and post-summer break follow-up, Mean (SE); [underlined: Total dietary behavior]; Baseline: Int: 4.6 (0.2), Comp: 4.2 (0.2); Baseline to post-intervention change: Int: 0.2 (0.2), Comp: −0.6 (0.2), p=0.021 ↑; Baseline to post-summer break follow-up change: Int: −0.5 (0.2), Comp: −0.8 (0.2), p=0.271; Results were similar when adjusted for child sex (see paper for details).; Model adjustments: None; Funding source(s): NR
Tarro, 2019,^90^ European Youth Tackling Obesity (EYTO)-Kids project; Spain, RCT-Cluster; Total Baseline N: 192; Total Analytic N: 169; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Did not complete post-intervention survey; Grade level: Middle/Junior high school; Age (Mean (SD)): 13.1 (0.59) y; Female: 56%; Race/ethnicity: West Europe: 83%; East Mediterranean: 8%; East-Central Europe: 3%; American Regions: 5%; African Regions: 1%; SES: NR | Int: Social marketing and nutrition training (2h) to teach younger children (N=73; Cluster N=4); Comp: No intervention (N=96; Cluster N=3); Theory/framework: NR; Intervention duration: 10 mo; Outcome measurement: Diet intake assessed using EnKid Questionnaire and the HABITS Questionnaire (sugary drinks) self-reported by adolescents at baseline and post-intervention | Baseline and post-intervention intake, %; [underlined: ≥1 Fruit/d:]; Baseline: Int: 36.5% vs Comp: 37.7%;; Post-intervention: Int: 41.2% vs Comp: 36.7%; Difference in change: p=0.655; [underlined: ≥1 Vegetable/d:]; Baseline: Int: 24.5% vs Comp: 23.4%;; Post-intervention: Int: 33.7% vs Comp: 23.2%; Difference in change: p=0.735; [underlined: ≥1 Sugary drink every d:]; Baseline: Int: 52.1% vs Comp: 52.7%;; Post-intervention: Int: 50.1% vs Comp: 53.4%; Difference in change: p=0.678; [underlined: No gummy or sweets during wk:]; Baseline: Int: 89.8% vs Comp: 86.2%;; Post-intervention: Int: 91.4% vs Comp: 89.0%; Difference in change: p=0.850; [underlined: No fast food during wk:]; Baseline: Int: 89.8% vs Comp: 82.9%;; Post-intervention: Int: 89.2% vs Comp: 78.3%; Difference in change: p=0.503; Similar results seen when sugary drinks analyzed separately (commercial juice, soft drinks, and carbonated drinks) and when girls and boys were analyzed separately.; Model adjustments: None; Funding source(s): Obra Social La Caixa
Toral, 2012 ^129^; Brazil, RCT-Cluster; Total Baseline N: 860; Total Analytic N: 771; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: Transfer to other school, absent on data collection day; Grade level: Middle/Junior high school; Age (Range): 56.9% 11-13 y, 42.4% 14-16 y, 0.7% 17-19 y; Female: 59.5%; Race/ethnicity: NR; SES: Family income (Brazilian minimum monthly salary - BMMS): <2 BMMS: 34.2%, 2-4.9 BMMS: 33.2%, ≥5 BMMS: 23.3%, Didn’t know/no answer: 9.3% | Int: Printed educational magazines promoting healthy eating handed out monthly at school and newsletters tailored to child’s stage of change promoting fruit and vegetable consumption mailed monthly to home. (N=448; Cluster N=4); Comp: No intervention (N=323; Cluster N=6); Theory/framework: Transtheoretical Model; Intervention duration: 6 mo; Outcome measurement: Intake of fruits and vegetables self-reported by child and recorded into categories ranging from <1 svg/d to ≥5 svg/d at baseline and post-intervention | Fruit and vegetable intake at post-intervention, %; Adequate (≥5 svg/d): Int: 9.4%, Comp: 8.4%; Inadequate (<5 svg/d): Int: 90.6%, Comp: 91.6%; Int vs Comp: p=0.626; Model adjustments: None; Funding source(s): ILSI Brazil
Viggiano, 2015 ^130^; Italy, RCT-Cluster; Total Baseline N: 3,110; Total Analytic N: 2,156 at post-intervention; 1,045 at 12-mo follow-up; Total Baseline Cluster N: 20; Total Analytic Cluster N: 19 at post-intervention; N=14 at 12-mo follow-up; Criteria for exclusion from analysis: Did not complete post-intervention assessments; Grade level: Middle/Junior high school and High school; Age (Mean): ~13.2 y; Female: 47%; Race/ethnicity: NR; SES: NR | Int: Kalèdo game promoting nutrition knowledge and healthy lifestyle played weekly (N=1,076 at post-intervention; N=624 at 12-mo follow-up; Cluster N=10 at post-intervention; N=8 at 12-mo follow-up); Comp: No intervention (N=1,080 at post-intervention; N=421 at 12-mo follow-up; Cluster N=9 at post-intervention; N=6 at 12-mo follow-up); Theory/framework: NR; Intervention duration: 20 wk; Outcome measurement: Eating behavior and food habits assessed with a 23-item Adolescent Food Habits Checklist (AFHC) and a 14-item dietary questionnaire on food habits at baseline, post-intervention, and 12-mo follow-up; maximum scores indicate the healthiest habit. | Food questionnaire scores post-intervention and 12-mo follow-up, Mean (95% CI); [underlined: AFHC (range 0-23)]; [underlined: All schools]; Post-intervention: Int: 14.4 (14.0, 14.8) vs Comp: 10.9 (10.6, 11.2). p<0.001 ↑; 12-mo: Int: 11.6 (11.1, 12.0) vs Comp: 10.5 (9.9, 11.0), p=0.248; [underlined: Middle schools]; Post-intervention: Int. 15.0 (14.5, 15.4) vs Comp: 11.2 (10.7, 11.6), p<0.001 ↑; 12-mo: Int: 10.7 (9.8, 11.6) vs Comp: 10.4 (9.4, 11.5), p=0.666; [underlined: Diet questionnaire - food habits (range 0-42)]; [underlined: All schools]; Post-intervention: Int: 32.4 (32.0, 32.8) vs Comp: 27.6 (27.3, 28.0), p<0.001 ↑; 12-mo: Int: 29.3 (28.9, 29.7) vs Comp: 28.6 (28.2, 29.1), p=0.507; [underlined: Middle schools]; Post-intervention: Int: 32.6 (32.0, 33.2) vs Comp: 27.8 (27.2, 28.4), p<0.001 ↑; 12-mo: Int: 28.2 (27.5, 28.9) vs Comp: 28.6 (27.8, 29.4), p=0.426; Model adjustments: Baseline diet; school (random effect); Funding source(s): Second University of Naples, Associazione Culturale Kaledo, Regione Campania (Assessorato all’Istruzione), Provincia di Napoli, Provincia di Salerno Assessorato allo Sport, Comune di Cercola (Assessorato all’istruzione) and Fondazione per l’Assistenza all’Infanzia
Yamaoka, 2011 ^133^; Japan, RCT-Cluster; Total Baseline N: 466; Total Analytic N: 459; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Did not receive/complete follow-up FFQ; Grade level: Middle/Junior high school; Age (Range): ~13-15 y; Female: 100%; Race/ethnicity: NR; SES: NR | Int: Twelve group dietary education and counseling sessions given every 2 weeks by a teacher/dietitian to improve nutrition knowledge and motivate changes in behavior, in addition to standard health science education (N=225; Cluster N=6); Comp: Standard health science education (N=234; Cluster N=6); Theory/framework: NR; Intervention duration: 6 mo; Outcome measurement: Intake during the previous month assessed with 82-item FFQ administered at baseline and post-intervention | Change in nutrient intake from baseline to post-intervention, Mean (SD); [underlined: Fiber (log transformed g/d)]; Int: −0.010 (0.012), Comp: −0.028 (0.026);; Adjusted mean difference: −0.015, p=0.297; [underlined: Salt (log transformed g/d)]; Int: −0.008 (0.015), Comp: −0.031 (0.026);; Adjusted mean difference: −0.022, p=0.130; Note: Results similar when separated by meal type (breakfast, lunch, dinner).; Model adjustments: Baseline intake; Funding source(s): Ministry of Education, Culture, Sports, Science and Technology (Japan)
Zota, 2016,^98^ DIATROFI Program; Greece, RCT-Cluster; Total Baseline N: 14,869; Total Analytic N: 3,627; Total Baseline Cluster N: 146; Total Analytic Cluster N: 146; Criteria for exclusion from analysis: Missing a pre-or post-intervention questionnaire, missing information required to link pre- and post-intervention surveys; Grade level: Elementary school and Middle/Junior high school and High school; Age (Range): 4-18 y; Female: ~53%; Race/ethnicity: NR; SES: Maternal education: Low: ~26%, Medium: ~54%, High: ~20%; Family affluence scale: Low: ~29%, Medium: ~54%, High: ~17%; Food insecurity: 51% | Int: Nutrition education with one free, healthy meal daily (N=1,609; Cluster N=73); Comp: One free, healthy meal per day at school without nutrition education (N=2,018; Cluster N=73); Theory/framework: NR; Intervention duration: 1 academic y; Outcome measurement: Intake assessed using a modified version of a semi-quantitative FFQ, completed by a parent at pre- and post-intervention | Increased weekly consumption of food groups provided by the program from pre- to post-intervention, OR (95% CI); [underlined: Adolescents (12-18 y, Int: N=422, Comp: N=649)]; [underlined: Milk or yogurt:] 0.82 (0.64, 1.06), p=NS; [underlined: Vegetables:] 1.40 (1.09, 1.80), p<0.05 ↑; [underlined: Fruits:] 1.03 (0.78, 1.36), p=NS; [underlined: Whole grains:] 0.83 (0.62, 1.12), p=NS; Model adjustments: Sex; region; maternal, paternal, and child country of birth; maternal and paternal education; sports outside school; type of household, weight status; Family Affluence Scale; food insecurity; school near Roma establishments; number of children in the family (all considered in stepwise model); Funding source(s): Stavros Niarchos Foundation

a Abbreviations: BMI: body mass index; CBT: Cognitive-Behavioral Therapy; CI: confidence interval; Comp: comparator; d: day; g: gram; h: hour; kcal: kilocalorie; HPM: Health Promotion Model; Int: intervention; min: minute; mo: month; N: sample size; NR: not reported; NS: non-significant; OR: odds ratio; oz; ounce; p: p-value; RCT: randomized controlled trial; RDA: Recommended Dietary Allowance; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; TPB: Theory of Planned Behavior; vs: versus; wk: week; WHO: World Health Organization; x: times; y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator

Table 10 Risk of bias for randomized controlled trials examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Amaro, 2006^107^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Bere, 2006^142^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Bessems, 2012^109^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Brito Beck da Silva, 2015^110^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Brito Beck da Silva, 2019^111^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Chamberland, 2017^112^ | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Chung, 2018^113^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Dehdari, 2014^114^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Dehdari, 2016^115^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Dohnke, 2018^116^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Forneris, 2010^117^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Ghasab Shirazi, 2019^127^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Gratton, 2007,^152^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | HIGH | LOW | SOME CONCERNS
Karimi-Shahanjarini, 2013^118^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Keshani, 2019^119^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Lane, 2018^120^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Leung, 2014,^105^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Martens, 2008^121^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
Mora, 2018^122^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Øvrebø, 2019^123^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Rees, 2010^124^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Rennie, 2015^125^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Ribeiro-Silva, 2014^79^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
Sahingoz, 2019^126^ | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Takacs, 2020^128^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Tarro, 2019^90^ | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW
Toral, 2012^129^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Viggiano, 2015^130^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Wang, 2015^131^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Wang, 2015^132^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Yamaoka, 2011^133^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Zota, 2016^98^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS

a All studies cluster-RCTs except when otherwise noted

Table 11 Evidence examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Cohen, 2015,^24^ Modifying Eating and Lifestyles at School Study (MEALS Study); United States (Massachusetts), RCT-Cluster; Total Baseline N: 2,638; Total Analytic N: 2,638 (968 with complete data used to calculate estimates); Total Baseline Cluster N: 14; Total Analytic Cluster N: 14; Grade level: Elementary and Middle/Junior high school; Age (Mean): 11.5 y (Range: 8-16); Female: 53%; Race/ethnicity: White: ~6%; Black: ~4%; Asian: ~3%; Hispanic: ~86%; SES: Eligible free/reduced price: ~91% | Int1: Chef intervention/training only (N=379; Cluster N=2); Int2: Smart Café cafeteria-based intervention only (N=651; Cluster N=4); Int3: Chef intervention/training followed by a Smart Café cafeteria-based intervention (N=672; Cluster N=2); Comp: Control (delayed intervention) (N=936; Cluster N=6); Theory/framework: Choice architecture strategies; Intervention duration: Chef intervention: 7 mo; Smart Café: 4 mo; Outcome measurement: Lunch selection and consumption measured on 2 randomly selected, nonconsecutive days at baseline and during the 2 intervention data collection periods by direct observation and weighing of remaining food after lunch by study staff | Selection after 3 mo of intervention, Mean % of students selecting, OR (95% CI); (Note: Before Smart Cafe intervention initiated); [underlined: Fruit]: Comp + Int 2 (ref): 60.1, Int 1 + Int 3: 66.9; 1.46 (0.67, 3.21), p>0.05; [underlined: Vegetables]: Comp + Int 2 (ref): 46.6, Int 1 + Int 3: 57.8, 1.75 (1.36, 2.24), p<0.05 ↑; Intake after 3 mo of intervention, Mean (SE), Difference (95% CI); (Note: Before Smart Cafe intervention initiated); [underlined: Entree (%)]: Comp + Int 2 (ref): 73.9 (4.0), Int 1 + Int 3: 71.7 (5.1), −2.2 (−11.3, 6.9), p>0.05; [underlined: Fruit (%)]: Comp + Int 2 (ref): 72.1 (7.9), Int 1 + Int 3: 73.2 (9.4), 1.1 (−15.1, 17.2), p>0.05; [underlined: Fruit (cups)]: Comp + Int 2 (ref): 0.42 (0.05), Int 1 + Int 3: 0.42 (0.06), 0.00 (−0.10, 0.11), p>0.05; [underlined: Vegetables (%)]: Comp + Int 2 (ref): 48.2 (8.9), Int 1 + Int 3: 40.5 (9.8), −7.8 (−31.5, 16.0), p>0.05; [underlined: Vegetables (cups)]: Comp + Int 2 (ref): 0.24 (0.04), Int 1 + Int 3: 0.20 (0.05), −0.04 (−0.16, 0.08), p>0.05; Selection after 7 mo of intervention, Mean % of students selecting, OR (95% CI); [underlined: Fruit]: Comp (ref): 51.1; Int 1: 71.6, 3.08 (2.23, 4.25); Int 2: 54.3, 1.45 (1.13, 1.87); Int 3: 78.1, 3.10 (2.26, 4.25), all p<0.05 ↑; [underlined: Vegetables]: Comp (ref): 33.7; Int 1: 64.2, 2.54 (1.83, 3.54); Int 2: 50.6, 1.91 (1.46, 2.50); Int 3: 76.4, 7.38 (5.26, 10.35), all p<0.05 ↑; Intake after 7 mo of intervention, Mean (SE), Difference (95% CI); [underlined: Entree (%)]: Comp (ref): 80.7 (4.8); Int 1: 68.1 (6.9), −12.6 (−26.2, 1.1); Int 2: 81.6 (5.6), 0.9 (−9.9, 12.0); Int 3: 84.6 (7.1), 3.9 (−10.0, 17.8); all p>0.05; [underlined: Fruit (%)]: Comp (ref): 67.4 (6.7); Int 1: 88.1 (9.9), 20.7 (−1.3, 42.7); Int 2: 63.0 (8.6), −4.4 (−23.8, 15.0); Int 3: 58.6 (8.9), −8.8 (−28.7, 11.1); all p>0.05; [underlined: Fruit (cups)]: Comp (ref): 0.34 (0.05); Int 1: 0.51 (0.07), 0.17 (0.03, 0.30), p<0.05 ↑; Int 2: 0.34 (0.07), −0.00 (−0.13, 0.11), p>0.05; Int 3: 0.30 (0.07), −0.04 (−0.17, 0.08), p>0.05; [underlined: Vegetables (%)]: Comp (ref): 28.9 (5.8); Int 1: 59.7 (6.1), 30.8 (17.7, 43.8), p<0.05 ↑; Int 2: 18.2 (6.3), −10.7 (−23.8, 2.4), p>0.05; Int 3: 53.4 (7.1), 24.5 (10.0, 39.0), p<0.05 ↑; [underlined: Vegetables (cups)]: Comp (ref): 0.14 (0.03); Int 1: 0.30 (0.03), 0.16 (0.09, 0.22), p<0.05 ↑; Int 2: 0.09 (0.03), −0.05 (−0.12, 0.01), p>0.05; Int 3: 0.27 (0.04), 0.13 (0.05, 0.19), p<0.05 ↑; Note: Data on milk intake in the Smart Cafe schools presented in the paper, but intervention implementation was inconsistent, and some data were collapsed, limiting usefulness; Model adjustments: Age; sex; race/ethnicity; baseline selection or consumption (depending on outcome); school (random effect); Funding source(s): Arbella Insurance; Nutritional Epidemiology of Cancer Education and Career Development Program
Coleman, 2012,^25^ The Healthy Options for Nutrition Environments in Schools (Healthy ONES); United States (San Diego County, California), RCT-Cluster; Total Baseline N: 4,033; Total Analytic N: NR; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: NR; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: Non-Hispanic White: 21%; Black: 26%; Hispanic/Latino: 42%; Other/Mixed: 11%; SES: Eligible for free/reduced price lunch: 100% | Int: Implementation of school nutrition policy and environmental changes to eliminate unhealthy foods/beverages at school, develop nutrition services as source of healthy eating, and have staff model healthy eating (N=NR; Cluster N=4); Comp: No intervention (N=NR; Cluster N=4); Theory/framework: Evidence-based public health rapid improvement process model; Intervention duration: 2 y; Outcome measurement: Food brought from home directly observed in cafeteria and recess/playground environments, and via observation of school trash for food in the classroom and at school-wide events. Observations were made ~1 x/mo during school year in addition to holidays for both intervention years. | Outside food and beverages at baseline and intervention year 1 and 2, Mean (variability)*; [underlined: Outside unhealthy foods (items/child/wk)]:; Baseline: Int: 0.47 (0.22), Comp: 0.67 (0.31); Year 1: Int: 0.71 (0.24), Comp: 1.03 (0.38); Year 2: Int: 0.32 (0.30), Comp: 0.89 (0.55);; Group by time interaction: p=0.01 ↑; Group by time by environment (recess/classroom/lunch) interaction: p=0.02 ↑ (significant differences between groups for recess - decrease in outside unhealthy foods for intervention and increase for control, no significant differences between groups for classroom/lunch); [underlined: Outside unhealthy beverages (items/child/wk)]:; Baseline: Int: 0.26 (0.11), Comp: 0.32 (0.12); Year 1: Int: 0.23 (0.10), Comp: 0.35 (0.10); Year 2: Int: 0.09 (0.05), Comp: 0.28 (0.15);; Group by time interaction: p=0.01 ↑; Group by time by environment interaction: p=NS; [underlined: Outside healthy foods (items/child/wk)]:; Baseline: Int: 0.20 (0.11), Comp: 0.26 (0.09); Year 1: Int: 0.24 (0.11), Comp: 0.35 (0.16); Year 2: Int: 0.17 (0.11), Comp: 0.37 (0.28);; Group by time interaction: p=0.01 ↑; Group by time by environment interaction: p=0.002 ↑ (significant difference between groups for recess - decrease in outside healthy food for intervention and no change for control, significant difference between groups for lunch - increase in outside healthy food for intervention and decrease for control, no significant difference between groups for classroom); [underlined: Outside healthy beverages (items/child/wk)]:; Baseline: Int: 0.10 (0.08), Comp: 0.12 (0.05); Year 1: 0.14 (0.07), Comp: 0.19 (0.06); Year 2: 0.09 (0.07), Comp: 0.16 (0.08); Group by time interaction: p=NS; Group by time by environment interaction: p=NS; *Did not report whether SD or SE; Note: Schools were unit of analysis; Model adjustments: None; Funding source(s): USDA National Research Initiative
Cullen, 2015 ^26^; United States (Houston, Texas), RCT-Cluster; Total Baseline N: NR; Total Analytic N: 427; Total Baseline Cluster N: 4; Total Analytic Cluster N: 4; Criteria for exclusion from analysis: NR; Age: NR; Female: NR%; Race/ethnicity: White: 59%; Black: 10%; Asian: 10%; Hispanic: 21% (across entire school district); SES: Eligibility for free or reduced price meals (across entire school district): 26% | Int: New NSLP guidelines for fruits and vegetables (3 servings) (N=212; Cluster N=2); Comp: Current USDA meal pattern for fruits and vegetables (2 servings) (N=215; Cluster N=2); Theory/framework: NR; Intervention duration: 1 semester; Outcome measurement: Students’ food selection and intake was recorded via direct observation in the cafeteria during lunch by trained research staff assigned to specific schools; school visits occurred 1 d/wk during the semester | Food selection at lunch, % selecting or Mean (SE); [underlined: Fruit (%)]: Int: 45%, Comp: 21%, p<0.001 ↑; [underlined: Fruit (cups)]: Int: 0.25 (0.02), Comp: 0.12 (0.02), p<0.001 ↑; [underlined: Juice (%)]: Int: 52%, Comp: 43%, p=NS; [underlined: Juice (cups)]: Int: 0.27 (0.02), Comp: 0.22 (0.02), p<0.05 ↑; [underlined: Fruit and juice (%)]: Int: 78%, Comp: 58%, p<0.001 ↑; [underlined: Fruit and juice (cups)]: Int: 0.52 (0.02), Comp: 0.33 (0.02), p<0.001 ↑; [underlined: Total vegetables (%)]: Int: 52%, Comp: 41%, p<0.05 ↑; [underlined: Total vegetables (cups)]: Int: 0.23 (0.02), Comp: 0.14 (0.02), p<0.01 ↑; [underlined: Dark green vegetables (%)]: Int: 11%, Comp: 14%, p=NS; [underlined: Dark green vegetables (cups)]: Int: 0.02 (0.01), Comp: 0.03 (0.01), p=NS; [underlined: Red orange vegetables (%)]: Int: 20%, Comp, 20%, p=NS; [underlined: Red orange vegetables (cups)]: Int: 0.05 (0.01), Comp: 0.04 (0.01), p=NS; [underlined: Starchy vegetables (%)]: Int 39%, Comp: 27%, p<0.01 ↑; [underlined: Starchy vegetables (cups)]: Int: 0.12 (0.01), Comp: 0.06 (0.01), p<0.001 ↑; [underlined: Other vegetables (%)]: Int: 17%, Comp: 16%, p=NS; [underlined: Other vegetables (cups)]: Int: 0.05 (0.01), Comp: 0.05 (0.01), p=NS; [underlined: Legumes (%)]: Int: 9%, Comp: 4%, p<0.05 ↑; [underlined: Legumes (cups)]: Int: 0.03 (0.01), Comp: 0.01 (0.01), p<0.05 ↑; [underlined: Grains (%)]: Int: 100%, Comp: 99%, p=NS; [underlined: Grains (oz eq)]: Int: 2.56 (0.09), Comp: 2.65 (0.09), p=NS; [underlined: Whole grains (%)]: Int: 49%, Comp: 52%, p=NS; [underlined: Whole grains (oz eq)]: Int: 0.55 (0.05), Comp: 0.70 (0.05), p<0.05 ↓; [underlined: Protein foods (%):] Int: 100%, Comp: 97%, p<0.01 ↑; [underlined: Protein foods (oz eq)]: Int: 2.15 (0.06), Comp: 2.18 (0.06), p=NS; [underlined: Milk (%)]: Int: 76%, Comp: 74%, p=NS; [underlined: Milk (oz)]: Int: 5.89 (0.25), Comp: 5.64 (0.25), p=NS; Food consumed at lunch, Mean (SE); [underlined: Fruit (cups)]: Int: 0.19 (0.02), Comp: 0.09 (0.02), p<0.001 ↑; [underlined: Fruit (%)]: Int: 76% (4), Comp: 78% (6), p=NS; [underlined: Juice (cups)]: Int: 0.21 (0.02), Comp: 0.17 (0.02), p=NS; [underlined: Juice (%)]: Int: 75% (3), Comp: 78% (4), p=NS; [underlined: Fruit and juice (cups)]: Int: 0.39 (0.02), Comp: 0.26 (0.02), p<0.001 ↑; [underlined: Fruit and juice (%)]: Int: 76% (3), Comp: 79% (3), p=NS; [underlined: Total vegetables (cups)]: Int: 0.17 (0.02), Comp: 0.10 (0.02), p<0.01 ↑; [underlined: Total vegetables (%)]: 53% (5), Comp: 52% (6), p=NS; [underlined: Dark green vegetables (cups)]: Int: 0.01 (0.00), Comp: 0.01 (0.00), p=NS; [underlined: Dark green vegetables (%)]: Int: 67% (10), Comp: 55% (9), p=NS; [underlined: Red orange vegetables (cups)]: Int: 0.03 (0.01), Comp: 0.03 (0.01), p=NS; [underlined: Red orange vegetables (cups)]: Int: 40% (8), Comp: 40% (9), p=NS; [underlined: Starchy vegetables (cups)]: Int: 0.10 (0.01), Comp: 0.06 (0.01), p<0.05 ↑; [underlined: Starchy vegetables (%)]: Int: 52% (6), Comp: 43% (7), p=NS; [underlined: Other vegetables (cups)]: Int: 0.03 (0.01), Comp: 0.02 (0.01), p=NS; [underlined: Other vegetables (%)]: Int: 29% (8), Comp: 30% (9), p=NS; [underlined: Legumes (cups)]: Int: 0.03 (0.01), Comp: 0.01 (0.01), p<0.01 ↑; [underlined: Legumes (%)]: Int: 66% (12), Comp: 41% (20), p=NS; [underlined: Grains (oz eq)]: Int: 2.13 (0.09), Comp: 2.43 (0.09), p<0.05 ↓; [underlined: Grains (%)]: Int: 83% (4), Comp: 100% (4), p<0.001 ↓; [underlined: Whole grains (oz eq)]: Int: 0.37 (0.04), Comp: 0.56 (0.04), p<0.01 ↓; [underlined: Whole grains (%)]: Int: 67% (4), Comp: 81% (4), p<0.05 ↓; [underlined: Protein foods (oz eq)]: Int: 1.84 (0.08), Comp: 2.05 (0.08), p=NS; [underlined: Protein foods (%)]: Int: 84% (3), Comp: 96% (3), p<0.01 ↓; [underlined: Milk (oz)]: Int: 4.68 (0.27), Comp: 5.07 (0.26), p=NS; [underlined: Milk (%)]: Int: 79% (10), Comp: 103% (10), p=NS; Model adjustments: Sex; school SES; Funding source(s): NIH, USDA/Agricultural Research Service
Folta, 2006,^28^ Shape Up Somerville: Audio Adventures; United States (Somerville, Massachusetts), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 8; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: Could not implement bean dishes in school; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: ~48%; Race/ethnicity: White: ~48%; Black: ~18%; Asian: ~7%; Native American: ~0.5%; Hispanic: ~26%; SES: Free/reduced price lunch: ~65% | Int: Introduction of variety of bean/legume dishes in school meals with a series of audio messages promoting bean/legume consumption (N=487 [81] students enrolled per school; Cluster N=3); Comp: Introduction of variety of bean/legume dishes in school meals (N=393 [91] students enrolled per school; Cluster N=3); Theory/framework: SCT; Theory of reasoned action; Intervention duration: ~3 mo; Outcome measurement: Choice of bean main dish (compared to standard main dish - hot dog) measured by direct observation by trained data collectors at the end of the cafeteria line on each day bean dishes were served | Choice of bean dish during intervention, OR (95% CI); [underlined: Choice of beans (all dishes)], Int vs Comp (ref): 0.93 (0.81, 1.07), p=0.31; [underlined: Choice of bean taco], Int vs Comp (ref): 0.96 (0.80, 1.14), p=0.61; [underlined: Choice of bean chili] , Int vs Comp (ref): 1.50 (1.12, 2.04), p=0.01 ↑; Note: Effects on bean dish selection varied by intervention dose delivered, with the intervention school with highest dose having greater odds of selection and intervention school with lowest dose having lower odds of selection (see paper for more detail); Model adjustments: Grade; sex; Funding source(s): General Mills’ Champions Youth Nutrition and Fitness Grant
French, 2004,^134^ Trying Alternative Cafeteria Options in Schools (TACOS); United States (Minneapolis–St Paul metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 20; Total Analytic Cluster N: 20; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school and High school; Age: NR; Female: NR; Race/ethnicity: Non-White: 14% (Range between schools: 3%-77%); SES: Eligible free/reduced price lunch: 9%, Range between schools: 1%-57% | Int: School-based environmental intervention to promote lower-fat food choices (N=NR; Cluster N=10); Comp: No intervention (N=NR; Cluster N=10); Theory/framework: NR; Intervention duration: 2 y; Outcome measurement: Lower-fat food sales collected on a weekly basis in electronic format from trained school food service staff during year 1 and year 2 of the intervention. Fruit and vegetable score created by summing responses to 6 questions on usual intake during past year; lower and higher fat food choices assessed with 6 and 22 questions respectively; assessed at baseline, and year 1 and 2 of the intervention with mailed survey (random sample 75 students/school) | Food choices at baseline (N~1,125), year 1 (N~1,125), and year 2 (N~1,155), Mean; [underlined: Fruit and vegetable score]; Int: 2.7, 2.9, 2.9; Comp: 2.8, 3.1, 3.1; Time by group interaction: p=0.95; [underlined: Low-fat/high-fat food choices]; Int: 0.29, 0.28, 0.28; Comp: 0.23, 0.26, 0.24; Time by group interaction: p=0.62; Lower-fat a la carte food sales; [underlined: Mean % of sales]; Year 1: Int: 27.5%, Comp: 19.6%, p=0.096; Year 2: Int: 33.6%, Comp: 22.1%, p=0.042 ↑; [underlined: Rate of increase in mean % of sales]; Year 1: Int: 10%, Comp: −2.8%, p=0.002 ↑; Year 2: Int: 2.0%, Comp: 1.2%, p=0.76; Model adjustments: Sex; grade; race/ethnicity; school (random effect); Funding source(s): NIH, CDC
Greene, 2017 ^135^; United States (Upstate New York), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 10; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Randomized to vegetable intervention group; Grade level: Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: White: 53%; Black: 26%; Hispanic: 14%; Other: 7%; SES: Participates in economic assistance program: 70% | Int1: Changes to the convenience, visibility, and attractiveness of fruit in the lunchroom to encourage students to make healthier food choices at school (N=NR; Cluster N=4); Int2: Changes to the convenience, visibility, and attractiveness of vegetables in the lunchroom to encourage students to make healthier food choices at school (Randomized group, but not analyzed in present paper) (N=NR; Cluster N=3); Comp: No changes to the lunchroom (N=NR; Cluster N=3); Theory/framework: Behavioral economics; Intervention duration: 6 wk; Outcome measurement: Trained field researchers visited each cafeteria pre-intervention (February) and during the intervention (March, April) to record tray waste using the quarter-waste method to visually estimate and record the remaining amount of each individual food item on trays of students who ordered a school lunch | Pre and post-intervention selection and intake (units of item), Mean (SE); [underlined: Fruit selection]; Int (Pre): 0.59 (0.59), Int (Post): 0.80 (0.61), p<0.001 ↑; Comp (Pre): 0.64 (0.64), Comp (Post): 0.50 (0.60), p<0.001 ↓; Difference-in-difference coefficient: 0.366, p<0.001 ↑; [underlined: Fruit consumption among those who selected fruit]; Int (Pre): 0.73 (0.50), Int (Post): 0.83 (0.48), p<0.001 ↑; Comp (Pre): 0.85 (0.55), Comp (Post): 0.71 (0.56), p<0.001 ↓; Difference-in-difference coefficient: 0.227, p=0.017 ↑; [underlined: Fruit consumption across all trays]; Int (Pre): 0.40 (0.52), Int (Post): 0.58 (0.55), p<0.001 ↑; Comp (Pre): 0.47 (0.59), Comp (Post): 0.32 (0.51), p<0.001 ↓; Difference-in-difference coefficient: 0.339, p=0.001 ↑; [underlined: Vegetable selection]; Int (Pre): 0.67 (0.74), Int (Post): 0.98 (0.83), p<0.001 ↑; Comp (Pre): 0.81 (0.76), Comp (Post): 0.89 (0.89), p=0.004 ↑; Difference-in-difference coefficient: 0.246, p=0.074; [underlined: Vegetable consumption among those who selected fruit]; Int (Pre): 0.57 (0.52), Int (Post): 0.86 (0.58), p<0.001 ↑; Comp (Pre): 0.80 (0.51), Comp (Post): 1.07 (0.69), p<0.001 ↑; Difference-in-difference coefficient: 0.062, p=0.701; [underlined: Vegetable consumption across all trays]; Int (Pre): 0.29 (0.47), Int (Post): 0.57 (0.63), p<0.001 ↑; Comp (Pre): 0.48 (0.56), Comp (Post): 0.61 (0.74), p<0.001 ↑; Difference-in-difference coefficient: 0.191, p=0.180; [underlined: White milk selection]; Int (Pre): 0.10 (0.30), Int (Post): 0.14 (0.35), p<0.001 ↑; Comp (Pre): 0.28 (0.46), Comp (Post): 0.21 (0.42), p<0.000 ↓; Difference-in-difference coefficient: 0.101, p=0.076; [underlined: White milk consumption among those who selected white milk]; Int (Pre): 0.76 (0.39), Int (Post): 0.76 (0.36), p=0.875; Comp (Pre): 0.84 (0.34), Comp (Post): 0.78 (0.37), p=0.006 ↓; Difference-in-difference coefficient: 0.091, p=0.259; [underlined: White milk consumption across all trays]; Int (Pre): 0.07 (0.25), Int (Post): 0.11 (0.30), p<0.001 ↑; Comp (Pre): 0.23 (0.41), Comp (Post): 0.17 (0.36), p<0.001 ↓; Difference-in-difference coefficient: 0.098, p=0.072; Note: Unit of analysis was trays (Int: N=4139, Comp: N=3613); Model adjustments: Race/ethnicity; SES; Funding source(s): USDA National Institute of Food and Agriculture, Childhood Obesity Prevention: Integrated Research, Education, and Extension to Prevent Childhood Obesity
He, 2009,^140^ Northern Fruit and Vegetable Pilot Programme (NFVPP); Canada, RCT-Cluster; Total Baseline N: 1,586; Total Analytic N: 1,277; Total Baseline Cluster N: 26; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Missing values, outliers; Grade level: Middle/Junior high school; Age (Mean (SD)): 11.6 y (1.2); Female: 55%; Race/ethnicity: NR; SES: NR | Int1: Free fruit and vegetable snacks 3 x/wk (N=470; Cluster N=9); Int2: Free fruit and vegetable snacks 3 x/week and enhanced nutrition education program (N=400; Cluster N=9); Comp: No intervention (N=407; Cluster N=8); Theory/framework: NR; Intervention duration: 21 wk; Outcome measurement: Intake measured via validated pre-coded 24-h fruit and vegetable recall questionnaire administered on days following fruit/vegetable distribution once at baseline and post-intervention | Post-intervention intake, Mean (SE); [underlined: Fruit and vegetables at school (svg/d)]: Int1: 1.8 (0.2), Int2: 1.9 (0.1), Comp: 1.4 (0.2); Int1 vs Comp: p>0.05, Int2 vs Comp: p<0.05 ↑, Int1 vs Int2: p>0.05; [underlined: Fruit and vegetables at home (svg/d)]: Int1: 2.5 (0.2), Int2: 2.5 (0.2), Comp: 2.4 (0.3); Int1 vs Comp: p>0.05, Int2 vs Comp: p>0.05, Int1 vs Int2: p>0.05; Model adjustments: Baseline intake; age; sex; school clustering effect; school location (urban vs rural); existing fruit and vegetable programme; Funding source(s): Ontario Ministry of Health Promotion
Johnston, 2011 ^136^; United States (Houston, Texas), RCT-Cluster; Total Baseline N: 78; Total Analytic N: 76; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: No longer at school; Grade level: Middle/Junior high school; Age (Mean (SD)): 12.1 (0.6) y; Female: ~53%; Race/ethnicity: Mexican American (total school population): 95%; SES: Eligible free/reduced price lunch (total school population): 81% | Int: Weekly provision of raw vegetable snacks (carrots, celery, broccoli) in class with peanut butter accompaniment in addition to weight-loss intervention (nutrition education and physical activity) (N=39; Cluster N=1); Comp: Weekly provision of raw vegetable snacks (carrots, celery, broccoli) in class with no accompaniment in addition to weight-loss intervention (nutrition education and physical activity) (N=37; Cluster N=1); Theory/framework: NR; Intervention duration: 4 mo; Outcome measurement: Intake measured by weighing bags of vegetables provided to children following consumption and variety (0-3 types) consumed by visual inspection on 3 d; vegetable resistance (no report of vegetable intake over 7 d) assessed with Block Dietary Data Systems | Vegetable intake (oz) at baseline and post-intervention, Mean; Baseline: Int: 1.33, Comp: 1.83; Follow-up: Int: 1.74, Comp: 1.45; Difference in change between groups: p<0.001 ↑; Among vegetable resistant children (n=39): p<0.05 ↑; Vegetable variety (types) at baseline and post-intervention; Baseline and follow-up: NR; Difference in change between groups: p<0.001 ↑; Among vegetable resistant children (n=39): p<0.01 ↑; Model adjustments: None; Funding source(s): USDA Agricultural Research Service
Kocken, 2012 ^137^; The Netherlands, RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 40; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: Withdrawal of caterers responsible for vending machines, incomplete data registration; Grade level: Middle/Junior high school and High school; Age: NR; Female: NR; Race/ethnicity: NR; SES: NR | Int: Intervention promoting the sale of lower-calorie food products from school vending machines in 3 successive 6 wk phases (1: increasing availability of lower-calorie products; 2: labeling products as favorable, moderately unfavorable, or favorable; 3: reducing price of lower-calorie products) (N=778 [484] students enrolled per school; Cluster N=13); Comp: No changes to school vending machines (N=833 [504] students enrolled per school; Cluster N=15); Theory/framework: NR; Intervention duration: 18 wk; Outcome measurement: During all 3 phases, records were kept of sales from the vending machines. Sales were registered using standard registration forms which included a standardized list of almost 400 different products that were categorized by the Dutch Nutrition Centre according to the 3 food groups (extra foods, beverages, and basic foods), and the 3 categories (favorable, moderately unfavorable, and favorable). | Products sold during phases 1, 2, and 3 of intervention, Mean Proportions (%) (SD) and Mean Change in Proportions (%) (SD); [underlined: Extra Foods (snacks containing empty calories): Favorable (<100 kcal)]; Phase 1: Int: 1.6 (1.9) vs Comp: 0.9 (1.5), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 1: Not allowed: Int: 3.6 vs Comp: 0.4, Allowed: Int: 1.2 vs Comp: 1.6, p<0.05 ↑; Phase 2: Int: 1.9 (1.8) vs Comp: 0.8 (1.1), p=NS; Change from Phase 1 to Phase 2: Int: 0.2 (0.7) vs Comp: −0.1 (1.3), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 2: Not allowed: Int: 4.1 vs Comp: 0.8, Allowed: Int: 1.3 vs Comp: 1.1, p<0.05 ↑; Phase 3: Int: 1.2 (1.1) vs Comp: 0.8 (1.2), p=NS; Change from Phase 2 to Phase 3: Int: −0.2 (1.2) vs Comp: 0.0 (0.8), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 3: p=NS; [underlined: Extra Foods: Moderately unfavorable (100-170 kcal)]; Phase 1: Int: 44.2 (15.3) vs Comp: 20.1 (7.8), p<0.05 ↑; Phase 2: Int: 44.9 (13.5) vs Comp: 18.3 (8.1), p<0.05 ↑; Change from Phase 1 to Phase 2: Int: 0.8 (4.3) vs Comp: −1.8 (7.9), p=NS; Phase 3: Int: 46.5 (14.0) vs Comp: 19.7 (9.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: 2.6 (7.0) vs Comp: 1.4 (5.8), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Extra Foods: Unfavorable (>170 kcal)]; Phase 1: Int: 54.2 (16.4) vs Comp: 78.9 (7.6), p<0.05 ↑; Phase 2: Int: 53.2 (14.1) vs Comp: 80.8 (8.3), p<0.05 ↑; Change from Phase 1 to Phase 2: Int: −1.0 (4.4) vs Comp: 1.9 (8.2), p=NS; Phase 3: Int: 52.3 (14.1) vs Comp: 79.4 (8.6), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: −2.4 (8.0) vs Comp: −1.4 (5.5), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Beverages: Favorable (Light drinks, waters, fruit juices)]; Phase 1: Int: 38.3 (15.9) vs Comp: 22.4 (15.3), p<0.10; Phase 2: Int: 37.2 (14.0) vs Comp: 26.0 (14.1), p<0.10; Change from Phase 1 to Phase 2: Int: −1.1 (9.3) vs Comp: 3.7 (7.3), p=NS; Phase 3: Int: 42.2 (14.4) vs Comp: 26.6 (15.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: 4.5 (6.0) vs Comp: 0.6 (5.9), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Beverages: Unfavorable (Regular soft drinks, sweetened fruit juices)]; Phase 1: Int: 61.7 (15.9) vs Comp: 77.6 (15.3), p<0.10; Phase 2: Int: 62.8 (14.0) vs Comp: 74.0 (14.1), p<0.10; Change from Phase 1 to Phase 2: Int: 1.1 (9.3) vs Comp: −3.7 (7.3), p=NS; Phase 3: Int: 57.8 (14.4) vs Comp: 73.4 (15.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: −4.5 (6.0) vs Comp: −0.6 (5.9), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; Model adjustments: Number of shops in school surroundings; Funding source(s): The Netherlands Organization for Health Research and Development
Lai, 2020 ^32^; United States (Chicago Heights, Illinois), RCT-Cluster; Total Baseline N: 17,346 observations; Total Analytic N: 14,130 observations (Children contributed multiple observations); Total Baseline Cluster N: 28; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: Experimenter or teacher error, data recording error, child not following directions; Grade level: Elementary and Middle/Junior high school; Age: NR; Female: 51%; Race/ethnicity: White: 4%; Black: 39%; Hispanic: 57%; Multiracial: 1%; SES: Eligible for free or reduced-price school lunch: ~95% | Int1: Verbal prompt in cafeteria line (N=548 children, 2,882 observations; Cluster N=NR); Int2: Health prompt in cafeteria line (N=582 children, 3,034 observations; Cluster N=NR); Int3: Taste prompt in cafeteria line (N=515 children, 2,866 observations; Cluster N=NR); Int4: Incentives attached to white milk cartons in cafeteria line with no prompt (N=539 children, 2,494 observations; Cluster N=NR); Comp: No intervention (N=466 children, 2,854 observations; Cluster N=NR); Theory/framework: Rational Choice Theory; Intervention duration: 5 d; Outcome measurement: Food selection and consumption during lunch recorded by researchers; milk intake calculated by weight and food consumption by visual inspection | Difference in selection of white milk over chocolate milk, β (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: 2.22 (0.59), p<0.01 ↑; Int2 vs Comp: 2.16 (0.65), p<0.01 ↑; Int3 vs Comp: 1.52 (0.69), p<0.01 ↑; Int4 vs Comp: 2.52 (0.37), p<0.01 ↑; Int1, Int2, and Int3 vs Comp: p<0.01 ↑; Int4 vs Comp: p<0.01 ↑; Int1 vs Int2: p=0.94; Int1 vs Int3, p=0.41; Int2 vs Int3, p=0.44; Int1 vs Int4, Int2 vs Int4, Int3 vs Int4: all p>0.10; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: 1.39 (0.39); p<0.01 ↑; Int2 vs Comp: 1.31 (0.48); p<0.01 ↑; Int3 vs Comp: 0.80 (0.49); p=0.11; Int4 vs Comp: 1.45 (0.45); p<0.01 ↑; Difference in milk intake (mL), β (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: −7.20 (7.17), p=NS; Int2 vs Comp: −5.57 (11.31), p=NS; Int3 vs Comp: −4.56 (7.00), p=NS; Int4 vs Comp: −20.16 (6.58), p<0.01 ↓; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: 3.88 (5.81), p=NS; Int2 vs Comp: −4.67 (11.66), p=NS; Int3 vs Comp: −13.24 (11.31), p=NS; Int4 vs Comp: −24.76 (10.03), p<0.05 ↓; Difference in added sugars intake (g), β (SE); [underlined: During intervention (study days 3-7)]; Int1 vs Comp: −0.52 (0.25), p<0.05 ↑; Int2 vs Comp: −0.66 (0.27), p<0.05 ↑; Int3 vs Comp: −0.63 (0.28), p<0.05 ↑; Int4 vs Comp: −1.56 (0.53), p<0.01 ↑; [underlined: Post-treatment (study days 8-9)]; Int1 vs Comp: −0.05 (0.18), p=NS; Int2 vs Comp: −0.34 (0.38), p=NS; Int3 vs Comp: −0.61 (0.32), p<0.1 ↑; Int4 vs Comp: −0.98 (0.44), p<0.05 ↑; Model adjustments: Baseline white milk intake; Funding source(s): Cornell Center for Behavioral Economics and Child Nutrition Programs
Prell, 2005 ^139^; Sweden, RCT-Cluster; Total Baseline N: 390; Total Analytic N: 228; Total Baseline Cluster N: 5; Total Analytic Cluster N: 5; Criteria for exclusion from analysis: Did not complete baseline and/or follow-up questionnaires; Grade level: Middle/Junior high school; Age (Mean): ~ 14 y; Female: 47%; Race/ethnicity: Native country is Sweden: ~90%; SES: NR | Int1: School canteen modification to increase fish intake (N=58; Cluster N=2); Int2: Modifications to the school canteen and home economics syllabus to increase fish intake (N=87; Cluster N=2); Comp: No intervention (N=83; Cluster N=1); Theory/framework: TPB; Intervention duration: 1 school y; Outcome measurement: Fish intake measured individually by structured observations in the school canteen 1 x/wk when fish was served for 5 wk; children were categorized as noneaters, tasters, or eaters of fish; assessed at baseline and ~1 y follow-up | Fish intake, Relative Position (95% CI)*; Int1: 0.10 (−0.02, 0.22); Int2: 0.15 (0.06, 0.24); Comp: −0.08 (−0.17, 0.01); Int1 vs Comp, p=NS; Int2 > Comp, p=Sig ↑ (value NR); Note: Results were similar when analyzed separately for girls and boys.; *Relative position ranges from −1 to 1. Values close to 0 indicate a lack of systematic disagreement between baseline and follow-up data, and positive values indicate an increase in consumption. No overlap of confidence intervals between groups indicates significance.; Model adjustments: None; Funding source(s): Kunskapsplattform for Livsmedelsbranschen
Raju, 2010 ^39^; United States, RCT-Cluster; Total Baseline N: ~31,000; Total Analytic N: NR (646 of 1,659 homerooms with complete data); Total Baseline Cluster N: 55; Total Analytic Cluster N: 55; Criteria for exclusion from analysis: Missing data; Grade level: Elementary and Middle/Junior high school; Age (Range): 5-14y; Female: NR; Race/ethnicity: NR; SES: NR | Int1: Personal pledge and incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=NR); Int2: Competition and incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=); Comp: Only incentives for selecting ≥2 fruit and/or vegetables (N=NR; Cluster N=NR); Theory/framework: Behavior modification theories; Intervention duration: 6 wk; Outcome measurement: Fruit and vegetable choice: trained cafeteria staff kept record of whether students chose ≥2 fruit and/or vegetables during lunch at 1-wk follow-up and 10-wk follow-up; unit of analysis was the proportion of students at the homeroom level | Selection of ≥2 fruits and/or vegetables at lunch, Change in proportion from baseline to 10-wk follow-up*; [underlined: Younger children (Grades 1-2)]:; Int1: 0.08, Int2: 0.24, Comp: 0.09; Int1 vs Comp, Pr=NS; Int2 > Comp, Pr>0.95 ↑; Int1 < Int2, Pr>0.95 ↑; [underlined: Older children (Grades 3-8)]:; Int1: 0.07, Int2: 0.11, Comp: 0.03; Int1 > Comp, Pr>0.95 ↑; Int2 > Comp, Pr>0.90 ↑; Int1 < Int2, Pr>0.95 ↑; *Pr = posterior probability (Pr>0.95 analogous to p<0.05); Model adjustments: Baseline proportion of students choosing fruits and vegetables; homeroom; school; Funding source(s): NR
Shemilt, 2004 ^44^; United Kingdom, RCT-Cluster; Total Baseline N: 6,076; Total Analytic N: 3,008 at 3 mo, 3,007 at 12 mo; Total Baseline Cluster N: 41; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Missing data, children originally in grade 6 and 11 no longer attending intervention or control schools; Grade level: Elementary and Middle/Junior high school; Age (Mean): ~10 y; Female: ~50%; Race/ethnicity: White: ~93%; Black: ~1%; Asian: ~6%; SES: Eligible for free school meals: ~34% | Int: Funding to start school breakfast club (N=1,504 at 3 mo, N=1,676 at 12 mo; Cluster N=15); Comp: No intervention (N=1,504 at 3 mo, N=1,331 at 12 mo; Cluster N=11); Theory/framework: NR; Intervention duration: 1 y; Outcome measurement: Intake assessed with questionnaire developed by researchers and based on the WHO Health Behaviour in School-Aged Children Questionnaire and European Network of Health Promoting Schools Questionnaire; administered by school staff at baseline, after 3 mo of intervention, and after 12 mo of intervention | Has fresh fruit for breakfast after 3 mo and 12 mo of intervention, % and OR (CI); [underlined: 3 mo]: Int: 13%, Comp: 17%; Int vs Comp (ref): 0.74 (0.53, 1.02); [underlined: 12 mo]: Int: 12%, Comp: 13%; Int vs Comp (ref): 0.97 (0.68, 1.38); Model adjustments: School type; baseline intake; sex; eligibility for free school meals; Funding source(s): United Kingdom Department of Health National Health Service Executive
Wansink, 2013 ^138^; United States (Wayne County, New York), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 6; Total Analytic Cluster N: 6; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: NR; authors note Wayne County is predominantly white; SES: Free/reduced-price lunch participation (Range): 13-44% per school | Int: Pre-sliced apples in cafeteria (N=NR; Cluster N=3); Comp: No intervention – whole apples (N=NR; Cluster N=3); Theory/framework: Behavioral economics; Intervention duration: 1 wk; Outcome measurement: Tray waste measured on 2 separate days (a few days after introduction of intervention and ~1 wk after initial visit) to assess apple sales, apple consumption, and apple waste | Post-intervention behavior, %; [underlined: Fruit sales per day (N=334)]: Int: 10.0% vs Comp: 6.0%, p=0.31; [underlined: Fruit eaten per student (N=306)]: Int: 73.0% vs Comp: 49.0%, p=0.09; [underlined: Fruit wasted per student (N=334)]: Int: 31.0% vs Comp: 51.0%, p=0.11; [underlined: Students consuming more than half of apples (N=306)]: Int: 71.0% vs Comp: 40.0%, p=0.02 ↑; [underlined: Students wasting half or more of apples (N=334)]: Int: 32.0% vs Comp: 60.0%, p=0.02 ↑; Model adjustments: None; Funding source(s): USDA

a Abbreviations: β: beta; CDC: Centers for Disease Control and Prevention; CI: confidence interval; Comp: comparator; d: day; g: gram; h: hour; kcal: kilocalorie; Int: intervention; mL: milliliter; mo: month; N: sample size; NIH: National Institute of Health; NR: not reported; NS: non-significant; OR: odds ratio; oz; ounce; oz eq: ounce equivalent; p: p-value; RCT: randomized controlled trial; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; TPB: Theory of Planned Behavior; USDA: United States Department of Agriculture; vs: versus; wk: week; x: time(s); y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator

Table 12 Risk of bias for randomized controlled trials examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Cohen, 2015^24^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Coleman, 2012^25^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Cullen, 2015^26^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Folta, 2006^28^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
French, 2004^134^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Greene, 2017^135^ | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS
He, 2009^140^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Johnston, 2011^136^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Kocken, 2012^137^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Lai, 2020^32^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Prell, 2005^139^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS
Raju, 2010^39^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Shemilt, 2004^44^ | LOW | LOW | HIGH | LOW | LOW | SOME CONCERNS
Wansink, 2013^138^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a All studies cluster-RCTs

Table 13 Evidence examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Teens Eating for Energy and Nutrition at Schools (TEENS)
Birnbaum, 2002,^143^ TEENS; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: 3,878; Total Analytic N: 3,503; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Absent from school during survey or parent/student refusal; Grade level: Middle/Junior high school; Age: NR; Female: ~49%%; Race/ethnicity: White: 68.7%; Black: 10.4%; Asian or Pacific Islanders: 6.9%; Multi-racial: 5.6%; Other: 8.5%; SES: Parents’ highest education: Both HS or less: ~13%, One HS or less: ~5%, One trade school/some college: ~17%, One college or more: ~19%, Both college or more: ~21%, Other/unknown: ~25% | Int1: Exposed only to improvements to offerings and promotion of fruits and vegetables and healthier à la carte snacks at school (N=845; Cluster N=NR); Int2: Exposed to nutrition education and offerings and promotion of fruits and vegetables and healthier à la carte snacks at school (N=677; Cluster N=NR); Int3: Children selected as peer leaders and exposed to nutrition education and offerings and promotion of fruits and vegetables and healthier à la carte snacks at school (N=226; Cluster N=NR); Comp: No intervention wait list control (N=1,755; Cluster N=8); Theory/framework: SCT; Intervention duration: 1 y; Outcome measurement: Intake measured via modified and validated version of Behavioral Risk Factor Surveillance System administered by trained staff at baseline and after 1 y of the 2 y intervention | Intake at baseline and 1 y (svg/d), Mean (SD); [underlined: Fruit and vegetable intake]; Time by Group interaction: p=0.023; Int1: Baseline: 4.76 (0.03), 1 y: 4.44 (0.04), Change: p=0.135; Int2: Baseline: 4.51 (0.04), 1 y: 4.95 (0.04), Change: p=0.056; Int3: Baseline: 4.88 (0.06), 1 y: 5.80 (0.05), Change: p=0.012 ↑; Comp: Baseline: 4.76 (0.04), 1 y: 4.80 (0.03), Change: p=0.801; [underlined: Fruit intake]; Time by Group interaction: p=0.014 ↑; Int1: - slope, Change: p=0.087; Int2: + slope, Change: p=0.052; Int3: + slope, Change: p=0.01 ↑; Comp: Change: p=0.742; [underlined: Vegetable intake]; Time by Group interaction: p=0.107; Int1: Change: p=0.300; Int2: + slope, Change: p=0.097; Int3: + slope, Change: p=0.059; Comp: Change: p=0.895; Model adjustments: Race; parent’s education; Funding source(s): National Cancer Institute
Lytle, 2004,^149^ TEENS; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: 640 for recall, 3,878 for survey; Total Analytic N: 455 for recall, 2,883 for survey; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Absent from school during survey or parent/student refusal, not randomly selected for 24-h recall; Grade level: Middle/Junior high school; Age: NR; Female: 0.51%; Race/ethnicity: White: 68.4%; Black: 8.4%; Asian/Pacific Islander: 8.4%; Native American: 1.5%; Hispanic/Latino: 3.1%; Multiracial: 5.1%; Other: 5.3%; SES: Receives free/reduced price lunch: 22.9% | Int: Nutrition education, parent newsletters/behavioral coupons, and improvements to offerings and promotion of fruits and vegetables and healthier ala carte snacks at school (N=288 for 24-h recall; N=1,452 for survey; Cluster N=8); Comp: No intervention wait list control (N=167 for 24-h recall, N=1,431 for survey; Cluster N=8); Theory/framework: SCT; Intervention duration: 2 y; Outcome measurement: Intake measured via modified and validated version of Behavioral Risk Factor Surveillance System administered by trained staff in full cohort and via 24-h recall administered via trained/certified interviewers in a subcohort of children at baseline, after 1 y of intervention, and post-intervention | Intake at post-intervention (24-h recall), Mean and Mean difference (95% CI); [underlined: Total fruits and vegetables (svg)]: Int: 3.60, Comp: 4.09;; Int vs Comp (ref): −0.492 (−1.032, 0.049); [underlined: Fruits and vegetables excluding potatoes (svg)]: Int: 2.62, Comp: 2.94;; Int vs Comp (ref): −0.326 (−0.910, 0.259); [underlined: Fruits and vegetables (svg/1000 kcal)]: Int: 1.67, Comp: 1.81;; Int vs Comp (ref): −0.141(−0.425, 0.144); [underlined: Fruits (svg)]: Int: 1.48, Comp: 1.62;; Int vs Comp (ref): −0.143 (−0.711, 0.425); [underlined: Vegetables including potatoes (svg)]: Int: 2.08, Comp: 2.46;; Int vs Comp (ref): −0.383 (−1.000, 0.233); Intake at post-intervention (survey), Mean and Mean difference (95% CI); [underlined: Fruit score]: Int: 2.34, Comp: 2.40; Int vs Comp (ref): −0.060 (−0.309, 0.190); [underlined: Vegetable score]: Int: 1.73, Comp: 1.70; Int vs Comp (ref): 0.031 (−0.250, 0.312); Model adjustments: Sex; race; household structure; parental work status; parental educational attainment; receiving free or reduced-price lunch; baseline intake; total energy intake; Funding source(s): National Cancer Institute
Lytle, 2004,^149^ TEENS; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; ([underlined: Note:] Continued from Lytle, 2004 above; analyses stratified by intervention components received); Total Baseline N: 640 for recall, 3,878 for survey; Total Analytic N: 455 for recall, 2,883 for survey; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Criteria for exclusion from analysis: Absent from school during survey or parent/student refusal, not randomly selected for 24-h recall, exposed to education during 7th or 8th grade but not both years; Grade level: Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: NR; SES: NR | Int1: Exposed to both nutrition education, parent newsletters and behavioral coupons, and improvements to offerings and promotion of fruits and vegetables and healthier ala carte snacks at school during both 7th and 8th grade (N=NR; Cluster N=NR); Int2: Exposed to improvements to offerings and promotion of fruits and vegetables and healthier ala carte snacks at school only (N=NR; Cluster N=NR); Comp: No intervention wait list control (N=167 for 24h recall, N=1,431 for survey; Cluster N=8); Theory/framework: SCT; Intervention duration: 2 y; Outcome measurement: Intake measured via modified and validated version of Behavioral Risk Factor Surveillance System administered by trained staff in full cohort and via 24 h recall administered via trained/certified interviewers in a subcohort of children at baseline, after 1 y of intervention, and post-intervention | Intake at post-intervention (24-h recall), Mean and Mean difference (95% CI); [underlined: Total fruits and vegetables (svg)]: Int1: 3.93, Int2: 3.83, Comp: 4.10; Int1 vs Comp (ref): −0.16 (−0.57, 0.25); Int2 vs Comp (ref): −0.26 (−1.21, 0.68); Intake at post-intervention (survey), Mean and Mean difference (95% CI); [underlined: Fruit and vegetable score]: Int1: 4.15, Int2: 3.78, Comp: 4.14; Int1 vs Comp (ref): 0.01 (−0.34, 0.35); Int2 vs Comp (ref): −0.36 (−0.93, 0.21); Model adjustments: Sex; race; household structure; parental work status; parental educational attainment; receiving free or reduced-price lunch; baseline intake; total energy intake; Funding source(s): National Cancer Institute
Lytle, 2006,^148^ TEENS; United States (Twin Cities metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 16; Total Analytic Cluster N: 13; Criteria for exclusion from analysis: No a la carte line at school; Grade level: Middle/Junior high school; Age: NR; Female: ~51%%; Race/ethnicity: White: 72.9%; SES: Lower SES (based on qualifying for free/reduced price lunch and parental education/occupation): 19.8% | Int: Nutrition education, parent newsletters/behavioral coupons, and improvements to offerings and promotion of fruits and vegetables and healthier ala carte snacks at school (N=NR; Cluster N=8); Comp: No intervention wait list control (N=NR; Cluster N=5); Theory/framework: SCT; Intervention duration: 2 y; Outcome measurement: Purchases of “foods to promote” (5 g or less of fat, 100% fruit juice, water and low fat milk, fruits or vegetables, other lower fat versions of popular entrees) and “foods to limit” assessed by observation by study staff for 5 d at baseline and post-intervention | Sales of foods to promote and limit at baseline and post-intervention, %; [underlined: Foods to promote]:; Baseline: Int: 10%, Comp: 4%; Follow-up: Int: 36%, Comp: 18%; [underlined: Foods to limit]:; Baseline: Int: 90%, Comp: 96%; Follow-up: Int: 64%, Comp: 82%; Difference in proportion at follow-up: p=0.07 (one-tailed test); Model adjustments: None; Funding source(s): National Cancer Institute, Minnesota Obesity Center
Unnamed Study - China
Wang, 2015 ^132^; China, RCT-Cluster; Total Baseline N: 195; Total Analytic N: 188; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Did not complete baseline and/or follow-up questionnaires, did not participate in interventions as required; Grade level: Middle/Junior high school; Age (Mean (SD)): 12.8 (0.45) y; Female: 52%; Race/ethnicity: Han nationality: 88%; Minority nationality: 12%; SES: Parent education: Junior school or lower: 6%; Middle school: 68%; High school: 21%; College/University or higher: 5% | Int1: Health promotion program including weekly curriculum, monthly peer support activities, monthly school nutrition group, posters to publicize healthy eating, informational brochures, and parent involvement (N=62; Cluster N=1); Int2: Health education curriculum only (N=65; Cluster N=1); Comp: No intervention (N=61; Cluster N=1); Theory/framework: WHO socio-ecological framework; Intervention duration: 3 mo; Outcome measurement: Eating behavior score measured using a questionnaire on the weekly consumption of fresh fruit, vegetables, dairy products, breakfast, dessert, fried food, and soft drinks (scale 0-7); assessed at baseline and after 3 mo of the 6 mo intervention | Eating behavior score (food consumption), Mean and Mean change; Baseline: Int1: 3.16, Int2: 2.78, Comp: 2.64; 3 mo: Int1: 4.13, Int2: 3.54, Comp: 3.02; Change: Int1: 0.97, Int2: 0.76, Comp: 0.38; Between group comparisons: p=0.000 ↑; Model adjustments: None; Funding source(s): Griffith University School of Public Health
Wang, 2017 ^151^; China, RCT-Cluster; Total Baseline N: 130; Total Analytic N: 123; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Did not complete questionnaires; Grade level: Middle/Junior high school; Age (Mean (SD)): 12.7 (0.5) y; Female: 50%; Race/ethnicity: Han nationality: 87.8%; SES: NR | Int: Health promotion program including 26 weekly 15-min nutrition curriculum sessions delivered by trained teachers, 6 monthly 30-min peer support activities, informational brochure distributed twice during the intervention, monthly school nutrition group, posters to publicize healthy eating, and parent involvement (N=62; Cluster N=1); Comp: No intervention (N=61; Cluster N=1); Theory/framework: WHO socio-ecological framework; Intervention duration: 6 mo; Outcome measurement: Self-administered food frequency questionnaire to assess intake during the past week based on the 2004 China Adolescent Behavioural Risk Factor Survey. Administered in the classroom pre-intervention (July 2012) and post-intervention (June 2013) | Intake at post-intervention, OR (95% CI); Int vs Comp (ref); [underlined: No soft drinks:] 1.994 (1.310, 3.035), p=0.001 ↑; [underlined: No desserts:] 3.959 (2.426, 6.462), p=0.000 ↑; [underlined: No fried foods:] 3.634 (2.256, 5.852), p=0.000 ↑; [underlined: Fresh fruits daily:] 1.334 (0.871, 2.042), p=0.185; [underlined: Vegetables daily:] 2.512 (1.407, 4.484), p=0.002 ↑; [underlined: At least one glass of milk daily:] 1.422 (0.878, 2.303), p=0.152; Model adjustments: None; Funding source(s): Griffith University, School of Public Health
Unnamed Study - Finland
Anttonen, 2011 ^141^; Finland, RCT-Cluster; Total Baseline N: 739; Total Analytic N: 700; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Lost to follow-up; Grade level: Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: NR; SES: NR | Int: School intervention over one academic year focused on reducing intake of sugar, increasing intake of fiber, fruits, and vegetables, and improving quality of snacks eaten during the school day through nutrition education and environmental strategies. (Two schools also received a brief dental hygiene intervention.) (N=360; Cluster N=6); Comp: No intervention (N=340; Cluster N=6); Theory/framework: SCT; Intervention duration: 1 school y; Outcome measurement: Intake and habits assessed with computer-assisted questionnaire administered under the supervision of a dental nurse at baseline and post-intervention | Dietary habits at baseline and post-intervention, %; [underlined: Consumes warm course at lunch every day or almost every day]; Baseline: Int: 85.3%, Comp: 84.8%; Post-intervention: Int: 88.5%, Comp: 78.9%; p=0.024 ↑; [underlined: Consumes salad and raw vegetables at lunch every day or almost every day]; Baseline: Int: 61.5%, Comp: 53.8%; Post-intervention: Int: 58.3%, Comp: 51.7%; p=NS; [underlined: Consumes bread at lunch every day or almost every day]; Baseline: Int: 38.5%, Comp: 36.5%; Post-intervention: Int: 54.3%, Comp: 42.4%; p<0.001 ↑; [underlined: Generally juice or fizzy drinks for quenching thirst at school]; Baseline: Int: 21.3%, Comp: 17.0%; Post-intervention: Int: 18.2%, Comp: 25.4%; p=0.004 ↑; [underlined: Generally juice or fizzy drinks for quenching thirst at home]; Baseline: Int: 54.3%, Comp: 48.0%; Post-intervention: Int: 56.3%, Comp: 53.3%; p=NS; [underlined: Sweets every day or almost every day]; Baseline: Int: 6.3%, Comp: 5.1%; Post-intervention: Int: 1.7%, Comp: 5.3%; p=0.051; [underlined: Total dietary score]; Data NR, p=NS; Model adjustments: None; Funding source(s): Finnish Innovation Fund Sitra, National Public Health Institute of Finland, Finnish Bread Information, Finnish Heart Association, University of Oulu
Hoppu, 2010 ^145^; Finland, RCT-Cluster; Total Baseline N: 769; Total Analytic N: 659 for questionnaire, 287 for 48-h recall; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Did not complete baseline and/or follow-up questionnaires, not selected for 48-h diet recall; Grade level: Middle/Junior high school; Age (Mean): 13.8 y; Female: 56%; Race/ethnicity: NR; SES: Parent education (University degree): ~20% | Int: A school-based intervention with nutrition education and improvement of food environment (N=338 for questionnaire, N=147 for 48-h recall; Cluster N=6); Comp: No intervention (N=321 for questionnaire, N=140 for 48-h recall; Cluster N=6); Theory/framework: SCT; Intervention duration: 1 school y (~9 mo); Outcome measurement: Eating habits and frequency of food use measured using structured questionnaires mailed to children’s homes at baseline and post-intervention; a randomly selected subgroup completed computer-assisted 48-h diet recalls performed at school by trained nutritionists | Change (decrease, increase, stay the same) in intake frequency; [underlined: Rye bread]: >Girls: Int > Comp, p=0.03 ↑; Boys: Int vs Comp, p=NS; [underlined: Sweets]: Girls: Int < Comp, p=0.006 ↑; Boys: Int vs Comp, p=NS; [underlined: Vegetables]: Girls: Int vs Comp, p=NS; Boys: Int vs Comp, p=NS; [underlined: Fruit]: Girls: Int vs Comp, p=NS; Boys: Int vs Comp, p=NS; Change in consumption at school for snack (% consuming); [underlined: Bread]: Girls: Int vs Comp, p=NS; Boys: Int vs Comp, p=NS; [underlined: Sweets]: Girls: Int < Comp, p=0.03 ↑; Boys: Data NR; [underlined: Fruit]: Girls: Int vs Comp, p=NS; Boys: Int vs Comp, p=NS; [underlined: Sugary soft drinks]: Girls: Data NR; Boys: Int < Comp, p=0.03 ↑; Vegetable and fruit intake (48-h recall), Change from baseline; [underlined: Vegetables (g)]: Int: 3, Comp: −4, p=NS; [underlined: Vegetables (g/MJ)]: Int: 2, Comp: 0, p=NS; [underlined: Fruit (g)]: Int: −5, Comp: −29, p=NS; [underlined: Fruit (g/MJ)]: Int: 29, Comp: −6, p=0.04 ↑; Nutrient intake (48-h recall), Change from baseline; [underlined: Sucrose (% energy)]: Int:-2.3, Comp: 0.1, p=0.01 ↑; [underlined: Fiber (g/MJ)]: Int: 0.0, Comp: 0.0, p=NS; Model adjustments: School; Funding source(s): SITRA (Finnish Innovation Fund)
Individual studies (alphabetized by author)
Bere, 2006,^142^ Fruits and Vegetables Make the Marks (FVMM); Norway, RCT-Cluster; Total Baseline N: 577; Total Analytic N: 517; Total Baseline Cluster N: 19; Total Analytic Cluster N: 19; Criteria for exclusion from analysis: Not able to participate at post-intervention or 1-y follow-up, inconsistent responses; Grade level: Middle/Junior high school; Age (Mean): 11.3 y; Female: 48%; Race/ethnicity: NR; SES: NR | Int: (i) Classroom education, (ii) parental involvement, and (iii) a free fruit and vegetable subscription program (N=286; Cluster N=9); Comp: Paid fruit and vegetable subscription program (N=231; Cluster N=10); Theory/framework: SCT; Intervention duration: ~8-9 mo; Outcome measurement: Validated 24-h fruit and vegetable recall for a school day read aloud to the pupils by a project worker conducted at baseline, at post-intervention, and 1-y follow-up | Intake at post-intervention and 1-y follow-up, Adjusted Mean (95% CI); [underlined: Fruit and vegetables at school (portions/d)]:; Post-intervention: Int: 0.84 (0.68, 1.00), Comp: 0.27 (0.11, 0.43); Int vs Comp: p<0.001 ↑; 1-y follow-up: Int: 0.39 (0.23, 0.54), Comp: 0.18 (0.04, 0.33); Int vs Comp: p=0.07; [underlined: Fruit and vegetables all day (portions/d):]; Post-intervention: Int: 2.47 (2.11, 2.83), Comp: 1.84 (1.49, 2.19); Int vs Comp: p=0.02 ↑; 1-y follow-up: Int: 2.09 (1.76, 2.42), Comp: 1.57 (1.24, 1.89); Int vs Comp: p=0.03 ↑; Model adjustments: Baseline scores; gender; school; pupils’ habitual fruit and vegetable intake; preferences; parent’s educational level; household income; Funding source(s): Norwegian Research Council, Free fruit made possible by the Norwegian Fruit and Vegetable Marketing Board
Bogart, 2014,^144^ Students for Nutrition and eXercise (SNaX); United States (Los Angeles, California), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 10; Total Analytic Cluster N: 10; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school; Age: NR; Female: NR; Race/ethnicity: Latino: 75%; Asian/Pacific Islander: 5%; Black: 14%; White: 6%; SES: NSLP Eligible (Mean): 84% | Int: Multicomponent obesity-prevention intervention combining school-wide environmental changes, multimedia, encouragement to eat healthy school cafeteria foods, and peer-led education (7th grade only) (N=1,515 [323] per school; Cluster N=5); Comp: Wait-list control (N=1,524 [266] per school; Cluster N=5); Theory/framework: SCT; Intervention duration: 5 wk; Outcome measurement: Each school provided cafeteria participation records (number of fruit and vegetables served) and school store sales data (number of snacks sold) for each day of the intervention semester. Totals were divided by the number of students in attendance to derive proportions representing number of fruit and vegetables and meals served, and number of snacks sold, per student each day. Means of each proportion over the days before, during, and after the intervention were calculated. | Pre, during, and post-intervention proportion served or sold per child, Mean (SD) and Adjusted Mean Difference in Change (SE); [underlined: Cafeteria fruit servings]; Int: Pre: 0.45 (0.25), During: 0.54 (0.21), Post: 0.45 (0.18); Comp: Pre: 0.54 (0.17), During: 0.55 (0.15), Post: 0.49 (0.13); During: Int vs Comp (ref): 0.07 (0.03), p<0.01 ↑; Post: Int vs Comp (ref): 0.04 (0.02), p<0.10; [underlined: Cafeteria vegetable servings]; Int: Pre: 0.18 (0.08), During: 0.18 (0.04), Post: 0.15 (0.05); Comp: Pre: 0.20 (0.09), During: 0.19 (0.09), Post: 0.19 (0.10); During: Int vs Comp (ref): 0.004 (0.03), p=NS; Post: Int vs Comp (ref): −0.02 (0.02), p=NS; [underlined: Snack sales]; Int: Pre: 0.41 (0.18), During: 0.36 (0.12), Post: 0.33 (0.10); Comp: Pre: 0.41 (0.17), During: 0.40 (0.19), Post: 0.36 (0.16); During: Int vs Comp (ref): −0.05 (0.01), p<0.001 ↑; Post: Int vs Comp (ref): −0.03 (0.01), p<0.01 ↑; Note: Schools were the unit of analysis; Model adjustments: None; Funding source(s): National Institute of Minority Health and Health Disparities
He, 2009,^140^ Northern Fruit and Vegetable Pilot Programme (NFVPP); Canada, RCT-Cluster; Total Baseline N: 1,586; Total Analytic N: 1,277; Total Baseline Cluster N: 26; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Missing values, outliers; Grade level: Middle/Junior high school; Age (Mean (SD)): 11.6 y (1.2); Female: 55%; Race/ethnicity: NR; SES: NR | Int1: Free fruit and vegetable snacks 3 x/wk (N=470; Cluster N=9); Int2: Free fruit and vegetable snacks 3 x/wk and enhanced nutrition education program (N=400; Cluster N=9); Comp: No intervention (N=407; Cluster N=8); Theory/framework: NR; Intervention duration: 21 wk; Outcome measurement: Intake measured via validated pre-coded 24-h fruit and vegetable recall questionnaire administered on days following fruit/vegetable distribution once at baseline and post-intervention | Intake at post-intervention (svg/d), Mean (SE); [underlined: Fruit and vegetables at school]: Int1: 1.8 (0.2), Int2: 1.9 (0.1), Comp: 1.4 (0.2); Int1 vs Comp: p>0.05, Int2 vs Comp: p<0.05 ↑, Int1 vs Int2: p>0.05; [underlined: Fruit and vegetables at home]: Int1: 2.5 (0.2), Int2: 2.5 (0.2), Comp: 2.4 (0.3); Int1 vs Comp: p>0.05, Int2 vs Comp: p>0.05, Int1 vs Int2: p>0.05; Model adjustments: Baseline intake; age; sex; school clustering effect; school location (urban vs rural); existing fruit and vegetable programme; Funding source(s): Ontario Ministry of Health Promotion
Ickovics, 2019 ^146^; United States (New Haven, Connecticut), RCT-Cluster; Total Baseline N: 719; Total Analytic N: 595; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: Absent, opted out, moved; Grade level: Middle/Junior high school; Age (Mean (SD)): 10.9 (0.62) y; Female: 54%; Race/ethnicity: Non-Hispanic White: 18%; Non-Hispanic Black: 35%; Hispanic: 47%; SES: Eligible for free lunch (Mean): 71 | Int1: Nutrition education and improved nutrition environmental policies in school (N=152; Cluster N=3); Int2: Physical activity education and nutrition education and improved nutrition environmental policies in school (N=152; Cluster N=3); Int3: Physical activity education (N=178; Cluster N=3); Comp: Delayed intervention control (N=113; Cluster N=3); Theory/framework: NR; Intervention duration: 3 y; Outcome measurement: Diet and nutritional habits obtained from self-reported student surveys based on Youth Risk Behavior Survey and School-Based Nutrition Monitoring Questionnaire at baseline, after 1-y of intervention, after 2-y of intervention, and post-intervention | Post-intervention consumption, Mean (SD) or % and OR; [underlined: Unhealthy food consumption (total/d)]: Int/Int2: 1.83 (0.11) vs Int3/Comp: 2.23 (0.12), p=0.02 ↑; [underlined: Sugar-sweetened beverages (≤2d in past wk)]: Int/Int2: 37.95% vs Int3/Comp: 27.18%; Int/Int2 vs Int3/Comp (ref): 1.36, p=0.025 ↑; [underlined: Fast food (any in past wk)]: Int/Int2: 26.34% vs Int3/Comp: 35.20%; Int/Int2 vs Int3/Comp (ref): 0.58, p=0.02 ↑; [underlined: Healthy food (total/d)]: Data NR, NS; [underlined: Healthy drinks (total/d)]: Data NR, NS; Intervention by time and intervention by sex interactions: NS; Model adjustments: Age; sex; race/ethnicity; BMI; time; Funding source(s): National Institute of Child Health and Human Development, CDC, Yale Griffin Prevention Research Center
Kocken, 2015 ^147^; The Netherlands, RCT-Cluster; Total Baseline N: 824; Total Analytic N: 614; Total Baseline Cluster N: 38; Total Analytic Cluster N: 26; Criteria for exclusion from analysis: Withdrawal/change of vending machine companies, non-response; Grade level: Middle/Junior high school; Age (Mean (SD)): 13.6 (0.7) y; Female: 55%; Race/ethnicity: Native Dutch ethnicity: 72%; SES: NR | Int: Multicomponent intervention consisting of (i) health education and (ii) changes to school vending machines to promote healthier eating (N=303; Cluster N=12); Comp: No intervention (N=311; Cluster N=14); Theory/framework: TPB; Intervention duration: ~6 mo; Outcome measurement: Questionnaire taken at pre-intervention and post-intervention. Self-reported purchase of soft drinks and extra foods measured, as well as how often soft drinks and extra foods were brought from home in the previous week. | Post-intervention purchase ≥1 x/wk, % and OR (95% CI); [underlined: Soft drinks]; School vending machine: Int: 19% vs Comp (ref): 20%, 1.01 (0.51, 1.98), p=NS; School canteen or tuck shop: Int: 18% vs Comp (ref): 17%, 1.10 (0.57, 2.11), p=NS; Shop in the school surroundings: Int: 34% vs Comp (ref): 36%, 1.00 (0.58, 1.74), p=NS; Brought from home: Int: 43% vs Comp (ref): 56%, 0.55 (0.34, 0.88), p<0.05 ↑; [underlined: Extra foods (snacks containing empty calories)]; School vending machine: Int: 20% vs Comp (ref): 20%, 1.02 (0.54, 1.93), p=NS; School canteen or tuck shop: Int: 25% vs Comp (ref): 30%, 0.86 (0.45, 1.63), p=NS; Shop in the school surroundings: Int: 45% vs Comp (ref): 49%, 0.89 (0.53, 1.51), p=NS; Brought from home: Int: 52% vs Comp (ref): 52%, 0.95 (0.64, 1.41), p=NS; Note: N varied slightly by analysis (Int: N=248-258, Comp: N=255-265); Model adjustments: Pre-test; age; gender; ethnicity; education; BMI; Funding source(s): Netherlands Organization for Health Research and Development
Pedersen, 2016 ^150^; Denmark, RCT-Cluster; Total Baseline N: 1,488; Total Analytic N: NR; Total Baseline Cluster N: 17; Total Analytic Cluster N: 17; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school and High school; Age (Mean): 12.9 y (Range: 11-16 y); Female: 50%; Race/ethnicity: NR; SES: NR | Int1: Text messaging to report intake and remind adolescents of goals (N=NR; Cluster N=NR); Int2: Text messaging to report intake and remind adolescent of goals with one nutrition education session (N=NR; Cluster N=NR); Comp: “Minimal intervention” (N=NR; Cluster N=NR); Theory/framework: SCT; Intervention duration: 11 wk; Outcome measurement: An 8-item FFQ was used to measure fruit and vegetable intake on a typical week at baseline and wk 11 | Fruit and vegetable intake (averaged across 8 questions) at baseline and wk 11, Mean; Int1: Baseline: 3.50, Wk 11: 3.45; Int2: Baseline: 3.39, Wk 11: 3.32; Comp: Baseline: 2.89, Wk 11: 3.39; Change: Int 1 & 2 vs Comp: p=0.47; Note: The effect on fruit and vegetable intake was modified by participation rate such that sending >50% of possible text messages significantly increased fruit and vegetable intake, while sending less did not (Data in paper); Model adjustments: Gender and participation rate (both in secondary analysis); Funding source(s): Danish Ministry of Science, Technology and Innovation
Prell, 2005 ^139^; Sweden, RCT-Cluster; Total Baseline N: 390; Total Analytic N: 228; Total Baseline Cluster N: 5; Total Analytic Cluster N: 5; Criteria for exclusion from analysis: Did not complete baseline and/or follow-up questionnaires; Grade level: Middle/Junior high school; Age (Mean): ~14 y; Female: 47%; Race/ethnicity: Native country is Sweden: ~90%; SES: NR | Int1: School canteen modification to increase fish intake (N=58; Cluster N=2); Int2: Modifications to the school canteen and home economics syllabus to increase fish intake (N=87; Cluster N=2); Comp: No intervention (N=83; Cluster N=1); Theory/framework: TPB; Intervention duration: 1 school y; Outcome measurement: Fish intake measured individually by structured observations in the school canteen 1 x/wk when fish was served for 5 wk; children were categorized as noneaters, tasters, or eaters of fish; assessed at baseline and post-intervention | Fish intake, Relative Position (95% CI)*; Int1: 0.10 (−0.02, 0.22); Int2: 0.15 (0.06, 0.24); Comp: −0.08 (−0.17, 0.01); Int1 vs Comp, p=NS; Int2 > Comp, p=significant (value NR) ↑; Note: Results were similar when analyzed separately for girls and boys.; *Relative position ranges from −1 to 1. Values close to 0 indicate a lack of systematic disagreement between baseline and follow-up data, and positive values indicate an increase in consumption. No overlap of confidence intervals between groups indicates significance.; Model adjustments: None; Funding source(s): Kunskapsplattform for Livsmedelsbranschen

a Abbreviations: BMI: body mass index; CDC: Centers for Disease Control and Prevention; CI: confidence interval; Comp: comparator; d: day; eq: equivalent; g: gram; h: hour; kcal: kilocalorie; Int: intervention; min: minute; MJ: megajoules; mo: month; N: sample size; NR: not reported; NS: non-significant; OR: odds ratio; oz; ounce; p: p-value; RCT: randomized controlled trial; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; TPB: Theory of Planned Behavior; vs: versus; wk: week; x: time(s); y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention

Table 14 Risk of bias for randomized controlled trials examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in middle and junior high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Anttonen, 2011^141^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Bere, 2006^142^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Birnbaum, 2002^143^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Bogart, 2014^144^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
He, 2009^140^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Hoppu, 2010^145^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Ickovics, 2019^146^ | LOW | LOW | LOW | LOW | LOW | LOW
Kocken, 2015^147^ | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS
Lytle, 2004^149^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Lytle, 2006^148^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS
Pedersen, 2016^150^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Prell, 2005^139^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS
Wang, 2015^132^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Wang, 2017^151^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a All studies cluster-RCTs

## High school

### Conclusion statements and grades

#### Teaching and educational interventions

Limited evidence from this rapid review suggests curriculum-based nutrition education may improve dietary intake (particularly vegetable intake) in high school adolescents. (Grade: Limited)

Insufficient evidence is available from this rapid review to determine the relationship between non-curriculum-based nutrition education (such as games and reading materials) and dietary intake in high school adolescents. (Grade: Grade not assignable)

#### Behavioral and environmental interventions and combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

Insufficient evidence is available from this rapid review to determine the relationship between behavioral or environmental interventions or those that combine behavioral or environmental components with teaching or educational components and dietary intake in high school adolescents. (Grade: Grade not assignable)

#### All interventions

Insufficient evidence is available from this rapid review to determine the relationship between any intervention type and food selection in high school adolescents. (Grade: Grade not assignable)

### Summary of the evidence

- Eighteen RCTs examined school-based strategies to improve diet quality and diet and food intake in high school-aged adolescents
  ○ Twelve of these studies examined teaching and educational interventions
  ○ Four examined behavioral or environmental strategies
  ○ The remaining two examined a combination of teaching/educational and behavioral/environmental strategies

#### Teaching and educational interventions

- Eight studies utilized comparable curriculum-based strategies, though interventions varied somewhat in content, delivery, and duration
- The vast majority of studies assessed intake as the main outcome of interest
  ○ Vegetable intake was a commonly studied outcome and tended to be beneficially impacted by the interventions
  ○ Fruit intake was also commonly assessed but showed inconsistent results
  ○ Outcomes such as legume intake, low-fat food intake, and overall diet quality also showed beneficial change, though they were measured in too few studies to draw conclusions
  ○ The following components appear to be associated with more beneficial outcomes, although more research is needed to confirm:
    ■ Longer duration
    ■ Parental involvement
    ■ Self-monitoring/record keeping
- The remaining four studies examined game-based, reading materials, or other types of teaching interventions; but there was too much heterogeneity to draw conclusions
  ○ Strategies such as using the Kalèdo game for nutrition education show promise, but more research is needed
- This body of evidence is limited by:
  ○ High heterogeneity in intervention content, duration, and outcomes assessed;
  ○ Limited generalizability to the US population due to cultural differences and missing racial/ethnic and SES data;
  ○ Limited follow up beyond the intervention period to determine persistence of effects; and
  ○ Attrition greater than 30% in multiple studies.

#### Behavioral and environmental interventions

- Four studies examined behavioral or environmental interventions, two in the cafeteria, one in vending machines, and one in a single snack session
- Cafeteria strategies such as removing competitive foods and increasing low-fat à la carte options offer promising targets for future research
- Although multiple interventions show promise, there were too few studies to draw conclusions

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

- Two studies examined combined strategies, but the interventions were too disparate to draw conclusions

### Synthesis of the evidence

This body of evidence on high-school aged adolescents includes 18 RCTs, including 14 cluster-RCTs^98,110,124,130,134,137,150,153–159^ and 4 parallel RCTs.^152,160–162^ It contains a large variety of interventions, though the majority utilized a teaching or educational strategy.

#### Teaching and educational interventions

##### Description of the evidence

Twelve RCTs examined the effect of teaching or educational interventions promoting acceptance of healthier foods and dietary patterns on diet and diet-related behaviors in high school aged adolescents. Two-thirds of the studies were cluster-RCTs,^98,110,124,130,154,156,158,159^ while the remaining studies were parallel, randomizing participants at the individual level.^152,160–162^ A broad range of high and very high HDI countries were represented by these studies, with two each conducted in the United States,^160,161^ United Kingdom,^124,152^ and Brazil^110,154^; and one study in each of the following: Canada,^158^ Greece,^98^ Iran,^156^ Italy,^130^ the Netherlands,^162^ and Thailand.^159^ The analytic sample size of the cluster-RCTs ranged from 1^159^ to 73^98^ clusters and 113^159^ to 3,627^98^ individual participants. Analytic samples for the 4 parallel RCTs ranged in size from 40^160^ to 198.^152^

Seven studies were conducted solely in high school-aged adolescents,^154,156,158–162^ while the remaining five studies enrolled participants across middle/junior high school and high school.^98,110,124,130,152^ The majority of studies did not report race/ethnicity or SES data. The three that reported race/ethnicity data enrolled highly diverse samples: one study from the United States enrolled 88 percent Black students,^160^ a second US study enrolled a >99 percent minority racial/ethnic groups,^161^ and one UK study enrolled 53 percent White, 19 percent Asian, and 16 percent Black participants.^124^ The studies providing socioeconomic status data reported large proportions of lower income and lower maternal/caregiver education levels.^98,110,124,156,161^

The majority of teaching/educational interventions utilized a new or existing nutrition curriculum involving a combination of strategies (e.g., food diaries, discussion groups). However, some used game-based learning, educational reading materials, or other strategies to target these outcomes. Five studies reported the theories and/or models that informed the intervention.^124,152,156,159,161^ A small group of studies included an active control or multiple intervention groups in addition to a non-intervention control,^124,152,156,159,162^ but the majority compared the intervention group to a non-intervention control only.^98,110,130,154,158,160,161^ All studies assessed overall intake across the full day or diet quality score, most commonly through FFQs and dietary recalls. Study findings and participant characteristics are provided in Table 15; the risk of bias assessments are detailed in Table 16. Studies are organized by the overall strategy implemented, as well as the intensity and duration of the intervention.

##### Curriculum-based nutrition education

Eight articles examined curriculum-based interventions with a combination of teaching and educational strategies; their duration ranged from 1 day to 1 academic year.

Brito beck da Silva and colleagues^110^ administered eight 50-minute general nutrition education sessions over the course of 9 months to a large sample of middle/junior high school and high school students age 10-17 years in Brazil. Children also received educational materials encouraging a healthy lifestyle to take home. Self-administered food frequency questionnaires at baseline and post-intervention examined intake of a broad list of foods and beverages including beans, rice, legumes, vegetables, fruit, milk, candies, snacks, processed meats, and soft drinks. Participants in the intervention group consumed legumes and vegetables significantly more than the control group post-intervention, but no other foods or beverages were significantly different. Age was adjusted for in the analyses, but data were not separated by age group, so the unique impact on high school-aged adolescents cannot be determined.

The Greek study^98^ examined the effect of adding a nutrition education program to the daily free, healthy meal received by a large sample of elementary, middle, and high school students over the course of 1 school year (see Elementary school or results in children). Educational materials included age-appropriate workbooks and games, school media, interactive events, and informational leaflets for parents and school staff. The control group received the free, healthy meal but no educational content. Parents reported adolescent intake on a semi-quantitative FFQ at baseline and post-intervention. Adolescents (aged 12-18 years) who received the educational materials had a significantly greater weekly consumption of vegetables post-intervention compared to the control group. There were no significant between-group differences in intake of milk/yogurt, fruit, or whole grains post intervention. Notably, loss to follow-up was high (76 percent) due to missing questionnaires or information required to link participant information pre- and post-intervention.

One US study administered the Diet for a Healthy Planet with Teen Battle Chefs curriculum daily for 19 weeks in a racially/ethnically diverse group of ninth grade students.^161^ The intervention aimed to build knowledge and skills related to cooking and growing, food marketing and production, and the personal and environmental factors affecting nutrition. Additional components included experiential learning activities (e.g., neighborhood food assessments) and personal nutrition challenges. Baseline and post-intervention assessments identified a total diet quality score, which reflected consumption of high nutritional quality foods. Scores were significantly higher in the intervention group at the end of 19 weeks compared to an art class control group.

A second US study^160^ examined the impact of a Mindfulness-Based Eating Awareness Training (MB-EAT) program delivered over 12 weekly 45-minute sessions in a small sample of ninth graders. Intervention content aimed to improve diet, physical activity, and emotional health using focused meditation techniques. A control group received the standard health education curriculum. A self-reported dietary recall assessed intake at baseline, 3-month follow-up, and 6-month follow-up; diet was not assessed immediately post intervention. At the 6-month follow-up, students in the intervention group consumed significantly more servings of low calorie, low fat, and low saturated fat foods compared to the control group.

One intervention targeting fruit and vegetable intake in Thailand consisted of four weekly 50-minute lessons on fruit and vegetables and either their cosmetic benefits for the skin and body or their health benefits for growth and disease prevention, both of which were accompanied by a handout on fruit and vegetables.^159^ Activities included quizzes, group discussions, and intake recording. Participants completed 3-day food diaries at baseline, post-intervention, and 3-week follow up. Both intervention groups significantly increased overall fruit intake and variety of fruit intake directly after the intervention compared to the control group; however, these effects were no longer significant at the 3-week follow-up. The group receiving education on cosmetic benefits had significantly higher vegetable intake post-intervention and at the 3-week follow-up compared to the health benefits group and the control group, though there were no between-group differences in variety of vegetables consumed. Vegetable intake in the health benefits group did not differ from the control group at the 3-week follow-up. This sample was 69 percent female, but data were not stratified by sex.

Fonseca et al^154^ randomized a low-income, Brazilian population of ninth graders to either an intervention consisting of three 45-minute nutrition education sessions or a control group. The intervention focused on healthy eating; food classification; labels; advertising; and the salt, sugar, and fat content of healthy and unhealthy meals using food models. The intervention took place over a brief 1-2-week period, and a self-reported FFQ measured intake at baseline and post-intervention for a broad range of foods and beverages. Intervention participants reported more frequent consumption of raw/cooked vegetables and less frequent soft drink consumption post-intervention compared to control participants. No other food or beverage items were significantly different between groups.

The Canadian study^158^ presented two 45-65-minute nutrition education sessions focused on increasing knowledge about sugar, interpreting nutrition facts panels, and designing healthy dietary patterns. Food and beverage models representing life-sized portions of >150 items provided hands-on experience to supplement the educational content. The outcome measure was a single question, given directly after the second educational session, asking students how often they limit intake of high-sugar foods. There was no significant difference between the intervention group and a delayed intervention control.

The RCT conducted in Iran examined the effects of a nutrition education intervention based on the Health Action Process Approach.^156^ The intervention aimed to increase fruit and vegetable intake using one 20-minute group discussion, a brochure on the importance of a healthy diet and fruit and vegetable consumption, action planning to consume fruit and vegetables, and 1 month of self-monitoring using a calendar. A second group received the same intervention with the addition of a single session for the students’ mothers on the importance of fruit and vegetables. Intake was assessed using two open-ended questions on daily servings at baseline, 1-month follow-up, and 6-month follow-up. Daily servings of fruit and vegetables at both follow-up time points were higher in both intervention groups compared to a control group. Maternal involvement conferred an additional benefit, with that intervention group consuming significantly more of both fruit and vegetables than the intervention group without maternal involvement.

##### Game-based learning

One intervention conducted in Italy used the Kalèdo board game designed to increase knowledge of the Mediterranean diet and promote a healthy lifestyle in middle/junior high school and high school students.^130^ Eating behavior and food habits were assessed with an Adolescent Food Habits Checklist and a dietary questionnaire on food habits at baseline, post-intervention, and 12-month follow-up. After 20 weeks of exposure, high school students showed significantly improved eating behavior and food habits compared to a control group. These differences remained significant at 12-month follow-up.

##### Educational reading materials

One study from the United Kingdom^124^ administered a pre-test to female participants aged 12-16 years and then provided an educational leaflet tailored from their responses with guidance on the following target foods: brown bread, whole-grain cereal, fruit, and vegetables. Control participants received a generic leaflet based on national guidelines that was not tailored to the individual. Three-day dietary recalls at baseline and 3-month follow-up revealed a significant increase in brown bread intake in both groups, and intervention group intake was significantly higher than the control group at follow-up. Fruit intake decreased in both groups but was not significantly different between groups at follow-up. Whole-grain cereal and vegetable intake did not vary significantly across time or between groups.

##### Other strategies

Two RCTs^152,162^ utilized educational strategies that did not fit cleanly into curriculum-based interventions, game-based learning, or educational reading materials.

Gratton et al^152^ conducted a study in the United Kingdom and randomized participants to one of two interventions aimed at increasing fruit and vegetable consumption or to a control group. The interventions ran for 1 week and enrolled students in multiple grade levels, including high school. The first intervention used a volition-based intervention where students wrote down how, where, and when they would eat five portions of fruit and vegetables daily for the following 7 days, and then put those plans into action. The second intervention consisted of a motivational approach, which included reading a statement raising awareness of the health benefits of fruit and vegetables and documenting four personal beliefs on the benefits of consuming fruit and vegetables, four barriers to consuming, and four means of overcoming those barriers. The control group received a volition-based intervention on homework completion. Participants completed a 7-day food diary at baseline and post intervention. This study had a notably high attrition rate (56 percent). Post intervention, both intervention groups increased fruit and vegetable intake relative to baseline levels; however, only the volition-based intervention participants consumed significantly more fruit and vegetables than the control group.

A Dutch study examined the effect of social norm messaging for a single day on adolescent fruit intake.^162^ Both intervention groups read a brief general message during class detailing the benefits of healthy eating and the importance of consuming fruit as part of a healthy diet. One intervention group then received a descriptive norm message stating that previous survey results found a majority of high school students try to eat sufficient fruit themselves. The other intervention group received an injunctive norm message stating a majority of high school students think other high school students should eat sufficient fruit. The control group received the general message with no final statement on social norms. Fruit intake was assessed 3 days later for the previous 2 days via a self-reported single question. The descriptive norm group reported significantly greater fruit intake than the injunctive norm group; however, neither group’s intake differed significantly from the general message control group.

##### Summary

Studies of interventions using teaching and educational strategies provided the largest contribution to the body of evidence in the high school-aged population. The majority of these studies focused on a nutrition education, curriculum-based component, the content of which varied across interventions. Most included broad nutrition education focused on the importance of a healthy diet with guidance on the foods and beverages to increase and those to limit. There was a trend toward more substantial, beneficial effects from longer duration interventions. Parental involvement also tended to confer additional benefit. Vegetable intake appeared to be the most responsive outcome to this type of intervention, showing significant, beneficial change across all studies that measured it. However, further research is needed to confirm these trends. Additional types of interventions beneficially influenced these outcomes, such as the use of an educational board game or mindfulness training, which suggests a need for further research in those areas, as well. Overall, future work on teaching and educational interventions in high school adolescents will help solidify which specific components most effectively improve dietary quality in this age group.

##### Assessment of the evidence

Limited evidence from this rapid review suggests curriculum-based nutrition education may improve dietary intake (particularly vegetable intake) in high school adolescents. This conclusion statement received a grade of Limited. Insufficient evidence was available to draw conclusions related to curriculum-based nutrition education and food selection or non-curriculum-based nutrition education interventions and dietary intake or food selection; therefore, conclusions were not drawn, and these bodies of evidence were not graded. As outlined and described below, the body of evidence underlying the conclusion statement was assessed for the following elements when grading the strength of evidence.

- Risk of Bias: Key areas of potential risk of bias affected many of these studies. Three studies reported attrition >30 percent, creating potential bias in the outcome data. Only one study had a pre-registered protocol,^156^ introducing concerns about study fidelity and selective reporting in the remaining studies. Multiple studies also failed to provide adequate details on the randomization method used, instead using phrases such as “participants were randomized” but not providing further detail.
- Consistency: Findings across these eight studies were consistent in direction, particularly related to vegetable intake. All five studies examining vegetable intake reported significantly increased intake post-intervention; however, this is a relatively small number of studies and it was difficult to compare the magnitude of effect across them. Many studies also assessed fruit intake but showed mixed results. Other outcomes appeared less frequently, but those related to dietary quality tended to show beneficial change. Considerable inconsistency came in the curriculum-based interventions themselves, which each contained a different combination of strategies, such as group discussions, self-monitoring and record keeping, and parental involvement. They also varied substantially in duration. These differences limited the ability to compare across studies and identify the most effective interventions. Furthermore, the outcomes varied widely across studies, and the resulting data for most food groups were inconsistent in both direction and magnitude.
- Directness: The studies in this body of evidence directly examined the relationship between teaching and educational interventions and dietary intake but did not assess many other interventions, comparators, and outcomes of interest for the broader research question in this age group.
- Precision: The number of participants and clusters enrolled across studies varied considerably, and the studies in this body of evidence did not report power calculations. Given the relatively small number of studies underlying this conclusion statement, it was difficult to compare effect magnitudes and confidence intervals. Additionally, although statistically significant, it was difficult to assess the practical significance of the observed changes in intake.
- Generalizability: There were substantial limits to generalizability in this body of evidence. Although all studies were conducted in high or very high HDI countries, only two were conducted in the United States, and four of the remaining six were conducted in countries with potential cultural differences affecting generalizability to the US population (Brazil, Iran, Thailand). These studies also reported very little data on race/ethnicity or SES of the enrolled participants, limiting the ability to determine applicability across groups.

#### Behavioral and environmental interventions

##### Description of the evidence

Four cluster-RCTs examined the effect of school-based behavioral and environmental interventions on diet and diet-related behaviors in high school-aged adolescents. Two of these studies enrolled high school-aged participants exclusively^153,155^ and two enrolled middle school through high school-aged participants.^134,137^ Two studies were conducted in the United States,^134,153^ one in the Netherlands,^137^ and one in Sweden.^155^ The analytic sample sizes ranged from 2^155^ to 28^137^ clusters and 41^155^ to 4,614^153^ individual participants.

Participants were predominantly White, though one study enrolled a large, roughly equal proportion of Black and Hispanic students (44 percent each).^153^ Eligibility for free or reduced-price school meals was reported in the two US studies and varied from 1-57 percent of students across schools in one study^134^ to over 95 percent in the other.^153^ The European studies did not report race/ethnicity or socioeconomic status data. The interventions varied across studies, with two focusing on environmental changes to the school cafeteria,^134,153^ one on environmental changes to school vending machines,^137^ and the fourth on manipulating snack proximity.^155^ No study reported the theory or model underlying the intervention. One study contained two intervention groups in addition to a non-intervention control,^153^ one compared two experimental conditions,^155^ and the remaining two studies compared the intervention group to a non-intervention control.^134,137^ Outcome data were derived primarily from school-level purchasing information, although two studies directly measured selection and intake during the targeted school-based eating occasion.^134,155^ Evidence from these studies and participant characteristics are described in Table 17; the risk of bias assessments are described in Table 18.

##### All behavioral and environmental interventions

French and colleagues^134^ conducted a 2-year intervention in the United States in which schools promoted lower-fat food choices by increasing availability of à la carte options in the cafeteria in conjunction with peer promotion activities, such as taste tests and media campaigns. Each school reported food sales, and a subset of participants provided intake data at baseline, year one, and year two of the trial. The intervention schools showed a steeper rate of increase in the percentage of lower-fat purchases in year one and an overall greater percentage of sales from lower-fat items in year two compared to the control schools. There were no significant changes in fruit and vegetable food choices or in the ratio of lower fat to higher fat food choices.

The second US intervention was also cafeteria based, randomizing three schools to one of two 4-week cafeteria-based interventions or to a control condition where no changes were made.^153^ The first intervention promoted healthy food choices by removing competitive foods from the school cafeteria. The second included healthy food nudges such as more visible, convenient placement and ease of consumption for healthier foods, as well as marketing strategies to increase the appeal of the healthy foods. Researchers obtained food purchase data from school cafeteria registers at baseline and during the final week of intervention. The healthy choice intervention that removed competitive foods resulted in a greater increase in meals served with a vegetable, though there were no differences in meals served with fruit or milk. There were no significant differences between the healthy nudges intervention and the control group. Researchers did not measure food intake.

The Dutch study of seventh through twelfth grade students introduced a series of cumulative changes to school vending machines over the course of 18 weeks in 6-week phases aimed at promoting the sale of lower-calorie food products.^137^ Phase one increased availability of lower-calorie products; phase two added informational media such as flyers and posters in addition to labeling items as favorable (<100 kcal), moderately unfavorable (100-170 kcal), or unfavorable (>170 kcal); and phase three reduced the price of lower-calorie products. Across all phases, the intervention schools had significantly higher sales of moderately unfavorable foods and significantly lower sales of unfavorable foods compared to the control schools. Favorable food represented a small portion of overall sales at baseline, and sales did not change overall during the intervention; however, when results were stratified based on whether or not students were allowed to leave campus, favorable food sales in the first and second phases were significantly higher in the intervention schools that did not allow students to leave campus. Favorable beverage sales were significantly higher and unfavorable beverage sales were significantly lower in intervention participants in the third phase only, when all intervention components were in effect.

Langlet et al^155^ examined the effect of snack placement on consumption in a small sample of Swedish high school students during a 1-hour classroom task on a single day. One group had snacks (crackers, grapes, and chocolate) placed at least 6 meters away (distal), while the other group had snacks placed within arm’s reach (proximal). Students self-served and were able to consume as much of the snacks as desired. Snack bowls were weighed pre- and post-intervention, with group intake validated using video recordings. The proximal group served themselves crackers and grapes a greater number of times; however, actual intake of those two snacks did not vary between groups. In contrast, close proximity resulted in significantly larger portions taken per serving and significantly greater consumption of chocolate compared to the distal group, though the number of servings taken did not vary between groups.

##### Summary

Overall, there is very little evidence on behavioral or environmental interventions in high-school aged participants, making it difficult to draw conclusions. The available evidence suggests cafeteria-based interventions that remove competitive foods or promote lower-fat items may facilitate healthier food choices; however, direct comparison of the interventions in this body of evidence is difficult, and their findings are not consistent across all outcomes of interest. Additional research on each of these strategies and their effect on actual food intake would strengthen the evidence base. Vending machine changes may also promote beneficial changes, but bolstering those findings requires additional research.

##### Assessment of the evidence

There was insufficient evidence examining the effects of behavioral and environmental interventions in high school adolescents; therefore, conclusions were not drawn, and the body evidence was not graded.

#### Combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies)

##### Description of the evidence

Two theory-based interventions, both cluster-RCTs, combined a teaching or educational component with a behavioral or environmental component.^150,157^ One study was conducted in the United States with ninth grade students,^157^ while the other was conducted in Denmark with both fifth and ninth grade students.^150^ The analytic sample sizes ranged from 12^157^ to 17^150^ clusters. Analytic sample sizes at the individual participant level were not reported, but the studies enrolled 1,488^150^ and 2,213^157^ participants at baseline.

The US study enrolled predominantly White participants (84 percent); the Danish study did not report race/ethnicity data, and neither study provided data on socioeconomic status. Both interventions aimed to increase fruit and vegetable consumption and measured overall intake as their primary outcome. Table 19 summarizes participant characteristics and evidence from these studies, and Table 20 details their risk of bias assessments.

##### All combined interventions

The US study examined the effectiveness of Gimme 5, a 3-year multi-component program in which a school marketing campaign was combined with five 55-minute classroom workshops (with taste tests), school meal modification, and parental involvement to increase fruit and vegetable availability at home.^157^ Participants self-reported number of fruit and vegetable servings consumed each day at baseline and mid-intervention. Fruit and vegetable intake was significantly higher in the intervention group at the 2-year interim assessment; however, between-group differences at post-intervention were not significant.^*^

* Nicklas TA, Johnson CC, Myers L, Farris RP, Cunningham A. Outcomes of a high school program to increase fruit and vegetable consumption: “Gimme 5: A Fresh Nutrition Concept for Students.” J School Health. 1998;68:248–253. doi: 10.1111/j.1746-1561.1998.tb06348.x 9719999

The Danish intervention involved participants setting goals for fruit and vegetable consumption and receiving text message reminders and merit-based prizes.^150^ A second intervention group employed the same strategies with the addition of one 45-minute lesson on the importance of eating fruit and vegetables and a hands-on food weighing activity. A third control group received minimal intervention. A short, self-reported FFQ measured fruit and vegetable intake at baseline and 11-week follow up. This study enrolled participants from both fifth and ninth grade and combined data after finding no differences between age groups. There was no effect of either intervention on fruit and vegetable intake at the 11-week follow up compared to the control; however, greater participation in the text-messaging component related to higher intake in both intervention groups.

##### Summary

Both studies that combined teaching/educational with behavioral/environmental strategies targeted fruit and vegetable intake in high school-aged participants, though the specific intervention components and overall study duration varied substantially, as did the findings. The longer duration study that incorporated school meal changes and parental involvement showed significant effects, suggesting these components may be important for promoting change. Participant compliance was a key predictor of beneficial change in the second study, even though the overall intervention showed no effect. These findings point toward intervention priorities for future research. However, it is difficult with multi-component interventions to determine if specific components drive the effect or if the overall package is required to see comparable effects; far more research is needed to validate these findings.

##### Assessment of the evidence

There was insufficient evidence examining the effects of combined interventions (teaching and educational strategies paired with behavioral and/or environmental strategies) in high school adolescents; therefore, conclusions were not drawn, and the body evidence was not graded.

Table 15 Evidence examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Barnes, 2016 ^160^; United States (Augusta, Georgia), RCT-Parallel; Total Baseline N: 40; Total Analytic N: 40; Grade level: High school; Age (Mean (SD)): 16.2 (1.2) y; Female: 69%; Race/ethnicity: White: 2%; Black: 88%; Other: 10%; SES: NR | Int: Mindfulness-Based Eating Awareness Training (MB-EAT) program delivered over 12 weekly 45-min sessions. (N=18); Comp: Health education control (N=22); Theory/framework: NR; Intervention duration: 12 wk; Outcome measurement: Intake assessed by a self-reported dietary recall at baseline, post-intervention, and 3-mo follow-up | Change in intake from baseline to 3-mo follow-up, Mean; [underlined: Low-calorie foods (svg/wk)]; Int: 7.7 > Comp: data NR ; p<0.02 ↑; [underlined: Low-fat foods (svg/wk)]; Int: 5.8, Comp: −1.4; p<0.02 ↑; [underlined: Foods with low saturated fat (svg/wk)]; Int: 4.6, Comp: −2.7; p<0.02 ↑; [underlined: Foods with no saturated fat (svg/wk)]; Int: 5.1 > Comp: data NR; p<0.10; Results for post-intervention: Data NR (figure only); Model adjustments: NR; Funding source(s): Medical College of Georgia
Brito Beck da Silva, 2015 ^110^; Brazil, RCT-Cluster; Total Baseline N: 833; Total Analytic N: 630; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Criteria for exclusion from analysis: Absent for data collection, refusal to participate in second stage of study; Grade level: Middle/Junior high school and High school; Age (Mean): ~13.25 y; Female: 57.6%; Race/ethnicity: NR; SES: Brazilian Economic Classification Criteria (A-highest to E-lowest): Class E: ~58%, Class B-D: ~42 % | Int: Nutrition education delivered by nutritionists consisting of eight 50-min sessions focusing on a variety of nutrition topics, with additional workshops to reinforce concepts; children were also given educational materials to bring home to the family (N=265; Cluster N=1); Comp: No intervention (N=365; Cluster N=1); Theory/framework: NR; Intervention duration: 9 mo; Outcome measurement: Intake during the previous week assessed with self-administered FFQ at baseline and post-intervention and dichotomized as more frequent (≥5 d/wk) or less frequent (≤4 d/wk) consumption | Odds of more frequent consumption at post-intervention, Int vs Comp (ref), OR (95% CI); [underlined: Beans]: 1.09 (0.87, 1.36); [underlined: Rice]: 1.11 (0.89, 1.39); [underlined: Legumes]: 1.18 (1.03, 1.37) ↑; [underlined: Vegetables]: 1.17 (1.01, 1.35) ↑; [underlined: Fruit]: 1.13 (0.93, 1.37); [underlined: Milk]: 1.14 (0.91, 1.44); [underlined: Candies]: 1.15 (0.92, 1.44); [underlined: Snacks]: 0.95 (0.73, 1.23); [underlined: Processed meats]: 1.16 (0.88, 1.52); [underlined: Soft drinks]: 1.10 (0.88, 1.37); No change in regression parameters when pubertal stage was added to the model; Model adjustments: Sex; age; SES; physical activity; Funding source(s): NR
Bukhari, 2011 ^161^; United States (Brooklyn, New York), RCT-Parallel; Total Baseline N: 98; Total Analytic N: NR; Criteria for exclusion from analysis: NR; Grade level: High school; Age: NR; Female: NR; Race/ethnicity: ~99% minority groups; SES: Annual household income below the poverty level: ~33% | Int: Diet for a Healthy Planet with Teen Battle Chefs curriculum delivered daily for 19 wk focusing on nutrition-related attitudinal and behavior changes (N=NR); Comp: Art class (N=NR); Theory/framework: SCT; Social ecological model; Intervention duration: 19 wk; Outcome measurement: Intake assessed with 15 items from the CDC’s Youth Risk Behavior Survey and summed to derive a total score (range: 0 - 72; foods of low nutritional quality reverse scored) at pre- and post-intervention | Change in total score from pre- to post-intervention, Mean change (% change); Int: 4.9 (20.4%), p<0.01 vs Comp: 1.6 (5.7%), p=NS; p<0.05 ↑; Model adjustments: NR; Funding source(s): Gateway Institute for Pre-College Education
Fonseca, 2019 ^154^; Brazil, RCT-Cluster; Total Baseline N: 676; Total Analytic N: 461; Total Baseline Cluster N: 7; Total Analytic Cluster N: 7; Criteria for exclusion from analysis: Absent for post-intervention questionnaire administration; Grade level: High school; Age (Mean (SD)): 14.8 (1.0) y; Female: 47.1%; Race/ethnicity: NR; SES: NR | Int: Three 45-min nutrition education sessions consisting of participatory activities focusing on healthy eating, food classification, food labels, food advertising, and the sugar, salt, and fat content of healthy and unhealthy meals using food models (N=273; Cluster N=4); Comp: No intervention (N=188; Cluster N=3); Theory/framework: NR; Intervention duration: 1-2 wk; Outcome measurement: Intake during the previous week assessed with self-administered FFQ at baseline and post-intervention and dichotomized as more frequent (≥5 d/wk) or less frequent (≤4 d/wk) consumption | Odds of more frequent consumption at post-intervention, Int vs Comp (ref), OR (95% CI); [underlined: Beans]: 1.29 (0.50, 3.30), p=0.560; [underlined: Deep-fried snacks]: 0.41 (0.12, 1.36), p=0.143; [underlined: Cold cuts]: 0.40 (0.11, 1.44), p=0.161; [underlined: Raw/cooked vegetables]: 2.38 (1.26, 4.51), p=0.007 ↑; [underlined: Raw salad]: 1.50 (0.78, 2.90), p=0.222; [underlined: Cooked vegetables]: 1.45 (0.61, 3.46), p=0.400; [underlined: Crackers]: 0.44 (0.18, 1.10), p=0.079; [underlined: Cookies]: 1.79 (0.36, 1.74), p=0.560; [underlined: Packaged snacks]: 0.80 (0.28, 2.24), p=0.672; [underlined: Sweets]: 0.55 (0.27, 1.13), p=0.103; [underlined: Fresh fruit]: 1.17 (0.60, 2.29), p=0.642; [underlined: Milk]: 1.88 (0.97, 3.67), p=0.063; [underlined: Soft drinks]: 0.36 (0.15, 0.86), p=0.021 ↑; Model adjustments: Pre-intervention intake; attendance at all meetings; Funding source(s): Conselho Nacional de Desenvolvimento Científico e Tecnológico Edital
Gratton, 2007 ^152^; United Kingdom, RCT-Parallel; Total Baseline N: 450; Total Analytic N: 198; Criteria for exclusion from analysis: Did not complete questionnaires at baseline or post-intervention, questionnaires could not be matched between baseline and follow-up; Grade level: Middle/Junior high school and High school; Age (Mean (SD)): 13.1 (1.32) y (Range: 11-16); Female: 52%; Race/ethnicity: NR; SES: NR | Int1: Volition-based intervention to increase fruit and vegetable intake (N=103); Int2: Motivational intervention to increase fruit and vegetable intake (N=52); Comp: Volition-based intervention focused on homework completion (N=43); Theory/framework: TPB; Intervention duration: 1 wk; Outcome measurement: Participants completed a 7-d food diary at baseline (1-wk pre-intervention) and 1-wk follow-up where they recorded the type and portion sizes of fruit and vegetables eaten/d | Fruit and vegetable intake at baseline and 1-wk follow up, Mean (SD); Int1: Baseline: 2.24 (0.99), 1-wk follow-up: 2.77 (1.25), p<0.001 ↑; Int2: Baseline: 2.05 (0.97), 1-wk follow-up: 2.36 (1.18), p<0.001 ↑; Comp: Baseline: 1.95 (1.13), 1-wk follow-up: 1.91 (1.13), p=NS; Int1 vs Comp: p<0.001 ↑; Int2 vs Comp: p=NS; Int1 vs Int2: p=NS; Model adjustments: Attitudes; subjective norm; perceived behavioural control; intentions; Funding source(s): NR
Lin, 2017 ^156^; Iran, RCT-Cluster; Total Baseline N: 1,455; Total Analytic N: 1,455; Total Baseline Cluster N: 48; Total Analytic Cluster N: 48; Grade level: High school; Age (Mean): ~14.4 y; Female: 49%; Race/ethnicity: NR; SES: Maternal education (Mean): ~5.6 y | Int1: Nutrition education for adolescents based on Health Action Process Approach designed to increase fruit and vegetable intake. (N=462; Cluster N=16); Int2: Nutrition education for adolescents and their mothers based on Health Action Process Approach designed to increase fruit and vegetable intake. (N=510; Cluster N=16); Comp: No intervention (N=483; Cluster N=16); Theory/framework: Health Action Process Approach; Intervention duration: 1 d (calendar to track intake for 1 mo); Outcome measurement: Intake assessed using 2 open-ended questions on daily servings at baseline, 1-mo follow-up, and 6-mo follow-up. | Intake (svg/d) at 1-mo and 6-mo follow-up, Mean (SD) and Adjusted mean difference (SE); [underlined: Fruit]:; 1-mo follow-up:; Int1: 3.31 (1.06), Int2: 4.49 (1.16), Comp: 3.04 (1.18); Difference: Int1 vs Comp (ref): 0.57 (0.21), p=0.006 ↑; Int2 vs Comp (ref): 1.43 (0.23), p<0.001 ↑; Int2 vs Int1 (ref): 0.87 (0.23), p<0.001 ↑; 6-mo follow-up:; Int1: 3.28 (1.18), Int2: 4.47 (1.36), Comp: 2.76 (1.24); Difference: Int1 vs Comp (ref): 0.58 (0.20), p<0.001 ↑; Int2 vs Comp (ref): 1.63 (0.23), p<0.001 ↑; Int2 vs Int1 (ref): 0.86 (0.22), p<0.001 ↑; [underlined: Vegetable]:; 1-mo follow-up:; Int1: 2.33 (1.02), Int2: 2.89 (1.25), Comp: 2.08 (0.96); Difference: Int1 vs Comp: 0.45 (0.17), p=0.008 ↑; Int2 vs Comp: 0.92 (0.19), p<0.001 ↑; Int2 vs Int1 (ref): 0.47 (0.19), p=0.01 ↑; 6-mo follow-up:; Int1: 2.34 (1.09), Int2: 2.92 (1.18), Comp: 1.91 (0.95); Difference: Int1 vs Comp: 0.61 (0.17), p<0.001 ↑; Int2 vs Comp: 1.09 (0.18), p<0.001 ↑; Int2 vs Int1 (ref): 0.48 (0.18), p=0.008 ↑; Model adjustments: Sex; age; maternal education level; Funding source(s): NR
Rees, 2010 ^124^; United Kingdom, RCT-Cluster; Total Baseline N: 823; Total Analytic N: 637; Total Baseline Cluster N: 8; Total Analytic Cluster N: 8; Criteria for exclusion from analysis: Completing <2 dietary recalls at either baseline or 3-mo follow up; Grade level: Middle/Junior high school and High school; Age (Range): 12-16 y; Female: 100%; Race/ethnicity: White: 53%; Asian: 19%; Black: 16%; Mixed: 10%; SES: Schools were low income and/or high ethnic diversity (overall sample was “lower than average income”) | Int: Tailored leaflet based on responses to questionnaire (N=323; Cluster N=NR); Comp: Generic leaflet (N=314; Cluster N=NR); Theory/framework: TPB; Transtheoretical Model; Intervention duration: 1 d; Outcome measurement: Participants were provided with three 24-h dietary recall sheets over three different days at baseline, and again at 3-mo follow-up, to record food and drink intake from the previous day. | Change in intake (svg/d) from baseline to 3-mo follow-up, Mean; [underlined: Brown bread]: Int: 0.12 ; Comp: 0.07 (between group p<0.05 ↑; within group, both p<0.05 ↑); [underlined: Wholegrain cerea]l: Int: 0.00 ; Comp: −0.03 (between & within group, all p=NS); [underlined: Fruit]: Int: −0.15 ; Comp: −0.11 (between group p=NS; within group, both p<0.05 ↓); [underlined: Vegetables]: Int: 0.00 ; Comp: −0.03 (between & within group, all p=NS); Model adjustments: School; location; school year; ethnicity; Funding source(s): The Food Standards Agency
Santaló, 2019 ^158^; Canada, RCT-Cluster; Total Baseline N: 203; Total Analytic N: 203; Total Baseline Cluster N: 16; Total Analytic Cluster N: 16; Grade level: High school; Age (Mean (SD)): 15.9 (1) y; Female: 74.3%; Race/ethnicity: NR; SES: NR | Int: Two 45-65 min nutrition education sessions focused on increasing knowledge about sugar and skills to interpret nutrition fact labels and design healthy eating patterns. Sessions included brief educational lectures and utilized experiential learning including life-sized food and beverage models. (N=102; Cluster N=8); Comp: Delayed intervention control (N=101; Cluster N=8); Theory/framework: NR; Intervention duration: 2 wk; Outcome measurement: Frequency of limiting intake of foods high in sugar assessed with single Likert scale question (1 - rarely to 7 - always) at baseline and post-intervention | Frequency of limiting foods high in added sugars, Mean (SD); Baseline: Int: 4.1 (1.4), Comp: 4.1 (1.6); Post-intervention: Int: 4.3 (1.6), Comp: 4.3 (1.7); Difference in change: p=0.67; Model adjustments: None; Funding source(s): No external funding
Somsri, 2016 ^159^; Thailand, RCT-Cluster; Total Baseline N: 131; Total Analytic N: 113; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Criteria for exclusion from analysis: Missing data; Grade level: High school; Age (Mean): ~16.2 y; Female: 69%; Race/ethnicity: NR; SES: NR | Int1: Nutrition education activities consisting of 4 weekly 50-min sessions on the cosmetic benefits of fruit and vegetables, and a handout on fruit and vegetables for self-study (N=41; Cluster N=1); Int2: Nutrition education activities consisting of 4 weekly 50-min sessions on the health benefits of fruit and vegetables, and a handout on fruit and vegetables for self-study (N=35; Cluster N=1); Comp: Handout on fruit and vegetables for self-study without nutrition education activities (N=37; Cluster N=1); Theory/framework: SCT; Intervention duration: 4 wk; Outcome measurement: Intake assessed with a 3-d diary of fruit and vegetables consumed on 3 consecutive days (2 weekdays and 1 weekend day) at baseline, post-intervention, and 3-wk follow-up; daily servings were converted to grams; variety assessed based on number of fruit and vegetable types and colors eaten | Intake at post-intervention and 3-wk follow-up, Median (IQR); [underlined: Fruit (g)]; Post-intervention:; Int1: 120.00 (143.20), Int2: 93.60 (130.40), Comp: 43.20 (91.20); p=0.002; Int1 > Comp, p<0.01 ↑; Int2 > Comp, p<0.01 ↑; Int1 vs Int2, p=NS; 3-wk follow-up:; Int1: 96.80 (167.20), Int2: 63.20 (133.60), Comp: 41.60 (85.60); p=0.09; Int1 vs Comp, Int2 vs Comp, and Int1 vs Int2: All p=NS; [underlined: Fruit types (number)]; Post-intervention:; Int1: 1.33 (1.33), Int2: 1.00 (1.00), Comp: 0.33 (1.00); p=0.002; Int1 > Comp, p<0.01 ↑; Int2 > Comp, p<0.01 ↑; Int1 vs Int2, p=NS; 3-wk follow-up:; Int1: 1.00 (1.34), Int2: 0.67 (1.34), Comp: 0.67 (0.50); p=0.09; Int1 vs Comp, Int2 vs Comp, and Int1 vs Int2: All p=NS (Similar results were found for the number of colors of fruit consumed); [underlined: Vegetables (g)]; Post-intervention:; Int1: 123.30 (100.00), Int2: 78.40 (56.80), Comp: 51.60 (61.60), p=0.001; Int1 > Comp, p<0.01 ↑; Int2 vs Comp, p=NS; Int1 > Int2, p<0.01 ↑; 3-wk follow-up:; Int1: 110.00 (76.80), Int2: 66.80 (45.20), Comp: 46.80 (53.60), p=0.001; Int1 > Comp, p<0.01 ↑; Int2 vs Comp, p=NS; Int1 > Int2, p<0.01 ↑; [underlined: Vegetable types (number)]; Post-intervention:; Int1: 4.00 (3.00), Int2: 3.00 (2.33), Comp: 3.00 (3.17); p=0.16; Int1 vs Comp, Int2 vs Comp, and Int1 vs Int2: All p=NS; 3-wk follow-up:; Int1: 3.33 (2.67), Int2: 2.67 (1.66), Comp: 2.67 (2.34); p=0.08; Int1 vs Comp, Int2 vs Comp, and Int1 vs Int2: All p=NS; (Similar results were found for the number of colors of vegetables consumed); Model adjustments: None; Funding source(s): China Medical Board, Faculty of Public Health, Mahidol University
Stok, 2014 ^162^; The Netherlands, RCT-Parallel; Total Baseline N: 96; Total Analytic N: 80; Criteria for exclusion from analysis: Absent at follow-up; Grade level: High school; Age (Mean (SD)): 15.5 (0.75) y (Range: 14-17 y); Female: 62%; Race/ethnicity: NR; SES: NR | Int1: General info on fruit consumption with descriptive norm message (majority of high school students try to eat sufficient fruit) (N=NR); Int2: General info on fruit consumption with injunctive norm message (majority of high school students think others should eat sufficient fruit) (N=NR); Comp: General info on fruit consumption only (N=NR); Theory/framework: NR; Intervention duration: 1 d; Outcome measurement: Follow-up assessment 3 d after classroom intervention measured fruit consumption on the previous 2 d with a single question; intake was averaged across the 2 d for each participant | Fruit consumption at follow-up, Mean (SD) pieces; Int1: 2.3 (1.6); Int2: 1.5 (0.9), Comp: 1.7 (1.0); Int1 vs Int2 (ref): p=0.02 ↑; Int1 vs Comp: p=0.057; Int2 vs Comp: p=0.68; Model adjustments: Age; autonomous motivation; Funding source(s): European Community FP7 Research Program
Viggiano, 2015 ^130^; Italy, RCT-Cluster; Total Baseline N: 3,110; Total Analytic N: 2,156 at post-intervention; N=1,045 at 12-mo follow-up; Total Baseline Cluster N: 20; Total Analytic Cluster N: 19 at post-intervention; N=14 at 12-mo follow-up; Criteria for exclusion from analysis: Did not complete post-intervention assessments; Grade level: Middle/Junior high school and High school; Age (Mean): ~13.2 y; Female: 47%; Race/ethnicity: NR; SES: NR | Int: Kalèdo game promoting nutrition knowledge and healthy lifestyle played weekly (N=1,076 post-intervention; N=624 at 12-mo follow-up; Cluster N=10 post-intervention; N=8 at 12-mo follow up); Comp: No intervention (N=1,080 post-intervention; N=421 at 12-mo follow up; Cluster N=9 post-intervention; N=6 at 12-mo follow-up; Theory/framework: NR; Intervention duration: 20 wk; Outcome measurement: Eating behavior and food habits assessed with a 23-item Adolescent Food Habits Checklist (AFHC) and a 14-item dietary questionnaire on food habits at baseline, post-intervention, and 12-mo follow up; maximum scores indicate the healthiest habit | Food questionnaire scores post-intervention and 12-mo follow up, Mean (95% CI); [underlined: AFHC (range 0-23)]; All schools; Post-intervention: Int: 14.4 (14.0, 14.8) vs Comp: 10.9 (10.6, 11.2). p<0.001 ↑; 12-mo: Int: 11.6 (11.1, 12.0) vs Comp: 10.5 (9.9, 11.0), p=0.248; High schools; Post-intervention: Int: 13.2 (12.4, 14.0) vs Comp: 10.2 (9.3, 11.1), p<0.001 ↑; 12-mo: Int: 14.5 (12.9, 16.1) vs Comp: 10.5 (8.4, 12.6), p=0.008 ↑; [underlined: Diet questionnaire - food habits (range 0-42)]; All schools; Post-intervention: Int: 32.4 (32.0, 32.8) vs Comp: 27.6 (27.3, 28.0), p<0.001 ↑; 12-mo: Int: 29.3 (28.9, 29.7) vs Comp: 28.6 (28.2, 29.1), p=0.507; High schools; Post-intervention: Int: 31.9 (31.0, 32.9) vs Comp: 27.4 (26.3, 28.4), p<0.001 ↑; 12-mo: Int: 32.8 (31.5, 34.0) vs Comp: 28.3 (26.7, 29.9), p=0.002 ↑; Model adjustments: Baseline diet; school (random effect); Funding source(s): Second University of Naples, Associazione Culturale Kaledo, Regione Campania (Assessorato all’Istruzione), Provincia di Napoli, Provincia di Salerno Assessorato allo Sport, Comune di Cercola (Assessorato all’istruzione) and Fondazione per l’Assistenza all’Infanzia
Zota, 2016,^98^ DIATROFI Program; Greece, RCT-Cluster; Total Baseline N: 14,869; Total Analytic N: 3,627; Total Baseline Cluster N: 146; Total Analytic Cluster N: 146; Criteria for exclusion from analysis: Missing a pre-or post-intervention questionnaire, missing information required to link pre- and post-intervention surveys; Grade level: Elementary school and Middle/Junior high school and High school; Age (Range): 4-18 y; Female: ~53%; Race/ethnicity: NR; SES: Maternal education: Low: ~26%, Medium: ~54%, High: ~20%; Family affluence scale: Low: ~29%, Medium: ~54%, High: ~17%; Food insecurity: 51% | Int: Nutrition education with one free, healthy meal daily (N=1,609; Cluster N=73); Comp: One free, healthy meal per day at school without nutrition education (N=2,018; Cluster N=73); Theory/framework: NR; Intervention duration: 1 academic y; Outcome measurement: Intake assessed using a modified version of a semi-quantitative FFQ, completed by a parent at pre- and post-intervention | Increased weekly consumption of food groups provided by the program from pre- to post-intervention, OR (95% CI); [underlined: Adolescents (12-18 y, Int: N=422, Comp: N=649)]; [underlined: Milk or yogurt]: 0.82 (0.64, 1.06), p=NS; [underlined: Vegetables]: 1.40 (1.09, 1.80), p<0.05 ↑; [underlined: Fruit]: 1.03 (0.78, 1.36), p=NS; [underlined: Whole grains]: 0.83 (0.62, 1.12), p=NS; Model adjustments: Sex; region; maternal, paternal, and child country of birth; maternal and paternal education; sports outside school; type of household, weight status; Family Affluence Scale; food insecurity; school near Roma establishments; number of children in the family (all considered in stepwise model); Funding source(s): Stavros Niarchos Foundation

a Abbreviations: CI: confidence interval; Comp: comparator; d: day; FFQ: food frequency questionnaire; h: hour; Int: intervention; IQR: interquartile range; min: minute; mo: month; N: sample size; NR: not reported; NS: non-significant; OR: odds ratio; p: p-value; RCT: randomized controlled trial; ref: reference group; SCT: Social Cognitive Theory; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; TPB: Theory of Planned Behavior; vs: versus; wk: week; y: year

b Color coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, red text with ↓: statistically significant effects (as reported in article) in favor of comparator

Table 16 Risk of bias for randomized controlled trials examining the effect of teaching and educational interventions on dietary intake and dietary intake-related behaviors in high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Barnes, 2016,^160^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Brito Beck da Silva, 2015^110^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Bukhari, 2011,^161^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Fonseca, 2019^154^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Gratton, 2007,^152^ Parallel | SOME CONCERNS | NOT APPLICABLE | LOW | HIGH | LOW | SOME CONCERNS
Lin, 2017^156^ | LOW | LOW | LOW | LOW | LOW | LOW
Rees, 2010^124^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Santaló, 2019^158^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Somsri, 2016^159^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Stok, 2014,^162^ Parallel | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS
Viggiano, 2015^130^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Zota, 2016^98^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS

a All studies cluster-RCTs except when otherwise noted

Table 17 Evidence examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
Boehm, 2020 ^153^; United States (Bridgeport, Connecticut), RCT-Cluster; Total Baseline N: 4,614; Total Analytic N: 4,614; Total Baseline Cluster N: 3; Total Analytic Cluster N: 3; Grade level: High school; Age: NR; Female: NR; Race/ethnicity: White: ~8%; Black: ~44%; Asian: ~3%; Hispanic: ~44%; Other: ~3%; SES: Eligible for free or reduced price meals: >95% | Int1: Removal of competitive foods from the school cafeteria (N=1,177; Cluster N=1); Int2: Marketing and nudging strategies (Smarter Lunchroom) to encourage fruit and milk selection (N=2,140; Cluster N=1); Comp: No intervention (N=1,297; Cluster N=1); Theory/framework: NR; Intervention duration: 4 wk; Outcome measurement: Food purchases assessed using data from school cafeteria registers during the baseline period (~7 mo pre-intervention) and during the intervention (4 wk) | Average share of entrees served with meal component daily, Difference-in-difference estimate (SE); [underlined: Vegetables]: Int1 vs Comp (ref): 0.060 (0.020), p<0.01 ↑; Int2 vs Comp (ref): 0.036 (0.034), p=NS; [underlined: Fruit]: Int1 vs Comp (ref): −0.067 (0.039), p=NS; Int2 vs Comp (ref): 0.054 (0.059), p=NS; [underlined: Milk]: Int1 vs Comp (ref): −0.060 (0.042), p=NS; Int2 vs Comp (ref): −0.004 (0.044), p=NS; Average competitive foods sold daily, Difference-in-difference estimate (SE); Int2 vs Comp (ref): 13.85 (19.06), p=NS; Model adjustments: Seasonal variation in school meal participation; type of entrée served each day; Funding source(s): Robert Wood Johnson Foundation
French, 2004,^134^ Trying Alternative Cafeteria Options in Schools (TACOS); United States (Minneapolis–St Paul metropolitan area, Minnesota), RCT-Cluster; Total Baseline N: NR; Total Analytic N: NR; Total Baseline Cluster N: 20; Total Analytic Cluster N: 20; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school and High school; Age: NR; Female: NR; Race/ethnicity: Non-White: 14% (Range between schools: 3%-77%); SES: Eligible free/reduced price lunch: 9% (Range between schools: 1%-57%) | Int: School-based environmental intervention to promote lower-fat food choices (N=NR; Cluster N=10); Comp: No intervention (N=NR; Cluster N=10); Theory/framework: NR; Intervention duration: 2 y; Outcome measurement: Lower-fat food sales collected on a weekly basis in electronic format from trained school food service staff during year 1 and year 2 of the intervention. Fruit and vegetable score created by summing responses to 6 questions on usual intake during past year; lower and higher fat food choices assessed with 6 and 22 questions respectively; assessed at baseline, and year 1 and 2 of the intervention with mailed survey (random sample 75 students/school) | Food choices at baseline (N~1,125), year 1 (N~1,125), and year 2 (N~1,155), Mean; [underlined: Fruit and vegetable score]; Int: 2.7, 2.9, 2.9;; Comp: 2.8, 3.1, 3.1; Time by group interaction: p=0.95; [underlined: Low-fat/high-fat food choices]; Int: 0.29, 0.28, 0.28; Comp: 0.23, 0.26, 0.24; Time by group interaction: p=0.62; Lower-fat a la carte food sales; [underlined: Mean % of sales]; Year 1: Int: 27.5%, Comp: 19.6%, p=0.096; Year 2: Int: 33.6%, Comp: 22.1%, p=0.042 ↑; [underlined: Rate of increase in mean % of sales]; Year 1: Int: 10%, Comp: −2.8%, p=0.002 ↑; Year 2: Int: 2.0%, Comp: 1.2%, p=0.76; Model adjustments: Sex; grade; race/ethnicity; school (random effect); Funding source(s): NIH, CDC
Kocken, 2012 ^137^; The Netherlands, RCT-Cluster; Total Baseline N: 22,611; Total Analytic N: NR; Total Baseline Cluster N: 40; Total Analytic Cluster N: 28; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school and High school; Age: NR; Female: NR; Race/ethnicity: NR; SES: NR | Int: Intervention promoting the sale of lower-calorie food products from school vending machines in 3 successive 6 wk phases (1: increasing availability of lower-calorie products; 2: labeling products as favorable, moderately unfavorable, or favorable; 3: reducing price of lower-calorie products) (N=NR; Cluster N=13); Comp: No changes to school vending machines (N=NR; Cluster N=15); Theory/framework: NR; Intervention duration: 18 wk; Outcome measurement: During all 3 phases, records were kept of sales from the vending machines. Sales were registered using standard registration forms which included a standardized list of almost 400 different products that were categorized by the Dutch Nutrition Centre according to the 3 food groups (extra foods, beverages, and basic foods), and the 3 categories (favorable, moderately unfavorable, and favorable). | Products sold during phases 1, 2, and 3 of intervention, Mean Proportions (%) (SD) and Mean Change in Proportions (%) (SD); [underlined: Extra Foods (snacks containing empty calories): Favorable (<100 kcal)]; Phase 1: Int: 1.6 (1.9) vs Comp: 0.9 (1.5), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 1: Not allowed: Int: 3.6 vs Comp: 0.4, Allowed: Int: 1.2 vs Comp: 1.6, p<0.05 ↑; Phase 2: Int: 1.9 (1.8) vs Comp: 0.8 (1.1), p=NS; Change from Phase 1 to Phase 2: Int: 0.2 (0.7) vs Comp: −0.1 (1.3), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 2: Not allowed: Int: 4.1 vs Comp: 0.8, Allowed: Int: 1.3 vs Comp: 1.1, p<0.05 ↑; Phase 3: Int: 1.2 (1.1) vs Comp: 0.8 (1.2), p=NS; Change from Phase 2 to Phase 3: Int: −0.2 (1.2) vs Comp: 0.0 (0.8), p=NS; Group by “school’s permission to leave the school area” interaction, Phase 3: p=NS; [underlined: Extra Foods: Moderately unfavorable (100-170 kcal)]; Phase 1: Int: 44.2 (15.3) vs Comp: 20.1 (7.8), p<0.05 ↑; Phase 2: Int: 44.9 (13.5) vs Comp: 18.3 (8.1), p<0.05 ↑; Change from Phase 1 to Phase 2: Int: 0.8 (4.3) vs Comp: −1.8 (7.9), p=NS; Phase 3: Int: 46.5 (14.0) vs Comp: 19.7 (9.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: 2.6 (7.0) vs Comp: 1.4 (5.8), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Extra Foods: Unfavorable (>170 kcal)]; Phase 1: Int: 54.2 (16.4) vs Comp: 78.9 (7.6), p<0.05 ↑; Phase 2: Int: 53.2 (14.1) vs Comp: 80.8 (8.3), p<0.05 ↑; Change from Phase 1 to Phase 2: Int: −1.0 (4.4) vs Comp: 1.9 (8.2), p=NS; Phase 3: Int: 52.3 (14.1) vs Comp: 79.4 (8.6), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: −2.4 (8.0) vs Comp: −1.4 (5.5), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Beverages: Favorable (Light drinks, waters, fruit juices)]; Phase 1: Int: 38.3 (15.9) vs Comp: 22.4 (15.3), p<0.10; Phase 2: Int: 37.2 (14.0) vs Comp: 26.0 (14.1), p<0.10; Change from Phase 1 to Phase 2: Int: −1.1 (9.3) vs Comp: 3.7 (7.3), p=NS; Phase 3: Int: 42.2 (14.4) vs Comp: 26.6 (15.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: 4.5 (6.0) vs Comp: 0.6 (5.9), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; [underlined: Beverages: Unfavorable (Regular soft drinks, sweetened fruit juices)]; Phase 1: Int: 61.7 (15.9) vs Comp: 77.6 (15.3), p<0.10; Phase 2: Int: 62.8 (14.0) vs Comp: 74.0 (14.1), p<0.10; Change from Phase 1 to Phase 2: Int: 1.1 (9.3) vs Comp: −3.7 (7.3), p=NS; Phase 3: Int: 57.8 (14.4) vs Comp: 73.4 (15.0), p<0.05 ↑; Change from Phase 2 to Phase 3: Int: −4.5 (6.0) vs Comp: −0.6 (5.9), p=NS; Group by “school’s permission to leave the school area” interaction: p=NS for all phases; Model adjustments: Number of shops in school surroundings; Funding source(s): The Netherlands Organization for Health Research and Development
Langlet, 2017 ^155^; Sweden, RCT-Cluster; Total Baseline N: 41; Total Analytic N: 41; Total Baseline Cluster N: 2; Total Analytic Cluster N: 2; Grade level: High school; Age (Mean): ~16.7 y; Female: 54%; Race/ethnicity: NR; SES: NR | Int: Snack food situated at least 6 meters away (N=24; Cluster N=1); Comp: Snack food put within arm’s reach (N=17; Cluster N=1); Theory/framework: NR; Intervention duration: 60 min; Outcome measurement: Intake assessed by weighing food served and left over following the work period and confirmed with video recordings | Intake during work period, Mean (SD); [underlined: Grapes (kcal)]: Int: 170.2 (100.3) vs Comp: 176.4 (145.7), p=0.913; [underlined: Grapes (kcal/time served)]: Int: 80.5 (32.7) vs Comp: 53.1 (17.9), p=0.430; [underlined: Chocolate (kcal)]: Int: 254.2 (241.9) vs Comp: 397.2 (262.2), p=0.012 ↑; [underlined: Chocolate (kcal/time served)]: Int: 187.0 (167.1) vs Comp: 260.0 (202.3), p=0.037; [underlined: Crackers (kcal)]: Int: 79.1 (91.9) vs Comp: 152.6 (169.6), p=0.246; [underlined: Crackers (kcal/time served)]: Int: 43.5 (39.9) vs Comp: 58.9 (40.8), p=0.656; Selection of food during work period, Mean (SD); [underlined: Grapes (times served)]: Int: 1.9 (1.0) vs Comp: 3.3 (2.1), p=0.006 ↔; [underlined: Chocolate (times served)]: Int: 0.9 (0.8) vs Comp: 1.6 (1.1), p=0.150; [underlined: Crackers (times served)]: Int: 1.1 (1.1) vs Comp: 2.4 (2.8), p=0.011 ↔; Model adjustments: None; Funding source(s): European Community’s Information and Communication Technology Programme

a Abbreviations: CDC: Centers for Disease Control and Prevention; CI: confidence interval; Comp: comparator; d: day; Int: intervention; kcal: kilocalorie; min: minute; mo: month; N: sample size; NIH: National Institutes of Health; NR: not reported; NS: non-significant; OR: odds ratio; p: p-value; RCT: randomized controlled trial; ref: reference group; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving; vs: versus; wk: week; y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention; Bolded, blue text with ↔: statistically significant effects (as reported in article) in which the interpretation of results is unclear

Table 18 Risk of bias for randomized controlled trials examining the effect of behavioral and environmental interventions on dietary intake and dietary intake-related behaviors in high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
Boehm, 2020^153^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
French, 2004^134^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Kocken, 2012^137^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Langlet, 2017^155^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a All studies cluster-RCTs

Table 19 Evidence examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in high school adolescents^a^,^b^

Study Information | Intervention, Comparator, Outcomes | Results
O’Neil, 2002,^157^ Gimme 5; United States (New Orleans, Louisiana), RCT-Cluster; Total Baseline N: 2,213; Total Analytic N: NR; Total Baseline Cluster N: 12; Total Analytic Cluster N: 12; Criteria for exclusion from analysis: NR; Grade level: High school; Age (Range): ~14-15 y; Female: 56%; Race/ethnicity: White: 84%; Black: 4%; Other: 12%; SES: NR | Int: Gimme 5 nutrition program delivered over 3 y to increase fruit and vegetable consumption (N=NR; Cluster N=6); Comp: No intervention (N=NR; Cluster N=6); Theory/framework: PRECEDE-PROCEED model; Intervention duration: 3 academic y; Outcome measurement: Intake assessed by self-reported number of fruit and vegetable servings consumed on daily basis at baseline and after 2 y of intervention | Change in fruit and vegetable intake from baseline to after 2 y of intervention, % (svg/d); Int: 14% (0.35 svg/d) vs Comp: data NR, p<0.001 ↑; Note: Original publication from this trial reported on outcomes through the full 3 y of intervention, finding no group differences at post-intervention.^c^; Model adjustments: None; Funding source(s): National Cancer Institute, USDA/Agricultural Research Service
Pedersen, 2016 ^150^; Denmark, RCT-Cluster; Total Baseline N: 1,488; Total Analytic N: NR; Total Baseline Cluster N: 17; Total Analytic Cluster N: 17; Criteria for exclusion from analysis: NR; Grade level: Middle/Junior high school and High school; Age (Mean): 12.9 y (Range: 11-16 y); Female: 50%; Race/ethnicity: NR; SES: NR | Int1: Text messaging to report intake and remind adolescents of goals (N=NR; Cluster N=NR); Int2: Text messaging to report intake and remind adolescent of goals with one nutrition education session (N=NR; Cluster N=NR); Comp: “Minimal intervention” (N=NR; Cluster N=NR); Theory/framework: SCT; Intervention duration: 11 wk; Outcome measurement: An 8-item FFQ was used to measure fruit and vegetable intake on a typical week at baseline and wk 11 | Fruit and vegetable intake (averaged across 8 questions) at baseline and wk 11, Mean; Int1: Baseline: 3.50, Wk 11: 3.45; Int2: Baseline: 3.39, Wk 11: 3.32; Comp: Baseline: 2.89, Wk 11: 3.39; Change: Int1+Int2 vs Comp: p=0.47; Note: The effect on fruit and vegetable intake was modified by participation rate such that sending >50% of possible text messages significantly increased fruit and vegetable intake, while sending less did not ↑ (Data in paper); Model adjustments: Gender and participation rate (both in secondary analysis); Funding source(s): Danish Ministry of Science, Technology and Innovation

a Abbreviations: Comp: comparator; d: day; FFQ: food frequency questionnaire; Int: intervention; N: sample size; NR: not reported; p: p-value; RCT: randomized controlled trial; ref: reference group; SES: socioeconomic status; svg: serving; vs: versus; wk: week; y: year

b Color and symbol coding: Bolded, green text with ↑: statisitically significant effects (as reported in article) in favor of intervention

c Nicklas TA, Johnson CC, Myers L, Farris RP, Cunningham A. Outcomes of a high school program to increase fruit and vegetable consumption: “Gimme 5: A Fresh Nutrition Concept for Students.” J School Health. 1998;68:248–253. doi: 10.1111/j.1746-1561.1998.tb06348.x 9719999

Table 20 Risk of bias for randomized controlled trials examining the effect of interventions that combine educational strategies with behavioral and environmental strategies on dietary intake and dietary intake-related behaviors in high school adolescents^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome Measurement | Selection of the reported result
O’Neil, 2002^157^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
Pedersen, 2016^150^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS

a Both studies cluster-RCTs

## Discussion

In this rapid review of school-based strategies to improve acceptance of healthier foods and dietary patterns in children and adolescents, teaching and educational interventions provided the largest contribution to the body of evidence across all grade levels. Curriculum-based approaches were the most studied type of intervention across grade levels, with studies generally reporting benefits on dietary intake. Most curricula focused on general nutrition and healthy eating. A common component of successful curricula was parental involvement, which tended to have beneficial effects in all grade levels. However, there was a wide range in the type and intensity of parental involvement. Other common strategies differed based on the age of the students. In elementary school, successful curricula frequently included games and a taste testing component (typically fruit and vegetables). In contrast, effective curricula in middle and junior high school often included a digital media or technology component. Most interventions in high school included activities such as goal setting in order to facilitate behavior change. Teaching and educational interventions were delivered by a variety of educators; across grade levels, interventions with beneficial impacts on diet tended to be delivered by researchers or nutritionists. Fewer studies examined non-curriculum-based interventions, particularly in middle/junior high and high school. Although game-based interventions (board and electronic games) were more studied in elementary school children compared to adolescents in higher grade levels, beneficial effects on dietary outcomes were observed in all grade levels. Few studies examined educational reading materials and videos, but across grade levels, brief exposure had consistent beneficial effects on expressed food choice and/or intake immediately following exposure to the intervention. Teaching and educational interventions mostly targeted fruit and vegetable intake, with generally beneficial effects for fruit intake in elementary school children and beneficial effects for vegetable intake in middle and junior high and high school adolescents. Dairy, lower nutrition quality foods and beverages, and overall diet quality were other commonly studied outcomes, but results were mixed for all grade levels.

A variety of behavioral and environmental interventions were tested across elementary, middle and junior high, and high schools. Most evidence on this broad category of interventions was available for elementary and middle or junior high school students, with several studies examining both age groups; very few studies tested the effects of behavioral and environmental interventions in high schools. Regarding food and beverage selection, most studies across elementary school and middle and junior high school reported benefits of the tested intervention on one or more targeted items, most commonly fruit, vegetables, and low-fat or white milk. Several types of behavioral and environmental strategies were successful at modifying child or adolescent food and beverage choices at school, such as those utilizing nudges or modifying food presentation; however, a relatively small number of studies were available for any single type of behavioral or environmental intervention, and these more specific types of interventions were often still heterogeneous. Regarding consumption, fruit and vegetable intake were the most commonly assessed outcomes across both elementary school and middle and junior high school. Vegetable intake was predominantly beneficially affected by behavioral and environmental strategies. Beneficial effects also tended to be reported for fruit intake, but results were less consistent. Similar to selection, a variety of strategies were implemented in successful interventions, but relatively few studies examined any one type of behavioral or environmental intervention. Further research is needed to strengthen the evidence base on the different types of school-based behavioral and environmental interventions and their effects on child and adolescent food choice and dietary intake.

As with studies which examined educational interventions or behavioral and environmental interventions alone, the RCTs that tested the effect of combined interventions implemented a variety of strategies. Behavioral and environmental components commonly targeted the availability of different types of food at school (e.g., increasing access to nutrient-dense foods, reducing the availability of less favorable foods) and the promotion of nutrient-dense foods; but other strategies were also implemented. The educational component was predominantly a nutrition curriculum and a variety of activities were completed as part of these curricula, including fruit and vegetable tastings, food preparation, games, and educational books and videos. Most interventions included some level of parental involvement. Similar to the body of evidence as a whole, most studies focused on interventions implemented in elementary schools and middle and junior high schools, with very few studies conducted in high schools. Across age groups, intake (or sometimes selection) of a variety of food items tended to be positively impacted by combined interventions, including fruit, vegetables, and foods and beverages to limit (such as sugar-sweetened beverages, desserts, fast foods); individual nutrients and other food items were not commonly assessed. Although some studies conducted in middle and junior high schools compared combined interventions to interventions that implemented educational, behavioral, or environmental strategies alone, no studies conducted in elementary school made this comparison.

### Strengths and potential limitations of the rapid review process

NESR rapid reviews streamline scope and systematic review methods to meet decision and timeframe requirements of a review sponsor. NESR collaborated with members of the OPS SNRAD team to develop the rapid review protocol examining school-based strategies to improve child and adolescent food choice and dietary intake. The rapid review protocol was approved by the sponsor and was not registered. Post-hoc protocol changes that tighten the focus of the review and center on the strongest evidence are common components of rapid reviews. The following amendments were made to the protocol following literature screening and prior to data extraction, to tailor the scope of the review to meet decision requirements:

- excluding non-randomized controlled trials to focus on the strongest evidence available;
- excluding weight and body composition as outcomes to focus on the primary outcomes of the rapid review;
- excluding studies that did not provide minimal information on the content of the intervention being tested^*^; and,
  * Although the amount of detail on the intervention provided in a publication may be limited by factors such as journal word limits, only three studies were excluded based on this criterion due to extremely limited information provided on intervention content.
- excluding interventions that could not be broadly implemented in a school/classroom environment (e.g., experiments conducted one-on-one with students).

An external expert group, while typically involved in NESR systematic reviews, was not recruited for this rapid review. However, this rapid review involved subject matter experts who peer reviewed the report. The review team considered this expert input prior to finalizing the report.

Compared to the methods of a systematic review, the review team applied slightly abbreviated methodology for screening and risk of bias assessment, which may have limited the review process:

- [underlined: Screening]: A hand search of the reference lists of included articles was not conducted, potentially increasing the likelihood that some relevant articles were not captured in the search.
- [underlined: Risk of bias assessment]: Verification of the initial risk of bias assessment by a second reviewer was completed, rather than dual independent assessment of risk of bias for each included article, potentially increasing the likelihood of errors in final risk of bias judgements.

The precise impact that each modification had on the results of the review is unknown; however, modifications to the standard systematic review process were relatively minor and unlikely to change the conclusions of the review.