# Methods

## Develop a protocol

NESR coordinated development of the rapid review protocol with the OPS SNRAD team to define the scope of the research question and determine the research approach appropriate to meet project objectives, a priori. Below is a description of the protocol approved by the OPS SNRAD team at the beginning of the project, in addition to amendments made to the protocol following literature screening and prior to data extraction to tailor the scope of the review to meet decision requirements.

The analytic framework for this rapid review examining the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake and dietary intake-related behaviors is presented in Figure 1. An analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated.

The interventions of interest were strategies implemented through schools to improve acceptance of new foods and encourage healthier dietary patterns in school-aged children and adolescents, such as teaching and educational interventions and exposures, or behavioral and/or environmental interventions, exposures, and policies. The interventions could be single-component or multi-component, with most components focused on food and nutrition (≥75 percent of intervention). This criterion was established to ensure that the interventions assessed were aimed towards improving acceptance of new foods and encouraging healthier dietary patterns, but to prevent exclusion of interventions that had a minor focus on other topics (e.g., a single lesson on physical activity).

The comparators were:

- standard curriculum or environmental policies in place at school,
- different strategies implemented through schools to improve acceptance of new foods and encourage healthier dietary patterns,
- non-school-based strategies to improve acceptance of new foods and encourage healthier dietary patterns,
- school-based interventions that do not pertain to improving acceptance of new foods and encouraging healthier dietary patterns, and
- identical school-based strategy to the intervention but without the component(s) that address improved acceptance of new foods and encouragement of healthier dietary patterns.

The outcomes, assessed in school-aged children and adolescents, or adults, were:

- dietary intake (including diet quality, dietary pattern, and food and beverage groups, such as fruit, vegetables, whole grains, meats/meat alternates, milk and dairy, and sugar-sweetened beverages),
- select macronutrient and micronutrient intake (saturated fat, added sugars, fiber, and sodium), and
- dietary intake-related behaviors (including expressed food preferences [the choice of one food item over another, e.g., food purchase, frequency of choice, portions, plate/food waste]).

The key confounders, which may impact the relationships of interest, were sex, age, race/ethnicity, socioeconomic status, baseline diet, physical activity, and anthropometry. These were considered during risk of bias assessment of individual studies.

Updates to the rapid review protocol were made following completion of literature screening but prior to data extraction to tailor the scope of the review to meet decision requirements. These updates included:

- excluding non-randomized controlled trials to focus on the strongest evidence available;
- excluding weight and body composition as an outcome to focus on the primary outcome of the rapid review;
- excluding studies that did not provide minimal information on the content of the intervention being tested; and,
- excluding interventions that could not be broadly implemented in a school/classroom environment (e.g., experiments conducted one-on-one with students).

Additionally, based on requester communication goals for this rapid review, graded conclusion statements were developed in place of the originally planned ungraded summary statements.

Figure 1 Analytic framework

Analytic framework for this rapid review examining the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake and dietary intake-related behaviors. The analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated.

## Search for and select studies

The inclusion and exclusion criteria for the rapid review examining the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake, and dietary intake-related behaviors is presented in Table 1. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search will be included in or excluded from the rapid review. Search strategies to identify all potentially relevant articles that address the rapid review question were developed by a NESR librarian and reviewed by NESR analysts. The search strategies were implemented in three databases: PubMed, Web of Science, and Education Resources Information Center (ERIC). The full search strategies are described in Appendix 2.

The results of the electronic database searches, after removal of duplicates, were screened by NESR analysts using the support of systematic review software (DistillerSR, Evidence Partners Inc., Ottawa, Ontario, Canada). Following calibration between NESR analysts, 10 percent of articles at the title level and 20 percent of articles at the abstract level were independently screened by two NESR analysts to determine if an a priori threshold for agreement (Cohen’s kappa ≥0.8) was met at either level to proceed with screening by single NESR analysts. The a priori threshold was not met for either the title or abstract screening levels; therefore, all articles at both levels were independently screened by two NESR analysts. Finally, all articles were independently screened by two NESR analysts at the full-text level. If agreement could not be reached on inclusion decisions, an additional analyst adjudicated the decision. A manual search of the reference lists of included articles was not conducted.

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials | - Non-randomized controlled trials (including quasi-experimental and controlled before and after studies); - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Strategies implemented through schools to improve acceptance of new foods and encourage healthier dietary patterns, such as teaching/educational interventions and exposures or environmental interventions, exposures, and policies. Interventions may be:; ○ Single-component; ○ Multi-component, with most components focused on food and nutrition (≥75 percent of intervention; Note: Strategies may include a portion that is implemented in a different setting (e.g., child’s home) or delivered to another individual (e.g., education for family members), but the intervention/exposure should be delivered primarily to the child in a school setting. | - Strategies that exclusively or primarily target availability or affordability of water; - Strategies that exclusively or primarily focus on provision of free meals; - Strategies that are based exclusively or primarily (>50 percent) outside of school; - Strategies that are delivered exclusively or primarily (>50 percent) to the child’s parent or caregiver; - Multi-component interventions that are not predominantly focused on food and nutrition (<75 percent of intervention); - Interventions in which minimal information on the content of the intervention being tested is not available; - Interventions that cannot be broadly implemented in the classroom or school setting (e.g., experiments conducted one-on-one with students, studies that examine mechanisms)
Comparator | - Standard curriculum or environmental policies in place at school (i.e., no new intervention or policy); - Different strategy implemented through schools to improve acceptance of new foods and encourage healthier dietary patterns; - Non-school-based strategy to improve acceptance of new foods and encourage healthier dietary patterns; - School-based intervention/exposure that does not pertain to improving acceptance of new foods and encouraging healthier dietary patterns; - Identical school-based strategy to the intervention/exposure but without the component(s) that addresses improved acceptance of new foods and encouragement of healthier dietary patterns | - No comparator
Outcomes | - Dietary intake; ○ Diet quality; ○ Dietary pattern; ○ Food and beverage groups, such as:; ■ Fruits; ■ Vegetables; ■ Whole grains; ■ Meats/meat alternates; ■ Milk and dairy; ■ Sugar-sweetened beverages; ○ Macronutrient and micronutrient intake, specifically:; ■ Saturated fat; ■ Added sugars; ■ Fiber; ■ Sodium; - Dietary intake-related behaviors; ○ Expressed food preference (choice of one food item over another; e.g., food purchase, frequency of choice, portions, plate/food waste) | - Water intake; - Intake of macronutrients or micronutrients not specified in the inclusion criteria; - Measures of food and nutrition knowledge; - Measures of attitudes towards foods (e.g., willingness to taste, food neophobia); - Measures of meal skipping, consumption of certain meals (e.g., ate breakfast or not, frequency of eating)
Publication date | - January 2000 – September 2020 | - Before January 2000, after September 2020
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, and conference proceedings)
Language | - Articles published in English | - Articles published in languages other than English
Country^*^; * In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018, 2019, or 2020 the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ) | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or low human development
Study participants | - Human participants; ○ Males; ○ Females | - Non-human participants (e.g., animal studies, invitro models)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (5-18 years); - Age at outcome:; ○ Children and adolescents (5-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); ○ Children (2-4 years); ○ Adults (19-64 years); ○ Older adults (65 years and older); - Age at outcome:; ○ Infants and toddlers (birth to 24 months); ○ Children (2-4 years)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or condition | - Studies that exclusively enroll participants diagnosed with a disease or condition (e.g., diabetes, students with neurocognitive developmental conditions or eating disorders known to influence food acceptance such as autism or avoidant/restrictive food intake disorder)

## Extract data and assess the risk of bias

A single NESR analyst extracted data from each included study. The data items were chosen a priori and were related to the study characteristics, participant characteristics, intervention(s), comparator(s), outcome(s), and results. A second NESR analyst reviewed the extracted data and verified accuracy and completeness. The revised Cochrane Risk-of-Bias 2.0 (RoB 2.0) tool was used to assess risk of bias for randomized controlled trials (RCTs). The most recent versions of RoB 2.0 at the time of review were used according to study design: the 2019 version of RoB 2.0 was used for individually randomized trials,^†^ whereas the 2016 version of RoB 2.0 was used for cluster-RCTs.^*^ One NESR analyst independently completed the appropriate risk of bias tool for all included studies and a second NESR analyst verified the accuracy of answers.

† Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi: 10.1136/bmj.l4898.31462531

* Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601.

## Synthesize the evidence

NESR analysts qualitatively compared, contrasted, combined, and evaluated the body of evidence available to answer the rapid review question. The qualitative synthesis of evidence, which is accompanied by summary data tables and a description of the body of evidence, identifies and explains similarities and differences between studies and determines whether certain factors impact the relationships being examined. The evidence was synthesized by the school level of included students (elementary school, middle and junior high school, high school) and the type of intervention assessed (teaching and educational interventions, behavioral and environmental interventions, combined interventions that paired teaching and educational strategies with behavioral and/or environmental strategies). Examples of the types of intervention strategies included in each category are described in Table 2.

Table 2 Intervention types and examples

Intervention | Examples Type
Teaching and educational interventions | - New or enhanced nutrition curriculum (both knowledge- and behavioral-based); - Game-based learning (board and electronic games); - Educational reading materials and videos
Behavioral and environmental interventions | - Behavioral nudges (verbal or through online ordering systems) towards more favorable food and beverage items; - Incentives (e.g., small prizes or praise) for choosing or consuming certain food and beverage items at lunch; - Changes to food and beverage items available at school; - Changes to how food and beverages are promoted or are presented in the cafeteria line, such as placing healthier options in a more prominent location; - Changes to enhance food palatability
Combined interventions | - New or enhanced nutrition curriculum and changes to food and beverage items available at school; - Educational videos and incentives for choosing certain food and beverage items; - Peer-led education and promotion of certain food and beverage items

## Develop conclusion statements and grade the evidence

After the body of evidence was described and synthesized, the NESR team considered the strengths and limitations of the body of evidence, and then developed conclusion statements answering the rapid review question. Conclusion statements reflect concise, carefully constructed answers to the review question. For each school level and intervention type, the five-member NESR project team developed a conclusion statement or conclusion statements and discussed and revised the statement(s) until consensus was reached.

The strength of the evidence underlying each conclusion statement was then discussed and graded by the NESR team using pre-established criteria for risk of bias, consistency, directness, precision, and generalizability. Based on these five elements, each conclusion statement received an overall grade of Strong, Moderate, Limited, or Grade Not Assignable using the NESR Grading Rubric (Appendix 3).^*^ This grade indicates the strength of evidence underlying each conclusion statement and communicates key findings clearly to the requester. It also indicates how likely the conclusions are to change as a result of future research, with weaker grades indicating a lower level of confidence and a greater potential for change. Grade not assignable reflects evidence upon which a conclusion cannot be drawn due to an inadequate amount, quality, or consistency of findings.

* Detailed description of considerations made during grading is available in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC .

## Recommend future research

Research gaps and methodological limitations identified throughout the rapid review process were documented. These gaps and limitations were used to develop research recommendations that describe the research, data, and methodological advances needed to strengthen the body of evidence.

## Peer review

Two non-government and three Federal government content experts, who completed conflict of interest requirements, reviewed the draft report, and it was revised to address their comments (see Acknowledgments and funding).