# Introduction

Childhood and adolescence are important periods for establishing eating habits, which in turn influence short- and long-term health.^*^ Many children and adolescents in the United States consume as much as two-thirds of their daily meals at school^†^; therefore, schools can play an influential role in establishing healthy eating habits.^‡^ A challenge to children and adolescents adopting a healthier dietary pattern is their natural resistance to trying or accepting new foods and beverages that they do not typically consume.^§^,^**^ The purpose of this project was for the Nutrition Evidence Systematic Review (NESR) team of the Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), USDA, to conduct a rapid review for the Office of Policy Support (OPS), FNS, USDA, in order to identify and summarize evidence on school-based interventions for improving eating habits in children and adolescents. Specifically, the research question was: What is the effect of school-based strategies that aim to improve acceptance of healthier foods and dietary patterns in children and adolescents on dietary intake and dietary intake-related behaviors?

* Dalwood P, Marshall S, Burrows TL, McIntosh A, Collins CE. Diet quality indices and their associations with health-related outcomes in children and adolescents: an updated systematic review. Nutr J. 2020;19:118. doi:10.1186/s12937-020-00632-x 33099309

† Child Nutrition Tables. Food and Nutrition Service, U.S. Department of Agriculture. Updated August 13, 2021. Accessed August 30, 2021. https://www.fns.usda.gov/pd/child-nutrition-tables

‡ Briefel RR, Wilson A, Gleason PM. Consumption of low-nutrient, energy-dense foods and beverages at school, home, and other locations among school lunch participants and nonparticipants. J Am Diet Assoc. 2009;109(2 Suppl):S79–S90. doi:10.1016/j.jada.2008.10.064 19166676

§ Dovey TM, Staples PA, Gibson EL, Halford JCG. Food neophobia and ‘picky/fussy’ eating in children: A review. Appetite. 2008;50:181–193. doi:10.1016/j.appet.2007.09.009 17997196

** Birch LL, Fisher JO. Development of eating behaviors among children and adolescents. Pediatrics. 1998;101:539–542.12224660

NESR specializes in conducting food- and nutrition-related reviews using rigorous, protocol-driven methodology. Joint conversations between the requester and the NESR team determined a rapid review would be the most appropriate product to deliver relevant and timely information within the resource requirements of the requester. The NESR team coordinated with the OPS Special Nutrition Research and Analysis Division (SNRAD) to develop a protocol to answer the research question. Results of this rapid review project can be used to inform Federal communication, research, and program guidance, as well as the development of effective school-based interventions targeting diet and dietary behaviors.