# Acknowledgments and funding

NESR staff: developed the protocol for examining the scientific evidence, including the inclusion and exclusion criteria; reviewed all studies that met the set criteria; discussed the body of evidence for each question; and wrote and graded the conclusion statements.

NESR staff worked with the review sponsors, the OPS SNRAD team, to determine the scope of the question and develop the rapid review protocol.

- Maggie Applebaum
- Constance Newman, PhD
- Kelley Scanlon, PhD, RD
- Jinee Burdg, MPP, RDN, LDN (through March 2021)

NESR staff thank Federal and non-Federal scientist peer reviewers for their time and expertise.

- Jennifer Carlson, MPH, RD, Child Nutrition Programs, FNS, USDA
- Isobel Contento, PhD Teachers College Columbia University
- Deanna Hoelscher, PhD, RD, LD, CNS, University of Texas Health Science Center at Houston, School of Public Health in Austin
- Caitlin Merlo, MPH, RDN, Healthy Schools Branch, Division of Population Health, Centers for Disease Control and Prevention
- Amy Rosenthal, PhD, SNRAD, OPS, FNS, USDA