# Appendix 4 Excluded articles

The following table lists the articles excluded after full-text screening for this rapid review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

| Reference | Reason(s) for exclusion
1 | Evaluation of a fruit and vegetable distribution program--Mississippi, 2004-05 school year. MMWR Morb Mortal Wkly Rep. 2006. 55:957-61. | Study design
2 | Aarestrup AK, Suldrup Jørgensen T, Jørgensen SE, Hoelscher DM, Due P, Krølner R. Implementation of strategies to increase adolescents’ access to fruit and vegetables at school: process evaluation findings from the Boost study. BMC Public Health. 2015. 15:86. doi:10.1186/s12889-015-1399-9. | Outcome
3 | Abood DA, Black DR, Coster DC. Evaluation of a school-based teen obesity prevention minimal intervention. J Nutr Educ Behav. 2008. 40:168-74. doi:10.1016/j.jneb.2007.02.009. | Outcome
4 | Aceves-Martins M, Llauradó E, Tarro L, Moriña D, Papell-Garcia I, Prades-Tena J, Kettner-Høeberg H, Puiggròs F, Arola L, Davies A, Giralt M, Solà R. A school-based, peer-led, social marketing intervention to engage Spanish adolescents in a healthy lifestyle (“We Are Cool”-Som la Pera Study): a parallel-cluster randomized controlled study. Child Obes. 2017. 13:300-313. doi:10.1089/chi.2016.0216. | Other: Retracted
5 | Adab P, Barrett T, Bhopal R, Cade JE, Canaway A, Cheng KK, Clarke J, Daley A, Deeks J, Duda J, Ekelund U, Frew E, Gill P, Griffin T, Hemming K, Hurley K, Lancashire ER, Martin J, McGee E, Pallan MJ, Parry J, Passmore S. The West Midlands ActiVe lifestyle and healthy Eating in School children (WAVES) study: a cluster randomised controlled trial testing the clinical effectiveness and cost-effectiveness of a multifaceted obesity prevention intervention programme targeted at children aged 6-7 years. Health Technol Assess. 2018. 22:1-608. doi:10.3310/hta22080. | Intervention/exposure
6 | Adab P, Pallan MJ, Lancashire ER, Hemming K, Frew E, Barrett T, Bhopal R, Cade JE, Canaway A, Clarke JL, Daley A, Deeks JJ, Duda JL, Ekelund U, Gill P, Griffin T, McGee E, Hurley K, Martin J, Parry J, Passmore S, Cheng KK. Effectiveness of a childhood obesity prevention programme delivered through schools, targeting 6 and 7 year olds: cluster randomised controlled trial (WAVES study). BMJ. 2018. 360:k211. doi:10.1136/bmj.k211. | Intervention/exposure
7 | Adamo KB, Goldfield GS, Colapinto CK, Grattan KP, Harvey A, Barrowman N. Evaluating a fruit and vegetable program: in eastern Ontario schools. Can J Diet Pract Res. 2013. 74:167-74. doi:10.3148/74.4.2013.167. | Study design
8 | Adams MA, Bruening M, Ohri-Vachaspati P, Hurley JC. Location of school lunch salad bars and fruit and vegetable consumption in middle schools: a cross-sectional plate waste study. J Acad Nutr Diet. 2016. 116:407-416. doi:10.1016/j.jand.2015.10.011. | Study design
9 | Adams MA, Pelletier RL, Zive MM, Sallis JF. Salad bars and fruit and vegetable consumption in elementary schools: a plate waste study. J Am Diet Assoc. 2005. 105:1789-92. doi:10.1016/j.jada.2005.08.013. | Study design
10 | Agrawal R. Super Sprowtz: marrying arts and nutrition education to inspire children to eat more vegetables. Child Obes. 2012. 8:488-90. doi:10.1089/chi.2012.0085.agra. | Study design
11 | Aktac S, Kiziltan G, Avci S. The effect of family participation in nutrition education intervention on the nutritional status of preschool age children. Egitim Ve Bilim-Education and Science. 2019. 44:415-431. doi:10.15390/eb.2019.7819. | Comparator
12 | Alaimo K, Carlson JJ, Pfeiffer KA, Eisenmann JC, Paek HJ, Betz HH, Thompson T, Wen Y, Norman GJ. Project FIT: a school, community and social marketing intervention improves healthy eating among low-income elementary school children. J Community Health. 2015. 40:815-26. doi:10.1007/s10900-015-0005-5. | Intervention/exposure
13 | Alaimo K, Oleksyk SC, Drzal NB, Golzynski DL, Lucarelli JF, Wen Y, Velie EM. Effects of changes in lunch-time competitive foods, nutrition practices, and nutrition policies on low-income middle-school children’s diets. Child Obes. 2013. 9:509-23. doi:10.1089/chi.2013.0052. | Study design
14 | Alexander AG, Grant WL, Pedrino KJ, Lyons PE. A prospective multifactorial intervention on subpopulations of predominately Hispanic children at high risk for obesity. Obesity (Silver Spring). 2014. 22:249-53. doi:10.1002/oby.20557. | Intervention/exposure
15 | Alford TJ. Promise and hope for healthy schools. J Miss State Med Assoc. 2010. 51:253-4. | Study design
16 | Allirot X, da Quinta N, Chokupermal K, Urdaneta E. Involving children in cooking activities: A potential strategy for directing food choices toward novel foods containing vegetables. Appetite. 2016. 103:275-285. doi:10.1016/j.appet.2016.04.031. | Intervention/exposure
17 | Amani R, Soflaei M. Nutrition education alone improves dietary practices but not hematologic indices of adolescent girls in Iran. Food Nutr Bull. 2006. 27:260-4. doi:10.1177/156482650602700309. | Outcome, Country
18 | Ambusaidi A, Al-Yahyai R, Taylor S, Taylor N. School Gardening in Early Childhood Education in Oman: A Pilot Project with Grade 2 Students. Sci Educ Int. 2019. 30:45-55. doi:10.33828/sei.v30.i1.6 | Outcome
19 | Ames SL, Wurpts IC, Pike JR, MacKinnon DP, Reynolds KR, Stacy AW. Self-regulation interventions to reduce consumption of sugar-sweetened beverages in adolescents. Appetite. 2016. 105:652-62. doi:10.1016/j.appet.2016.06.036. | Intervention/exposure
20 | Amini M, Djazayery A, Majdzadeh R, Taghdisi MH, Sadrzadeh-Yeganeh H, Abdollahi Z, Hosseinpour-Niazi N, Chamari M, Nourmohammadi M. A School-Based Intervention to Reduce Excess Weight in Overweight and Obese Primary School Students. Biol Res Nurs. 2016. 18:531-40. doi:10.1177/1099800416654261. | Intervention/exposure
21 | Andersen R, Biltoft-Jensen A, Andersen EW, Ege M, Christensen T, Ygil KH, Thorsen AV, Damsgaard CT, Astrup A, Michaelsen KF, Tetens I. Effects of school meals based on the New Nordic Diet on intake of signature foods: a randomised controlled trial. The OPUS School Meal Study. Br J Nutr. 2015. 114:772-9. doi:10.1017/s0007114515002299. | Intervention/exposure
22 | Anderson EL, Howe LD, Kipping RR, Campbell R, Jago R, Noble SM, Wells S, Chittleborough C, Peters TJ, Lawlor DA. Long-term effects of the Active for Life Year 5 (AFLY5) school-based cluster-randomised controlled trial. BMJ Open. 2016. 6:e010957. doi:10.1136/bmjopen-2015-010957. | Intervention/exposure
23 | Angelopoulos PD, Milionis HJ, Grammatikaki E, Moschonis G, Manios Y. Changes in BMI and blood pressure after a school based intervention: The CHILDREN study. Eur J Publ Health. 2009. 19:319-325. doi:10.1093/eurpub/ckp004. | Intervention/exposure
24 | Angelucci M, Prina S, Royer H, Samek A. Incentives and Unintended Consequences: Spillover Effects in Food Choice. Am Econ J Econ Pol. 2019. 11:66-95. doi:10.1257/pol.20170588. | Outcome
25 | Annesi JJ, Smith AE, Walsh SM, Mareno N, Smith KR. Effects of an after-school care-administered physical activity and nutrition protocol on body mass index, fitness levels, and targeted psychological factors in 5- to 8-year-olds. Transl Behav Med. 2016. 6:347-57. doi:10.1007/s13142-015-0372-6. | Intervention/exposure
26 | Aperman-Itzhak T, Yom-Tov A, Vered Z, Waysberg R, Livne I, Eilat-Adar S. School-Based Intervention to Promote a Healthy Lifestyle and Obesity Prevention among Fifth- and Sixth-Grade Children. Am J Health Educ. 2018. 49:289-295. doi:10.1080/19325037.2018.1486755. | Study design
27 | Aquilani R, Parisi U, Bigoni N, Maggi L, Ghioni G, Zucchella M, Lombardi P, Covini C, Pastoris O, Dossena M, Verri M, Boschi F. School teachers can effectively manage primary prevention of adult cardiovascular disease. The Stradella Project. Preventive Medicine. 2007. 45:290-294. doi:10.1016/j.ypmed.2007.06.018. | Outcome
28 | Ardalan G, Alavian SM. School nutrition program; prevention of obesity and Fatty liver in children. Iran J Pediatr. 2014. 24:337-8. | Study design
29 | Ardic, A, Erdogan S. The effectiveness of the COPE healthy lifestyles TEEN program: a school-based intervention in middle school adolescents with 12-month follow-up. J Adv Nurs. 2017. 73:1377-1389. doi:10.1111/jan.13217. | Intervention/exposure
30 | Ariza C, Sánchez-Martínez F, Serral G, Valmayor S, Juárez O, Pasarín MI, Castell C, Rajmil L, López MJ. The Incidence of Obesity, Assessed as Adiposity, Is Reduced After 1 Year in Primary Schoolchildren by the POIBA Intervention. J Nutr. 2019. 149:258-269. doi:10.1093/jn/nxy259. | Intervention/exposure
31 | Arlinghaus KR, Moreno JP, Reesor L, Hernandez DC, Johnston CA. Compañeros: High School Students Mentor Middle School Students to Address Obesity Among Hispanic Adolescents. Prev Chronic Dis. 2017. 14:E92. doi:10.5888/pcd14.170130. | Intervention/exposure
32 | Arnold ME, Flesch JM, Ashton C, Black L, Brody B, Hosty M, Northway S. YA4-H! Youth Advocates for Health: Impact of a 4-H Teens-as-Teachers Program. J Ext. 2016. 54:6. | Study design
33 | Arrúa A, Curutchet MR, Rey N, Barreto P, Golovchenko N, Sellanes A, Velazco G, Winokur M, Giménez A, Ares G. Impact of front-of-pack nutrition information and label design on children’s choice of two snack foods: Comparison of warnings and the traffic-light system. Appetite. 2017. 116:139-146. doi:10.1016/j.appet.2017.04.012. | Study design, Outcome
34 | Ask AS, Hernes S, Aarek I, Johannessen G, Haugen M. Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast--a pilot study. Nutr J. 2006. 5:33. doi:10.1186/1475-2891-5-33. | Intervention/exposure
35 | Ask AS, Hernes S, Aarek I, Vik F, Brodahl C, Haugen M. Serving of free school lunch to secondary-school pupils - a pilot study with health implications. Public Health Nutr. 2010. 13:238-44. doi:10.1017/s1368980009990772. | Intervention/exposure
36 | Babio N, Vicent P, López L, Benito A, Basulto J, Salas-Salvadó, J. Adolescents’ ability to select healthy food using two different front-of-pack food labels: a cross-over study. Public Health Nutr. 2014. 17:1403-9. doi:10.1017/s1368980013001274. | Intervention/exposure, Outcome
37 | Bacopoulou F, Landis G, Rentoumis A, Tsitsika A, Efthymiou, V. Mediterranean diet decreases adolescent waist circumference. Eur J Clin Invest. 2017. 47:447-455. doi:10.1111/eci.12760. | Study design, Intervention/exposure
38 | Bagherniya M, Sharma M, Mostafavi Darani F, Maracy MR, Safarian M, Allipour Birgani R, Bitarafan, V, Keshavarz, SA. School-Based Nutrition Education Intervention Using Social Cognitive Theory for Overweight and Obese Iranian Adolescent Girls: A Cluster Randomized Controlled Trial. Int Q Community Health Educ. 2017. 38:37-45. doi:10.1177/0272684x17749566. | Intervention/exposure
39 | Bahreynian M, Salehi M, Khoshhali M, Kelishadi R. Impact of text message-based intervention for weight control and health-promoting lifestyle behaviors of overweight and obese children. J Educ Health Promot. 2020. 9:108. doi:10.4103/jehp.jehp_707_19. | Study design, Intervention/exposure
40 | Bai Y, Kim YH, Han YH, Hyun T. Impact of a school-based culinary nutrition education program on vegetable consumption behavior, intention, and personal factors among Korean second-graders. Nutr Res Pract. 2018. 12:527-534. doi:10.4162/nrp.2018.12.6.527. | Study design
41 | Bai Y, Suriano L, Wunderlich SM. Veggiecation: a novel approach to improve vegetable consumption among school-aged children. J Nutr Educ Behav. 2014. 46:320-321. doi:10.1016/j.jneb.2013.12.004. | Study design
42 | Ballard KT. Improved nutrition through school food programs. Pediatr Ann. 2013. 42:376-8. doi:10.3928/00904481-20130823-12. | Study design
43 | Banchonhattakit P, Duangsong R, Muangsom, N, Kamsong T, Phangwan K. Effectiveness of Brain-Based Learning and Animated Cartoons for Enhancing Healthy Habits Among School Children in Khon Kaen, Thailand. Asia Pac J Publ Health. 2015. 27:NP2028-NP2039. doi:10.1177/1010539512466425. | Intervention/exposure, Outcome
44 | Banchonhattakit P, Tanasugarn C, Pradipasen M, Miner KR, Nityasuddhi D. Effectiveness of school network for childhood obesity prevention (SNOCOP) in primary schools of Saraburi Province, Thailand. Southeast Asian J Trop Med Public Health. 2009. 40:816-34. | Intervention/exposure
45 | Bani Salameh A, Al-Sheyab N, El-Hneiti M, Shaheen A, Williams LM, Gallagher R. Effectiveness of a 12-week school-based educational preventive programme on weight and fasting blood glucose in “at-risk” adolescents of type 2 diabetes mellitus: Randomized controlled trial. Int J Nurs Pract. 2017. 23:e12528. doi:10.1111/ijn.12528. | Intervention/exposure
46 | Barbosa Filho VC, Bandeira ADS, Minatto G, Linard JG, Silva JAD, Costa RMD, Manta SW, Sá SAM, Matias TS, Silva KSD. Effect of a Multicomponent Intervention on Lifestyle Factors among Brazilian Adolescents from Low Human Development Index Areas: A Cluster-Randomized Controlled Trial. Int J Environ Res Public Health. 2019. 16:267. doi:10.3390/ijerph16020267. | Intervention/exposure
47 | Barbosa Filho VC, da Silva KS, Mota J, Vieira NFC, Gubert FDA, Lopes ADS. “For whom was it effective?” Moderators of the effect of a school-based intervention on potential physical activity determinants among Brazilian students. Prev Med. 2017. 97:80-85. doi:10.1016/j.ypmed.2017.01.007. | Intervention/exposure
48 | Barco Leme AC, Philippi ST, Fisberg RM. Changes in diet quality 6 and 12 months post-intervention: the Healthy Habits, Healthy Girls: a Brazilian study. Rev Nutr. 2020. 33:e1902184. doi:10.1590/1678-9865202033e190184. | Intervention/exposure
49 | Bartelink N, van Assema P, Jansen M, Savelberg H, Kremers S. The Moderating Role of the School Context on the Effects of the Healthy Primary School of the Future. Int J Environ Res Public Health. 2019. 16:2432. doi:10.3390/ijerph16132432. | Intervention/exposure, Comparator, Outcome
50 | Bartelink N, van Assema P, Kremers S, Savelberg H, Gevers D, Jansen M. Unravelling the Effects of the Healthy Primary School of the Future: For Whom and Where Is It Effective?. Nutrients. 2019. 11:2119. doi:10.3390/nu11092119. | Intervention/exposure
51 | Bartelink NHM, van Assema P, Kremers SPJ, Savelberg HHCM, Oosterhoff M, Willeboordse M, van Schayck OCP, Winkens B, Jansen MWJ. Can the Healthy Primary School of the Future offer perspective in the ongoing obesity epidemic in young children? A Dutch quasi-experimental study. BMJ Open. 2019. 9:e030676. doi:10.1136/bmjopen-2019-030676. | Study design, Outcome
52 | Bartelink NHM, van Assema P, Kremers SPJ, Savelberg HHCM, Oosterhoff M, Willeboordse M, van Schayck OCP, Winkens B, Jansen MWJ. One- and Two-Year Effects of the Healthy Primary School of the Future on Children’s Dietary and Physical Activity Behaviours: A Quasi-Experimental Study. Nutrients. 2019. 11:689. doi:10.3390/nu11030689. | Intervention/exposure
53 | Bartholomew JB, Jowers EM. Increasing frequency of lower-fat entrees offered at school lunch: an environmental change strategy to increase healthful selections. J Am Diet Assoc. 2006. 106:248-52. doi:10.1016/j.jada.2005.10.030. | Outcome
54 | Başkale H, Bahar Z. Outcomes of nutrition knowledge and healthy food choices in 5-to 6-year-old children who received a nutrition intervention based on Piaget’s theory. J Spec Pediatr Nurs. 2011. 16:263-79. doi:10.1111/j.1744-6155.2011.00300.x. | Comparator
55 | Battjes-Fries MC, Haveman-Nies A, Renes RJ, Meester HJ, van ’t Veer P. Effect of the Dutch school-based education programme ‘Taste Lessons’ on behavioural determinants of taste acceptance and healthy eating: a quasi-experimental study. Public Health Nutr. 2015. 18:2231-41. doi:10.1017/s1368980014003012. | Outcome
56 | Battjes-Fries MC, Haveman-Nies A, van Dongen EJ, Meester HJ, van den Top-Pullen R, de Graaf, K, van ’t Veer P. Effectiveness of Taste Lessons with and without additional experiential learning activities on children’s psychosocial determinants of vegetables consumption. Appetite. 2016. 105:519-26. doi:10.1016/j.appet.2016.06.016. | Outcome
57 | Bay JL, Vickers MH, Mora HA, Sloboda DhM, Morton SM. Adolescents as Agents of Healthful Change through Scientific Literacy Development: A School-University Partnership Program in New Zealand. Int J STEM Educ. 2017. 4(1):15. doi:10.1186/s40594-017-0077-0. | Study design, Intervention/exposure
58 | Bayer O, von Kries R, Strauss A, Mitschek, C, Toschke AM, Hose A, Koletzko BV. Short- and mid-term effects of a setting based prevention program to reduce obesity risk factors in children: a cluster-randomized trial. Clin Nutr. 2009. 28:122-8. doi:10.1016/j.clnu.2009.01.001. | Intervention/exposure
59 | Bayne-Smith M, Fardy PS, Azzollini A, Magel J, Schmitz KH, Agin D. Improvements in heart health behaviors and reduction in coronary artery disease risk factors in urban teenaged girls through a school-based intervention: the PATH program. Am J Public Health. 2004. 94:1538-43. doi:10.2105/ajph.94.9.1538. | Intervention/exposure
60 | Bean MK, Brady Spalding B, Theriault E, Dransfield KB, Sova A, Dunne Stewart M. Salad Bars Increased Selection and Decreased Consumption of Fruits and Vegetables 1 Month After Installation in Title I Elementary Schools: A Plate Waste Study. J Nutr Educ Behav. 2018. 50:589-597. doi:10.1016/j.jneb.2018.01.017. | Study design
61 | Bean MK, Powell P, Quinoy A, Ingersoll K, Wickham EP, 3rd, Mazzeo SE. Motivational interviewing targeting diet and physical activity improves adherence to paediatric obesity treatment: results from the MI Values randomized controlled trial. Pediatr Obes. 2015. 10:118-25. doi:10.1111/j.2047-6310.2014.226.x. | Intervention/exposure
62 | Bean MK, Theriault E, Grigsby T, Stewart MD, LaRose JG. A Cafeteria Personnel Intervention to Improve the School Food Environment. Am J Health Behav. 2019. 43:158-167. doi:10.5993/ajhb.43.1.13. | Study design, Age at intervention/exposure
63 | Beaulieu D, Godin G. Staying in school for lunch instead of eating in fast-food restaurants: results of a quasi-experimental study among high-school students. Public Health Nutr. 2012. 15:2310-9. doi:10.1017/s1368980012000821. | Outcome
64 | Beets MW, Tilley F, Kyryliuk R, Weaver RG, Moore JB, Turner-McGrievy G. Children select unhealthy choices when given a choice among snack offerings. J Acad Nutr Diet. 2014. 114:1440-6. doi:10.1016/j.jand.2014.04.022. | Intervention/exposure
65 | Beets MW, Turner-McGrievy B, Weaver RG, Huberty J, Moore JB, Ward DS, Freedman DA. Intervention leads to improvements in the nutrient profile of snacks served in afterschool programs: a group randomized controlled trial. Transl Behav Med. 2016. 6:329-38. doi:10.1007/s13142-015-0342-z. | Intervention/exposure, Outcome
66 | Beets MW, Weaver RG, Turner-McGrievy G, Huberty J, Moore JB, Ward DS, Freedman DA, Beighle A. Two-Year Healthy Eating Outcomes: An RCT in Afterschool Programs. Am J Prev Med. 2017. 53:316-326. doi:10.1016/j.amepre.2017.03.009. | Intervention/exposure
67 | Beets MW, Weaver RG, Turner-McGrievy G, Huberty J, Ward DS, Freedman D, Hutto B, Moore JB, Beighle A. Making Healthy Eating Policy Practice: A Group Randomized Controlled Trial on Changes in Snack Quality, Costs, and Consumption in After-School Programs. Am J Health Promot. 2016. 30:521-31. doi:10.4278/ajhp.141001-QUAN-486. | Intervention/exposure
68 | Belansky ES, Romaniello C, Morin C, Uyeki T, Sawyer RL, Scarbro S, Auld GW, Crane L, Reynolds K, Hamman RF, Marshall JA. Adapting and implementing a long-term nutrition and physical activity curriculum to a rural, low-income, biethnic community. J Nutr Educ Behav. 2006. 38:106-113. doi:10.1016/j.jneb.2005.11.011. | Intervention/exposure, Outcome
69 | Bell BM, Martinez L, Gotsis M, Lane HC, Davis JN, Antunez-Castillo L, Ragusa G, Spruijt-Metz D. Virtual Sprouts: A Virtual Gardening Pilot Intervention Increases Self-Efficacy to Cook and Eat Fruits and Vegetables in Minority Youth. Games Health J. 2018. 7:127-135. doi:10.1089/g4h.2017.0102. | Study design
70 | Bell L, Ullah S, Leslie E, Magarey A, Olds T, Ratcliffe J, Chen G, Miller M, Jones M, Cobiac, L. Changes in weight status, quality of life and behaviours of South Australian primary school children: results from the Obesity Prevention and Lifestyle (OPAL) community intervention program. BMC Public Health. 2019. 19:1338. doi:10.1186/s12889-019-7710-4. | Intervention/exposure
71 | Bere E, Hilsen M, Klepp KI. Effect of the nationwide free school fruit scheme in Norway. Br J Nutr. 2010. 104:589-94. doi:10.1017/s0007114510000814. | Study design
72 | Bere E, Klepp KI, Overby NC. Free school fruit: can an extra piece of fruit every school day contribute to the prevention of future weight gain? A cluster randomized trial. Food Nutr Res. 2014. 58:23194. doi:10.3402/fnr.v58.23194. | Study design
73 | Bere E, te Velde SJ, Småstuen MC, Twisk J, Klepp KI. One year of free school fruit in Norway--7 years of follow-up. Int J Behav Nutr Phys Act. 2015. 12:139. doi:10.1186/s12966-015-0301-6. | Study design
74 | Bere E, Veierød MB, Klepp KI. The Norwegian School Fruit Programme: evaluating paid vs. no-cost subscriptions. Prev Med. 2005. 41:463-70. doi:10.1016/j.ypmed.2004.11.024. | Study design
75 | Bere E, Veierød MB, Skare Ø, Klepp KI. Free School Fruit--sustained effect three years later. Int J Behav Nutr Phys Act. 2007. 4:5. doi:10.1186/1479-5868-4-5. | Study design
76 | Bergamaschi V, Olsen A, Laureati M, Zangenberg S, Pagliarini E, Bredie WLP. Variety in snack servings as determinant for acceptance in school children. Appetite. 2016. 96:628-635. doi:10.1016/j.appet.2015.08.010. | Study design, Outcome
77 | Bergmann L, Clifford D, Wolff C. Edutainment and teen modeling may spark interest in nutrition & physical activity in elementary school audiences. J Nutr Educ Behav. 2010. 42:139-41. doi:10.1016/j.jneb.2009.10.001. | Study design, Outcome
78 | Bernardo LM, Stein H, Flavin PM. The ABCDiet program: evaluation of project outcomes. School Nurse News. 2010. 27:16-9. | Study design
79 | Bersamin A, Izumi BT, Nu J, O’Brien DM, Paschall M. Strengthening adolescents’ connection to their traditional food system improves diet quality in remote Alaska Native communities: results from the Neqa Elicarvigmun Pilot Study. Transl Behav Med. 2019. 9:952-961. doi:10.1093/tbm/ibz087. | Study design
80 | Bessems KM, van Assema P, Crutzen R, Paulussen TG, de Vries NK. Examining the relationship between completeness of teachers’ implementation of the Krachtvoer healthy diet programme and changes in students’ dietary intakes. Public Health Nutr. 2013. 16:1273-80. doi:10.1017/s1368980012003618. | Study design
81 | Bevan S, Vitale T, Wengreen H. Farm field trips provide sensory-based experiences with fresh, local produce. J Nutr Educ Behav. 2012. 44:278-9. doi:10.1016/j.jneb.2011.12.002. | Study design
82 | Bevelander KE, Anschütz DJ, Engels RC. The effect of a fictitious peer on young children’s choice of familiar v. unfamiliar low- and high-energy-dense foods. Br J Nutr. 2012. 108:1126-33. doi:10.1017/s0007114511006374. | Outcome
83 | Bevelander KE, Engels RC, Anschütz DJ, Wansink B. The effect of an intervention on schoolchildren’s susceptibility to a peer’s candy intake. Eur J Clin Nutr. 2013. 67:829-35. doi:10.1038/ejcn.2013.122. | Intervention/exposure, Outcome
84 | Bhatia R, Jones P, Reicker Z. Competitive foods, discrimination, and participation in the National School Lunch Program. Am J Public Health. 2011. 101:1380-6. doi:10.2105/ajph.2011.300134. | Study design
85 | Bica LA, Jamelske EM, Lagorio CH. Increasing Fruit and Vegetable Consumption during Elementary School Snack Periods Using Incentives, Prompting and Role Modeling. J Child Nutr Manag. 2016. 40. | Study design
86 | Bica LA, Jamelske EM. USDA Fresh Fruit and Vegetable Program Creates Positive Change in Children’s Consumption and Other Behaviors Related to Eating Fruit and Vegetables. J Child Nutr Manag. 2012. 36. | Study design
87 | Bilić-Kirin V, Burazin J, Buljan V, Milicić V, Gmajnić R. Influence of health education regarding correct diet on anthropometric indexes in children. Coll Antropol. 2013. 37:1089-94. | Intervention/exposure, Comparator
88 | Bird EL, Oliver B. Pilot evaluation of a school-based health education intervention in the UK: Facts4Life. J Publ Health. 2017. 39:796-804. doi:10.1093/pubmed/fdx003. | Intervention/exposure
89 | Bisset SL, Potvin L, Daniel M, Paquette M. Assessing the impact of the primary school-based nutrition intervention Petits cuistots--parents en réseaux. Can J Public Health. 2008. 99:107-13. doi:10.1007/bf03405455. | Outcome
90 | Bjelland M, Bergh IH, Grydeland M, Klepp KI, Andersen LF, Anderssen SA, Ommundsen Y, Lien N. Changes in adolescents’ intake of sugar-sweetened beverages and sedentary behaviour: results at 8 month mid-way assessment of the HEIA study--a comprehensive, multi-component school-based randomized trial. Int J Behav Nutr Phys Act. 2011. 8:63. doi:10.1186/1479-5868-8-63. | Intervention/exposure
91 | Bjelland M, Hausken SES, Bergh IH, Grydeland M, Klepp KI, Andersen LF, Totland TH, Lien NN. Changes in adolescents’ and parents’ intakes of sugar-sweetened beverages, fruit and vegetables after 20 months: results from the HEIA study - a comprehensive, multi-component school-based randomized trial. Food & Nutrition Research. 2015. 59:25932. doi:10.3402/fnr.v59.25932. | Intervention/exposure
92 | Blitstein JL, Cates SC, Hersey J, Montgomery D, Shelley M, Hradek C, Kosa K, Bell L, Long V, Williams PA, Olson S, Singh A. Adding a Social Marketing Campaign to a School-Based Nutrition Education Program Improves Children’s Dietary Intake: A Quasi-Experimental Study. J Acad Nutr Diet. 2016. 116:1285-94. doi:10.1016/j.jand.2015.12.016. | Intervention/exposure
93 | Blom-Hoffman J, DuPaul GJ. School-based health promotion: The effects of a nutrition education program. School Psychology Review. 2003. 32:263-271. doi:10.1080/02796015.2003.12086197. | Study design
94 | Blum JE, Davee AM, Beaudoin CM, Jenkins PL, Kaley LA, Wigand DA. Reduced availability of sugar-sweetened beverages and diet soda has a limited impact on beverage consumption patterns in Maine high school youth. J Nutr Educ Behav. 2008. 40:341-7. doi:10.1016/j.jneb.2007.12.004. | Study design
95 | Boehm R, Schuknecht TJ, Cash SB. Cool Intentions: Adding Refrigerators to Elementary Classrooms Improves Fruit and Vegetable Access in a Pilot Study. J Nutr Educ Behav. 2018. 50:746-747. doi:10.1016/j.jneb.2018.04.278. | Outcome
96 | Bogart LM, Elliott MN, Cowgill BO, Klein DJ, Hawes-Dawson J, Uyeda K, Schuster MA. Two-Year BMI Outcomes From a School-Based Intervention for Nutrition and Exercise: A Randomized Trial. Pediatrics. 2016. 137(5):e20152493. doi:10.1542/peds.2015-2493. | Outcome
97 | Bogart LM, Elliott MN, Uyeda K, Hawes-Dawson J, Klein DJ, Schuster MA. Preliminary healthy eating outcomes of SNaX, a pilot community-based intervention for adolescents. J Adolesc Health. 2011. 48:196-202. doi:10.1016/j.jadohealth.2010.06.004. | Study design
98 | Bogart LM, Fu CM, Eyraud J, Cowgill BO, Hawes-Dawson J, Uyeda K, Klein DJ, Elliott MN, Schuster MA. Evaluation of the dissemination of SNaX, a middle school-based obesity prevention intervention, within a large US school district. Transl Behav Med. 2018. 8:724-732. doi:10.1093/tbm/ibx055. | Study design
99 | Bohnert AM, Ward AK. Making a Difference: Evaluating the Girls in the Game (GIG) After-School Program. J Early Adolesc. 2013. 33:104-130. doi:10.1177/0272431612466174. | Intervention/exposure
100 | Bolshakova VLJ, Gieng J, Sidhu CS. Teens-as-teachers nutrition program increases interest in science among schoolchildren and fosters self-efficacy in teens. Calif Agr. 2018. 72:135-143. doi:10.3733/ca.2018a0016. | Study design
101 | Bonsergent E, Agrinier N, Thilly N, Tessier S, Legrand K, Lecomte E, Aptel E, Hercberg S, Collin JF, Briançon S. Overweight and obesity prevention for adolescents: a cluster randomized controlled trial in a school setting. Am J Prev Med. 2013. 44:30-9. doi:10.1016/j.amepre.2012.09.055. | Intervention/exposure
102 | Bontrager Yoder AB, Liebhart JL, McCarty DJ, Meinen A, Schoeller D, Vargas C, LaRowe T. Farm to elementary school programming increases access to fruits and vegetables and increases their consumption among those with low intake. J Nutr Educ Behav. 2014. 46:341-9. doi:10.1016/j.jneb.2014.04.297. | Study design
103 | Brandstetter S, Klenk J, Berg S, Galm C, Fritz M, Peter R, Prokopchuk, D, Steiner RP, Wartha O, Steinacker J, Wabitsch M. Overweight prevention implemented by primary school teachers: a randomised controlled trial. Obes Facts. 2012. 5:1-11. doi:10.1159/000336255. | Intervention/exposure
104 | Branscum P, Sharma M, Wang LL, Wilson BR, Rojas-Guyler L. A true challenge for any superhero: an evaluation of a comic book obesity prevention program. Fam Community Health. 2013. 36:63-76. doi:10.1097/FCH.0b013e31826d7607. | Intervention/exposure
105 | Breslin G, Brennan D, Rafferty R, Gallagher AM, Hanna D. The effect of a healthy lifestyle programme on 8-9 year olds from social disadvantage. Arch Dis Child. 2012. 97:618-24. doi:10.1136/archdischild-2011-301108. | Intervention/exposure
106 | Bristow K, Jenkins S, Kelly P, Mattfeldt-Beman M. Does Tasting Local Sweet Potatoes Increase the Likelihood of Selection by High School Students?. J Child Nutr Manag. 2017. 41. | Study design
107 | Brown RD. The traffic light diet can lower risk for obesity and diabetes. NASN Sch Nurse. 2011. 26:152-4. doi:10.1177/1942602x11403491. | Study design
108 | Bruss MB, Michael TJ, Morris JR, Applegate B, Dannison L, Quitugua JA, Palacios RT, Klein DJ. Childhood obesity prevention: an intervention targeting primary caregivers of school children. Obesity (Silver Spring). 2010. 18:99-107. doi:10.1038/oby.2009.111. | Intervention/exposure
109 | Brzeziński M, Korzeniowska K, Szarejko K, Radziwiłł M, Myśliwiec M, Anyszek T, Czupryniak L, Berggren PO, Soszyński P. “PoZdro!” as an example of a successful multicenter programme for obesity management and healthy lifestyle promotion in children and adolescents - programme protocol and preliminary results from the first intervention site. Pediatr Endocrinol Diabetes Metab. 2020. 26:22-26. doi:10.5114/pedm.2020.94393. | Intervention/exposure
110 | Bucher T, Siegrist M, van der Horst K. Vegetable variety: an effective strategy to increase vegetable choice in children. Public Health Nutr. 2014. 17:1232-6. doi:10.1017/s1368980013002632. | Intervention/exposure, Outcome
111 | Burgess-Champoux TL, Chan HW, Rosen R, Marquart L, Reicks M. Healthy whole-grain choices for children and parents: a multi-component school-based pilot intervention. Public Health Nutr. 2008. 11:849-59. doi:10.1017/s1368980007001346. | Study design
112 | Burguera B, Colom A, Piñero E, Yanez A, Caimari M, Tur J, Frontera M, Couce M, Cardo E, Aguiló, A, Burguera A, Cabeza E. ACTYBOSS: activity, behavioral therapy in young subjects--after-school intervention pilot project on obesity prevention. Obes Facts. 2011. 4:400-6. doi:10.1159/000333436. | Study design, Intervention/exposure
113 | Burke RM, Meyer A, Kay C, Allensworth D, Gazmararian JA. A holistic school-based intervention for improving health-related knowledge, body composition, and fitness in elementary school students: an evaluation of the HealthMPowers program. Int J Behav Nutr Phys Act. 2014. 11:78. doi:10.1186/1479-5868-11-78. | Study design
114 | Burrows TL, Lucas H, Morgan PJ, Bray J, Collins CE. Impact Evaluation of an After-school Cooking Skills Program in a Disadvantaged Community: Back to Basics. Can J Diet Pract Res. 2015. 76:126-32. doi:10.3148/cjdpr-2015-005. | Study design
115 | Busch V, De Leeuw JR, Zuithoff NP, Van Yperen TA, Schrijvers AJ. A Controlled Health Promoting School Study in the Netherlands: Effects After 1 and 2 Years of Intervention. Health Promot Pract. 2015. 16:592-600. doi:10.1177/1524839914566272. | Intervention/exposure
116 | Busch V, van Opdorp PAJ, Broek J, Harmsen IA. Bright spots, physical activity investments that work: JUMP-in: promoting physical activity and healthy nutrition at primary schools in Amsterdam. Br J Sports Med. 2018. 52:1299-1301. doi:10.1136/bjsports-2017-097713. | Study design, Intervention/exposure
117 | Bush R, Capra S, Box S, McCallum D, Khalil S, Ostini R. An Integrated Theatre Production for School Nutrition Promotion Program. Children (Basel). 2018. 5:35. doi:10.3390/children5030035. | Study design
118 | Caballero B, Clay T, Davis SM, Ethelbah, B, Rock BH, Lohman T, Norman J, Story M, Stone EJ, Stephenson L, Stevens J. Pathways: a school-based, randomized controlled trial for the prevention of obesity in American Indian schoolchildren. Am J Clin Nutr. 2003. 78:1030-8. doi:10.1093/ajcn/78.5.1030. | Intervention/exposure
119 | Campbell AC, Barnum D, Ryden, V, Ishkanian S, Stock S, Chanoine JP. The Effectiveness of the Implementation of Healthy Buddies (TM), a School-Based, Peer-Led Health Promotion Program in Elementary Schools. Can J Diabetes. 2012. 36:181-+. doi:10.1016/j.jcjd.2012.07.001. | Intervention/exposure
120 | Campos Pastor MM, Serrano Pardo MD, Fernández Soto ML, Luna Del Castillo JD, Escobar-Jiménez, F. Impact of a ‘school-based’ nutrition intervention on anthropometric parameters and the metabolic syndrome in Spanish adolescents. Ann Nutr Metab. 2012. 61:281-8. doi:10.1159/000341495. | Study design
121 | Canterberry M, Francois S, van Hattum T, Rudov L, Carton TW. School Lunch Consumption Among 3 Food Service Providers in New Orleans. J Sch Health. 2018. 88:93-100. doi:10.1111/josh.12584. | Study design
122 | Cao Z, Hua J, Zhang D, Thapa JR, Wang S. A cohort study assessing the sustainable long-term effectiveness of a childhood-obesity intervention in China. Int J Epidemiol. 2019. 48:108-115. doi:10.1093/ije/dyy145. | Intervention/exposure
123 | Cappelli C, Pike JR, Riggs NR, Warren CM, Pentz MA. Executive function and probabilities of engaging in long-term sedentary and high calorie/low nutrition eating behaviors in early adolescence. Soc Sci Med. 2019. 237:112483. doi:10.1016/j.socscimed.2019.112483. | Study design
124 | Caraher M, Seeley A, Wu M, Lloyd S. When chefs adopt a school? An evaluation of a cooking intervention in English primary schools. Appetite. 2013. 62:50-9. doi:10.1016/j.appet.2012.11.007. | Outcome, Comparator
125 | Carraway-Stage V, Hovland J, Showers C, Díaz S, Duffrin MW. Food-based science curriculum yields gains in nutrition knowledge. J Sch Health. 2015. 85:231-40. doi:10.1111/josh.12243. | Outcome
126 | Casazza K, Ciccazzo M. The method of delivery of nutrition and physical activity information may play a role in eliciting behavior changes in adolescents. Eat Behav. 2007. 8:73-82. doi:10.1016/j.eatbeh.2006.01.007. | Intervention/exposure
127 | Caspi CE, Wang Q, Shanafelt A, Larson N, Wei S, Hearst MO, Nanney MS. School Breakfast Program Participation and Rural Adolescents’ Purchasing Behaviors in Food Stores and Restaurants. J Sch Health. 2017. 87:723-731. doi:10.1111/josh.12546. | Study design
128 | Centeio EE, McCaughtry N, Moore EWG, Kulik N, Garn A, Martin J, Shen B, Somers CL, Fahlman M. Building healthy communities: A comprehensive school health program to prevent obesity in elementary schools. Prev Med. 2018. 111:210-215. doi:10.1016/j.ypmed.2018.03.005. | Intervention/exposure
129 | Centis E, Marzocchi R, Di Luzio R, Moscatiello S, Salardi S, Villanova N, Marchesini G. A controlled, class-based multicomponent intervention to promote healthy lifestyle and to reduce the burden of childhood obesity. Pediatr Obes. 2012. 7:436-45. doi:10.1111/j.2047-6310.2012.00079.x. | Intervention/exposure
130 | Chaiopanont S. A 3-Years-Follow-Up Study of the Effect of the Weight Control Program on KAP and Behavior among Overweight and Obese School Children in Nonthaburi Province. J Med Assoc Thai. 2016. 99(8):853-60. | Study design, Intervention/exposure
131 | Chen Q, Goto K, Wolff C, Bianco-Simeral S, Gruneisen K, Gray K. Cooking up diversity. Impact of a multicomponent, multicultural, experiential intervention on food and cooking behaviors among elementary-school students from low-income ethnically diverse families. Appetite. 2014. 80:114-22. doi:10.1016/j.appet.2014.05.009. | Study design
132 | Chinchanachokchai S, Jamelske EM. Successes and Challenges in Using Group-Level Incentives to Increase Children’s Aggregate Fruit and Vegetable Consumption for Lunch in One Wisconsin Elementary School. J Child Nutr Manag. 2015. 39. | Study design
133 | Chomitz VR, McGowan RJ, Wendel JM, Williams SA, Cabral HJ, King SE, Olcott DB, Cappello M, Breen S, Hacker KA. Healthy Living Cambridge Kids: a community-based participatory effort to promote healthy weight and fitness. Obesity (Silver Spring). 2010. 18 Suppl 1:S45-53. doi:10.1038/oby.2009.431. | Study design
134 | Christensen CB, Mikkelsen BE, Toft U. The effect of introducing a free breakfast club on eating habits among students at vocational schools. BMC Public Health. 2019. 19:369. doi:10.1186/s12889-019-6701-9. | Intervention/exposure
135 | Christian MS, Evans CE, Ransley JK, Greenwood DC, Thomas JD, Cade JE. Process evaluation of a cluster randomised controlled trial of a school-based fruit and vegetable intervention: Project Tomato. Public Health Nutr. 2012. 15:459-65. doi:10.1017/s1368980011001844. | Study design
136 | Christison AL, Evans TA, Bleess BB, Wang H, Aldag JC, Binns HJ. Exergaming for Health: A Randomized Study of Community-Based Exergaming Curriculum in Pediatric Weight Management. Games Health J. 2016. 5:413-421. doi:10.1089/g4h.2015.0097. | Intervention/exposure
137 | Chu YL, Warren CA, Sceets CE, Murano P, Marquart L, Reicks M. Acceptance of two US Department of Agriculture commodity whole-grain products: a school-based study in Texas and Minnesota. J Am Diet Assoc. 2011. 111:1380-4. doi:10.1016/j.jada.2011.06.003. | Study design
138 | Cirignano SM, Fitzgerald N, Hughes LJ, Savoca L, Morgan K, Grenci A. In-Classroom Fruit and Vegetable Tastings Offer Potential for Increasing Consumption among Third through Sixth Grade Children. J Child Nutr Manag. 2014. 38. | Study design, Outcome
139 | Coborn JE, Marquart L, Burgess-Champoux TL, Rosen RA. Building Healthier Children through Family-Style Service in School Cafeterias. J Child Nutr Manag. 2015. 39. | Study design
140 | Cohen JF, Jahn JL, Richardson S, Cluggish SA, Parker E, Rimm EB. Amount of Time to Eat Lunch Is Associated with Children’s Selection and Consumption of School Meal Entrée, Fruits, Vegetables, and Milk. J Acad Nutr Diet. 2016. 116:123-8. doi:10.1016/j.jand.2015.07.019. | Study design
141 | Cohen JF, Kraak VI, Choumenkovitch SF, Hyatt RR, Economos CD. The CHANGE study: a healthy-lifestyles intervention to improve rural children’s diet quality. J Acad Nutr Diet. 2014. 114:48-53. doi:10.1016/j.jand.2013.08.014. | Intervention/exposure
142 | Cohen JF, Richardson S, Austin SB, Economos CD, Rimm EB. School lunch waste among middle school students: nutrients consumed and costs. Am J Prev Med. 2013. 44:114-21. doi:10.1016/j.amepre.2012.09.060. | Study design
143 | Cohen JF, Rimm EB, Austin SB, Hyatt RR, Kraak VI, Economos CD. A food service intervention improves whole grain access at lunch in rural elementary schools. J Sch Health. 2014. 84:212-9. doi:10.1111/josh.12133. | Intervention/exposure, Outcome
144 | Cohen JF, Smit LA, Parker E, Austin SB, Frazier AL, Economos CD, Rimm EB. Long-term impact of a chef on school lunch consumption: findings from a 2-year pilot study in Boston middle schools. J Acad Nutr Diet. 2012. 112:927-33. doi:10.1016/j.jand.2012.01.015. | Study design
145 | Cohen JFW, Richardson S, Rimm EB. Impact of the Updated USDA School Meal Standards, Chef-Enhanced Meals, and the Removal of Flavored Milk on School Meal Selection and Consumption. J Acad Nutr Diet. 2019. 119:1511-1515. doi:10.1016/j.jand.2019.04.003. | Study design
146 | Colby S, Moret L, Olfert MD, Kattelmann K, Franzen-Castle L, Riggsbee K, Payne M, Ellington A, Springer C, Allison C, Wiggins S, Butler R, Mathews D, White AA. Incorporating Technology Into the iCook 4-H Program, a Cooking Intervention for Adults and Children: Randomized Controlled Trial. JMIR Pediatr Parent. 2019. 2:e11235. doi:10.2196/11235. | Intervention/exposure, Outcome
147 | Coleman KJ, Tiller CL, Sanchez J, Heath EM, Sy O, Milliken G, Dzewaltowski DA. Prevention of the epidemic increase in child risk of overweight in low-income schools: the El Paso coordinated approach to child health. Arch Pediatr Adolesc Med. 2005. 159:217-24. doi:10.1001/archpedi.159.3.217. | Intervention/exposure
148 | Collins CE, Dewar DL, Schumacher TL, Finn T, Morgan PJ, Lubans DR. 12 month changes in dietary intake of adolescent girls attending schools in low-income communities following the NEAT Girls cluster randomized controlled trial. Appetite. 2014. 73:147-55. doi:10.1016/j.appet.2013.11.003. | Intervention/exposure
149 | Collins PH. Coordinating school efforts to help address the obesity epidemic in North Carolina. N C Med J. 2006. 67(4):293-5. | Study design
150 | Contento IR, Koch PA, Lee H, Calabrese-Barton A. Adolescents demonstrate improvement in obesity risk behaviors after completion of choice, control & change, a curriculum addressing personal agency and autonomous motivation. J Am Diet Assoc. 2010. 110:1830-9. doi:10.1016/j.jada.2010.09.015. | Intervention/exposure
151 | Contento IR, Koch PA, Lee H, Sauberli W, Calabrese-Barton A. Enhancing personal agency and competence in eating and moving: formative evaluation of a middle school curriculum--Choice, Control, and Change. J Nutr Educ Behav. 2007. 39:S179-86. doi:10.1016/j.jneb.2007.02.006. | Intervention/exposure
152 | Conway, P, Haller IV, Lutfiyya MN. School-aged overweight and obese children in rural America. Dis Mon. 2012. 58:639-50. doi:10.1016/j.disamonth.2012.08.006. | Study design
153 | Cook S, Gerber S, Heines K, Martin C, Reeder B, Schmidt S, Sidebottom E, Wimsatt S. Combating Obesity: Teaching Children to Eat Right. Ky Nurse. 2017. 65(2):10-11. | Study design
154 | Copperstone C, McNeill G, Aucott L, Jackson DM. A pilot study to improve sugar and water consumption in Maltese school children. Int J Adolesc Med Health. 2019. doi:10.1515/ijamh-2018-0134. | Study design
155 | Coppinger T, Lacey S, O’Neill C, Burns C. ‘Project Spraoi’: A randomized control trial to improve nutrition and physical activity in school children. Contemp Clin Trials Commun. 2016. 3:94-101. doi:10.1016/j.conctc.2016.04.007. | Other: Protocol
156 | Coppins DF, Margetts BM, Fa JL, Brown M, Garrett F, Huelin S. Effectiveness of a multi-disciplinary family-based programme for treating childhood obesity (the Family Project). Eur J Clin Nutr. 2011. 65:903-9. doi:10.1038/ejcn.2011.43. | Intervention/exposure
157 | Costa-Urrutia P, Álvarez-Fariña R, Abud C, Franco-Trecu V, Esparza-Romero J, López-Morales CM, Rodríguez-Arellano ME, Valle Leal J, Colistro V, Granados J. Effect of multi-component school-based program on body mass index, cardiovascular and diabetes risks in a multi-ethnic study. BMC Pediatr. 2019. 19:401. doi:10.1186/s12887-019-1787-x. | Study design, Intervention/exposure, Comparator
158 | Cotts TB, Durussel-Weston JE, Goldberg CS, Palma-Davis LM, Aaronson SM, Eagle KA. Project healthy schools: a school based health education program to prevent childhood obesity. Agro Food Industry Hi-Tech. 2007. 18(5):32-34. | Intervention/exposure
159 | Coulthard H, Palfreyman Z, Morizet D. Sensory evaluation of a novel vegetable in school age children. Appetite. 2016. 100:64-9. doi:10.1016/j.appet.2016.01.030. | Study design, Outcome
160 | Covelli MM. Efficacy of a school-based cardiac health promotion intervention program for African-American adolescents. Appl Nurs Res. 2008. 21:173-80. doi:10.1016/j.apnr.2006.12.004. | Intervention/exposure
161 | Cown MH, Grossman BM, Giraudo SQ. Nutrition Education Intervention to Improve Nutrition-Related Knowledge, Attitudes, and Behaviors for Hispanic Children. Ecol Food Nutr. 2017. 56:493-513. doi:10.1080/03670244.2017.1381606. | Study design, Intervention/exposure
162 | Craven KW, Moore JB, Swart AS, Keene AF, Kolasa KM. School-based nutrition education intervention: effect on achieving a healthy weight among overweight ninth-grade students. J Public Health Manag Pract. 2011. 17:141-6. doi:10.1097/PHH.0b013e3181df0db4. | Intervention/exposure
163 | Crepinsek MK, Singh A, Bernstein LS, McLaughlin JE. Dietary effects of universal-free school breakfast: findings from the evaluation of the school breakfast program pilot project. J Am Diet Assoc. 2006. 106:1796-803. doi:10.1016/j.jada.2006.08.013. | Intervention/exposure
164 | Crespo NC, Elder JP, Ayala GX, Slymen DJ, Campbell NR, Sallis JF, McKenzie TL, Baquero B, Arredondo EM. Results of a multi-level intervention to prevent and control childhood obesity among Latino children: the Aventuras Para Niños Study. Ann Behav Med. 2012. 43:84-100. doi:10.1007/s12160-011-9332-7. | Intervention/exposure
165 | Croker H, Lucas R, Wardle J. Cluster-randomised trial to evaluate the ‘Change for Life’ mass media/ social marketing campaign in the UK. BMC Public Health. 2012. 12:404. doi:10.1186/1471-2458-12-404. | Intervention/exposure
166 | Crouch D. How nurse intervention is tackling child obesity. Nurs Times. 2004. 100(31):26-7. | Study design
167 | Cullen KW, Zakeri I, Pryor EW, Baranowski T, Baranowski J, Watson K. Goal Setting Is Differentially Related to Change in Fruit, Juice, and Vegetable Consumption among Fourth-Grade Children. Health Educ Behav. 2004. 31:258-269. doi:10.1177/1090198103260518. | Study design, Interven/exposure
168 | Cullen KW, Watson KB, Konarik M. Differences in fruit and vegetable exposure and preferences among adolescents receiving free fruit and vegetable snacks at school. Appetite. 2009. 52:740-744. doi:10.1016/j.appet.2009.04.001. | Outcome
169 | Cunha DB, de Souza Bda S, da Veiga GV, Pereira RA, Sichieri R. Readiness for behavioral change and variation in food consumption among adolescents from a school-based community trial in Duque de Caxias, RJ. Rev Bras Epidemiol. 2015. 18:655-65. doi:10.1590/1980-5497201500030011. | Study design, Intervention/exposure
170 | Cunningham-Sabo L, Lohse B. Cooking with Kids positively affects fourth graders’ vegetable preferences and attitudes and self-efficacy for food and cooking. Child Obes. 2013. 9:549-56. doi:10.1089/chi.2013.0076. | Outcome
171 | Cunningham-Sabo L, Lohse B. Impact of a school-based cooking curriculum for fourth-grade students on attitudes and behaviors is influenced by gender and prior cooking experience. J Nutr Educ Behav. 2014. 46:110-20. doi:10.1016/j.jneb.2013.09.007. | Outcome
172 | Cunningham-Sabo L, Snyder MP, Anliker J, Thompson J, Weber JL, Thomas O, Ring K, Stewart D, Platero H, Nielsen L. Impact of the Pathways food service intervention on breakfast served in American-Indian schools. Prev Med. 2003. 37:S46-54. doi:10.1016/j.ypmed.2003.08.007. | Intervention/exposure, Outcome
173 | da Silva LS, Fisberg M, de Souza Pires MM, Nassar SM, Sottovia CB. The effectiveness of a physical activity and nutrition education program in the prevention of overweight in schoolchildren in Criciúma, Brazil. Eur J Clin Nutr. 2013. 67:1200-4. doi:10.1038/ejcn.2013.178. | Intervention/exposure
174 | D’Adamo CR, McArdle PF, Balick L, Peisach E, Ferguson T, Diehl A, Bustad, K, Bowden B, Pierce BA, Berman BM. Spice MyPlate: Nutrition Education Focusing Upon Spices and Herbs Improved Diet Quality and Attitudes Among Urban High School Students. Am J Health Promot. 2016. 30:346-56. doi:10.1177/0890117116646333. | Study design
175 | Dagger RM, Davies IG, Mackintosh KA, Stone GL, George KP, Fairclough SJ, Boddy LM. The CHANGE! Project: Changes in Body Composition and Cardiorespiratory Fitness in 10- to 11-Year-Old Children After Completing the CHANGE! Intervention. Pediatr Exerc Sci. 2018. 30:81-89. doi:10.1123/pes.2015-0200. | Intervention/exposure
176 | Dämon S, Dietrich S, Widhalm K. PRESTO--Prevention Study of Obesity: a project to prevent obesity during childhood and adolescence. Acta Paediatr Suppl. 2005. 94:47-8. doi:10.1111/j.1651-2227.2005.tb02131.x. | Intervention/exposure
177 | Damsgaard CT, Dalskov SM, Laursen RP, Ritz C, Hjorth MF, Lauritzen L, Sorensen LB, Petersen RA, Andersen MR, Stender S, Andersen R, Tetens I, Molgaard C, Astrup A, Michaelsen KF. Provision of healthy school meals does not affect the metabolic syndrome score in 8-11-year-old children, but reduces cardiometabolic risk markers despite increasing waist circumference. Br J Nutr. 2014. 112:1826-1836. doi:10.1017/s0007114514003043. | Intervention/exposure
178 | Danielzik S, Pust S, Landsberg B, Müller MJ. First lessons from the Kiel Obesity Prevention Study (KOPS). Int J Obes (Lond). 2005. 29 Suppl 2:S78-83. doi:10.1038/sj.ijo.0803099. | Intervention/exposure
179 | Danielzik S, Pust S, Müller MJ. School-based interventions to prevent overweight and obesity in prepubertal children: process and 4-years outcome evaluation of the Kiel Obesity Prevention Study (KOPS). Acta Paediatr. 2007. 96:19-25. doi:10.1111/j.1651-2227.2007.00165.x. | Intervention/exposure
180 | Davee AM, Blum JE, Devore RL, Beaudoin CM, Kaley LA, Leiter JL, Wigand DA. The vending and à la carte policy intervention in Maine public high schools. Prev Chronic Dis. 2005. 2:A14. | Outcome
181 | Davis EM, Cullen KW, Watson KB, Konarik M, Radcliffe J. A Fresh Fruit and Vegetable Program improves high school students’ consumption of fresh produce. J Am Diet Assoc. 2009. 109:1227-31. doi:10.1016/j.jada.2009.04.017. | Study design
182 | Davis JN, Martinez LC, Spruijt-Metz D, Gatto NM. LA Sprouts: A 12-Week Gardening, Nutrition, and Cooking Randomized Control Trial Improves Determinants of Dietary Behaviors. J Nutr Educ Behav. 2016. 48:2-11.e1. doi:10.1016/j.jneb.2015.08.009. | Outcome
183 | Davis JN, Ventura EE, Alexander KE, Salguero LE, Weigensberg MJ, Crespo NC, Spruijt-Metz D, Goran MI. Feasibility of a home-based versus classroom-based nutrition intervention to reduce obesity and type 2 diabetes in Latino youth. Int J Pediatr Obes. 2007. 2:22-30. doi:10.1080/17477160601133077. | Intervention/exposure
184 | Davis JN, Ventura EE, Cook LT, Gyllenhammer LE, Gatto NM. LA Sprouts: a gardening, nutrition, and cooking intervention for Latino youth improves diet and reduces obesity. J Am Diet Assoc. 2011. 111:1224-30. doi:10.1016/j.jada.2011.05.009. | Study design
185 | Davis SM, Clay T, Smyth M, Gittelsohn J, Arviso V, Flint-Wagner H, Rock BH, Brice RA, Metcalfe L, Stewart D, Vu M, Stone EJ. Pathways curriculum and family interventions to promote healthful eating and physical activity in American Indian schoolchildren. Prev Med. 2003. 37:S24-34. doi:10.1016/j.ypmed.2003.08.011. | Intervention/exposure
186 | Day ME, Strange KS, McKay HA, Naylor PJ. Action schools! BC--Healthy Eating: effects of a whole-school model to modifying eating behaviours of elementary school children. Can J Public Health. 2008. 99:328-31. doi:10.1007/bf03403766. | Study design
187 | De Bourdeaudhuij I, Verbestel V, De Henauw S, Maes L, Huybrechts I, Mårild S, Eiben G, Moreno LA, Barba G, Kovács É, Konstabel K, Tornaritis M, Gallois K, Hebestreit A, Pigeot I. Behavioural effects of a community-oriented setting-based intervention for prevention of childhood obesity in eight European countries. Main results from the IDEFICS study. Obes Rev. 2015. 16 Suppl 2:30-40. doi:10.1111/obr.12347. | Intervention/exposure
188 | De Cock N, Van Lippevelde W, Vangeel J, Notebaert M, Beullens K, Eggermont S, Deforche B, Maes L, Goossens L, Verbeken S, Moens E, Vervoort L, Braet C, Huybregts L, Kolsteren P, Van Camp J, Lachat C. Feasibility and impact study of a reward-based mobile application to improve adolescents’ snacking habits. Public Health Nutr. 2018. 21:2329-2344. doi:10.1017/s1368980018000678. | Study design
189 | de Heer HD, Koehly L, Pederson R, Morera O. Effectiveness and spillover of an after-school health promotion program for Hispanic elementary school children. Am J Public Health. 2011. 101:1907-13. doi:10.2105/ajph.2011.300177. | Intervention/exposure
190 | De Henauw S, Huybrechts I, De Bourdeaudhuij I, Bammann K, Barba G, Lissner L, Mårild S, Molnár D, Moreno LA, Pigeot I, Tornaritis M, Veidebaum T, Verbestel V, Ahrens W. Effects of a community-oriented obesity prevention programme on indicators of body fatness in preschool and primary school children. Main results from the IDEFICS study. Obes Rev. 2015. 16 Suppl 2:16-29. doi:10.1111/obr.12346. | Intervention/exposure
191 | de Moraes MM, Mediano MFF, de Souza RAG, Moura AS, da Veiga GV, Sichieri R. Discouraging soft drink consumption reduces blood glucose and cholesterol of Brazilian elementary students: Secondary analysis of a randomized controlled trial. Prev Med. 2017. 100:223-228. doi:10.1016/j.ypmed.2017.04.035. | Other: Similar trial/results using full sample in Sichieri 2009
192 | DeBar LL, Ritenbaugh C, Aickin M, Orwoll, E, Elliot D, Dickerson J, Vuckovic, N, Stevens VJ, Moe E, Irving LM. Youth: a health plan-based lifestyle intervention increases bone mineral density in adolescent girls. Arch Pediatr Adolesc Med. 2006. 160:1269-76. doi:10.1001/archpedi.160.12.1269. | Intervention/exposure
193 | DeBar LL, Schneider M, Drews KL, Ford EG, Stadler DD, Moe EL, White M, Hernandez AE, Solomon S, Jessup, A, Venditti EM. Student public commitment in a school-based diabetes prevention project: impact on physical health and health behavior. BMC Public Health. 2011. 11:711. doi:10.1186/1471-2458-11-711. | Intervention/exposure
194 | DelCampo D, Baca JS, Jimenez D, Sanchez PR, DelCampo R. Just Be It! Healthy and Fit Increases Fifth Graders’ Fruit and Vegetable Intake, Physical Activity, and Nutrition Knowledge. J Ext. 2011. 49(1). | Study design
195 | Demir Acar M, Bayat M. The Effect of Diet-Exercise Trainings Provided to Overweight and Obese Teenagers through Creative Drama on Their Knowledge, Attitude, and Behaviors. Child Obes. 2019. 15:93-104. doi:10.1089/chi.2018.0046. | Intervention/exposure
196 | Derri V, Aggeloussis N, Petraki C. Health-Related Fitness and Nutritional Practices: Can They Be Enhanced in Upper Elementary School Students?. Phys Educat. 2004. 61(1):35-44. | Intervention/exposure
197 | DeVault N, Kennedy T, Hermann J, Mwavita M, Rask, P, Jaworsky A. It’s all about kids: preventing overweight in elementary school children in Tulsa, OK. J Am Diet Assoc. 2009. 109:680-7. doi:10.1016/j.jada.2008.12.021. | Study design
198 | Dewar DL, Morgan PJ, Plotnikoff RC, Okely AD, Collins CE, Batterham M, Callister R, Lubans DR. The nutrition and enjoyable activity for teen girls study: a cluster randomized controlled trial. Am J Prev Med. 2013. 45:313-7. doi:10.1016/j.amepre.2013.04.014. | Intervention/exposure
199 | Diao H, Wang H, Yang L, Li T. The impacts of multiple obesity-related interventions on quality of life in children and adolescents: a randomized controlled trial. Health Qual Life Outcomes. 2020. 18:213. doi:10.1186/s12955-020-01459-0. | Intervention/exposure
200 | Djalalinia S, Ramezani-Tehrani F, Malekafzali H, Hejazi F, Peykari N. Development and evaluation of a nutritional health program for adolescents. Iran J Nurs Midwifery Res. 2013. 18:425-7. | Intervention/exposure
201 | Dominguez PR, Gamiz F, Gil M, Moreno H, Zamora RM, Gallo M, de Brugada I. Providing choice increases children’s vegetable intake. Food Quality and Preference. 2013. 30:108-113. doi:10.1016/j.foodqual.2013.05.006. | Study design
202 | Dooyema CA, Belay B, Foltz JL, Williams N, Blanck HM. The childhood obesity research demonstration project: a comprehensive community approach to reduce childhood obesity. Child Obes. 2013. 9:454-9. doi:10.1089/chi.2013.0060. | Study design
203 | Dority BL, McGarvey MG, Kennedy, PF. Marketing Foods and Beverages in Schools: The Effect of School Food Policy on Students’ Overweight Measures. J Publ Pol Market. 2010. 29:204-218. doi:10.1509/jppm.29.2.204. | Study design
204 | Drozd M, Romaniello C, Wearner R, Carter V, Auld GW. Benefits of a nutrition book bag program. J Nutr Educ Behav. 2006. 38:259-61. doi:10.1016/j.jneb.2006.01.015. | Study design, Outcome
205 | Dubuy V, De Cocker K, De Bourdeaudhuij I, Maes L, Seghers J, Lefevre J, De Martelaer K, Brooke H, Cardon G. Evaluation of a real world intervention using professional football players to promote a healthy diet and physical activity in children and adolescents from a lower socio-economic background: a controlled pretest-posttest design. BMC Public Health. 2014. 14:457. doi:10.1186/1471-2458-14-457. | Intervention/exposure
206 | Duncan MJ, Eyre E, Bryant E, Clarke N, Birch S, Staples V, Sheffield D. The impact of a school-based gardening intervention on intentions and behaviour related to fruit and vegetable consumption in children. J Health Psychol. 2015. 20:765-73. doi:10.1177/1359105315573445. | Study design
207 | Duncan S, McPhee JC, Schluter PJ, Zinn C, Smith R, Schofield G. Efficacy of a compulsory homework programme for increasing physical activity and healthy eating in children: the healthy homework pilot study. Int J Behav Nutr Phys Act. 2011. 8:127. doi:10.1186/1479-5868-8-127. | Intervention/exposure
208 | Duncan S, Stewart T, McPhee J, Borotkanics R, Prendergast K, Zinn C, Meredith-Jones K, Taylor R, McLachlan C, Schofield G. Efficacy of a compulsory homework programme for increasing physical activity and improving nutrition in children: a cluster randomised controlled trial. Int J Behav Nutr Phys Act. 2019. 16:80. doi:10.1186/s12966-019-0840-3. | Intervention/exposure
209 | Dunker KLL, Claudino AM. Preventing weight-related problems among adolescent girls: A cluster randomized trial comparing the Brazilian ‘New Moves’ program versus observation. Obes Res Clin Pract. 2018. 12:102-115. doi:10.1016/j.orcp.2017.07.004. | Intervention/exposure
210 | Dunn C, Jayaratne KSU, Baughman K, Levine K. Teaching Basic Cooking Skills: Evaluation of the North Carolina Extension “Cook Smart, Eat Smart” Program. J Fam Consum Sci. 2014. 106(1):39-46. | Study design, Age at intervention/exposure
211 | Dunton GF, Liao Y, Grana R, Lagloire R, Riggs N, Chou CP, Robertson T. State-wide dissemination of a school-based nutrition education programme: a RE-AIM (Reach, Efficacy, Adoption, Implementation, Maintenance) analysis. Public Health Nutr. 2014. 17:422-30. doi:10.1017/s1368980012005186. | Study design
212 | Dupart G, Berry DC, D’Auria J, Sharpe L, McDonough L, Houser M, Flanary S, Koppelberger S. A Nurse-Led and Teacher-Assisted Adolescent Healthy Weight Program to Improve Health Behaviors in the School Setting. J Sch Nurs. 2019. 35:178-188. doi:10.1177/1059840517744020. | Study design
213 | Duster T, Waters A. Engaged Learning across the Curriculum: The Vertical Integration of Food for Thought. Lib Educ. 2006. 92(2):42-47. | Study design
214 | Dwyer J, Cosentino C, Li D, Feldman H, Garceau, A, Stevens M, Perry C, Hoelscher D, Webber LS, Zive M. Evaluating school-based interventions using the Healthy Eating Index. J Am Diet Assoc. 2002. 102:257-9. doi:10.1016/s0002-8223(02)90061-1. | Intervention/exposure
215 | Dwyer JT, Michell P, Cosentino C, Webber L, Seed JM, Hoelscher D, Snyder MP, Stevens M, Nader P. Fat-sugar see-saw in school lunches: impact of a low fat intervention. J Adolesc Health. 2003. 32:428-35. doi:10.1016/s1054-139x(03)00053-3. | Outcome
216 | Dzewaltowski DA, Estabrooks PA, Welk G, Hill J, Milliken G, Karteroliotis K, Johnston JA. Healthy youth places: a randomized controlled trial to determine the effectiveness of facilitating adult and youth leaders to promote physical activity and fruit and vegetable consumption in middle schools. Health Educ Behav. 2009. 36:583-600. doi:10.1177/1090198108314619. | Intervention/exposure
217 | Dzielska A, Mazur J, Nałęcz, H, Oblacińska A, Fijałkowska A. Importance of Self-Efficacy in Eating Behavior and Physical Activity Change of Overweight and Non-Overweight Adolescent Girls Participating in Healthy Me: A Lifestyle Intervention with Mobile Technology. Nutrients. 2020. 12:2128. doi:10.3390/nu12072128. | Intervention/exposure
218 | Eagle TF, Gurm R, Smith CA, Corriveau N, DuRussell-Weston J, Palma-Davis L, Aaronson S, Goldberg C, Kline-Rogers E, Cotts T, Jackson EA, Eagle KA. A middle school intervention to improve health behaviors and reduce cardiac risk factors. Am J Med. 2013. 126:903-8. doi:10.1016/j.amjmed.2013.04.019. | Study design, Intervention/exposure
219 | Economos CD, Hyatt RR, Goldberg JP, Must A, Naumova EN, Collins JJ, Nelson ME. A community intervention reduces BMI z-score in children: Shape Up Somerville first year results. Obesity (Silver Spring). 2007. 15:1325-36. doi:10.1038/oby.2007.155. | Intervention/exposure
220 | Eilat-Adar S, Koren-Morag N, Siman-Tov M, Livne I, Altmen H. School-based intervention to promote eating daily and healthy breakfast: a survey and a case-control study. Eur J Clin Nutr. 2011. 65:203-9. doi:10.1038/ejcn.2010.247. | Study design
221 | El Rayess F, Gandhi M, Mennillo H. Mark, Set, Go! School-Based Nutrition and Physical Activity Program: A Five-Year Evaluation. R I Med J (2013). 2017. 100(2):39-44. | Study design, Intervention/exposure
222 | Elbel B, Mijanovich T, Abrams C, Cantor J, Dunn L, Nonas C, Cappola K, Onufrak S, Park S. A water availability intervention in New York City public schools: influence on youths’ water and milk behaviors. Am J Public Health. 2015. 105:365-72. doi:10.2105/ajph.2014.302221. | Intervention/exposure
223 | Eliakim A, Nemet D, Balakirski Y, Epstein Y. The effects of nutritional-physical activity school-based intervention on fatness and fitness in preschool children. J Pediatr Endocrinol Metab. 2007. 20:711-8. doi:10.1515/jpem.2007.20.6.711. | Intervention/exposure
224 | Elinder LS, Heinemans N, Hagberg J, Quetel AK, Hagströmer M. A participatory and capacity-building approach to healthy eating and physical activity-SCIP-school: a 2-year controlled trial. Int J Behav Nutr Phys Act. 2012. 9:145. doi:10.1186/1479-5868-9-145. | Intervention/exposure
225 | Ellsworth D, Ernst J, Snelling A. A Mobile Farmers’ Market Brings Nutrition Education to Low-Income Students. Health Educ. 2015. 115:171-177. doi:10.1108/HE-03-2014-0031 | Study design, Outcome
226 | Elsbernd SL, Reicks MM, Mann TL, Redden JP, Mykerezi E, Vickers ZM. Serving vegetables first: A strategy to increase vegetable consumption in elementary school cafeterias. Appetite. 2016. 96:111-115. doi:10.1016/j.appet.2015.09.001. | Study design
227 | Engels HJ, Gretebeck RJ, Gretebeck KA, Jiménez L. Promoting healthful diets and exercise: efficacy of a 12-week after-school program in urban African Americans. J Am Diet Assoc. 2005. 105:455-9. doi:10.1016/j.jada.2004.12.003. | Study design
228 | Ensaff H, Crawford R, Russell JM, Barker ME. Preparing and sharing food: a quantitative analysis of a primary school-based food intervention. J Publ Health. 2017. 39:567-573. doi:10.1093/pubmed/fdw086. | Outcome
229 | Epstein-Solfield A, Arango C, Ogan D, Stendell-Hollis N. The Effects of a Nutrition Education Intervention on Third- and Fifth-Grade Students’ Fruit and Vegetable Knowledge, Preference And Consumption. J Child Nutr Manag. 2018. 42. | Study design
230 | Eriksen K, Haraldsdóttir J, Pederson R, Flyger HV. Effect of a fruit and vegetable subscription in Danish schools. Public Health Nutr. 2003. 6:57-63. doi:10.1079/phn2002356. | Comparator
231 | Ermetici F, Zelaschi RF, Briganti S, Dozio E, Gaeta M, Ambrogi F, Pelissero G, Tettamanti G, Corsi Romanelli MM, Carruba M, Morricone L, Malavazos AE. Association between a school-based intervention and adiposity outcomes in adolescents: The Italian “EAT” project. Obesity (Silver Spring). 2016. 24:687-95. doi:10.1002/oby.21365. | Study design
232 | Eskicioglu P, Halas J, Sénéchal M, Wood L, McKay E, Villeneuve S, Shen GX, Dean H, McGavock JM. Peer mentoring for type 2 diabetes prevention in first nations children. Pediatrics. 2014. 133:e1624-31. doi:10.1542/peds.2013-2621. | Intervention/exposure
233 | Evans A, Ranjit N, Rutledge R, Medina J, Jennings R, Smiley A, Stigler M, Hoelscher D. Exposure to multiple components of a garden-based intervention for middle school students increases fruit and vegetable consumption. Health Promot Pract. 2012. 13:608-16. doi:10.1177/1524839910390357. | Study design
234 | Evenhuis IJ, Jacobs SM, Vyth EL, Veldhuis L, de Boer MR, Seidell JC, Renders CM. The Effect of Supportive Implementation of Healthier Canteen Guidelines on Changes in Dutch School Canteens and Student Purchase Behaviour. Nutrients. 2020. 12:2419. doi:10.3390/nu12082419. | Study design
235 | Ezendam NP, Brug J, Borsboom, G, van Empelen P, Oenema A. Differential effects of the computer-tailored FATaintPHAT programme on dietary behaviours according to sociodemographic, cognitive and home environmental factors. Public Health Nutr. 2014. 17:431-9. doi:10.1017/s1368980012005344. | Intervention/exposure
236 | Ezendam NP, Brug J, Oenema A. Evaluation of the Web-based computer-tailored FATaintPHAT intervention to promote energy balance among adolescents: results from a school cluster randomized trial. Arch Pediatr Adolesc Med. 2012. 166:248-55. doi:10.1001/archpediatrics.2011.204. | Intervention/exposure
237 | Fagan HB, King RL, Laurent M, Taylor DS. An obesity prevention program in a Delaware elementary school. Del Med J. 2010. 82(4):133-6. | Study design
238 | Fahlman MM, Dake JA, McCaughtry N, Martin J. A pilot study to examine the effects of a nutrition intervention on nutrition knowledge, behaviors, and efficacy expectations in middle school children. J Sch Health. 2008. 78:216-22. doi:10.1111/j.1746-1561.2008.00289.x. | Study design
239 | Fairclough SJ, Hackett AF, Davies IG, Gobbi R, Mackintosh KA, Warburton GL, Stratton G, van Sluijs EM, Boddy LM. Promoting healthy weight in primary school children through physical activity and nutrition education: a pragmatic evaluation of the CHANGE! randomised intervention study. BMC Public Health. 2013. 13:626. doi:10.1186/1471-2458-13-626. | Intervention/exposure
240 | Fassnacht DB, Ali K, Silva C, Gonçalves S, Machado PP. Use of text messaging services to promote health behaviors in children. J Nutr Educ Behav. 2015. 47:75-80. doi:10.1016/j.jneb.2014.08.006. | Intervention/exposure, Comparator
241 | Favuzzi N, Trerotoli P, Forte MG, Bartolomeo N, Serio G, Lagravinese D, Vino F. Evaluation of an Alimentary Education Intervention on School Canteen Waste at a Primary School in Bari, Italy. Int J Environ Res Public Health. 2020. 17(7):2558. doi:10.3390/ijerph17072558. | Study design
242 | Feng D, Song H, Esperat MC, Black I. A Multicomponent Intervention Helped Reduce Sugar-Sweetened Beverage Intake in Economically Disadvantaged Hispanic Children. Am J Health Promot. 2016. 30:594-603. doi:10.4278/ajhp.140801-QUAN-384. | Intervention/exposure
243 | Fernandes PS, Bernardo CDO, Campos RM, Vasconcelos FA. Evaluating the effect of nutritional education on the prevalence of overweight/obesity and on foods eaten at primary schools. J Pediatr (Rio J). 2009. 85:315-21. doi:10.2223/jped.1917. | Study design
244 | Ferreira CM, Goldszmidt R, Andrade EB. The short- and long-term impact of an incentive intervention on healthier eating: a quasi-experiment in primary- and secondary-school cafeterias in Brazil. Public Health Nutr. 2019. 22:1675-1685. doi:10.1017/s1368980019000223. | Study design
245 | Ferreira JO, Jardim PC, Peixoto Mdo R. Evaluation of project promoting health in adolescents. Rev Saude Publica. 2013. 47:257-65. doi:10.1590/s0034-8910.2013047004120. | Intervention/exposure, Publication language
246 | Fisher MC, Villegas E, Sutter C, Musaad SM, Koester B, Fiese BH. Sprouts Growing Healthy Habits: Curriculum Development and Pilot Study. Front Public Health. 2019. 7:65. doi:10.3389/fpubh.2019.00065. | Outcome
247 | Fitzgibbon ML, Stolley MR, Schiffer LA, Braunschweig CL, Gomez, SL, Van Horn L, Dyer AR. Hip-Hop to Health Jr. Obesity Prevention Effectiveness Trial: postintervention results. Obesity (Silver Spring). 2011. 19:994-1003. doi:10.1038/oby.2010.314. | Intervention/exposure, Age at intervention/exposure
248 | Flores R, Eckart J, Nash K, Kwitowski E. Implementation of Vegan Entrées in a Washington, D.C. Elementary School. J Child Nutr Manag. 2019. 43. | Study design
249 | Fogarty AW, Antoniak M, Venn AJ, Davies L, Goodwin A, Salfield N, Britton JR, Lewis SA. A natural experiment on the impact of fruit supplementation on asthma symptoms in children. Eur Respir J. 2009. 33:481-5. doi:10.1183/09031936.00162907. | Outcome
250 | Fogarty AW, Antoniak M, Venn AJ, Davies L, Goodwin A, Salfield N, Stocks J, Britton J, Lewis SA. Does participation in a population-based dietary intervention scheme have a lasting impact on fruit intake in young children?. Int J Epidemiol. 2007. 36:1080-5. doi:10.1093/ije/dym133. | Study design
251 | Foley BC, Shrewsbury VA, Hardy LL, Flood VM, Byth K, Shah S. Evaluation of a peer education program on student leaders’ energy balance-related behaviors. BMC Public Health. 2017. 17:695. doi:10.1186/s12889-017-4707-8. | Study design
252 | Folkvord F, Anastasiadou DT, Anschütz D. Memorizing fruit: The effect of a fruit memory-game on children’s fruit intake. Prev Med Rep. 2017. 5:106-111. doi:10.1016/j.pmedr.2016.12.001. | Intervention/exposure
253 | Folkvord F, Anschütz D, Geurts M. Watching TV Cooking Programs: Effects on Actual Food Intake Among Children. J Nutr Educ Behav. 2020. 52:3-9. doi:10.1016/j.jneb.2019.09.016. | Intervention/exposure
254 | Folta SC, Kude JF, Goldberg JP, Hyatt RR, Must A, Naumova EN, Nelson ME, Economos CD. Changes in diet and physical activity resulting from the Shape Up Somerville community intervention. BMC Pediatr. 2013. 13:157. doi:10.1186/1471-2431-13-157. | Intervention/exposure
255 | Fornari LS, Giuliano I, Azevedo F, Pastana A, Vieira C, Caramelli B. Children First Study: how an educational program in cardiovascular prevention at school can improve parents’ cardiovascular risk. Eur J Prev Cardiol. 2013. 20:301-9. doi:10.1177/2047487312437617. | Intervention/exposure
256 | Foster GD, Linder B, Baranowski T, Cooper DM, Goldberg L, Harrell JS, Kaufman F, Marcus MD, Treviño RP, Hirst K. A school-based intervention for diabetes risk reduction. N Engl J Med. 2010. 363:443-53. doi:10.1056/NEJMoa1001933. | Intervention/exposure
257 | Francis M, Nichols SS, Dalrymple N. The effects of a school-based intervention programme on dietary intakes and physical activity among primary-school children in Trinidad and Tobago. Public Health Nutr. 2010. 13:738-47. doi:10.1017/s1368980010000182. | Intervention/exposure
258 | Franckle RL, Falbe J, Gortmaker S, Barrett JL, Giles C, Ganter C, Blaine RE, Buszkiewicz J, Taveras EM, Kwass JA, Land T, Davison KK. Student obesity prevalence and behavioral outcomes for the massachusetts childhood obesity research demonstration project. Obesity (Silver Spring). 2017. 25:1175-1182. doi:10.1002/oby.21867. | Intervention/exposure
259 | Fraser C, Lewis K, Manby M. Steps in the Right Direction, Against the Odds, An Evaluation of a Community-Based Programme Aiming to Reduce Inactivity and Improve Health and Morale in Overweight and Obese School-Age Children. Child Soc. 2012. 26:124-137. doi:10.1111/j.1099-0860.2010.00329.x. | Study design, Intervention/exposure
260 | Freeman R, Oliver M. Do school break-time policies influence child dental health and snacking behaviours? An evaluation of a primary school programme. Br Dent J. 2009. 206:619-25; discussion 616. doi:10.1038/sj.bdj.2009.518. | Study design
261 | French SA, Jeffery RW, Story M, Breitlow KK, Baxter JS, Hannan P, Snyder MP. Pricing and promotion effects on low-fat vending snack purchases: the CHIPS Study. Am J Public Health. 2001. 91:112-7. doi:10.2105/ajph.91.1.112. | Intervention/exposure, Age at intervention/exposure
262 | French SA. Pricing effects on food choices. J Nutr. 2003. 133:841S-843S. doi:10.1093/jn/133.3.841S. | Study design
263 | French SA. Public health strategies for dietary change: schools and workplaces. J Nutr. 2005. 135:910-2. doi:10.1093/jn/135.4.910. | Study design, Publication status
264 | Frenn M, Malin S, Bansal N, Delgado M, Greer Y, Havice M, Ho M, Schweizer H. Addressing health disparities in middle school students’ nutrition and exercise. J Community Health Nurs. 2003. 20:1-14. doi:10.1207/s15327655jchn2001_01. | Outcome
265 | Frenn M, Malin S, Bansal NK. Stage-based interventions for low-fat diet with middle school students. J Pediatr Nurs. 2003. 18:36-45. doi:10.1053/jpdn.2003.6. | Intervention/exposure, Outcome
266 | Frenn M, Malin S, Brown RL, Greer, Y, Fox, J, Greer J, Smyczek S. Changing the tide: an Internet/video exercise and low-fat diet intervention with middle-school students. Appl Nurs Res. 2005. 18:13-21. doi:10.1016/j.apnr.2004.04.003. | Intervention/exposure, Outcome
267 | Frenn M, Malin S. Diet and exercise in low-income culturally diverse middle school students. Public Health Nurs. 2003. 20:361-8. doi:10.1046/j.1525-1446.2003.20504.x. | Study design
268 | Fulkerson JA, French SA, Story M, Nelson H, Hannan PJ. Promotions to increase lower-fat food choices among students in secondary schools: description and outcomes of TACOS (Trying Alternative Cafeteria Options in Schools). Public Health Nutr. 2004. 7:665-74. doi:10.1079/phn2003594. | Study design
269 | Funderburk K, Struempler B, Parmer SM, Griffin JB. Body Quest Parent: A Text Message Parent Education Intervention to Supplement a School-Based Obesity Prevention Initiative for Third-Graders. J Nutr Educ Behav. 2018. 50:415-417.e1. doi:10.1016/j.jneb.2018.01.007. | Study design, Outcome
270 | Fung C, Kuhle S, Lu C, Purcell M, Schwartz M, Storey K, Veugelers PJ. From “best practice” to “next practice”: the effectiveness of school-based health promotion in improving healthy eating and physical activity and preventing childhood obesity. Int J Behav Nutr Phys Act. 2012. 9:27. doi:10.1186/1479-5868-9-27. | Intervention/exposure
271 | Gao Y, Huang Y, Zhang Y, Liu F, Feng CX, Liu, T, Li C, Ling DD, Mu Y, Tarver SL, Wang M, Sun W. Evaluation of fast food behavior in pre-school children and parents following a one-year intervention with nutrition education. Int J Environ Res Public Health. 2014. 11:6780-90. doi:10.3390/ijerph110706780. | Country
272 | García-Vázquez J. Effects of the School for Health network on students’ behaviour in Asturias (Spain). Health Promot Int. 2017. 32:271-279. doi:10.1093/heapro/dau076. | Intervention/exposure
273 | Gatto NM, Martinez LC, Spruijt-Metz D, Davis JN. RETRACTED: LA sprouts randomized controlled nutrition and gardening program reduces obesity and metabolic risk in latino youth (Retracted article. See vol. 23, pg. 2522, 2015). Obesity. 2015. 23:1244-1251. doi:10.1002/oby.21077. | Retraction notice
274 | Gatto NM, Ventura EE, Cook LT, Gyllenhammer LE, Davis JN. LA Sprouts: a garden-based nutrition intervention pilot program influences motivation and preferences for fruits and vegetables in Latino youth. J Acad Nutr Diet. 2012. 112:913-20. doi:10.1016/j.jand.2012.01.014. | Intervention/exposure, Outcome
275 | Gentile DA, Welk G, Eisenmann JC, Reimer RA, Walsh DA, Russell DW, Callahan R, Walsh M, Strickland S, Fritz K. Evaluation of a multiple ecological level child obesity prevention program: Switch what you Do, View, and Chew. BMC Med. 2009. 7:49. doi:10.1186/1741-7015-7-49. | Intervention/exposure
276 | Ghaffari M, Tavassoli E, Esmaillzadeh A, Hassanzadeh A. Effect of Health Belief Model based intervention on promoting nutritional behaviors about osteoporosis prevention among students of female middle schools in Isfahan, Iran. J Educ Health Promot. 2012. 1:14. doi:10.4103/2277-9531.98572. | Outcome
277 | Ghammam R, Maatoug J, Zammit N, Kebaili R, Boughammoura L, Al’Absi M, Lando H, Ghannem H. Long term effect of a school based intervention to prevent chronic diseases in Tunisia, 2009-2015. Afr Health Sci. 2017. 17:1137-1148. doi:10.4314/ahs.v17i4.23. | Intervention/exposure
278 | Gharlipour Z, Ghaffari M, Hoseini, Z, Heidarabadi AB, Tavassoli E, Hozuri M, Jang SA, Reisi M, Sahraiyan M. Investigation of educational intervention based on Theory of Planned Behavior on breakfast consumption among middle school students of Qom City in 2012. J Educ Health Promot. 2015. 4:39. doi:10.4103/2277-9531.157224. | Outcome
279 | Gibbs L, Staiger PK, Johnson B, Block K, Macfarlane S, Gold L, Kulas J, Townsend M, Long C, Ukoumunne O. Expanding children’s food experiences: the impact of a school-based kitchen garden program. J Nutr Educ Behav. 2013. 45:137-46. doi:10.1016/j.jneb.2012.09.004. | Study design
280 | Giles CM, Kenney EL, Gortmaker SL, Lee RM, Thayer JC, Mont-Ferguson H, Cradock AL. Increasing water availability during afterschool snack: evidence, strategies, and partnerships from a group randomized trial. Am J Prev Med. 2012. 43:S136-42. doi:10.1016/j.amepre.2012.05.013. | Intervention/exposure
281 | Glasson C, Chapman K, Gander K, Wilson T, James E. The efficacy of a brief, peer-led nutrition education intervention in increasing fruit and vegetable consumption: a wait-list, community-based randomised controlled trial. Public Health Nutr. 2012. 15:1318-26. doi:10.1017/s1368980012000043. | Age at intervention/exposure
282 | Glasson C, Chapman K, Wilson T, Gander K, Hughes C, Hudson N, James E. Increased exposure to community-based education and ‘below the line’ social marketing results in increased fruit and vegetable consumption. Public Health Nutr. 2013. 16:1961-70. doi:10.1017/s1368980013001614. | Intervention/exposure, Age at intervention/exposure
283 | Godfrey JR. National school lunch nutrition standards: making kids hungry or healthy?. Child Obes. 2013. 9:71-3. doi:10.1089/chi.2013.9103. | Study design
284 | Goggans MH, Lambert L, Chang Y. Offer versus Serve or Serve Only: Does Service Method Affect Elementary Children’s Fruit and Vegetable Consumption?. J Child Nutr Manag. 2011. 35. | Study design
285 | Golley R, Baines E, Bassett P, Wood L, Pearce J, Nelson M. School lunch and learning behaviour in primary schools: an intervention study. Eur J Clin Nutr. 2010. 64:1280-8. doi:10.1038/ejcn.2010.150. | Outcome
286 | Gombosi RL, Olasin RM, Bittle JL. Tioga County Fit for Life: a primary obesity prevention project. Clin Pediatr (Phila). 2007. 46:592-600. doi:10.1177/0009922807299315. | Study design
287 | Gómez, SF, Casas Esteve R, Subirana I, Serra-Majem, L, Fletas Torrent M, Homs C, Bawaked RA, Estrada L, Fíto M, Schröder H. Effect of a community-based childhood obesity intervention program on changes in anthropometric variables, incidence of obesity, and lifestyle choices in Spanish children aged 8 to 10 years. Eur J Pediatr. 2018. 177:1531-1539. doi:10.1007/s00431-018-3207-x. | Intervention/exposure
288 | González-Jiménez E, Cañadas GR, Fernández-Castillo R, Cañadas-De la Fuente GA. Analysis of the life-style and dietary habits of a population of adolescents. Nutr Hosp. 2013. 28:1937-42. doi:10.3305/nh.2013.28.6.6850. | Study design
289 | Gorely T, Nevill ME, Morris JG, Stensel DJ, Nevill A. Effect of a school-based intervention to promote healthy lifestyles in 7-11 year old children. Int J Behav Nutr Phys Act. 2009. 6:5. doi:10.1186/1479-5868-6-5. | Intervention/exposure
290 | Górnicka M, Wiszniewska Z, Wojtaś M, Wawrzyniak A, Kanigowska A. Assessing schoolchildren’s ability to make proper use of a food and nutrition pyramid. Rocz Panstw Zakl Hig. 2013. 64(2):149-54. | Outcome
291 | Graf C, Koch B, Falkowski G, Jouck S, Christ H, Staudenmaier K, Tokarski W, Gerber A, Predel HG, Dordel S. School-based prevention: effects on obesity and physical performance after 4 years. J Sports Sci. 2008. 26:987-94. doi:10.1080/02640410801930176. | Intervention/exposure
292 | Graf C, Koch B, Falkowski G, Jouck S, Christ H, Stauenmaier K, Bjarnason-Wehrens B, Tokarski W, Dordel S, Predel HG. Effects of A School-Based Intervention on BMI and Motor Abilities in Childhood. J Sports Sci Med. 2005. 4(3):291-9. | Intervention/exposure
293 | Grassi E, Evans A, Ranjit N, Pria SD, Messina L. Using a mixed-methods approach to measure impact of a school-based nutrition and media education intervention study on fruit and vegetable intake of Italian children. Public Health Nutr. 2016. 19:1952-63. doi:10.1017/s1368980015003729. | Study design
294 | Gray C, Lytle LA, Mays R, Taylor G, Perry C, Story M. Foods on students’ trays when they leave the cafeteria line as a proxy for foods eaten at lunch in a school-based study. J Am Diet Assoc. 2002. 102:407-9. doi:10.1016/s0002-8223(02)90094-5. | Study design
295 | Gray HL, Contento IR, Koch PA. Linking implementation process to intervention outcomes in a middle school obesity prevention curriculum, ‘Choice, Control and Change’. Health Educ Res. 2015. 30:248-61. doi:10.1093/her/cyv005. | Intervention/exposure
296 | Greece JA, Kratze A, DeJong W, Cozier, YC, Quatromoni PA. Body Mass Index and Sociodemographic Predictors of School Lunch Purchase Behavior during a Year-Long Environmental Intervention in Middle School. Behav Sci (Basel). 2015. 5:324-40. doi:10.3390/bs5020324. | Study design
297 | Greening L, Harrell KT, Low AK, Fielder CE. Efficacy of a school-based childhood obesity intervention program in a rural southern community: TEAM Mississippi Project. Obesity (Silver Spring). 2011. 19:1213-9. doi:10.1038/oby.2010.329. | Intervention/exposure
298 | Greenwood, B, Ralston PA, Young-Clark I, Cornille T, Brown LL, Davis KE, Salley TJ, Goehrig MH, Mullins AP, Gaskins DJ. Nutrition Education Initiative: A School-Based Program to Promote Healthy Eating Practices of Preadolescents. J Fam Consum Sci. 2009. 101(2):47-52. | Study design
299 | Greve J, Heinesen E. Evaluating the impact of a school-based health intervention using a randomized field experiment. Econ Hum Biol. 2015. 18:41-56. doi:10.1016/j.ehb.2015.03.005. | Intervention/exposure
300 | Grey M, Berry, D, Davidson M, Galasso P, Gustafson E, Melkus G. Preliminary testing of a program to prevent type 2 diabetes among high-risk youth. J Sch Health. 2004. 74:10-5. doi:10.1111/j.1746-1561.2004.tb06595.x. | Intervention/exposure
301 | Grey M, Jaser SS, Holl MG, Jefferson, V, Dziura J, Northrup, V. A multifaceted school-based intervention to reduce risk for type 2 diabetes in at-risk youth. Prev Med. 2009. 49:122-8. doi:10.1016/j.ypmed.2009.07.014. | Intervention/exposure
302 | Grubliauskiene A, Verhoeven M, Dewitte S. The joint effect of tangible and non-tangible rewards on healthy food choices in children. Appetite. 2012. 59:403-8. doi:10.1016/j.appet.2012.06.003. | Outcome
303 | Grydeland M, Bergh, IH, Bjelland M, Lien N, Andersen LF, Ommundsen Y, Klepp KI, Anderssen SA. Intervention effects on physical activity: the HEIA study - a cluster randomized controlled trial. Int J Behav Nutr Phys Act. 2013. 10:17. doi:10.1186/1479-5868-10-17. | Intervention/exposure
304 | Grydeland M, Bjelland M, Anderssen SA, Klepp KI, Bergh IH, Andersen LF, Ommundsen Y, Lien N. Effects of a 20-month cluster randomised controlled school-based intervention trial on BMI of school-aged boys and girls: the HEIA study. Br J Sports Med. 2014. 48:768-73. doi:10.1136/bjsports-2013-092284. | Intervention/exposure
305 | Guagliano JM, Rosenkranz RR. Physical activity promotion and obesity prevention in Girl Scouts: Scouting Nutrition and Activity Program+. Pediatr Int. 2012. 54:810-5. doi:10.1111/j.1442-200X.2012.03681.x. | Intervention/exposure
306 | Gucciardi E, Nagel R, Szwiega S, Chow, BYY, Barker CE, Nezon J, Bian H, Butler A. Evaluation of a Sensory-Based Food Education Program on Fruit and Vegetable Consumption among Kindergarten Children. J Child Nutr Manag. 2019. 43. | Study design
307 | Gur K, Erol S, Kadioglu H, Ergun A, Boluktas R. The impact on adolescents of a Transtheoretical Model-based programme on fruit and vegetable consumption. Public Health Nutr. 2019. 22:2500-2508. doi:10.1017/s136898001900137x. | Study design
308 | Haerens L, De Bourdeaudhuij I, Maes L, Vereecken C, Brug J, Deforche B. The effects of a middle-school healthy eating intervention on adolescents’ fat and fruit intake and soft drinks consumption. Public Health Nutr. 2007. 10:443-9. doi:10.1017/s1368980007219652. | Intervention/exposure
309 | Haerens L, Deforche B, Maes L, Brug J, Vandelanotte C, De Bourdeaudbuij I. A computer-tailored dietary fat intake intervention for adolescents: Results of a randomized controlled trial. Annals of Behavioral Medicine. 2007. 34:253-262. doi:10.1007/bf02874550. | Outcome
310 | Haerens L, Deforche B, Maes L, Cardon G, Stevens V, De Bourdeaudhuij I. Evaluation of a 2-year physical activity and healthy eating intervention in middle school children. Health Educ Res. 2006. 21:911-21. doi:10.1093/her/cyl115. | Intervention/exposure
311 | Haerens L, Deforche B, Maes L, Stevens V, Cardon G, De Bourdeaudhuij I. Body mass effects of a physical activity and healthy food intervention in middle schools. Obesity (Silver Spring). 2006. 14:847-54. doi:10.1038/oby.2006.98. | Intervention/exposure
312 | Hagedorn RL, White JA, Franzen-Castle L, Colby SE, Kattelmann KK, White AA, Olfert MD. Teens Implementing a Childhood Obesity Prevention Program in the Community: Feasibility and Perceptions of a Partnership with HSTA and iCook 4-H. Int J Environ Res Public Health. 2018. 15:934. doi:10.3390/ijerph15050934. | Study design
313 | Haghani S, Shahnazi H, Hassanzadeh A. Effects of Tailored Health Education Program on Overweight Elementary School Students’ Obesity-Related Lifestyle: A School-Based Interventional Study. Oman Med J. 2017. 32:140-147. doi:10.5001/omj.2017.25. | Intervention/exposure
314 | Hamdi N, Ellison B, McCaffrey J, Metcalfe JJ, Hoffman A, Haywood P, Prescott MP. Implementation of a Multi-Component School Lunch Environmental Change Intervention to Improve Child Fruit and Vegetable Intake: A Mixed-Methods Study. Int J Environ Res Public Health. 2020. 17:3971. doi:10.3390/ijerph17113971. | Study design
315 | Hanbazaza MA, Triador L, Ball GD, Farmer A, Maximova K, First Nation A, Willows ND. The Impact of School Gardening on Cree Children’s Knowledge and Attitudes toward Vegetables and Fruit. Can J Diet Pract Res. 2015. 76:133-9. doi:10.3148/cjdpr-2015-007. | Study design
316 | Hanks AS, Just DR, Brumberg A. Marketing Vegetables in Elementary School Cafeterias to Increase Uptake. Pediatrics. 2016. 138:e20151720. doi:10.1542/peds.2015-1720. | Comparator
317 | Hanks AS, Just DR, Smith LE, Wansink B. Healthy convenience: nudging students toward healthier choices in the lunchroom. J Public Health (Oxf). 2012. 34:370-6. doi:10.1093/pubmed/fds003. | Study design
318 | Hanks AS, Just DR, Wansink B. Smarter lunchrooms can address new school lunchroom guidelines and childhood obesity. J Pediatr. 2013. 162:867-9. doi:10.1016/j.jpeds.2012.12.031. | Study design
319 | Hannan P, French SA, Story M, Fulkerson JA. A pricing strategy to promote sales of lower fat foods in high school cafeterias: acceptability and sensitivity analysis. Am J Health Promot. 2002. 17:1-6, ii. doi:10.4278/0890-1171-17.1.Tahp-1. | Study design
320 | Hao M, Han W, Yamauchi T. Short-Term and Long-Term Effects of a Combined Intervention of Rope Skipping and Nutrition Education for Overweight Children in Northeast China. Asia Pac J Public Health. 2019. 31:348-358. doi:10.1177/1010539519848275. | Outcome
321 | Harley A, Lemke M, Brazauskas R, Carnegie NB, Bokowy L, Kingery L. Youth Chef Academy: Pilot Results From a Plant-Based Culinary and Nutrition Literacy Program for Sixth and Seventh Graders. J Sch Health. 2018. 88:893-902. doi:10.1111/josh.12703. | Study design
322 | Harnack L, Himes JH, Anliker J, Clay T, Gittelsohn J, Jobe JB, Ring K, Snyder P, Thompson J, Weber JL. Intervention-related bias in reporting of food intake by fifth-grade children participating in an obesity prevention study. Am J Epidemiol. 2004. 160:1117-21. doi:10.1093/aje/kwh328. | Intervention/exposure
323 | Harnack L, Snyder P, Story M, Holliday R, Lytle L, Neumark-Sztainer D. Availability of a la carte food items in junior and senior high schools: a needs assessment. J Am Diet Assoc. 2000. 100:701-3. doi:10.1016/s0002-8223(00)00204-2. | Study design
324 | Harrabi I, Maatoug J, Gaha M, Kebaili R, Gaha R, Ghannem H. School-based Intervention to Promote Healthy Lifestyles in Sousse, Tunisia. Indian J Community Med. 2010. 35:94-9. doi:10.4103/0970-0218.62581. | Intervention/exposure
325 | Harrell TK, Davy BM, Stewart JL, King DS. Effectiveness of a school-based intervention to increase health knowledge of cardiovascular disease risk factors among rural Mississippi middle school children. South Med J. 2005. 98:1173-80. doi:10.1097/01.smj.0000182499.59715.07. | Intervention/exposure
326 | Harrington KF, Kohler CL, McClure LA, Franklin FA. Fourth graders’ reports of fruit and vegetable intake at school lunch: does treatment assignment affect accuracy?. J Am Diet Assoc. 2009. 109:36-44. doi:10.1016/j.jada.2008.10.006. | Outcome
327 | Haß J, Lischetzke T, Hartmann M. Does the distribution frequency matter? A subgroup specific analysis of the effectiveness of the EU School Fruit and Vegetable Scheme in Germany comparing twice and thrice weekly deliveries. Public Health Nutr. 2018. 21:1375-1387. doi:10.1017/s1368980017003949. | Study design
328 | Hatzis CM, Papandreou C, Kafatos AG. School health education programs in Crete: evaluation of behavioural and health indices a decade after initiation. Prev Med. 2010. 51:262-7. doi:10.1016/j.ypmed.2010.05.015. | Study design, Intervention/exposure
329 | Hawkins KR, Burton JH, Apolzan JW, Thomson JL, Williamson DA, Martin CK. Efficacy of a school-based obesity prevention intervention at reducing added sugar and sodium in children’s school lunches: the LA Health randomized controlled trial. Int J Obes (Lond). 2018. 42:1845-1852. doi:10.1038/s41366-018-0214-y. | Intervention/exposure
330 | Healy N, Joram E, Matvienko O, Woolf S, Knesting K. Impact of an Intuitive Eating Education Program on High School Students’ Eating Attitudes. Health Educ. 2015. 115:214-228. doi:10.1108/HE-03-2014-0043. | Outcome
331 | Heath EM, Coleman KJ. Evaluation of the institutionalization of the coordinated approach to child health (CATCH) in a U.S./Mexico border community. Health Educ Behav. 2002. 29:444-60. doi:10.1177/109019810202900405. | Intervention/exposure
332 | Hector D, Edwards S, Gale J, Ryan H. Achieving equity in Crunch&Sip(®): a pilot intervention of supplementary free fruit and vegetables in NSW classrooms. Health Promot J Austr. 2017. 28:238-242. doi:10.1071/he16095. | Study design
333 | Heller E, Johnson T. Healthy Foods in Schools. NCSL Legisbrief. 2016. 24(22):1-2. | Study design
334 | Hendy HM, Williams KE, Camise TS. Kid’s Choice Program improves weight management behaviors and weight status in school children. Appetite. 2011. 56:484-94. doi:10.1016/j.appet.2011.01.024. | Intervention/exposure
335 | Henry C, Whiting SJ, Finch SL, Zello GA, Vatanparast, H. Impact of replacing regular chocolate milk with the reduced-sugar option on milk consumption in elementary schools in Saskatoon, Canada. Appl Physiol Nutr Metab. 2016. 41:511-5. doi:10.1139/apnm-2015-0501. | Study design
336 | Henry C, Whiting SJ, Phillips T, Finch SL, Zello GA, Vatanparast, H. Impact of the removal of chocolate milk from school milk programs for children in Saskatoon, Canada. Appl Physiol Nutr Metab. 2015. 40:245-50. doi:10.1139/apnm-2014-0242. | Study design
337 | Heo M, Jimenez CC, Lim J, Isasi CR, Blank AE, Lounsbury DW, Fredericks L, Bouchard M, Faith MS, Wylie-Rosett J. Effective nationwide school-based participatory extramural program on adolescent body mass index, health knowledge and behaviors. BMC Pediatr. 2018. 18:7. doi:10.1186/s12887-017-0975-9. | Intervention/exposure
338 | Herbert PC, Lohrmann DK, Seo DC, Stright AD, Kolbe LJ. Effectiveness of the energize elementary school program to improve diet and exercise. J Sch Health. 2013. 83:780-6. doi:10.1111/josh.12094. | Intervention/exposure
339 | Hermann JR, Parker SP, Brown BJ, Siewe YJ, Denney BA, Walker SJ. After-school gardening improves children’s reported vegetable intake and physical activity. J Nutr Educ Behav. 2006. 38:201-2. doi:10.1016/j.jneb.2006.02.002. | Study design
340 | Heuser L, Herbig S. The childhood obesity challenge--Tap into Fitness: program overview and results analysis. J Ky Med Assoc. 2008. 106(3):118-22. | Study design, Intervention/exposure
341 | Hildebrand DA, Jacob T, Garrard-Foster D. Food and Fun for Everyone: a community nutrition education program for third- and fourth-grade students suitable for school wellness programs. J Nutr Educ Behav. 2012. 44:93-5. doi:10.1016/j.jneb.2011.03.138. | Study design, Intervention/exposure
342 | Himes JH, Ring K, Gittelsohn J, Cunningham-Sabo L, Weber J, Thompson J, Harnack L, Suchindran C. Impact of the Pathways intervention on dietary intakes of American Indian schoolchildren. Prev Med. 2003. 37:S55-61. doi:10.1016/j.ypmed.2003.08.003. | Intervention/exposure
343 | Hoelscher DM, Feldman HA, Johnson CC, Lytle LA, Osganian SK, Parcel GS, Kelder SH, Stone EJ, Nader PR. School-based health education programs can be maintained over time: results from the CATCH Institutionalization study. Prev Med. 2004. 38:594-606. doi:10.1016/j.ypmed.2003.11.017. | Intervention/exposure, Outcome
344 | Hoelscher DM, Springer AE, Ranjit N, Perry CL, Evans AE, Stigler M, Kelder SH. Reductions in child obesity among disadvantaged school children with community involvement: the Travis County CATCH Trial. Obesity (Silver Spring). 2010. 18 Suppl 1:S36-44. doi:10.1038/oby.2009.430. | Intervention/exposure
345 | Hoffman PK, Davey CS, Larson N, Grannon KY, Hanson C, Nanney MS. School district wellness policy quality and weight-related outcomes among high school students in Minnesota. Health Educ Res. 2016. 31:234-46. doi:10.1093/her/cyv101. | Study design
346 | Holben DH, Weber MA. Implementation and Evaluation of Farm-to-YOUth! A Fruit and Vegetable Produce Education Program. J Child Nutr Manag. 2018. 42. | Study design, Outcome
347 | Hollar D, Lombardo M, Lopez-Mitnik G, Hollar TL, Almon M, Agatston AS, Messiah SE. Effective multi-level, multi-sector, school-based obesity prevention programming improves weight, blood pressure, and academic performance, especially among low-income, minority children. J Health Care Poor Underserved. 2010. 21:93-108. doi:10.1353/hpu.0.0304. | Intervention/exposure
348 | Hollar D, Messiah SE, Lopez-Mitnik G, Hollar TL, Almon M, Agatston AS. Healthier options for public schoolchildren program improves weight and blood pressure in 6- to 13-year-olds. J Am Diet Assoc. 2010. 110:261-7. doi:10.1016/j.jada.2009.10.029. | Intervention/exposure
349 | Holzmann SL, Schäfer H, Groh, G, Plecher DA, Klinker G, Schauberger G, Hauner H, Holzapfel C. Short-Term Effects of the Serious Game “Fit, Food, Fun” on Nutritional Knowledge: A Pilot Study among Children and Adolescents. Nutrients. 2019. 11:2031. doi:10.3390/nu11092031. | Outcome
350 | Höner O, Demetriou Y. Effects of a health-promotion programme in sixth grade German students’ physical education. Eur J Sport Sci. 2014. 14 Suppl 1:S341-51. doi:10.1080/17461391.2012.704080. | Intervention/exposure
351 | Hopkins LC, Holloman C, Melnyk B, Fristad M, Goodway JD, Kennel JA, Eneli I, Gunther C. Participation in structured programming may prevent unhealthy weight gain during the summer in school-aged children from low-income neighbourhoods: feasibility, fidelity and preliminary efficacy findings from the Camp NERF study. Public Health Nutr. 2019. 22:1100-1112. doi:10.1017/s1368980018003403. | Intervention/exposure
352 | Hopper A. Coast Medical Alliance fights obesity-related diseases with its community health project in Gulfport schools. J Miss State Med Assoc. 2003. 44(2):61-3. | Study design
353 | Hopper CA, Munoz, KD, Gruber MB, Nguyen KP. The effects of a family fitness program on the physical activity and nutrition behaviors of third-grade children. Res Q Exerc Sport. 2005. 76:130-9. doi:10.1080/02701367.2005.10599275. | Intervention/exposure
354 | Horne PJ, Tapper K, Lowe CF, Hardman CA, Jackson MC, Woolner J. Increasing children’s fruit and vegetable consumption: a peer-modelling and rewards-based intervention. Eur J Clin Nutr. 2004. 58:1649-60. doi:10.1038/sj.ejcn.1602024. | Study design
355 | Hovdenak IM, Stea TH, Twisk J, Te Velde SJ, Klepp KI, Bere E. Tracking of fruit, vegetables and unhealthy snacks consumption from childhood to adulthood (15 year period): does exposure to a free school fruit programme modify the observed tracking?. Int J Behav Nutr Phys Act. 2019. 16:22. doi:10.1186/s12966-019-0783-8. | Study design
356 | Hovland JA, McLeod SM, Duffrin MW Johanson G, Berryman DE. School-based screening of the dietary intakes of third graders in rural Appalachian Ohio. J Sch Health. 2010. 80:536-43. doi:10.1111/j.1746-1561.2010.00539.x. | Study design
357 | Hovland JA, Carraway-Stage VG, Cela A, Collins C, Díaz, SR, Collins A, Duffrin MW. Food-Based Science Curriculum Increases 4th Graders Multidisciplinary Science Knowledge. J Food Sci. 2013. 12:81-86. doi:10.1111/1541-4329.12016. | Outcome
358 | Hrafnkelsson H, Magnusson KT, Thorsdottir I, Johannsson E, Sigurdsson EL. Result of school-based intervention on cardiovascular risk factors. Scand J Prim Health Care. 2014. 32:149-55. doi:10.3109/02813432.2014.982363. | Intervention/exposure
359 | Hu C, Ye D, Li Y, Huang Y, Li L, Gao Y, Wang S. Evaluation of a kindergarten-based nutrition education intervention for pre-school children in China. Public Health Nutr. 2010. 13:253-60. doi:10.1017/s1368980009990814. | Country
360 | Huang SH, Weng KP, Hsieh KS, Ou SF, Lin CC, Chien KJ, Liu PY, Ho TY. Effects of a classroom-based weight-control intervention on cardiovascular disease in elementary-school obese children. Acta Paediatr Taiwan. 2007. 48:201-6. doi:10.7097/APT.200708.0201. | Intervention/exposure, Country, Outcome
361 | Hughes RJ, Edwards KL, Clarke GP, Evans CE, Cade JE, Ransley JK. Childhood consumption of fruit and vegetables across England: a study of 2306 6-7-year-olds in 2007. Br J Nutr. 2012. 108:733-42. doi:10.1017/s0007114511005939. | Study design
362 | Hunsberger M, McGinnis P, Smith J, Beamer BA, O’Malley J. Elementary school children’s recess schedule and dietary intake at lunch: a community-based participatory research partnership pilot study. BMC Public Health. 2014. 14:156. doi:10.1186/1471-2458-14-156. | Study design
363 | Hutchinson J, Christian MS, Evans CE, Nykjaer C, Hancock N, Cade JE. Evaluation of the impact of school gardening interventions on children’s knowledge of and attitudes towards fruit and vegetables. A cluster randomised controlled trial. Appetite. 2015. 91:405-14. doi:10.1016/j.appet.2015.04.076. | Outcome, Other: Intake results in other publication
364 | Huys N, Cardon G, De Craemer M, Hermans N, Renard S, Roesbeke M, Stevens W, De Lepeleere S, Deforche B. Effect and process evaluation of a real-world school garden program on vegetable consumption and its determinants in primary schoolchildren. PLoS One. 2019. 14:e0214320. doi:10.1371/journal.pone.0214320. | Study design
365 | IlløKken KE, Bere E, Øverby NC, Høiland R, Petersson KO, Vik FN. Intervention study on school meal habits in Norwegian 10-12-year-old children. Scand J Public Health. 2017. 45:485-491. doi:10.1177/1403494817704108. | Intervention/exposure
366 | In-Iw S, Saetae T, Manaboriboon B. The Effectiveness of School-Based Nutritional Education Program among Obese Adolescents: A Randomized Controlled Study. Int J Pediatr. 2012. 2012:608920. doi:10.1155/2012/608920. | Intervention/exposure, Health status
367 | Irwin BR, Speechley M, Wilk P, Clark AF, Gilliland JA. Promoting healthy beverage consumption habits among elementary school children: results of the Healthy Kids Community Challenge ‘Water Does Wonders’ interventions in London, Ontario. Can J Public Health. 2020. 111:257-268. doi:10.17269/s41997-019-00262-9. | Study design
368 | Irwin C, Irwin R, Richey P, Miller M, Boddie J, Dickerson T. Get fit with the Grizzlies: a community-school-home initiative to fight childhood obesity led by a professional sports organization. Stud Health Technol Inform. 2012. 172:163-7. doi:10.3233/978-1-61499-088-8-163 | Study design, Intervention/exposure
369 | Ishikawa M, Kubota N, Kudo K, Meadows M, Umezawa A, Otaa T. Changes in Children’s Consumption of Tomatoes through a School Lunch Programme Developed by Agricultural High-School Students. Health Educ J. 2013. 72:545-554. doi:10.1177/0017896912450904. | Study design
370 | Isoldi KK, Dolar V. Cooking Up Energy: A Culinary Education Program for Children with Parent Outreach. Am J Health Behav. 2020. 44:543-558. doi:10.5993/ajhb.44.5.1. | Study design
371 | Iversen CS, Nigg C, Titchenal CA. The impact of an elementary after-school nutrition and physical activity program on children’s fruit and vegetable intake, physical activity, and body mass index: Fun 5. Hawaii Med J. 2011. 70:37-41. | Study design
372 | Iward JL, Hoelscher DM, Briley ME. Food choices of third-grade children in Texas. J Am Diet Assoc. 2002. 102:409-12. doi:10.1016/s0002-8223(02)90095-7. | Study design
373 | Jacobson J. Fighting obesity, locally and nationally. Am J Nurs. 2012. 112:17. doi:10.1097/01.NAJ.0000415110.15993.a1. | Study design
374 | Jaenke RL, Collins CE, Morgan PJ, Lubans DR, Saunders KL, Warren JM. The impact of a school garden and cooking program on boys’ and girls’ fruit and vegetable preferences, taste rating, and intake. Health Educ Behav. 2012. 39:131-41. doi:10.1177/1090198111408301. | Study design
375 | Jago R, McMurray RG, Drews KL, Moe EL, Murray T, Pham TH, Venditti EM, Volpe SL. HEALTHY intervention: fitness, physical activity, and metabolic syndrome results. Med Sci Sports Exerc. 2011. 43:1513-22. doi:10.1249/MSS.0b013e31820c9797. | Intervention/exposure
376 | Jakubowski TL, Perron T, Farrell A, Kenner C, Hullings C. The Smart Nutrition and Conditioning for Kids (SNACK) Program: An Approach to Increasing Nutrition Knowledge of Second-Grade Students. MCN Am J Matern Child Nurs. 2018. 43:278-284. doi:10.1097/nmc.0000000000000463. | Outcome
377 | Jamelske E, Bica LA, McCarty DJ, Meinen A. Preliminary findings from an evaluation of the USDA Fresh Fruit and Vegetable Program in Wisconsin schools. WMJ. 2008. 107(5):225-30. | Study design
378 | Jamelske EM, Bica LA. Impact of the USDA Fresh Fruit and Vegetable Program on Children’s Consumption. J Child Nutr Manag. 2012. 36. | Study design
379 | James J, Thomas P, Kerr D. Preventing childhood obesity: two year follow-up results from the Christchurch obesity prevention programme in schools (CHOPPS). BMJ. 2007. 335:762. doi:10.1136/bmj.39342.571806.55. | Outcome
380 | Jan S, Bellman C, Barone J, Jessen L, Arnold M. Shape it up: a school-based education program to promote healthy eating and exercise developed by a health plan in collaboration with a college of pharmacy. J Manag Care Pharm. 2009. 15:403-13. doi:10.18553/jmcp.2009.15.5.403. | Study design, Outcome
381 | Jansen E, Mulkens S, Jansen A. How to promote fruit consumption in children. Visual appeal versus restriction. Appetite. 2010. 54:599-602. doi:10.1016/j.appet.2010.02.012. | Intervention/exposure
382 | Jarpe-Ratner E, Folkens S, Sharma S, Daro D, Edens NK. An Experiential Cooking and Nutrition Education Program Increases Cooking Self-Efficacy and Vegetable Consumption in Children in Grades 3-8. J Nutr Educ Behav. 2016. 48:697-705.e1. doi:10.1016/j.jneb.2016.07.021. | Study design
383 | Jenike MR, Lutz K, Vaaler C, Szabo S, Mielke JE. Thinking About Food, Drink, and Nutrition among Ninth Graders in the United States Midwest: A Case Study of Local Partnership Research. Human Organization. 2011. 70:139-152. doi:10.17730/humo.70.2.n477783327l05247. | Study design
384 | Jensen BW, von Kappelgaard LM, Nielsen BM, Husby, I, Bugge A, El-Naaman B, Andersen LB, Trolle E, Heitmann BL. Intervention effects on dietary intake among children by maternal education level: results of the Copenhagen School Child Intervention Study (CoSCIS). Br J Nutr. 2015. 113:963-74. doi:10.1017/s0007114515000021. | Intervention/exposure
385 | Jimenez MM, Receveur O, Trifonopoulos M, Kuhnlein H, Paradis G, Macaulay AC. Comparison of the dietary intakes of two different groups of children (grades 4 to 6) before and after the Kahnawake Schools Diabetes Prevention Project. J Am Diet Assoc. 2003. 103:1191-4. doi:10.1016/s0002-8223(03)00980-5. | Study design
386 | Jimoh F, Lund EK, Harvey LJ, Frost C, Lay, WJ, Roe MA, Berry R, Finglas PM. Comparing Diet and Exercise Monitoring Using Smartphone App and Paper Diary: A Two-Phase Intervention Study. JMIR Mhealth Uhealth. 2018. 6:e17. doi:10.2196/mhealth.7702. | Study design, Intervention/exposure
387 | Johnson BA, Kremer PJ, Swinburn BA, de Silva-Sanigorski AM. Multilevel analysis of the Be Active Eat Well intervention: environmental and behavioural influences on reductions in child obesity risk. Int J Obes (Lond). 2012. 36:901-7. doi:10.1038/ijo.2012.23. | Intervention/exposure
388 | Johnson CC, Myers L, Mundorf, AR, O’Malley K, Spruance LA, Harris DM. Lunch Salad Bars in New Orleans’ Middle and High Schools: Student Intake of Fruit and Vegetables. Int J Environ Res Public Health. 2017. 14:415. doi:10.3390/ijerph14040415. | Study design
389 | Johnson RK, Frary C, Wang MQ. The nutritional consequences of flavored-milk consumption by school-aged children and adolescents in the United States. J Am Diet Assoc. 2002. 102:853-6. doi:10.1016/s0002-8223(02)90192-6. | Study design
390 | Johnston CA, Tyler C, Fullerton G, McFarlin BK, Poston WS, Haddock, CK, Reeves RS, Foreyt JP. Effects of a school-based weight maintenance program for Mexican-American children: results at 2 years. Obesity (Silver Spring). 2010. 18:542-7. doi:10.1038/oby.2009.241. | Intervention/exposure
391 | Johnston CA, Tyler C, McFarlin BK, Poston WSC, Haddock K, Reeves R, Foreyt JP. Weight loss in overweight Mexican American children: A randomized, controlled trial. Pediatrics. 2007. 120:E1450-E1457. doi:10.1542/peds.2006-3321. | Intervention/exposure
392 | Johnston CA, Moreno JP, El-Mubasher A, Gallagher M, Tyler C, Woehler D. Impact of a School-Based Pediatric Obesity Prevention Program Facilitated by Health Professionals. J Sch Health. 2013. 83(3):171-181. doi:10.1111/josh.12013. | Outcome
393 | Jones BA, Madden GJ, Wengreen HJ. The FIT Game: preliminary evaluation of a gamification approach to increasing fruit and vegetable consumption in school. Prev Med. 2014. 68:76-9. doi:10.1016/j.ypmed.2014.04.015. | Study design
394 | Jones E, Zuest L, Bulger S, Elliott E, Cho K, Lilly C. Initial Findings of a Multicomponent School Health Intervention in Rural Appalachia: The Greenbrier CHOICES Project. Health Educ Behav. 2020. 47:332-343. doi:10.1177/1090198119897612. | Intervention/exposure
395 | Jones M, Dailami N, Weitkamp E, Salmon D, Kimberlee R, Morley A, Orme J. Food sustainability education as a route to healthier eating: evaluation of a multi-component school programme in English primary schools. Health Educ Res. 2012. 27:448-58. doi:10.1093/her/cys016. | Study design
396 | Jones M, Pitt H, Oxford L, Bray I, Kimberlee R, Orme J. Association between Food for Life, a Whole Setting Healthy and Sustainable Food Programme, and Primary School Children’s Consumption of Fruit and Vegetables: A Cross-Sectional Study in England. Int J Environ Res Public Health. 2017. 14:639. doi:10.3390/ijerph14060639. | Study design
397 | Jones M, Taylor Lynch K, Kass AE, Burrows A, Williams J, Wilfley DE, Taylor CB. Healthy weight regulation and eating disorder prevention in high school students: a universal and targeted Web-based intervention. J Med Internet Res. 2014. 16:e57. doi:10.2196/jmir.2995. | Study design
398 | Jones S, Spence M, Hardin S, Clemente N, Schoch A. Youth Can! results of a pilot trial to improve the school food environment. J Nutr Educ Behav. 2011. 43:284-7. doi:10.1016/j.jneb.2010.10.005. | Study design
399 | Jones-Taylor M. Early Care and Education Settings Are Vital for Childhood Obesity Prevention. Child Obes. 2015. 11:489-90. doi:10.1089/chi.2015.0156. | Study design
400 | Jønsson SR, Angka S, Olsen K, Tolver A, Olsen A. Repeated exposure to vegetable-enriched snack bars may increase children’s liking for the bars - but not for the vegetables. Appetite. 2019. 140:1-9. doi:10.1016/j.appet.2019.05.002. | Intervention/exposure, Outcome
401 | Jordan KC, Erickson ED, Cox, R, Carlson EC, Heap, E, Friedrichs M, Moyer-Mileur LJ, Shen S, Mihalopoulos NL. Evaluation of the Gold Medal Schools program. J Am Diet Assoc. 2008. 108:1916-20. doi:10.1016/j.jada.2008.08.002. | Intervention/exposure
402 | Joulaei H, Nwagwu, E, Nasihatkon A, Azadbahkt L, Shenavar R, Keshtkar V, Ahmadi SM. To assess the effects of nutritional intervention based on advocacy approach on malnutrition status among school-aged children in Shiraz. J Res Med Sci. 2013. 18(9):739-45. | Study design
403 | Joyner D, Wengreen HJ, Aguilar SS, Spruance LA, Morrill BA, Madden GJ. The FIT Game III: Reducing the Operating Expenses of a Game-Based Approach to Increasing Healthy Eating in Elementary Schools. Games Health J. 2017. 6:111-118. doi:10.1089/g4h.2016.0096. | Study design
404 | Jung LH, Choi JH, Bang HM, Shin JH, Heo YR. A comparison of two differential methods for nutrition education in elementary school: lecture-and experience-based learning program. Nutr Res Pract. 2015. 9:87-91. doi:10.4162/nrp.2015.9.1.87. | Comparator
405 | Just D, Price J. Default options, incentives and food choices: evidence from elementary-school children. Public Health Nutr. 2013. 16:2281-8. doi:10.1017/s1368980013001468. | Study design
406 | Just DR, Wansink B, Hanks AS. Chefs move to schools. A pilot examination of how chef-created dishes can increase school lunch participation and fruit and vegetable intake. Appetite. 2014. 83:242-7. doi:10.1016/j.appet.2014.08.033. | Study design
407 | Kafatos A, Manios Y, Moschandreas J. Health and nutrition education in primary schools of Crete: follow-up changes in body mass index and overweight status. Eur J Clin Nutr. 2005. 59:1090-2. doi:10.1038/sj.ejcn.1602216. | Intervention/exposure
408 | Kafatos I, Manios Y, Moschandreas J, Kafatos A. Health and nutrition education program in primary schools of Crete: changes in blood pressure over 10 years. Eur J Clin Nutr. 2007. 61:837-45. doi:10.1038/sj.ejcn.1602584. | Intervention/exposure
409 | Kain J, Concha F, Moreno L, Leyton B. School-based obesity prevention intervention in Chilean children: effective in controlling, but not reducing obesity. J Obes. 2014. 2014:618293. doi:10.1155/2014/618293. | Intervention/exposure
410 | Kain J, Leyton B, Cerda R, Vio F, Uauy R. Two-year controlled effectiveness trial of a school-based intervention to prevent obesity in Chilean children. Public Health Nutr. 2009. 12:1451-61. doi:10.1017/s136898000800428x. | Intervention/exposure
411 | Kain J, Uauy R, Albala, Vio F, Cerda R, Leyton B. School-based obesity prevention in Chilean primary school children: methodology and evaluation of a controlled study. Int J Obes Relat Metab Disord. 2004. 28:483-93. doi:10.1038/sj.ijo.0802611. | Intervention/exposure
412 | Kalantari N, Mohammadi NK, Rafieifar S, Eini-Zinab H, Aminifard A, Malmir H, Ashoori N, Abdi S, Gholamalizadeh M, Doaei S. Indicator for Success of Obesity Reduction Programs in Adolescents: Body Composition or Body Mass Index? Evaluating a School-based Health Promotion Project after 12 Weeks of Intervention. Int J Prev Med. 2017. 8:73. doi:10.4103/ijpvm.IJPVM_306_16. | Intervention/exposure
413 | Kandiah J, Jones C. Nutrition Knowledge and Food Choices of Elementary School Children. Early Child Dev Care. 2002. 172:269-73. doi:10.1080/03004430212123. | Comparator, Outcome
414 | Kararo MJ, Orvis KS, Knobloch NA. Eat Your Way to Better Health: Evaluating a Garden-based Nutrition Program for Youth. Horttechnology. 2016. 26:663-668. doi:10.21273/horttech03225-16. | Study design
415 | Karczewski SA, Carter JS, DeCator DD. The Role of Ethnicity in School-Based Obesity Intervention for School-Aged Children: A Pilot Evaluation. J Sch Health. 2016. 86:778-786. doi:10.1111/josh.12433. | Intervention/exposure
416 | Kastorini CM, Lykou A, Yannakoulia M, Petralias A, Riza E, Linos A. The influence of a school-based intervention programme regarding adherence to a healthy diet in children and adolescents from disadvantaged areas in Greece: the DIATROFI study. J Epidemiol Community Health. 2016. 70:671-7. doi:10.1136/jech-2015-205680. | Study design, Intervention/exposure
417 | Kebaili R, Harrabi I, Maatoug J, Ghammam R, Slim S, Ghannem H. School-based intervention to promote healthy nutrition in Sousse, Tunisia. Int J Adolesc Med Health. 2014. 26:253-8. doi:10.1515/ijamh-2013-0306. | Study design
418 | Keihner A, Rosen N, Wakimoto P, Goldstein L, Sugerman S, Hudes M, Ritchie L, McDevitt K. Impact of California Children’s Power Play! Campaign on Fruit and Vegetable Intake and Physical Activity among Fourth- and Fifth-Grade Students. Am J Health Promot. 2017. 31:189-191. doi:10.4278/ajhp.141125-ARB-592. | Intervention/exposure
419 | Keihner AJ, Meigs R, Sugerman S, Backman D, Garbolino T, Mitchell P. The Power Play! Campaign’s School Idea & Resource Kits improve determinants of fruit and vegetable intake and physical activity among fourth- and fifth-grade children. J Nutr Educ Behav. 2011. 43:S122-9. doi:10.1016/j.jneb.2011.02.010. | Intervention/exposure
420 | Kelder S, Hoelscher DM, Barroso CS, Walker JL, Cribb, P, Hu S. The CATCH Kids Club: a pilot after-school study for improving elementary students’ nutrition and physical activity. Public Health Nutr. 2005. 8:133-40. doi:10.1079/phn2004678. | Intervention/exposure
421 | Kelishadi R, Lajevardi B, Bahreynian M, Omid-Ghaemi V, Movahedian M. Acceptance and satisfaction of parents and students about a school-based dietary intervention in Isfahan, 2012-2013. J Educ Health Promot. 2016. 5:16. doi:10.4103/2277-9531.184556. | Study design
422 | Kelley MN, Lowe JR. A Culture-Based Talking Circle Intervention for Native American Youth at Risk for Obesity. J Community Health Nurs. 2018. 35:102-117. doi:10.1080/07370016.2018.1475796. | Intervention/exposure
423 | Kemirembe OMK, Radhakrishna RB, Gurgevich E, Yoder EP, Ingram PD. An Evaluation of Nutrition Education Program for Low-Income Youth. J Ext. 2011. 49(3). | Outcome
424 | Kesztyüs D, Lauer R, Kesztyüs T, Kilian R, Steinacker JM. Costs and effects of a state-wide health promotion program in primary schools in Germany - the Baden-Württemberg Study: A cluster-randomized, controlled trial. PLoS One. 2017. 12:e0172332. doi:10.1371/journal.pone.0172332. | Intervention/exposure
425 | Kesztyüs D, Schreiber A, Wirt T, Wiedom M, Dreyhaupt J, Brandstetter S, Koch, B, Wartha O, Muche R, Wabitsch M, Kilian R, Steinacker JM. Economic evaluation of URMEL-ICE, a school-based overweight prevention programme comprising metabolism, exercise and lifestyle intervention in children. Eur J Health Econ. 2013. 14:185-95. doi:10.1007/s10198-011-0358-3. | Intervention/exposure
426 | Keyes A, Brennan C, Hamilton J, Ford L, Heff, L, Husney, D, Brock, P, Harvey A, Haydon T, Le N, Lockard R, Martinez, G, Neville R, Peter J, Poole B, Riddle D, Ryckman E, Stegeman J, Velasquez A. Sowing the seeds for healthy minds and bodies. Child Obes. 2012. 8:396-9. doi:10.1089/chi.2012.0084.nowa. | Study design
427 | Khan M, Bell R. Effects of a School Based Intervention on Children’s Physical Activity and Healthy Eating: A Mixed-Methods Study. Int J Environ Res Public Health. 2019. 16:4320. doi:10.3390/ijerph16224320. | Intervention/exposure
428 | Kihm HS, Staiano A, Sandoval P. Project IPAL: Enhancing the Well-Being of Elementary School Children. J Fam Consum Sci. 2017. 109:54-56. doi:10.14307/JFCS109.1.54. | Study design
429 | Kilanowski JF, Gordon NH. Making a Difference in Migrant Summer School: Testing a Healthy Weight Intervention. Public Health Nurs. 2015. 32:421-9. doi:10.1111/phn.12175. | Intervention/exposure
430 | Kim J, Kim G, Park J, Wang Y, Lim H. Effectiveness of Teacher-Led Nutritional Lessons in Altering Dietary Habits and Nutritional Status in Preschool Children: Adoption of a NASA Mission X-Based Program. Nutrients. 2019. 11:1590. doi:10.3390/nu11071590. | Intervention/exposure, Age at intervention/exposure
431 | Kim K, Hong SA, Yun SH, Ryou HJ, Lee SS, Kim MK. The effect of a healthy school tuck shop program on the access of students to healthy foods. Nutr Res Pract. 2012. 6:138-45. doi:10.4162/nrp.2012.6.2.138. | Study design
432 | Kim OH, Park JK. Effects of an Integrated Health Care Program for Children. J Exerc Nutrition Biochem. 2017. 21:7-12. doi:10.20463/jenb.2016.0037. | Study design, Intervention/exposure
433 | Kim SO, Park SA. Garden-Based Integrated Intervention for Improving Children’s Eating Behavior for Vegetables. Int J Environ Res Public Health. 2020. 17:1257. doi:10.3390/ijerph17041257. | Study design
434 | King KM, Ling J. Results of a 3-year, nutrition and physical activity intervention for children in rural, low-socioeconomic status elementary schools. Health Educ Res. 2015. 30:647-59. doi:10.1093/her/cyv029. | Study design, Intervention/exposure
435 | Kipping RR, Howe LD, Jago R, Campbell R, Wells S, Chittleborough CR, Mytton J, Noble SM, Peters TJ, Lawlor DA. Effect of intervention aimed at increasing physical activity, reducing sedentary behaviour, and increasing fruit and vegetable consumption in children: active for Life Year 5 (AFLY5) school based cluster randomised controlled trial. BMJ. 2014. 348:g3256. doi:10.1136/bmj.g3256. | Intervention/exposure
436 | Kipping RR, Jago R, Lawlor DA. Diet outcomes of a pilot school-based randomised controlled obesity prevention study with 9-10 year olds in England. Prev Med. 2010. 51:56-62. doi:10.1016/j.ypmed.2010.04.011. | Intervention/exposure
437 | Kipping RR, Payne C, Lawlor DA. Randomised controlled trial adapting US school obesity prevention to England. Arch Dis Child. 2008. 93:469-73. doi:10.1136/adc.2007.116970. | Intervention/exposure
438 | Klish WJ, Karavias KE, White KS, Balch AJ, Fraley JK, Mikhail C, Abrams SH, Terrazas NL, Smith EO, Wong WW. Multicomponent school-initiated obesity intervention in a high-risk, Hispanic elementary school. J Pediatr Gastroenterol Nutr. 2012. 54:113-6. doi:10.1097/MPG.0b013e3182318b39. | Intervention/exposure
439 | Kobel S, Lämmle C, Wartha O, Kesztyüs D, Wirt T, Steinacker JM. Effects of a Randomised Controlled School-Based Health Promotion Intervention on Obesity Related Behavioural Outcomes of Children with Migration Background. J Immigr Minor Health. 2017. 19:254-262. doi:10.1007/s10903-016-0460-9. | Intervention/exposure
440 | Kobel S, Wartha O, Lämmle C, Dreyhaupt J, Steinacker JM. Intervention effects of a kindergarten-based health promotion programme on obesity related behavioural outcomes and BMI percentiles. Prev Med Rep. 2019. 15:100931. doi:10.1016/j.pmedr.2019.100931. | Intervention/exposure, Age at intervention/exposure, Age at outcome
441 | Kobel S, Wirt T, Schreiber A, Kesztyüs D, Kettner S, Erkelenz N, Wartha O, Steinacker JM. Intervention effects of a school-based health promotion programme on obesity related behavioural outcomes. J Obes. 2014. 2014:476230. doi:10.1155/2014/476230. | Intervention/exposure
442 | Koch PA, Contento IR, Gray HL, Burgermaster M, Bandelli L, Abrams E, Di Noia J. Food, Health, & Choices: Curriculum and Wellness Interventions to Decrease Childhood Obesity in Fifth-Graders. J Nutr Educ Behav. 2019. 51:440-455. doi:10.1016/j.jneb.2018.12.001. | Intervention/exposure
443 | Koch S, Lineberger S, Zajicek JM. Can an educational program on the nutritional benefits of citrus fruit positively influence the nutritional attitudes of children?. Horttechnology. 2005. 15:468-471. doi:10.21273/horttech.15.3.0468. | Study design
444 | Koch S, Waliczek TM, Zajicek JM. The effect of a summer garden program on the nutritional knowledge, attitudes, and behaviors of children. Horttechnology. 2006. 16:620-625. doi:10.21273/horttech.16.4.0620. | Study design, Outcome
445 | Kocken PL, Scholten AM, Westhoff E, De Kok BP, Taal EM, Goldbohm RA. Effects of a Theory-Based Education Program to Prevent Overweightness in Primary School Children. Nutrients. 2016. 8:12. doi:10.3390/nu8010012. | Intervention/exposure
446 | Kohri T, Kaba N, Itoh T, Sasaki S. Effects of the National School Lunch Program on Bone Growth in Japanese Elementary School Children. J Nutr Sci Vitaminol (Tokyo). 2016. 62:303-309. doi:10.3177/jnsv.62.303. | Study design
447 | Kong AS, Sussman AL, Yahne C, Skipper BJ, Burge MR, Davis SM. School-based health center intervention improves body mass index in overweight and obese adolescents. J Obes. 2013. 2013:575016. doi:10.1155/2013/575016. | Intervention/exposure
448 | Koo HC, Poh BK, Abd Talib R. The GReat-Child™ Trial: A Quasi-Experimental Intervention on Whole Grains with Healthy Balanced Diet to Manage Childhood Obesity in Kuala Lumpur Malaysia. Nutrients. 2018. 10:156. doi:10.3390/nu10020156. | Outcome
449 | Koo HC, Poh BK, Ruzita AT. GReat-Child Trial™ based on social cognitive theory improved knowledge, attitudes and practices toward whole grains among Malaysian overweight and obese children. BMC Public Health. 2019. 19:1574. doi:10.1186/s12889-019-7888-5. | Study design
450 | Kremer P, Waqa G, Vanualailai N, Schultz JT, Roberts G, Moodie M, Mavoa H, Malakellis M, McCabe MP, Swinburn BA. Reducing unhealthy weight gain in Fijian adolescents: results of the Healthy Youth Healthy Communities study. Obes Rev. 2011. 12 Suppl 2:29-40. doi:10.1111/j.1467-789X.2011.00912.x. | Intervention/exposure, Country
451 | Kristiansen AL, Bjelland M, Himberg-Sundet A, Lien N, Holst R, Frost Andersen L. Effects of a cluster randomized controlled kindergarten-based intervention trial on vegetable consumption among Norwegian 3-5-year-olds: the BRA-study. BMC Public Health. 2019. 19:1098. doi:10.1186/s12889-019-7436-3. | Age at intervention/exposure
452 | Kristjansdottir AG, Johannsson E, Thorsdottir I. Effects of a school-based intervention on adherence of 7-9-year-olds to food-based dietary guidelines and intake of nutrients. Public Health Nutr. 2010. 13:1151-61. doi:10.1017/s1368980010000716. | Intervention/exposure
453 | Kropp JD, Abarca-Orozco SJ, Israel GD, Diehl DC, Galindo-Gonzalez, S, Headrick LB, Shelnutt KP. A Plate Waste Evaluation of the Farm to School Program. J Nutr Educ Behav. 2018. 50:332-339.e1. doi:10.1016/j.jneb.2017.10.005. | Study design
454 | Kulik NL, Moore EW, Centeio EE, Garn AC, Martin JJ, Shen B, Somers CL, McCaughtry N. Knowledge, Attitudes, Self-Efficacy, and Healthy Eating Behavior Among Children: Results From the Building Healthy Communities Trial. Health Educ Behav. 2019. 46:602-611. doi:10.1177/1090198119826298. | Intervention/exposure
455 | Kulik N, Thomas EM, Fahlman MM, Garn AC, Centeio EE, Somers CL, McCaughtry N. Dietary Self-Efficacy and Dietary Intake by Race/Ethnicity among Elementary School Children. Health Educ J. 2019. 78:486-493. doi:10.1177/0017896918824138 | Study design
456 | Kuroko S, Black K, Chryssidis T, Finigan R, Hann C, Haszard J, Jackson R, Mahn K, Robinson C, Thomson C, Toldi O, Scullion N, Skidmore P. Create Our Own Kai: A Randomised Control Trial of a Cooking Intervention with Group Interview Insights into Adolescent Cooking Behaviours. Nutrients. 2020. 12:796. doi:10.3390/nu12030796. | Intervention/exposure
457 | LaBrosse L, Albrecht JA. Pilot intervention with adolescents to increase knowledge and consumption of folate-rich foods based on the Health Belief Model. International J Consum Stud. 2013. 37:271-278. doi:10.1111/ijcs.12004. | Outcome
458 | Lakkakula A, Geaghan JP, Wong WP, Zanovec, M, Pierce SH, Tuuri G. A cafeteria-based tasting program increased liking of fruits and vegetables by lower, middle and upper elementary school-age children. Appetite. 2011. 57:299-302. doi:10.1016/j.appet.2011.04.010. | Outcome
459 | Lakshman RR, Sharp, SJ, Ong KK, Forouhi NG. A novel school-based intervention to improve nutrition knowledge in children: cluster randomised controlled trial. BMC Public Health. 2010. 10:123. doi:10.1186/1471-2458-10-123. | Outcome
460 | Lambrinou CP, van Stralen MM, Androutsos O, Cardon G, De Craemer M, Iotova V, Socha P, Koletzko B, Moreno LA, Manios Y. Mediators of the effectiveness of a kindergarten-based, family-involved intervention on pre-schoolers’ snacking behaviour: the ToyBox-study. Public Health Nutr. 2019. 22:157-163. doi:10.1017/s1368980018002653. | Intervention/exposure, Age at intervention/exposure
461 | Lana A, Faya-Ornia G, López ML. Impact of a web-based intervention supplemented with text messages to improve cancer prevention behaviors among adolescents: results from a randomized controlled trial. Prev Med. 2014. 59:54-9. doi:10.1016/j.ypmed.2013.11.015. | Intervention/exposure
462 | Landry MJ, Markowitz AK, Asigbee FM, Gatto NM, Spruijt-Metz D, Davis JN. Cooking and Gardening Behaviors and Improvements in Dietary Intake in Hispanic/Latino Youth. Child Obes. 2019. 15:262-270. doi:10.1089/chi.2018.0110. | Outcome
463 | Lanerolle P, Atukorala S. Nutrition education improves serum retinol concentration among adolescent school girls. Asia Pac J Clin Nutr. 2006. 15:43-9. doi:10.2254/0964-7058.15.1.0226 | Study design
464 | Lange C, Schwartz C, Hachefa C, Cornil, Y, Nicklaus S, Chandon P. Portion size selection in children: Effect of sensory imagery for snacks varying in energy density. Appetite. 2020. 150:104656. doi:10.1016/j.appet.2020.104656. | Intervention/exposure
465 | Larsen AL, Liao Y, Alberts J, Huh J, Robertson T, Dunton GF. RE-AIM Analysis of a School-Based Nutrition Education Intervention in Kindergarteners. J Sch Health. 2017. 87:36-46. doi:10.1111/josh.12466. | Comparator
466 | Lau C, Stevens D, Jia J. Effects of an occupation-based obesity prevention program for children at risk. Occup Ther Health Care. 2013. 27:163-75. doi:10.3109/07380577.2013.783725. | Study design
467 | Laureati M, Bergamaschi V, Pagliarini E. School-based intervention with children. Peer-modeling, reward and repeated exposure reduce food neophobia and increase liking of fruits and vegetables. Appetite. 2014. 83:26-32. doi:10.1016/j.appet.2014.07.031. | Outcome
468 | Laurence S, Peterken R, Burns C. Fresh Kids: the efficacy of a Health Promoting Schools approach to increasing consumption of fruit and water in Australia. Health Promot Int. 2007. 22:218-26. doi:10.1093/heapro/dam016. | Study design
469 | Lawlor DA, Howe LD, Anderson EL, Kipping RR, Campbell R, Wells S, Chittleborough CR, Peters TJ, Jago R. The Active for Life Year 5 (AFLY5) school-based cluster randomised controlled trial: effect on potential mediators. BMC Public Health. 2016. 16:68. doi:10.1186/s12889-016-2734-5. | Intervention/exposure
470 | Laxer RE, Dubin JA, Brownson RC, Cooke M, Chaurasia A, Leatherdale ST. Noncomprehensive and Intermittent Obesity-Related School Programs and Policies May Not Work: Evidence from the COMPASS Study. J Sch Health. 2019. 89:818-828. doi:10.1111/josh.12820. | Study design
471 | Lazorick S, Fang X, Crawford Y. The MATCH Program: Long-Term Obesity Prevention Through a Middle School Based Intervention. Child Obes. 2016. 12:103-12. doi:10.1089/chi.2015.0073. | Study design
472 | Lazorick S, Fang X, Hardison GT, Crawford Y. Improved Body Mass Index Measures Following a Middle School-Based Obesity Intervention-The MATCH Program. J Sch Health. 2015. 85:680-7. doi:10.1111/josh.12301. | Study design
473 | Leach RA, Yates JM. Nutrition and youth soccer for childhood overweight: a pilot novel chiropractic health education intervention. J Manipulative Physiol Ther. 2008. 31:434-41. doi:10.1016/j.jmpt.2008.06.003. | Intervention/exposure
474 | Lee A, Ho M, Keung VM, Kwong AC. Childhood obesity management shifting from health care system to school system: intervention study of school-based weight management programme. BMC Public Health. 2014. 14:1128. doi:10.1186/1471-2458-14-1128. | Intervention/exposure
475 | Lee JH, Kim WK, Kim SH. Participation in the School Milk Program Contributes to Increased Milk Consumption and Dietary Nutrient Intake by Middle School Students in South Korea. Nutrients. 2019. 11:2386. doi:10.3390/nu11102386. | Study design
476 | Lee RM, Giles CM, Cradock AL, Emmons KM, Okechukwu C, Kenney EL, Thayer J, Gortmaker SL. Impact of the Out-of-School Nutrition and Physical Activity (OSNAP) Group Randomized Controlled Trial on Children’s Food, Beverage, and Calorie Consumption among Snacks Served. J Acad Nutr Diet. 2018. 118:1425-1437. doi:10.1016/j.jand.2018.04.011. | Intervention/exposure
477 | Leines D, Gold A, Van Offelen S. Go wild with fruits & veggies! Curriculum encourages children to eat more fruits and vegetables. J Nutr Educ Behav. 2014. 46:82-84. doi:10.1016/j.jneb.2013.03.018. | Study design
478 | Lent M, Hill TF, Dollahite JS, Wolfe WS, Dickin KL. Healthy children, healthy families: parents making a difference! A curriculum integrating key nutrition, physical activity, and parenting practices to help prevent childhood obesity. J Nutr Educ Behav. 2012. 44:90-2. doi:10.1016/j.jneb.2011.02.011. | Study design
479 | Lent MR, Vander Veur SS, McCoy TA, Wojtanowski AC, Sandoval B, Sherman S, Komaroff E, Foster GD. A randomized controlled study of a healthy corner store initiative on the purchases of urban, low-income youth. Obesity (Silver Spring). 2014. 22:2494-500. doi:10.1002/oby.20878. | Intervention/exposure
480 | Lepe S, Goodwin J, Mulligan KT, Balestracci K, Sebelia L, Greene G. Process Evaluation of a Policy, Systems, and Environmental Change Intervention in an Urban School District. J Nutr Educ Behav. 2019. 51:307-317. doi:10.1016/j.jneb.2018.07.017. | Study design
481 | Lerner-Geva L, Bar-Zvi E, Levitan G, Boyko V, Reichman B, Pinhas-Hamiel O. An intervention for improving the lifestyle habits of kindergarten children in Israel: a cluster-randomised controlled trial investigation. Public Health Nutr. 2015. 18:1537-44. doi:10.1017/s136898001400024x. | Outcome
482 | Leung MM, Green MC, Tate DF, Cai J, Wyka K, Ammerman AS. Fight for Your Right to Fruit: Psychosocial Outcomes of a Manga Comic Promoting Fruit Consumption in Middle-School Youth. Health Commun. 2017. 32:533-540. doi:10.1080/10410236.2016.1211074. | Outcome
483 | Leuven JRFW, Rutenfrans AHM, Dolfing AG, Leuven RSEW. School gardening increases knowledge of primary school children on edible plants and preference for vegetables. Food Sci Nutr. 2018. 6:1960-1967. doi:10.1002/fsn3.758. | Outcome
484 | Lewis RK, Lee FA, Brown KK, LoCurto J, Stowell D, Maryman J, Lovelady T, Williams G, Morris DM, McNair T. Youth empowerment implementation project evaluation results: A program designed to improve the health and well-being of low-income African-American adolescents. J Prev Interv Community. 2018. 46:28-42. doi:10.1080/10852352.2018.1385954. | Study design, Intervention/exposure
485 | Li B, Liu WJ, Adab P, Pallan M, Hemming K, Frew E, Lin R, Martin J, Liu W, Cheng KK. Cluster-randomised controlled trial to assess the effectiveness and cost-effectiveness of an obesity prevention programme for Chinese primary school-aged children: the CHIRPY DRAGON study protocol. BMJ Open. 2017. 7:e018415. doi:10.1136/bmjopen-2017-018415. | Other: Protocol
486 | Li B, Pallan M, Liu WJ, Hemming K, Frew, E, Lin R, Liu W, Martin J, Zanganeh M, Hurley K, Cheng KK, Adab P. The CHIRPY DRAGON intervention in preventing obesity in Chinese primary-school--aged children: A cluster-randomised controlled trial. PLoS Med. 2019. 16:e1002971. doi:10.1371/journal.pmed.1002971. | Intervention/exposure
487 | Liao LL, Lai IJ, Chang LC, Lee CK. Effects of a food advertising literacy intervention on Taiwanese children’s food purchasing behaviors. Health Educ Res. 2016. 31:509-20. doi:10.1093/her/cyw025. | Outcome
488 | Lin M, Pan LP, Han J, Li L, Jiang JX, Jin RM. Behavioral intervention reduces unhealthy eating behaviors in preschool children via a behavior card approach. J Huazhong Univ Sci Technolog Med Sci. 2016. 36:895-903. doi:10.1007/s11596-016-1681-9. | Intervention/exposure, Age at intervention/exposure
489 | Lin YC, Chen HJ, Wang Y, Min J, Wu HC, Carvajal NA, Yang HY. NASA Mission X Program for Healthy Eating and Active Living among Taiwanese Elementary School Students. J Pediatr Nurs. 2019. 49:e8-e14. doi:10.1016/j.pedn.2019.06.016. | Intervention/exposure
490 | Ling J, King KM, Speck BJ, Kim S, Wu D. Preliminary assessment of a school-based healthy lifestyle intervention among rural elementary school children. J Sch Health. 2014. 84:247-55. doi:10.1111/josh.12143. | Study design, Intervention/exposure
491 | List JA, Samek AS. The behavioralist as nutritionist: leveraging behavioral economics to improve child food choice and consumption. J Health Econ. 2015. 39:135-46. doi:10.1016/j.jhealeco.2014.11.002. | Intervention/exposure
492 | Little MA, Riggs NR, Shin HS, Tate EB, Pentz MA. The effects of teacher fidelity of implementation of pathways to health on student outcomes. Eval Health Prof. 2015. 38:21-41. doi:10.1177/0163278713489879. | Study design
493 | Llargues E, Franco R, Recasens A, Nadal A, Vila M, Pérez MJ, Manresa JM, Recasens I, Salvador G, Serra J, Roure E, Castells C. Assessment of a school-based intervention in eating habits and physical activity in school children: the AVall study. J Epidemiol Community Health. 2011. 65:896-901. doi:10.1136/jech.2009.102319. | Intervention/exposure
494 | Llargués E, Recasens A, Franco R, Nadal A, Vila M, Pérez MJ, Recasens I, Salvador G, Serra J, Roure E, Castell C. Medium-term evaluation of an educational intervention on dietary and physical exercise habits in schoolchildren: the Avall 2 study. Endocrinol Nutr. 2012. 59:288-95. doi:10.1016/j.endonu.2012.03.002. | Intervention/exposure
495 | Llauradó, E, Tarro L, Moriña D, Aceves-Martins M, Giralt M, Solà, R. Follow-up of a healthy lifestyle education program (the EdAl study): four years after cessation of randomized controlled trial intervention. BMC Public Health. 2018. 18:104. doi:10.1186/s12889-017-5006-0.
496 | Lloyd J, Creanor S, Logan S, Green C, Dean SG, Hillsdon M, Abraham, C, Tomlinson R, Pearson V, Taylor RS, Ryan E, Price L, Streeter A, Wyatt K. Effectiveness of the Healthy Lifestyles Programme (HeLP) to prevent obesity in UK primary-school children: a cluster randomised controlled trial. Lancet Child Adolesc Health. 2018. 2:35-45. doi:10.1016/s2352-4642(17)30151-7. | Intervention/exposure
497 | Lloyd JJ, Wyatt KM, Creanor S. Behavioural and weight status outcomes from an exploratory trial of the Healthy Lifestyles Programme (HeLP): a novel school-based obesity prevention programme. BMJ Open. 2012. 2:e000390. doi:10.1136/bmjopen-2011-000390. | Intervention/exposure
498 | Lo E, Coles R, Humbert ML, Polowski J, Henry CJ, Whiting SJ. Beverage intake improvement by high school students in Saskatchewan, Canada. Nutr Res. 2008. 28:144-50. doi:10.1016/j.nutres.2008.01.005. | Comparator
499 | Loeb KL, Radnitz C, Keller KL, Schwartz MB, Zucker N, Marcus S, Pierson RN, Shannon M, DeLaurentis D. The Application of Optimal Defaults to Improve Elementary School Lunch Selections: Proof of Concept. J Sch Health. 2018. 88:265-271. doi:10.1111/josh.12611. | Intervention/exposure, Outcome
500 | Long JD, Stevens KR. Using technology to promote self-efficacy for healthy eating in adolescents. J Nurs Scholarsh. 2004. 36:134-9. doi:10.1111/j.1547-5069.2004.04026.x. | Study design
501 | Long MW, Weber MR, Allan MJ, Ma Y, Jin Y, Aldous A, Elliot AJ, Burke H. Evaluation of a pragmatic trial of a collaborative school-based obesity prevention intervention in a low-income urban district. Prev Med. 2020. 133:106020. doi:10.1016/j.ypmed.2020.106020. | Intervention/exposure
502 | Long VA, Martin T, Janson-Sand C. The great beginnings program: impact of a nutrition curriculum on nutrition knowledge, diet quality, and birth outcomes in pregnant and parenting teens. J Am Diet Assoc. 2002. 102:S86-9. doi:10.1016/s0002-8223(02)90430-x. | Outcome
503 | Loong C, Leo L, Goh D, Lim PS, Loke WM. Promoting physical activity and improving dietary quality of Singaporean adolescents: effectiveness of a school-based fitness and wellness program. Int J Adolesc Med Health. 2018. 31(5). doi:10.1515/ijamh-2017-0049. | Study design, Intervention/exposure
504 | Loughridge JL, Barratt J. Does the provision of cooled filtered water in secondary school cafeterias increase water drinking and decrease the purchase of soft drinks?. J Hum Nutr Diet. 2005. 18:281-6. doi:10.1111/j.1365-277X.2005.00622.x. | Intervention/exposure
505 | Lowe CF, Horne PJ, Tapper K, Bowdery M, Egerton C. Effects of a peer modelling and rewards-based intervention to increase fruit and vegetable consumption in children. Eur J Clin Nutr. 2004. 58:510-22. doi:10.1038/sj.ejcn.1601838. | Study design
506 | Lubans DR, Morgan PJ, Callister R, Collins CE, Plotnikoff RC. Exploring the mechanisms of physical activity and dietary behavior change in the program x intervention for adolescents. J Adolesc Health. 2010. 47:83-91. doi:10.1016/j.jadohealth.2009.12.015. | Intervention/exposure
507 | Lubans DR, Smith JJ, Plotnikoff RC, Dally KA, Okely AD, Salmon J, Morgan PJ. Assessing the sustained impact of a school-based obesity prevention program for adolescent boys: the ATLAS cluster randomized controlled trial. Int J Behav Nutr Phys Act. 2016. 13:92. doi:10.1186/s12966-016-0420-8. | Intervention/exposure
508 | Lynch, BA, Gentile N, Maxson J, Quigg S, Swenson L, Kaufman T. Elementary School-Based Obesity Intervention Using an Educational Curriculum. J Prim Care Community Health. 2016. 7:265-71. doi:10.1177/2150131916644888. | Intervention/exposure
509 | Ma Y, Feng X, Ma J, He FJ, Wang H, Zhang J, Xie W, Wu T, Yin Y, Yuan J, MacGregor GA, Wu Y. Social support, social network and salt-reduction behaviours in children: a substudy of the School-EduSalt trial. BMJ Open. 2019. 9:e028126. doi:10.1136/bmjopen-2018-028126. | Study design, Outcome
510 | Maatoug J, Fredj SB, Msakni Z, Dendana E, Sahli J, Harrabi I, Chouikha F, Boughamoura L, Slama S, Farpour-Lambert N, Ghannem H. Challenges and results of a school-based intervention to manage excess weight among school children in Tunisia 2012-2014. Int J Adolesc Med Health. 2017. 29(2). doi:10.1515/ijamh-2015-0035. | Intervention/exposure
511 | Maatoug J, Msakni Z, Zammit N, Bhiri S, Harrabi I, Boughammoura L, Slama S, Larbi C, Ghannem H. School-Based Intervention as a Component of a Comprehensive Community Program for Overweight and Obesity Prevention, Sousse, Tunisia, 2009-2014. Prev Chronic Dis. 2015. 12:E160. doi:10.5888/pcd12.140518. | Intervention/exposure
512 | Machado SS, Ritchie LD, Thompson HR, Madsen KA. The Impact of a Multi-Pronged Intervention on Students’ Perceptions of School Lunch Quality and Convenience and Self-Reported Fruit and Vegetable Consumption. Int J Environ Res Public Health. 2020. 17:5987. doi:10.3390/ijerph17165987. | Study design
513 | Madden AM, Harrex R, Radalowicz J, Boaden DC, Lim J, Ash R. A kitchen-based intervention to improve nutritional intake from school lunches in children aged 12-16 years. J Hum Nutr Diet. 2013. 26:243-51. doi:10.1111/jhn.12037. | Study design
514 | Madden GJ, Price J, Wengreen H. Change and Maintaining Change in School Cafeterias: Economic and Behavioral-Economic Approaches to Increasing Fruit and Vegetable Consumption. Change and Maintaining Change. 2018. 65:101-125. doi:10.1007/978-3-319-96920-6_4. | Study design, Publication status
515 | Madsen K, Linchey J, Gerstein D, Ross M, Myers E, Brown K, Crawford P. Energy Balance 4 Kids with Play: Results from a Two-Year Cluster-Randomized Trial. Child Obes. 2015. 11:375-83. doi:10.1089/chi.2015.0002. | Intervention/exposure
516 | Madsen KA, Cotterman C, Crawford P, Stevelos J, Archibald A. Effect of the Healthy Schools Program on prevalence of overweight and obesity in California schools, 2006-2012. Prev Chronic Dis. 2015. 12:E77. doi:10.5888/pcd12.150020. | Intervention/exposure
517 | Madsen KA, Thompson HR, Wlasiuk L, Queliza E, Schmidt C, Newman TB. After-school program to reduce obesity in minority children: a pilot study. J Child Health Care. 2009. 13:333-46. doi:10.1177/1367493509344823. | Study design, Intervention/exposure
518 | Maes L, Cook TL, Ottovaere C, Matthijs C, Moreno LA, Kersting M, Papadaki A, Manios Y, Dietrich S, Hallström L, Haerens L, De Bourdeaudhuij I, Vereecken C. Pilot evaluation of the HELENA (Healthy Lifestyle in Europe by Nutrition in Adolescence) Food-O-Meter, a computer-tailored nutrition advice for adolescents: a study in six European cities. Public Health Nutr. 2011. 14:1292-302. doi:10.1017/s1368980010003563. | Intervention/exposure
519 | Majumdar D, Koch PA, Lee H, Contento IR, Islas-Ramos AD, Fu D. “Creature-101”: A Serious Game to Promote Energy Balance-Related Behaviors Among Middle School Adolescents. Games Health J. 2013. 2:280-290. doi:10.1089/g4h.2013.0045. | Study design
520 | Malakellis M, Hoare E, Sanigorski A, Crooks N, Allender S, Nichols M, Swinburn B, Chikwendu C, Kelly, PM, Petersen S, Millar L. School-based systems change for obesity prevention in adolescents: outcomes of the Australian Capital Territory ‘It’s Your Move!’. Aust N Z J Public Health. 2017. 41:490-496. doi:10.1111/1753-6405.12696. | Intervention/exposure
521 | Mallya A, Mensah FM, Contento IR, Koch PA, Barton AC. Extending Science beyond the Classroom Door: Learning from Students’ Experiences with the “Choice, Control and Change” (C3) Curriculum. J Res Sci Teach. 2012. 49:244-269. doi:10.1002/tea.21006. | Study design, Intervention/exposure
522 | Manios Y, Kafatos A. Health and nutrition education in primary schools in Crete: 10 years follow-up of serum lipids, physical activity and macronutrient intake. Br J Nutr. 2006. 95:568-575. doi:10.1079/bjn20051666. | Intervention/exposure
523 | Manios Y, Kafatos I, Kafatos A, Preventive Med Nutrition Clinic, Re. Ten-year follow-up of the Cretan Health and Nutrition Education Program on children’s physical activity levels. Preventive Medicine. 2006. 43:442-446. doi:10.1016/j.ypmed.2006.06.001. | Intervention/exposure, Outcome
524 | Manios Y, Moschandreas J, Hatzis C, Kafatos A. Health and nutrition education in primary schools of Crete: changes in chronic disease risk factors following a 6-year intervention programme. Br J Nutr. 2002. 88:315-24. doi:10.1079/bjn2002672. | Intervention/exposure
525 | Marcano-Olivier M, Pearson R, Ruparell A, Horne PJ, Viktor S, Erjavec, M. A low-cost Behavioural Nudge and choice architecture intervention targeting school lunches increases children’s consumption of fruit: a cluster randomised trial. Int J Behav Nutr Phys Act. 2019. 16:20. doi:10.1186/s12966-019-0773-x. | Comparator
526 | March L, Gould R. Compliance with the school meals initiative: effect on meal programs’ financial success. J Am Diet Assoc. 2001. 101:1199-201. doi:10.1016/s0002-8223(01)00294-2. | Study design
527 | Marchetti D, Fraticelli F, Polcini F, Lato R, Pintaudi B, Nicolucci A, Fulcheri M, Mohn A, Chiarelli F, Di Vieste G, Vitacolonna E. Preventing Adolescents’ Diabesity: Design, Development, and First Evaluation of “Gustavo in Gnam’s Planet”. Games Health J. 2015. 4:344-51. doi:10.1089/g4h.2014.0107. | Study design
528 | Marcus C, Nyberg G, Nordenfelt A, Karpmyr M, Kowalski J, Ekelund, U. A 4-year, cluster-randomized, controlled childhood obesity prevention study: STOPP. Int J Obes (Lond). 2009. 33:408-17. doi:10.1038/ijo.2009.38. | Intervention/exposure
529 | Marks L, Ogden J. Evaluation of an Online “Teachable Moment” Dietary Intervention. Health Educ. 2017. 117:39-52. doi:10.1108/HE-02-2016-0007. | Age at intervention/exposure
530 | Marsh S, Jiang Y, Carter K, Wall C. Evaluation of a Free Milk in Schools Program in New Zealand: Effects on Children’s Milk Consumption and Anthropometrics. J Sch Health. 2018. 88:596-604. doi:10.1111/josh.12649. | Study design
531 | Martins VJB, Filgueiras AR, Almeida VBP, de Moraes RCS, Sawaya AL. Changes in Thyroid and Glycemic Status and Food Intake in Children with Excess Weight Who Were Submitted for a Multi-Component School Intervention for 16 Months. Int J Environ Res Public Health. 2020. 17:3825. doi:10.3390/ijerph17113825. | Intervention/exposure
532 | Massarani FA, Citelli M, Canella DS, Koury JC. Healthy eating promoting in a Brazilian sports-oriented school: a pilot study. PeerJ. 2019. 7:e7601. doi:10.7717/peerj.7601. | Study design, Comparator
533 | Matvienko O. Impact of a nutrition education curriculum on snack choices of children ages six and seven years. J Nutr Educ Behav. 2007. 39:281-5. doi:10.1016/j.jneb.2007.01.004. | Intervention/exposure
534 | Mauriello LM, Ciavatta MM, Paiva AL, Sherman KJ, Castle PH, Johnson JL, Prochaska JM. Results of a multi-media multiple behavior obesity prevention program for adolescents. Prev Med. 2010. 51:451-6. doi:10.1016/j.ypmed.2010.08.004. | Intervention/exposure
535 | McAleese JD, Rankin LL. Garden-based nutrition education affects fruit and vegetable consumption in sixth-grade adolescents. J Am Diet Assoc. 2007. 107:662-5. doi:10.1016/j.jada.2007.01.015. | Study design
536 | McAuley KA, Taylor RW, Farmer VL, Hansen P, Williams SM, Booker CS, Mann JI. Economic evaluation of a community-based obesity prevention program in children: the APPLE project. Obesity (Silver Spring). 2010. 18:131-6. doi:10.1038/oby.2009.148. | Intervention/exposure
537 | McCabe BE, Plotnikoff RC, Dewar DL, Collins CE, Lubans DR. Social Cognitive Mediators of Dietary Behavior Change in Adolescent Girls. Am J Health Behav. 2015. 39:51-61. doi:10.5993/ajhb.39.1.6. | Intervention/exposure
538 | McCarthy E, Wolff C, Bianco-Simeral S, Crozier J, Goto K. The Effects of a School-Based Nutrition Intervention on Fruit and Vegetable Preferences, Self-Efficacy, and Consumption among Low-Income, Hispanic and White Middle-School Students. J Child Nutr Manag. 2012. 36. | Study design
539 | McCaughtry N, Fahlman M, Martin JJ, Shen B. Influences of Constructivist-Oriented Nutrition Education on Urban Middle School Students’ Nutrition Knowledge, Self-Efficacy, and Behaviors. Am J Health Educ. 2011. 42:276-285. doi:10.1080/19325037.2011.10599198. | Study design
540 | McDarby F, O’Hora D, O’Shea D, Byrne M. Taking the sweetness out of the ‘Share a Coke’ marketing campaign: the influence of personalized labelling on elementary school children’s bottled drink choices. Pediatr Obes. 2018. 13:63-69. doi:10.1111/ijpo.12193. | Intervention/exposure
541 | McMurray RG, Harrell JS, Bangdiwala SI, Bradley CB, Deng S, Levine A. A school-based intervention can reduce body fat and blood pressure in young adolescents. J Adolesc Health. 2002. 31:125-32. doi:10.1016/s1054-139x(02)00348-8. | Intervention/exposure
542 | McNeil DA, Wilson BN, Siever JE, Ronca M, Mah JK. Connecting children to recreational activities: results of a cluster randomized trial. Am J Health Promot. 2009. 23:376-87. doi:10.4278/ajhp.071010107. | Intervention/exposure
543 | Melnyk BM, Jacobson D, Kelly S, O’Haver J, Small L, Mays MZ. Improving the mental health, healthy lifestyle choices, and physical health of Hispanic adolescents: a randomized controlled pilot study. J Sch Health. 2009. 79:575-84. doi:10.1111/j.1746-1561.2009.00451.x. | Intervention/exposure
544 | Melnyk BM, Jacobson D, Kelly SA, Belyea MJ, Shaibi GQ, Small L, O’Haver JA, Marsiglia FF. Twelve-Month Effects of the COPE Healthy Lifestyles TEEN Program on Overweight and Depressive Symptoms in High School Adolescents. J Sch Health. 2015. 85:861-70. doi:10.1111/josh.12342. | Intervention/exposure
545 | Melo dos Santos M, Passos Oliveira V, Teixeira Lima SM, Clímaco Cruz KJ, Soares de Oliveira AR, Soares Severo J. Effectiveness of an educational intervention to reduce the consumption of high-calorie foods in public school children in Teresina, Piauí (Brazil). Nutr Hosp. 2015. 32:622-6. doi:10.3305/nh.2015.32.2.9183. | Study design, Comparator
546 | Meng L, Xu H, Liu A, van Raaij J, Bemelmans W, Hu X, Zhang Q, Du S, Fang H, Ma J, Xu G, Li Y, Guo H, Du L, Ma G. The costs and cost-effectiveness of a school-based comprehensive intervention study on childhood obesity in China. PLoS One. 2013. 8:e77971. doi:10.1371/journal.pone.0077971. | Country
547 | Meng Y, Manore MM, Schuna JM, Jr, Patton-Lopez MM, Branscum A, Wong SS. Promoting Healthy Diet, Physical Activity, and Life-Skills in High School Athletes: Results from the WAVE Ripples for Change Childhood Obesity Prevention Two-Year Intervention. Nutrients. 2018. 10:947. doi:10.3390/nu10070947. | Intervention/exposure
548 | Merrotsy A, McCarthy AL, Flack J, Lacey S, Coppinger T. Project Spraoi: a two-year longitudinal study on the effectiveness of a school-based nutrition and physical activity intervention on dietary intake, nutritional knowledge and markers of health of Irish schoolchildren. Public Health Nutr. 2019. 22:2489-2499. doi:10.1017/s1368980019001368. | Intervention/exposure
549 | Meseri R, Ergin, I, Mermer G, Hassoy H, Yoruk S, Catalgol S. School based multifaceted nutrition intervention decreased obesity in a high school: an intervention study from Turkey. Progr Nutr. 2017. 19:373-383. doi:10.23751/pn.v19i4.5327. | Study design
550 | Methner S, Maschkowski G, Hartmann M. The European School Fruit Scheme: impact on children’s fruit and vegetable consumption in North Rhine-Westphalia, Germany. Public Health Nutr. 2017. 20:542-548. doi:10.1017/s1368980016002652. | Study design
551 | Meyer MK. Influence of food choices on high school students’ perception of school foodservice. J Am Diet Assoc. 2000. 100:952-4. doi:10.1016/s0002-8223(00)00274-1. | Study design
552 | Mihas C, Mariolis A, Manios Y, Naska A, Arapaki A, Mariolis-Sapsakos T, Tountas Y. Evaluation of a nutrition intervention in adolescents of an urban area in Greece: short- and long-term effects of the VYRONAS study. Public Health Nutr. 2010. 13:712-9. doi:10.1017/s1368980009991625. | Comparator
553 | Millar L, Kremer P, de Silva-Sanigorski A, McCabe MP, Mavoa H, Moodie M, Utter J, Bell C, Malakellis M, Mathews L, Roberts G, Robertson N, Swinburn BA. Reduction in overweight and obesity from a 3-year community-based intervention in Australia: the ‘It’s Your Move!’ project. Obes Rev. 2011. 12 Suppl 2:20-8. doi:10.1111/j.1467-789X.2011.00904.x. | Intervention/exposure
554 | Millar L, Robertson N, Allender S, Nichols M, Bennett C, Swinburn B. Increasing community capacity and decreasing prevalence of overweight and obesity in a community based intervention among Australian adolescents. Prev Med. 2013. 56:379-84. doi:10.1016/j.ypmed.2013.02.020. | Intervention/exposure, Outcome
555 | Miller N, Reicks M, Redden JP, Mann T, Mykerezi E, Vickers Z. Increasing portion sizes of fruits and vegetables in an elementary school lunch program can increase fruit and vegetable consumption. Appetite. 2015. 91:426-30. doi:10.1016/j.appet.2015.04.081. | Study design
556 | Mittmann S, Austel A, Ellrott T. Behavioural Effects of a Short School-Based Fruit and Vegetable Promotion Programme. Health Educ. 2016. 116:222-237. doi:10.1108/HE-04-2014-0062 | Study design
557 | Mobley CC, Stadler DD, Staten MA, El Ghormli L, Gillis B, Hartstein J, Siega-Riz AM, Virus A. Effect of nutrition changes on foods selected by students in a middle school-based diabetes prevention intervention program: the HEALTHY experience. J Sch Health. 2012. 82:82-90. doi:10.1111/j.1746-1561.2011.00670.x. | Intervention/exposure
558 | Mohammadifard N, Sarrafzadegan N, Ghassemi GR, Nouri F, Pashmi R. Alteration in unhealthy nutrition behaviors in adolescents through community intervention: Isfahan Healthy Heart Program. ARYA Atheroscler. 2013. 9(1):89-97. | Country
559 | Mohammed Nawi A, Che Jamaludin FI. Effect of Internet-based Intervention on Obesity among Adolescents in Kuala Lumpur: A School-based Cluster Randomised Trial. Malays J Med Sci. 2015. 22:47-56. | Intervention/exposure
560 | Mokhtari F, Kazemi A, Ehsanpour S. Effect of educational intervention program for parents on adolescents’nutritional behaviors in Isfahan in 2016. J Educ Health Promot. 2017. 6:103. doi:10.4103/jehp.jehp_155_16. | Intervention/exposure, Age at intervention/exposure
561 | Montelpare WJ, McPherson MN, Boardman K, Zerpa CE. Evaluating the Wizards of Motion Cardiovascular Disease Prevention Module. J Sch Nurs. 2018. 34:350-358. doi:10.1177/1059840517709074. | Intervention/exposure
562 | Moore GF, Murphy S, Chaplin K, Lyons RA, Atkinson M, Moore L. Impacts of the Primary School Free Breakfast Initiative on socio-economic inequalities in breakfast consumption among 9-11-year-old schoolchildren in Wales. Public Health Nutr. 2014. 17:1280-9. doi:10.1017/s1368980013003133. | Intervention/exposure
563 | Moore JB, Pawloski LR, Goldberg P, Kyeung MO, Stoehr A, Baghi H. Childhood obesity study: a pilot study of the effect of the nutrition education program Color My Pyramid. J Sch Nurs. 2009. 25:230-9. doi:10.1177/1059840509333325. | Study design
564 | Mora T, Llargués E, Recasens A. Does health education affect BMI? Evidence from a school-based randomised-control trial. Econ Hum Biol. 2015. 17:190-201. doi:10.1016/j.ehb.2014.11.001. | Intervention/exposure
565 | Morales-Ruán Mdel C, Shamah-Levy T, Amaya-Castellanos CI, Salazar-Coronel AA, Jiménez-Aguilar A, Amaya-Castellanos MA, Méndez-Gómez Humarán, I. Effects of an intervention strategy for school children aimed at reducing overweight and obesity within the State of Mexico. Salud Publica Mex. 2014. 56 Suppl 2:s113-22. doi:10.21149/spm.v56s2.5175. | Intervention/exposure
566 | Moreno JP, Mohammed A, Moore CE, Johnston C. Benefits of a Snacking Intervention as Part of a School-Based Obesity Intervention for Mexican American Children. J Appl Res Child. 2015. 6(2):15. | Study design, Intervention/exposure
567 | Moreno JP, Johnston CA, Hernandez DC, LeNoble J, Papaioannou, MA, Foreyt JP. Impact of parental weight status on a school-based weight management programme designed for Mexican-American children. Pediatr Obes. 2016. 11:354-60. doi:10.1111/ijpo.12066. | Intervention/exposure
568 | Morgan AZ, Ulrich P, Simmons KP, Gropper SS, Connell LJ, Daniels MK, Latham E, Keiley MK. Effectiveness of a multi-faceted, school-based health intervention program with 4th graders in Alabama. Child Youth Serv Rev. 2014. 37:46-54. doi:10.1016/j.childyouth.2013.12.006. | Intervention/exposure
569 | Morgan PJ, Lubans DR, Callister R, Okely AD, Burrows TL, Fletcher R, Collins CE. The ‘Healthy Dads, Healthy Kids’ randomized controlled trial: efficacy of a healthy lifestyle program for overweight fathers and their children. Int J Obes (Lond). 2011. 35:436-47. doi:10.1038/ijo.2010.151. | Intervention/exposure
570 | Morgan PJ, Warren JM, Lubans DR, Saunders KL, Quick GI, Collins CE. The impact of nutrition education with and without a school garden on knowledge, vegetable intake and preferences and quality of school life among primary-school students. Public Health Nutr. 2010. 13:1931-40. doi:10.1017/s1368980010000959. | Study design
571 | Morris H, Skouteris H, Edwards S, Rutherford LM, Cutter-Mackenzie A, O’Connor A, Mantilla A, Huang TTK, Lording KM, Williams-Smith J. Feasibility of Conducting a Randomized Trial to Promote Healthy Eating, Active Play and Sustainability Awareness in Early Childhood Curricula. Early Child Dev Care. 2016. 186:1752-1764. doi:10.1080/03004430.2015.1131158. | Intervention/exposure, Age at intervention/exposure
572 | Morris JL, Neustadter A, Zidenberg-Cherr S. First-Grade Gardeners More Likely To Taste Vegetables. Calif Agr. 2001. 55:43-46. doi:10.3733/ca.v055n01p43 | Outcome
573 | Morris JL, Zidenberg-Cherr S. Garden-enhanced nutrition curriculum improves fourth-grade school children’s knowledge of nutrition and preferences for some vegetables. J Am Diet Assoc. 2002. 102:91-3. doi:10.1016/s0002-8223(02)90027-1. | Outcome
574 | Moss A, Smith S, Null D, Long Roth S, Tragoudas, U. Farm to School and Nutrition Education: Positively Affecting Elementary School-Aged Children’s Nutrition Knowledge and Consumption Behavior. Child Obes. 2013. 9:51-6. doi:10.1089/chi.2012.0056. | Study design
575 | Moya SA, Hampl JS. Project GLEAN: Implementing a School-Based Food Distribution Program. For Parents Particularly. Child Educ. 2003. 80(1):36-37. | Study design
576 | Muckelbauer R, Libuda L, Clausen K, Toschke AM, Reinehr T, Kersting M. Promotion and provision of drinking water in schools for overweight prevention: randomized, controlled cluster trial. Pediatrics. 2009. 123:e661-7. doi:10.1542/peds.2008-2186. | Intervention/exposure
577 | Müller MJ, Asbeck I, Mast M, Langnäse K, Grund A. Prevention of obesity--more than an intention. Concept and first results of the Kiel Obesity Prevention Study (KOPS). Int J Obes Relat Metab Disord. 2001. 25 Suppl 1:S66-74. doi:10.1038/sj.ijo.0801703. | Intervention/exposure
578 | Murillo AL, Safan M, Castillo-Chavez C, Phillips ED, Wadhera D. Modeling eating behaviors: The role of environment and positive food association learning via a Ratatouille effect. Math Biosci Eng. 2016. 13:841-855. doi:10.3934/mbe.2016020. | Study design
579 | Muros JJ, Zabala M, Oliveras-López MJ, Bouzas PR, Knox E, Rufián-Henares JÁ, López-García de la Serrana H. Effect of Physical Activity, Nutritional Education, and Consumption of Extra Virgin Olive Oil on Lipid, Physiological, and Anthropometric Profiles in a Pediatric Population. J Phys Act Health. 2015. 12:1245-52. doi:10.1123/jpah.2014-0236. | Intervention/exposure
580 | Muros JJ, Zabala M, Oliveras-López MJ, Ocaña-Lara FA, López-García de la Serrana H. Results of a 7-week school-based physical activity and nutrition pilot program on health-related parameters in primary school children in southern Spain. Pediatr Exerc Sci. 2013. 25:248-61. doi:10.1123/pes.25.2.248. | Intervention/exposure
581 | Murphy S, Moore GF, Tapper K, Lynch R, Clarke R, Raisanen L, Desousa C, Moore L. Free healthy breakfasts in primary schools: a cluster randomised controlled trial of a policy intervention in Wales, UK. Public Health Nutr. 2011. 14:219-26. doi:10.1017/s1368980010001886. | Intervention/exposure
582 | Muth ND, Chatterjee A, Williams D, Cross A, Flower K. Making an IMPACT: effect of a school-based pilot intervention. N C Med J. 2008. 69(6):432-40. | Study design, Intervention/exposure
583 | Muzaffar H, Castelli DM, Scherer J, Chapman-Novakofski K. The impact of web-based HOT (Healthy Outcomes for Teens) Project on risk for type 2 diabetes: a randomized controlled trial. Diabetes Technol Ther. 2014. 16:846-52. doi:10.1089/dia.2014.0073. | Intervention/exposure, Outcome
584 | Muzaffar H, Nikolaus CJ, Ogolsky BG, Lane A, Liguori C, Nickols-Richardson SM. Promoting Cooking, Nutrition, and Physical Activity in Afterschool Settings. Am J Health Behav. 2019. 43:1050-1063. doi:10.5993/ajhb.43.6.4. | Intervention/exposure, Comparator
585 | Myers EF, Gerstein DE, Foster J, Ross M, Brown K, Kennedy E, Linchey J, Madsen KA, Crawford PB. Energy balance for kids with play: design and implementation of a multi-component school-based obesity prevention program. Child Obes. 2014. 10:251-9. doi:10.1089/chi.2013.0075. | Intervention/exposure
586 | Myers G, Wright S, Blane S, Pratt IS, Pettigrew S. A process and outcome evaluation of an in-class vegetable promotion program. Appetite. 2018. 125:182-189. doi:10.1016/j.appet.2018.01.023. | Study design
587 | Myers J, Subczyk, W, Ketterman K, Carrico R. Health promotion schools of excellence: learning from the past to impact the future. J Ky Med Assoc. 2008. 106(3):98-103. | Study design
588 | Nabors L, Burbage M, Woodson KD, Swoboda C. Implementation of an after-school obesity prevention program: helping young children toward improved health. Issues Compr Pediatr Nurs. 2015. 38:22-38. doi:10.3109/01460862.2014.973081. | Intervention/exposure
589 | Naghashpour M, Shakerinejad G, Lourizadeh MR, Hajinajaf, S, Jarvandi F. Nutrition education based on health belief model improves dietary calcium intake among female students of junior high schools. J Health Popul Nutr. 2014. 32:420-9. doi:10.3329/JHPN.V32I3.2824. | Comparator
590 | Nakano T, Kasuga K, Murase T, Suzuki K. Changes in Healthy Childhood Lifestyle Behaviors in Japanese Rural Areas. J Sch Health. 2013. 83:231-238. doi:10.1111/josh.12021. | Study design
591 | Nanney MS, Haire-Joshu D, Elliott M, Hessler K, Brownson RC. Evaluating changeability to improve fruit and vegetable intake among school aged children. Nutr J. 2005. 4:34. doi:10.1186/1475-2891-4-34. | Study design
592 | Nanney MS, Leduc, R, Hearst M, Shanafelt A, Wang Q, Schroeder M, Grannon KY, Kubik MY, Caspi C, Harnack LJ. A Group Randomized Intervention Trial Increases Participation in the School Breakfast Program in 16 Rural High Schools in Minnesota. J Acad Nutr Diet. 2019. 119:915-922. doi:10.1016/j.jand.2018.12.007. | Outcome
593 | Narayanan N, Nagpal N, Zieve H, Vyas A, Tatum J, Ramos M, McCarter R, Jr, Lucas CT, Mietus-Snyder M. A School-Based Intervention Using Health Mentors to Address Childhood Obesity by Strengthening School Wellness Policy. Prev Chronic Dis. 2019. 16:E154. doi:10.5888/pcd16.190054. | Intervention/exposure
594 | Nathan N, Wolfenden L, Bell AC, Wyse R, Morgan PJ, Butler M, Sutherland R, Milat AJ, Hector D, Wiggers J. Effectiveness of a multi-strategy intervention in increasing the implementation of vegetable and fruit breaks by Australian primary schools: a non-randomized controlled trial. BMC Public Health. 2012. 12:651. doi:10.1186/1471-2458-12-651. | Outcome
595 | Nathan N, Yoong SL, Sutherland R, Reilly, K, Delaney T, Janssen L, Robertson K, Reynolds R, Chai LK, Lecathelinais C, Wiggers J, Wolfenden L. Effectiveness of a multicomponent intervention to enhance implementation of a healthy canteen policy in Australian primary schools: a randomised controlled trial. Int J Behav Nutr Phys Act. 2016. 13:106. doi:10.1186/s12966-016-0431-5. | Outcome
596 | Nelson MR, Kehr DP. Food-focused advertising literacy can increase nutrition knowledge in elementary school students. J Nutr Educ Behav. 2016. 48:749-751.e1. doi:10.1016/j.jneb.2016.08.013. | Outcome
597 | Nemet D, Geva D, Eliakim A. Health promotion intervention in low socioeconomic kindergarten children. J Pediatr. 2011. 158:796-801.e1. doi:10.1016/j.jpeds.2010.10.040. | Intervention/exposure
598 | Nemet D, Geva D, Pantanowitz M, Igbaria N, Meckel Y, Eliakim A. Health promotion intervention in Arab-Israeli kindergarten children. J Pediatr Endocrinol Metab. 2011. 24:1001-7. doi:10.1515/jpem.2011.387. | Intervention/exposure
599 | Nemet D, Geva D, Pantanowitz M, Igbaria N, Meckel Y, Eliakim A. Long term effects of a health promotion intervention in low socioeconomic Arab-Israeli kindergartens. BMC Pediatr. 2013. 13:45. doi:10.1186/1471-2431-13-45. | Intervention/exposure
600 | Neumark-Sztainer D, Haines J, Robinson-O’Brien R, Hannan PJ, Robins M, Morris B, Petrich CA. ‘Ready. Set. ACTION!’ A theater-based obesity prevention program for children: a feasibility study. Health Educ Res. 2009. 24:407-20. doi:10.1093/her/cyn036. | Intervention/exposure
601 | Neumark-Sztainer DR, Friend SE, Flattum CF, Hannan PJ, Story MT, Bauer KW, Feldman SB, Petrich CA. New moves-preventing weight-related problems in adolescent girls a group-randomized study. Am J Prev Med. 2010. 39:421-32. doi:10.1016/j.amepre.2010.07.017. | Intervention/exposure
602 | Newell SA, Huddy AD, Adams JK, Miller M, Holden L, Dietrich UC. The tooty fruity vegie project: changing knowledge and attitudes about fruits and vegetables. Aust N Z J Public Health. 2004. 28:288-95. doi:10.1111/j.1467-842x.2004.tb00709.x. | Outcome
603 | Nichols SD, Francis MP, Dalrymple N. Sustainability of a Curriculum-based Intervention on Dietary Behaviours and Physical Activity among Primary School Children in Trinidad and Tobago. West Indian Med J. 2014. 63:68-77. doi:10.7727/wimj.2014.011. | Intervention/exposure
604 | Nickel NC, Doupe M, Enns JE, Brownell M, Sarkar J, Chateau D, Burland E, Chartier M, Katz A, Crockett L, Azad MB, McGavock JM, Santos R. Differential effects of a school-based obesity prevention program: A cluster randomized trial. Matern Child Nutr. 2021. 17(1):e13009. doi:10.1111/mcn.13009. | Intervention/exposure
605 | Niederer I, Bürgi F, Ebenegger V, Marques-Vidal P, Schindler C, Nydegger A, Kriemler S, Puder JJ. Effects of a lifestyle intervention on adiposity and fitness in overweight or low fit preschoolers (Ballabeina). Obesity (Silver Spring). 2013. 21:E287-93. doi:10.1002/oby.20119. | Intervention/exposure
606 | Nolan GA, McFarland AL, Zajicek JM, Waliczek TM. The Effects of Nutrition Education and Gardening on Attitudes, Preferences, and Knowledge of Minority Second to Fifth Graders in the Rio Grande Valley Toward Fruit and Vegetables. Horttechnology. 2012. 22:299-304. doi:10.21273/horttech.22.3.299. | Study design, Outcome
607 | Norman Å, Zeebari Z, Nyberg G, Elinder LS. Parental support in promoting children’s health behaviours and preventing overweight and obesity - a long-term follow-up of the cluster-randomised healthy school start study II trial. BMC Pediatr. 2019. 19:104. doi:10.1186/s12887-019-1467-x. | Intervention/exposure
608 | Nowak AJ, Kolouch G, Schneyer L, Roberts KH. Building food literacy and positive relationships with healthy food in children through school gardens. Child Obes. 2012. 8:392-5. doi:10.1089/chi.2012.0084. | Study design
609 | Nyberg G, Norman Å, Sundblom E, Zeebari Z, Elinder LS. Effectiveness of a universal parental support programme to promote health behaviours and prevent overweight and obesity in 6-year-old children in disadvantaged areas, the Healthy School Start Study II, a cluster-randomised controlled trial. Int J Behav Nutr Phys Act. 2016. 13:4. doi:10.1186/s12966-016-0327-4. | Intervention/exposure
610 | Nyberg G, Sundblom E, Norman A, Elinder LS. A healthy school start - parental support to promote healthy dietary habits and physical activity in children: design and evaluation of a cluster-randomised intervention. BMC Public Health. 2011. 11:185. doi:10.1186/1471-2458-11-185. | Other: Protocol/design
611 | O’Brien SA, Shoemaker CA. An after-school gardening club to promote fruit and vegetable fourth grade consumption among fourth grade students: The assessment of social cognitive theory constructs. Horttechnology. 2006. 16:24-29. doi:10.21273/horttech.16.1.0024. | Outcome
612 | Ochoa-Avilés A, Verstraeten R, Huybregts L, Andrade S, Van Camp J, Donoso S, Ramírez PL, Lachat C, Maes L, Kolsteren P. A school-based intervention improved dietary intake outcomes and reduced waist circumference in adolescents: a cluster randomized controlled trial. Nutr J. 2017. 16:79. doi:10.1186/s12937-017-0299-5. | Intervention/exposure, Other: <75% of the intervention focused on food and nutrition
613 | Ofosu NN, Ekwaru JP, Bastian KA, Loehr SA, Storey K, Spence JC, Veugelers PJ. Long-term effects of comprehensive school health on health-related knowledge, attitudes, self-efficacy, health behaviours and weight status of adolescents. BMC Public Health. 2018. 18:515. doi:10.1186/s12889-018-5427-4. | Study design, Intervention/exposure
614 | Ojeda-Rodriguez A, Zazpe I, Morell-Azanza L, Chueca MJ, Azcona-sanjulian MC, Marti A. Improved Diet Quality and Nutrient Adequacy in Children and Adolescents with Abdominal Obesity after a Lifestyle Intervention. Nutrients. 2018. 10:1500. doi:10.3390/nu10101500. | Intervention/exposure
615 | Olan EL, Campbell LO, Jahani S. Examining Second Graders’ Healthy Food Choices: Through Literacy and Active Learning. Nutr Metab Insights. 2019. 12:1178638819839063. doi:10.1177/1178638819839063. | Study design, Outcome
616 | Olivares S, Zacarías I, Andrade M, Kain J, Lera L, Vio F, Morón C. Nutrition education in Chilean primary schools. Food Nutr Bull. 2005. 26:S179-85. doi:10.1177/15648265050262s208. | Study design
617 | Ørntoft C, Fuller CW, Larsen MN, Bangsbo J, Dvorak J, Krustrup P. ‘FIFA 11 for Health’ for Europe. II: effect on health markers and physical fitness in Danish schoolchildren aged 10-12 years. Br J Sports Med. 2016. 50:1394-1399. doi:10.1136/bjsports-2016-096124. | Intervention/exposure
618 | Osganian SK, Hoelscher DM, Zive M, Mitchell PD, Snyder P, Webber LS. Maintenance of effects of the eat smart school food service program: results from the CATCH-ON study. Health Educ Behav. 2003. 30:418-33. doi:10.1177/1090198103253509. | Intervention/exposure, Outcome
619 | Ostrowski L, Speiser PW, Accacha S, Altshuler L, Fennoy, I, Lowell B, Rapaport R, Rosenfeld, W, Shelov, SP, Ten S, Rosenbaum M. Demographics and anthropometrics impact benefits of health intervention: data from the Reduce Obesity and Diabetes Project. Obes Sci Pract. 2019. 5:46-58. doi:10.1002/osp4.310. | Intervention/exposure
620 | Øverby NC, Klepp KI, Bere E. Introduction of a school fruit program is associated with reduced frequency of consumption of unhealthy snacks. Am J Clin Nutr. 2012. 96:1100-3. doi:10.3945/ajcn.111.033399. | Study design
621 | Øvrum A, Bere E. Evaluating free school fruit: results from a natural experiment in Norway with representative data. Public Health Nutr. 2014. 17:1224-31. doi:10.1017/s1368980013002504. | Study design
622 | Pablos A, Nebot V, Vañó-Vicent V, Ceca D, Elvira L. Effectiveness of a school-based program focusing on diet and health habits taught through physical exercise. Appl Physiol Nutr Metab. 2018. 43:331-337. doi:10.1139/apnm-2017-0348. | Intervention/exposure
623 | Paek HJ, Jung Y, Oh HJ, Alaimo K, Pfeiffer K, Carlson JJ, Wen Y, Betz HH, Orth J. A Social Marketing Approach to Promoting Healthful Eating and Physical Activity in Low-Income and Ethnically Diverse Schools. Health Educ J. 2015. 74:351-363. doi:10.1177/0017896914540294 | Intervention/exposure, Outcome
624 | Pampaloni B, Cianferotti L, Gronchi G, Bartolini E, Fabbri S, Tanini A, Brandi ML. Growing Strong and Healthy with Mister Bone: An Educational Program to Have Strong Bones Later in Life. Nutrients. 2015. 7:9985-98. doi:10.3390/nu7125510. | Study design
625 | Pan HJ, Hung LJ, Chen CY. Effect of class-based lifestyle intervention on the management of childhood obesity. Obes Res Clin Pract. 2020. 14:184-190. doi:10.1016/j.orcp.2020.03.007. | Study design
626 | Panunzio MF, Antoniciello A, Cela EP, Ferguson LR, Bucci E, Petracca L, Bisceglia R, D’Ambrosio P, Buccinotti MC, Romagnolo G, D’Aprile AP, Carella F, Ugolini G. 15-week long school-based nutritional education program to promote Italian primary schoolchildren’s fruit and vegetable intake. Ann Ig. 2010. 22(5):481-4. | Study design
627 | Paradells VN, Monzo AP, Macagno LE, Lujan JFG, Abella CP. Effects of an intervention program (HHP) on the promotion of healthy habits in early adolescence. Nutr Hosp. 2015. 32:2640-2649. doi:10.3305/nh.2015.32.6.9858. | Intervention/exposure
628 | Paradis G, Lévesque L, Macaulay AC, Cargo M, McComber A, Kirby R, Receveur O, Kishchuk N, Potvin L. Impact of a diabetes prevention program on body size, physical activity, and diet among Kanien’keha:ka (Mohawk) children 6 to 11 years old: 8-year results from the Kahnawake Schools Diabetes Prevention Project. Pediatrics. 2005. 115:333-9. doi:10.1542/peds.2004-0745. | Intervention/exposure
629 | Park BK, Cho MS. Taste education reduces food neophobia and increases willingness to try novel foods in school children. Nutr Res Pract. 2016. 10:221-8. doi:10.4162/nrp.2016.10.2.221. | Study design, Outcome
630 | Parker L, Fox A. The Peterborough Schools Nutrition Project: a multiple intervention programme to improve school-based eating in secondary schools. Public Health Nutr. 2001. 4:1221-8. doi:10.1079/phn2001195. | Outcome, Comparator
631 | Parmer SM, Salisbury-Glennon J, Shannon D, Struempler B. School gardens: an experiential learning approach for a nutrition education program to increase fruit and vegetable knowledge, preference, and consumption among second-grade students. J Nutr Educ Behav. 2009. 41:212-7. doi:10.1016/j.jneb.2008.06.002. | Comparator
632 | Parsons WG, Garcia GM, Hoffman PK. Evaluating school wellness policy in curbing childhood obesity in Anchorage, Alaska. J Sch Nurs. 2014. 30:324-31. doi:10.1177/1059840513513155. | Intervention/exposure
633 | Passehl B, McCarroll C, Buechner J, Gearring C, Smith AE, Trowbridge F. Preventing childhood obesity: establishing healthy lifestyle habits in the preschool years. J Pediatr Health Care. 2004. 18:315-9. doi:10.1016/s0891524504002755. | Study design
634 | Patel AI, Bogart LM, Elliott MN, Lamb S, Uyeda KE, Hawes-Dawson J, Klein DJ, Schuster MA. Increasing the availability and consumption of drinking water in middle schools: a pilot study. Prev Chronic Dis. 2011. 8(3):A60. | Intervention/exposure
635 | Patel CB, Strommen JJ, Elliott AM, Muallem G, Eissa MA. Nutrition Mission. Tex Med. 2012. 108(4):e1. | Study design
636 | Patsopoulou A, Tsimtsiou, Z, Katsioulis A, Malissiova E, Rachiotis G, Hadjichristodoulou C. Evaluating the Efficacy of the Feeding Exercise Randomized Trial in Overweight and Obese Adolescents. Child Obes. 2017. 13:128-137. doi:10.1089/chi.2016.0192. | Intervention/exposure
637 | Patton-Lopez MM, Manore MM, Branscum A, Meng Y, Wong SS. Changes in Sport Nutrition Knowledge, Attitudes/Beliefs and Behaviors Following a Two-Year Sport Nutrition Education and Life-Skills Intervention among High School Soccer Players. Nutrients. 2018. 10:1636. doi:10.3390/nu10111636. | Intervention/exposure, Outcome
638 | Pbert L, Druker S, Barton B, Schneider KL, Olendzki B, Gapinski MA, Kurtz S, Osganian S. A School-Based Program for Overweight and Obese Adolescents: A Randomized Controlled Trial. J Sch Health. 2016. 86:699-708. doi:10.1111/josh.12428. | Intervention/exposure
639 | Pedrosa C, Oliveira BM, Albuquerque I, Simões-Pereira C, Vaz-de-Almeida MD, Correia F. Metabolic syndrome, adipokines and ghrelin in overweight and obese schoolchildren: results of a 1-year lifestyle intervention programme. Eur J Pediatr. 2011. 170:483-92. doi:10.1007/s00431-010-1316-2. | Intervention/exposure
640 | Pempek TA, Calvert SL. Tipping the balance: use of advergames to promote consumption of nutritious foods and beverages by low-income African American children. Arch Pediatr Adolesc Med. 2009. 163:633-7. doi:10.1001/archpediatrics.2009.71. | Intervention/exposure
641 | Peng W. Design and Evaluation of a Computer Game to Promote a Healthy Diet for Young Adults. Health Comm. 2009. 24:115-127. doi:10.1080/10410230802676490. | Age at intervention/exposure
642 | Peterson KE, Spadano-Gasbarro JL, Greaney ML, Austin SB, Mezgebu S, Hunt AT, Blood EA, Horan C, Feldman HA, Osganian SK, Bettencourt MF, Richmond TK. Three-Year Improvements in Weight Status and Weight-Related Behaviors in Middle School Students: The Healthy Choices Study. PLoS One. 2015. 10:e0134470. doi:10.1371/journal.pone.0134470. | Study design
643 | Peterson M, Goodwin S, Ellenberg D. Analysis of the American Cancer Society’s Generation Fit Project. Am J Health Educ. 2004. 35:141-149. doi:10.1080/19325037.2004.10603630. | Intervention/exposure
644 | Piana N, Ranucci C, Buratta L, Foglia E, Fabi M, Novelli F, Casucci S, Reginato E, Pippi R, Aiello C, Leonardi A, Romani G, De Feo P, Mazzeschi C. An innovative school-based intervention to promote healthy lifestyles. Health Educ J. 2017. 76:716-729. doi:10.1177/0017896917712549. | Study design
645 | Pierce B, Bowden B, McCullagh M, Diehl A, Chissell Z, Rodriguez R, Berman BM, Adamo CR D. A Summer Health Program for African-American High School Students in Baltimore, Maryland: Community Partnership for Integrative Health. Explore (NY). 2017. 13:186-197. doi:10.1016/j.explore.2017.02.002. | Study design, Intervention/exposure
646 | Piperakis SM, Sotiriou A, Georgiou, E, Thanou A, Zafiropoulou M. Understanding Nutrition: A Study of Greek Primary School Children Dietary Habits, before and after Classroom Nutrition Intervention. J Sci Educ Technol. 2004. 13:129-136. doi:10.1023/B:JOST.0000019645.03448.65. | Study design
647 | Pittman DW, Bland IR, Cabrera ID, Franck KE, Perkins EL, Schmidt NA, Allen HN, Atkins SR, Pittman SB. The Boss’ Healthy Buddies Nutrition Resource Is Effective for Elementary School Students. J Obes. 2018. 2018:4659874. doi:10.1155/2018/4659874. | Study design
648 | Plachta-Danielzik S, Landsberg B, Lange D, Seiberl J, Müller MJ. Eight-year follow-up of school-based intervention on childhood overweight--the Kiel Obesity Prevention Study. Obes Facts. 2011. 4:35-43. doi:10.1159/000324552. | Intervention/exposure
649 | Plachta-Danielzik S, Pust S, Asbeck I, Czerwinski-Mast M, Langnäse K, Fischer C, Bosy-Westphal A, Kriwy P, Müller MJ. Four-year follow-up of school-based intervention on overweight children: the KOPS study. Obesity (Silver Spring). 2007. 15:3159-69. doi:10.1038/oby.2007.376. | Intervention/exposure
650 | Pobocik RS, Haar CM, Dawson EE, Coleman P, Bakies K. Curriculum for Junior High School Students: Dairy Food Consumption Self-Efficacy. J Fam Consum Sci. 2009. 101(4):20-26. | Study design
651 | Poelman AAM, Cochet-Broch M, Cox DN, Vogrig D. Vegetable Education Program Positively Affects Factors Associated With Vegetable Consumption Among Australian Primary (Elementary) Schoolchildren. J Nutr Educ Behav. 2019. 51:492-497.e1. doi:10.1016/j.jneb.2018.11.002. | Outcome
652 | Poelman AAM, Cochet-Broch M, Cox DN, Vogrig D. VERTICAL: A Sensory Education Program for Australian Primary Schools to Promote Children’s Vegetable Consumption. J Nutr Educ Behav. 2017. 49:527-528.e1. doi:10.1016/j.jneb.2017.04.001. | Study design, Outcome
653 | Poelman AAM, Cochet-Broch M, Wiggins B, McCrea R, Heffernan JE, Beelen J, Cox DN. Effect of Experiential Vegetable Education Program on Mediating Factors of Vegetable Consumption in Australian Primary School Students: A Cluster-Randomized Controlled Trial. Nutrients. 2020. 12(8):2343. doi:10.3390/nu12082343. | Outcome
654 | Polonsky HM, Bauer KW, Fisher JO, Davey A, Sherman S, Abel ML, Hanlon A, Ruth KJ, Dale LC, Foster GD. Effect of a Breakfast in the Classroom Initiative on Obesity in Urban School-aged Children: A Cluster Randomized Clinical Trial. JAMA Pediatr. 2019. 173:326-333. doi:10.1001/jamapediatrics.2018.5531. | Outcome
655 | Pope L, Roche E, Morgan CB, Kolodinsky J. Sampling tomorrow’s lunch today: Examining the effect of sampling a vegetable-focused entrée on school lunch participation, a pilot study. Prev Med Rep. 2018. 12:152-157. doi:10.1016/j.pmedr.2018.09.010. | Study design
656 | Pope L, Wolf RL. The influence of labeling the vegetable content of snack food on children’s taste preferences: a pilot study. J Nutr Educ Behav. 2012. 44:178-82. doi:10.1016/j.jneb.2010.02.006. | Study design, Intervention/exposure, Outcome
657 | Pope M. Preventing Weight Gain in Children Who Are School Age and African-American. Pediatr Phys Ther. 2016. 28:207-16. doi:10.1097/pep.0000000000000243. | Intervention/exposure
658 | Poston SA, Shoemaker CA, Dzewaltowski DA. A comparison of a gardening and nutrition program with a standard nutrition program in an out-of-school setting. Horttechnology. 2005. 15:463-467. doi:10.21273/horttech.15.3.0463. | Intervention/exposure, Outcome
659 | Powers AR, Struempler BJ, Guarino A, Parmer SM. Effects of a nutrition education program on the dietary behavior and nutrition knowledge of second-grade and third-grade students. J Sch Health. 2005. 75:129-33. doi:10.1111/j.1746-1561.2005.tb06657.x | Study design
660 | Prelip M, Kinsler J, Thai CL, Erausquin JT, Slusser W. Evaluation of a school-based multicomponent nutrition education program to improve young children’s fruit and vegetable consumption. J Nutr Educ Behav. 2012. 44:310-8. doi:10.1016/j.jneb.2011.10.005. | Study design
661 | Prelip M, Slusser W, Thai CL, Kinsler J, Erausquin JT. Effects of a school-based nutrition program diffused throughout a large urban community on attitudes, beliefs, and behaviors related to fruit and vegetable consumption. J Sch Health. 2011. 81:520-9. doi:10.1111/j.1746-1561.2011.00622.x. | Study design
662 | Prescott MP, Burg X, Metcalfe JJ, Lipka AE, Herritt C, Cunningham-Sabo L. Healthy Planet, Healthy Youth: A Food Systems Education and Promotion Intervention to Improve Adolescent Diet Quality and Reduce Food Waste. Nutrients. 2019. 11:1869. doi:10.3390/nu11081869. | Study design
663 | Presti G, Cau S, Oppo A, Moderato P. Increased Classroom Consumption of Home-Provided Fruits and Vegetables for Normal and Overweight Children: Results of the Food Dudes Program in Italy. J Nutr Educ Behav. 2015. 47:338-44. doi:10.1016/j.jneb.2015.04.331. | Study design
664 | Price J, Just DR. Lunch, recess and nutrition: responding to time incentives in the cafeteria. Prev Med. 2015. 71:27-30. doi:10.1016/j.ypmed.2014.11.016. | Study design
665 | Puma J, Romaniello C, Crane L, Scarbro S, Belansky E, Marshall JA. Long-term student outcomes of the Integrated Nutrition and Physical Activity Program. J Nutr Educ Behav. 2013. 45:635-42. doi:10.1016/j.jneb.2013.05.006. | Intervention/exposure
666 | Qian L, Newman, IM, Shell DF, Cheng CM. Reducing Overweight and Obesity among Elementary Students in Wuhan, China. Int Electron J Health Educ. 2012. 15:62-71. | Study design
667 | Qian Y, Nayga RM, Thomsen MR, Rouse HL. The Effect of the Fresh Fruit and Vegetable Program on Childhood Obesity. Appl Econ Perspect Pol. 2016. 38:260-275. doi:10.1093/aepp/ppv017. | Study design, Outcome
668 | Quinn EL, Johnson DB, Podrabsky M, Saelens BE, Bignell W, Krieger J. Effects of a Behavioral Economics Intervention on Food Choice and Food Consumption in Middle-School and High-School Cafeterias. Prev Chronic Dis. 2018. 15:E91. doi:10.5888/pcd15.170377. | Study design
669 | Rafferty K, Zipay D, Patey C, Meyer J. Milk Enhancements Improve Milk Consumption and Increase Meal Participation in the NSLP: The School Milk Pilot Test. J Child Nutr Manag. 2009. 33. | Study design
670 | Raghoebar S, van Kleef E, de Vet E. Self-crafting vegetable snacks: testing the IKEA-effect in children. Br Food J. 2017. 119:1301-1312. doi:10.1108/bfj-09-2016-0443. | Intervention/exposure
671 | Rahimi A, Hashemzadeh M, Zare-Farashbandi F, Alavi Naeini AM, Hasanzadeh A. The effect of nutrition education course on awareness of obese and overweight female 1(st)-year High School students of Isfahan based on transtheoretical model of behavioral change. J Educ Health Promot. 2018. 7:76. doi:10.4103/jehp.jehp_120_17. | Outcome
672 | Rahmani K, Djazayery A, Habibi MI, Heidari H, Dorosti-Motlagh AR, Pourshahriari M, Azadbakht L. Effects of daily milk supplementation on improving the physical and mental function as well as school performance among children: results from a school feeding program. J Res Med Sci. 2011. 16(4):469-76. | Outcome
673 | Raiha T, Tossavainen K, Turunen H, Enkenberg J, Kiviniemi V. Effects of Nutrition Health Intervention on Pupils’ Nutrition Knowledge and Eating Habits. Scand J Educ Res. 2012. 56:277-294. doi:10.1080/00313831.2011.581688. | Intervention/exposure
674 | Raiha T, Tossavainen K, Turunen H, Enkenberg J, Halonen P. Adolescents’ Nutrition Health Issues: Opinions of Finnish Seventh-Graders. Health Edu. 2006. 106:114-132. doi:10.1108/09654280610650954. | Study design, Intervention/exposure
675 | Rainville AlJ, Choi K, Ragg M, King A, Carr DH. Nutrition Information at the Point of Selection in High Schools Does Not Affect Purchases. J Child Nutr Manag. 2010. 34. | Outcome
676 | Rajan S, Roberts KJ, Guerra L, Pirsch M, Morrell, E. Integrating Health Education in Core Curriculum Classrooms: Successes, Challenges, and Implications for Urban Middle Schools. J Sch Health. 2017. 87:949-957. doi:10.1111/josh.12563. | Outcome
677 | Ramos S, Vale S, Pinto A, Rodrigues P, Barbot A. Sustainability and Healthy Habits in School: Eating and Physical Activity. Int J Curric Instru 2020. 12:1-15. | Study design, Intervention/exposure
678 | Ramsay S, Safaii SA, Croschere T, Branen LJ, Wiest M. Kindergarteners’ Entree Intake Increases when Served a Larger Entree Portion in School Lunch: A Quasi-Experiment. J Sch Health. 2013. 83:239-242. doi: 10.1111/josh.12022. | Study design
679 | Rankins J, Weatherspoon L, Cook L, Reed, C, Shuford-Law J, Davis Y, Kissinger M, Ralston P. Influences of a chronic disease risk reduction curriculum called “Live!” on fat and fiber knowledge and attitudes of black and white adolescents. J Nutr Educ. 2000. 32:14-20. doi:10.1016/s0022-3182(00)70505-x. | Study design
680 | Ransley JK, Greenwood DC, Cade JE, Blenkinsop S, Schagen I, Teeman D, Scott E, White G, Schagen S. Does the school fruit and vegetable scheme improve children’s diet? A non-randomised controlled trial. J Epidemiol Community Health. 2007. 61:699-703. doi:10.1136/jech.2006.052696. | Study design
681 | Rappaport EB, Daskalakis C, Sendecki JA. Using routinely collected growth data to assess a school-based obesity prevention strategy. Int J Obes (Lond). 2013. 37:79-85. doi:10.1038/ijo.2012.126. | Outcome
682 | Ratcliffe MM, Merrigan KA, Rogers BL, Goldberg JP. The effects of school garden experiences on middle school-aged students’ knowledge, attitudes, and behaviors associated with vegetable consumption. Health Promot Pract. 2011. 12:36-43. doi:10.1177/1524839909349182. | Study design
683 | Rauber F, Hoffman DJ, Vitolo MR. Diet quality from pre-school to school age in Brazilian children: a 4-year follow-up in a randomised control study. Br J Nutr. 2014. 111:499-505. doi:10.1017/s0007114513002857. | Intervention/exposure, Age at intervention/exposure
684 | Rausch Herscovici C, Kovalskys I, De Gregorio MJ. Gender differences and a school-based obesity prevention program in Argentina: a randomized trial. Rev Panam Salud Publica. 2013. 34(2):75-82. | Intervention/exposure
685 | Redden JP, Mann T, Vickers Z, Mykerezi E, Reicks M, Elsbernd S. Serving first in isolation increases vegetable intake among elementary schoolchildren. PLoS One. 2015. 10:e0121283. doi:10.1371/journal.pone.0121283. | Study design
686 | Reesor L, Moreno JP, Johnston CA, Hernandez DC. School-Based Weight Management Program Curbs Summer Weight Gain Among Low-Income Hispanic Middle School Students. J Sch Health. 2019. 89:59-67. doi:10.1111/josh.12713. | Intervention/exposure
687 | Rendo-Urteaga T, Puchau, B, Chueca M, Oyarzabal M, Azcona-Sanjulian MC, Martinez JA, Marti A. Total antioxidant capacity and oxidative stress after a 10-week dietary intervention program in obese children. Eur J Pediatr. 2014. 173:609-616. doi:10.1007/s00431-013-2229-7. | Intervention/exposure
688 | Rerksuppaphol L, Rerksuppaphol S. Internet Based Obesity Prevention Program for Thai School Children-A Randomized Control Trial. J Clin Diagn Res. 2017. 11:Sc07-sc11. doi:10.7860/jcdr/2017/21423.9368. | Intervention/exposure
689 | Retraction of: Aceves-Martins M, Llauradó E, Tarro L, et al: A School-Based, Peer-Led, Social Marketing Intervention to Engage Spanish Adolescents in a Healthy Lifestyle (‘‘We Are Cool’’-Som la Pera Study): A Parallel Cluster Randomized Controlled Study [Child Obes 2017;13:300-313; doi: 10.1089/chi.2016.0216]. Child Obes. 2020. 16:544-545. doi:10.1089/chi.2016.0216.retract. | Other: Retraction notice
690 | Reverdy C, Chesnel F, Schlich P, Köster EP, Lange C. Effect of sensory education on willingness to taste novel food in children. Appetite. 2008. 51:156-65. doi:10.1016/j.appet.2008.01.010. | Outcome
691 | Reverdy C, Schlich P, Koster EP, Ginon E, Lange C. Effect of sensory education on food preferences in children. Food Qual Prefer. 2010. 21:794-804. doi:10.1016/j.foodqual.2010.03.008. | Outcome
692 | Reynolds KD, Franklin FA, Leviton LC, Maloy J, Harrington KF, Yaroch AL, Person S, Jester P. Methods, results, and lessons learned from process evaluation of the high 5 school-based nutrition intervention. Health Educ Behav. 2000. 27:177-86. doi:10.1177/109019810002700204. | Outcome
693 | Ribeiro RQ, Alves L. Comparison of two school-based programmes for health behaviour change: the Belo Horizonte Heart Study randomized trial. Public Health Nutr. 2014. 17:1195-204. doi:10.1017/s1368980013000189. | Intervention/exposure
694 | Riggs NR, Sakuma KL, Pentz MA. Preventing risk for obesity by promoting self-regulation and decision-making skills: pilot results from the PATHWAYS to health program (PATHWAYS). Eval Rev. 2007. 31:287-310. doi:10.1177/0193841x06297243. | Study design
695 | Rioux C, Lafraire J, Picard D. Visual exposure and categorization performance positively influence 3- to 6-year-old children’s willingness to taste unfamiliar vegetables. Appetite. 2018. 120:32-42. doi:10.1016/j.appet.2017.08.016. | Age at intervention/exposure
696 | Ritchie B, O’Hara L, Taylor J. ‘Kids in the Kitchen’ impact evaluation: engaging primary school students in preparing fruit and vegetables for their own consumption. Health Promot J Austr. 2015. 26:146-149. doi:10.1071/he14074. | Study design
697 | Ritenbaugh C, Teufel-Shone NI, Aickin MG, Joe JR, Poirier S, Dillingham DC, Johnson D, Henning S, Cole SM, Cockerham D. A lifestyle intervention improves plasma insulin levels among Native American high school youth. Prev Med. 2003. 36:309-19. doi:10.1016/s0091-7435(02)00015-4. | Study design, Outcome, Intervention/exposure
698 | Rito AI, Carvalho MA, Ramos C, Breda J. Program Obesity Zero (POZ)--a community-based intervention to address overweight primary-school children from five Portuguese municipalities. Public Health Nutr. 2013. 16:1043-51. doi:10.1017/s1368980013000244. | Study design, Intervention/exposure
699 | Robbins LB, Ling J, Clevenger K, Voskuil VR, Wasilevich E, Kerver JM, Kaciroti N, Pfeiffer KA. A School- and Home-Based Intervention to Improve Adolescents’ Physical Activity and Healthy Eating: A Pilot Study. J Sch Nurs. 2020. 36:121-134. doi:10.1177/1059840518791290. | Intervention/exposure
700 | Robertson TP, Zalles DR. Nutrition education program Nutrition Pathfinders teaches children how to make healthful food choices. J Nutr Educ Behav. 2005. 37:41-2. doi:10.1016/s1499-4046(06)60258-3. | Outcome
701 | Robles J, Gutierrez A, Seifert CF. Impact of a pilot pharmacy health-care professional out-of-school time physical activity and nutrition education program with exercise on fourth and fifth graders in a rural Texas community. SAGE Open Med. 2014. 2:2050312114547956. doi:10.1177/2050312114547956. | Study design, Intervention/exposure
702 | Roccaldo R, Censi L, D’Addezio L, Berni Canani S, Gennaro L. A teachers’ training program accompanying the “School Fruit Scheme” fruit distribution improves children’s adherence to the Mediterranean diet: an Italian trial. Int J Food Sci Nutr. 2017. 68:887-900. doi:10.1080/09637486.2017.1303826. | Study design
703 | Rogers VW, Hart PH, Motyka E, Rines EN, Vine J, Deatrick DA. Impact of Let’s Go! 5-2-1-0: a community-based, multisetting childhood obesity prevention program. J Pediatr Psychol. 2013. 38:1010-20. doi:10.1093/jpepsy/jst057. | Study design, Intervention/exposure
704 | Rohde JF, Larsen SC, Ängquist L, Olsen NJ, Stougaard M, Mortensen EL, Heitmann BL. Effects of the Healthy Start randomized intervention on dietary intake among obesity-prone normal-weight children. Public Health Nutr. 2017. 20:2988-2997. doi:10.1017/s1368980017002026. | Intervention/exposure, Age at intervention/exposure
705 | Romo ML, Abril-Ulloa V. Improving Nutrition Habits and Reducing Sedentary Time Among Preschool-Aged Children in Cuenca, Ecuador: A Trial of a School-Based Intervention. Prev Chronic Dis. 2018. 15:E96. doi:10.5888/pcd15.180053. | Age at intervention/exposure
706 | Romon M, Lommez A, Tafflet M, Basdevant A, Oppert JM, Bresson JL, Ducimetière P, Charles MA, Borys JM. Downward trends in the prevalence of childhood overweight in the setting of 12-year school- and community-based programmes. Public Health Nutr. 2009. 12:1735-42. doi:10.1017/s1368980008004278. | Intervention/exposure
707 | Ronsley R, Lee AS, Kuzeljevic B, Panagiotopoulos C. Healthy Buddies™ reduces body mass index z-score and waist circumference in Aboriginal children living in remote coastal communities. J Sch Health. 2013. 83:605-13. doi:10.1111/josh.12072. | Intervention/exposure
708 | Rosário R, Oliveira B, Araújo A, Lopes O, Padrão P, Moreira A, Teixeira V, Barros R, Pereira B, Moreira P. The impact of an intervention taught by trained teachers on childhood overweight. Int J Environ Res Public Health. 2012. 9:1355-67. doi:10.3390/ijerph9041355. | Outcome
709 | Rosemond TN, Blake CE, Jenkins KA, Buff SM, Moore JB. Dietary Improvements among African American Youth: Results of an Interactive Nutrition Promotion Program. Am J Health Educ. 2015. 46:40-47. doi: 10.1080/19325037.2014.977409. | Intervention/exposure
710 | Rosenbaum M, Nonas C, Weil R, Horlick M, Fennoy I, Vargas I, Kringas P. School-based intervention acutely improves insulin sensitivity and decreases inflammatory markers and body fatness in junior high school students. J Clin Endocrinol Metab. 2007. 92:504-8. doi:10.1210/jc.2006-1516. | Intervention/exposure
711 | Rosi A, Dall’Asta M, Brighenti F, Del Rio D, Volta E, Baroni I, Nalin M, Coti Zelati M, Sanna A, Scazzina F. The use of new technologies for nutritional education in primary schools: a pilot study. Publ Health. 2016. 140:50-55. doi:10.1016/j.puhe.2016.08.021. | Outcome
712 | Rosmawati NHN, Manan WMW, Izani NJN, Nurain NHN, Razlina AR. Impact of food nutrition intervention on food handlers’ knowledge and competitive food serving: a randomized controlled trial. Int Food Res J. 2017. 24:1046-1056. | Intervention/exposure, Outcome, Age at intervention/exposure
713 | Ruel MT. The Oriente Study: Program and Policy Impacts. J Nutr. 2010. 140:415-418. doi:10.3945/jn.109.114512. | Study design
714 | Rush E, Reed P, McLennan S, Coppinger T, Simmons D, Graham D. A school-based obesity control programme: Project Energize. Two-year outcomes. Br J Nutr. 2012. 107:581-7. doi:10.1017/s0007114511003151. | Intervention/exposure
715 | Ruzita AT Jr, Wan Azdie MA, Ismail MN. The effectiveness of nutrition education programme for primary school children. Malays J Nutr. 2007. 13(1):45-54. | Outcome
716 | Sabbag C, Surucuoglu MS. Influence of education on primary school students nutrition in Ankara, Turkey. Healthmed. 2012. 6(2):616-620. | Outcome
717 | Sabet Sarvestani R, Jamalfard MH, Kargar M, Kaveh MH, Tabatabaee HR. Effect of dietary behaviour modification on anthropometric indices and eating behaviour in obese adolescent girls. J Adv Nurs. 2009. 65:1670-5. doi:10.1111/j.1365-2648.2009.05029.x. | Intervention/exposure
718 | Sabinsky MS, Toft U, Sommer HM, Tetens I. Effect of implementing school meals compared with packed lunches on quality of dietary intake among children aged 7-13 years. J Nutr Sci. 2019. 8:e3. doi:10.1017/jns.2018.29. | Intervention/exposure
719 | Sacchetti R, Dallolio L, Musti MA, Guberti E, Garulli A, Beltrami P, Castellazzi F, Centis E, Zenesini C, Coppini C, Rizzoli C, Sardocardalano M, Leoni E. Effects of a school based intervention to promote healthy habits in children 8-11 years old, living in the lowland area of Bologna Local Health Unit. Ann Ig. 2015. 27:432-46. doi:10.7416/ai.2015.2030. | Study design
720 | Safdie M, Jennings-Aburto N, Lévesque L, Janssen, I, Campirano-Núñez F, López-Olmedo N, Aburto T, Rivera JA. Impact of a school-based intervention program on obesity risk factors in Mexican children. Salud Publica Mex. 2013. 55 Suppl 3:374-87. doi:10.21149/spm.v55s3.5138. | Intervention/exposure
721 | Saha S, Dawson J, Murimi M, Dodd S, Oldewage-Theron W. Effects of a nutrition education intervention on fruit and vegetable consumption-related dietary behavioural factors among elementary school children. Health Educ J. 2020. 79:963-973. doi:10.1177/0017896920944421. | Study design
722 | Sahota P, Christian M, Day R, Cocks K. The feasibility and acceptability of a primary school-based programme targeting diet and physical activity: the PhunkyFoods Programme. Pilot Feasibility Stud. 2019. 5:152. doi:10.1186/s40814-019-0542-2. | Intervention/exposure
723 | Sahota P, Rudolf MC, Dixey R, Hill AJ, Barth JH, Cade J. Evaluation of implementation and effect of primary school based intervention to reduce risk factors for obesity. BMJ. 2001. 323:1027-9. doi:10.1136/bmj.323.7320.1027. | Study design, Intervention/exposure
724 | Sahota P, Rudolf MC, Dixey R, Hill AJ, Barth JH, Cade J. Randomised controlled trial of primary school based intervention to reduce risk factors for obesity. BMJ. 2001. 323:1029-32. doi:10.1136/bmj.323.7320.1029. | Intervention/exposure
725 | Salgado MD, Mardones MAH, Ivanovic DM. Impact of a short nutrition education program on food and nutrition knowledge of school-age children graduating from elementary school: A follow-up study 1995-2000, Chillan, Chile. Ecol Food Nutr. 2005. 44:57-79. doi:10.1080/03670240590904344. | Outcome
726 | Sallis JF, McKenzie TL, Conway TL, Elder JP, Prochaska JJ, Brown M, Zive MM, Marshall SJ, Alcaraz JE. Environmental interventions for eating and physical activity: a randomized controlled trial in middle schools. Am J Prev Med. 2003. 24:209-17. doi:10.1016/s0749-3797(02)00646-3. | Intervention/exposure
727 | Salmoirago-Blotcher E, Druker S, Frisard C, Dunsiger SI, Crawford S, Meleo-Meyer F, Bock B, Pbert L. Integrating mindfulness training in school health education to promote healthy behaviors in adolescents: Feasibility and preliminary effects on exercise and dietary habits. Prev Med Rep. 2018. 9:92-95. doi:10.1016/j.pmedr.2018.01.009. | Intervention/exposure
728 | Sanchez-Vaznaugh EV, Sánchez BN, Baek J, Crawford PB. ‘Competitive’ food and beverage policies: are they influencing childhood overweight trends?. Health Aff (Millwood). 2010. 29:436-46. doi:10.1377/hlthaff.2009.0745. | Study design
729 | Sanders MJ, Reynolds J, Bagatell N, Treu JA, OʼConnor E, Katz DL. Promoting Healthy Lifestyles to Children at School: Using a Multidisciplinary Train-the-Trainer Approach. J Public Health Manag Pract. 2015. 21:E27-35. doi:10.1097/phh.0000000000000141. | Intervention/exposure, Outcome
730 | Sanigorski AM, Bell AC, Kremer PJ, Cuttler R, Swinburn BA. Reducing unhealthy weight gain in children through community capacity-building: results of a quasi-experimental intervention program, Be Active Eat Well. Int J Obes (Lond). 2008. 32:1060-7. doi:10.1038/ijo.2008.79. | Intervention/exposure
731 | Santos RG, Durksen A, Rabbanni R, Chanoine JP, Lamboo Miln A, Mayer T, McGavock JM. Effectiveness of peer-based healthy living lesson plans on anthropometric measures and physical activity in elementary school students: a cluster randomized trial. JAMA Pediatr. 2014. 168:330-7. doi:10.1001/jamapediatrics.2013.3688. | Intervention/exposure
732 | Schapiro NA, Green EK, Kaller S, Brindis CD, Rodriguez A, Alkebulan-Abakah M, Chen JL. Impact on Healthy Behaviors of Group Obesity Management Visits in Middle School Health Centers. J Sch Nurs. 2019. 37:87-98. doi:10.1177/1059840519842226. | Study design
733 | Schindler JM, Corbett D, Forestell CA. Assessing the effect of food exposure on children’s identification and acceptance of fruit and vegetables. Eat Behav. 2013. 14:53-6. doi:10.1016/j.eatbeh.2012.10.013. | Outcome
734 | Schmitt SA, Bryant LM, Korucu, I, Kirkham, L, Katare B, Benjamin T. The effects of a nutrition education curriculum on improving young children’s fruit and vegetable preferences and nutrition and health knowledge. Public Health Nutr. 2019. 22:28-34. doi:10.1017/s1368980018002586. | Outcome
735 | Schreier HM, Schonert-Reichl KA, Chen E. Effect of volunteering on risk factors for cardiovascular disease in adolescents: a randomized controlled trial. JAMA Pediatr. 2013. 167:327-32. doi:10.1001/jamapediatrics.2013.1100. | Intervention/exposure
736 | Schreinemachers P, Rai BB, Dorji D, Chen HP, Dukpa T, Thinley N, Sherpa PL, Yang RY. School gardening in Bhutan: Evaluating outcomes and impact. Food Secur. 2017. 9:635-648. doi:10.1007/s12571-017-0673-3. | Country
737 | Schultz CR. Removing junk food and beverages from school vending machines. Minn Med. 2010. 93(9):32-5. | Study design
738 | Schwartz MB, Henderson KE, Read M, Cornelius T. Student Acceptance of Plain Milk Increases Significantly 2 Years after Flavored Milk Is Removed from School Cafeterias: An Observational Study. J Acad Nutr Diet. 2018. 118:857-864. doi:10.1016/j.jand.2017.05.021. | Study design
739 | Schwartz MB, Novak SA, Fiore SS. The impact of removing snacks of low nutritional value from middle schools. Health Educ Behav. 2009. 36:999-1011. doi:10.1177/1090198108329998. | Study design
740 | Schwarz DF. The Philadelphia experience: actionable strategies for childhood obesity prevention. Child Obes. 2013. 9:282-5. doi:10.1089/chi.2013.9401. | Study design
741 | Sevil J, García-González L, Abós Á, Generelo E, Aibar A. Can High Schools Be an Effective Setting to Promote Healthy Lifestyles? Effects of a Multiple Behavior Change Intervention in Adolescents. J Adolesc Health. 2019. 64:478-486. doi:10.1016/j.jadohealth.2018.09.027. | Intervention/exposure
742 | Sevinc O, Bozkurt AI, Gundogdu, M, Aslan UB, Agbuga B, Aslan S, Dikbas E, Gokce Z. Evaluation of the effectiveness of an intervention program on preventing childhood obesity in Denizli, Turkey. Turk J Med Sci. 2011. 41:1097-1105. doi:10.3906/sag-1009-1179. | Outcome
743 | Shahnazi H, Bee Koon P, Abd Talib, R, Lubis SH, Ganjali Dashti M, Khatooni E, Bahreini Esfahani N. Can the BASNEF Model Help to Develop Self-Administered Healthy Behavior in Iranian Youth?. Iran Red Crescent Med J. 2016. 18:e23847. doi:10.5812/ircmj.23847. | Intervention/exposure, Outcome
744 | Shama ME, Abdou SS. Evaluating the Impact of Health Promoting School Initiative on Dietary Habits and BMI of Students in Oman. J Egypt Public Health Assoc. 2009. 84:119-39. | Intervention/exposure
745 | Shamah Levy T, Morales Ruán C, Amaya Castellanos C, Salazar Coronel A, Jiménez Aguilar A, Méndez Gómez Humarán, I. Effectiveness of a diet and physical activity promotion strategy on the prevention of obesity in Mexican school children. BMC Public Health. 2012. 12:152. doi:10.1186/1471-2458-12-152. | Intervention/exposure
746 | Sharif Ishak SIZ, Chin YS, Mohd Taib MN, Chan YM, Mohd Shariff, Z. Effectiveness of a school-based intervention on knowledge, attitude and practice on healthy lifestyle and body composition in Malaysian adolescents. BMC Pediatr. 2020. 20:122. doi:10.1186/s12887-020-02023-x. | Intervention/exposure
747 | Sharma A, Moon J, Bailey-Davis L. Loss Aversion of Time: Serving School Lunches Faster without Impacting Meal Experience. Ecol Food Nutr. 2018. 57:456-472. doi:10.1080/03670244.2018.1544562. | Study design
748 | Sharma B, Kim HY, Nam EW. Effects of School-based Health Promotion Intervention on Health Behaviors among School Adolescents in North Lima and Callao, Peru. J Lifestyle Med. 2018. 8:60-71. doi:10.15280/jlm.2018.8.2.60. | Intervention/exposure
749 | Sharma S, Fleming SE. One-year change in energy and macronutrient intakes of overweight and obese inner-city African American children: Effect of community-based Taking Action Together type 2 diabetes prevention program. Eat Behav. 2012. 13:271-274. doi:10.1016/j.eatbeh.2012.03.003. | Intervention/exposure
750 | Sharma S, Marshall A, Chow J, Ranjit N, Bounds G, Hearne K, Cramer N, Oceguera A, Farhat A, Markham C. Impact of a Pilot School-Based Nutrition Intervention on Fruit and Vegetable Waste at School Lunches. J Nutr Educ Behav. 2019. 51:1202-1210.e1. doi:10.1016/j.jneb.2019.08.002. | Study design
751 | Sharma SV, Markham C, Chow J, Ranjit N, Pomeroy M, Raber M. Evaluating a school-based fruit and vegetable co-op in low-income children: A quasi-experimental study. Prev Med. 2016. 91:8-17. doi:10.1016/j.ypmed.2016.07.022. | Study design
752 | Shaw-Perry M, Horner C, Treviño RP, Sosa ET, Hernandez I, Bhardwaj A. NEEMA: a school-based diabetes risk prevention program designed for African-American children. J Natl Med Assoc. 2007. 99(4):368-75. | Study design, Intervention/exposure
753 | Shen M, Hu M, Sun Z. Assessment of School-Based Quasi-Experimental Nutrition and Food Safety Health Education for Primary School Students in Two Poverty-Stricken Counties of West China. PLoS One. 2015. 10:e0145090. doi:10.1371/journal.pone.0145090. | Outcome
754 | Shi-Chang X, Xin-Wei Z, Shui-Yang X, Shu-Ming T, Sen-Hai Y, Aldinger C, Glasauer P. Creating health-promoting schools in China with a focus on nutrition. Health Promot Int. 2004. 19:409-18. doi:10.1093/heapro/dah402. | Country
755 | Shrewsbury VA, Venchiarutti RL, Hardy LL, Foley BC, Bonnefin A, Byth K, Hayes AJ, Flood VM, Steinbeck KS, Baur LA, Shah S. Impact and cost of the peer-led Students As LifeStyle Activists programme in high schools. Health Educ J. 2020. 79:3-20. doi:10.1177/0017896919856050. | Study design, Intervention/exposure
756 | Sibley BA, Ward RM, Yazvac TS, Zullig K, Potteiger JA. Making the Grade with Diet and Exercise. AASA J Scholarsh Pract. 2008. 5:38-45. | Study design
757 | Siega-Riz AM, El Ghormli L, Mobley C, Gillis B, Stadler D, Hartstein J, Volpe SL, Virus A, Bridgman J. The effects of the HEALTHY study intervention on middle school student dietary intakes. Int J Behav Nutr Phys Act. 2011. 8:7. doi:10.1186/1479-5868-8-7. | Intervention/exposure
758 | Siegel R, Lockhart MK, Barnes AS, Hiller E, Kipp R, Robison DL, Ellsworth SC, Hudgens ME. Small prizes increased healthful school lunch selection in a Midwestern school district. Appl Physiol Nutr Metab. 2016. 41:370-4. doi:10.1139/apnm-2015-0535. | Study design
759 | Silva C, Fassnacht DB, Ali K, Gonçalves S, Conceição E, Vaz A, Crosby RD, Machado PP. Promoting health behaviour in Portuguese children via Short Message Service: The efficacy of a text-messaging programme. J Health Psychol. 2015. 20:806-15. doi:10.1177/1359105315577301. | Intervention/exposure
760 | Singh AS, Chin A Paw MJ, Brug J, van Mechelen W. Dutch obesity intervention in teenagers: effectiveness of a school-based program on body composition and behavior. Arch Pediatr Adolesc Med. 2009. 163:309-17. doi:10.1001/archpediatrics.2009.2. | Intervention/exposure
761 | Singh AS, Chin A Paw MJ, Brug J, van Mechelen W. Short-term effects of school-based weight gain prevention among adolescents. Arch Pediatr Adolesc Med. 2007. 161:565-71. doi:10.1001/archpedi.161.6.565. | Intervention/exposure
762 | Skinner K, Hanning RM, Metatawabin J, Martin ID, Tsuji LJ. Impact of a school snack program on the dietary intake of grade six to ten First Nation students living in a remote community in northern Ontario, Canada. Rural Rem Health. 2012. 12:2122. | Study design
763 | Skybo TA, Ryan-Wenger N. A school-based intervention to teach third grade children about the prevention of heart disease. Pediatr Nurs. 2002. 28(3):223-9, 235. | Intervention/exposure
764 | Slawson DL, Dalton WT, 3rd, Dula TM, Southerland J, Wang L, Littleton MA, Mozen D, Relyea G, Schetzina K, Lowe EF, Stoots JM, Wu, T. College students as facilitators in reducing adolescent obesity disparity in Southern Appalachia: Team Up for Healthy Living. Contemp Clin Trials. 2015. 43:39-52. doi:10.1016/j.cct.2015.04.012. | Intervention/exposure, Other: protocol
765 | Slawta JN, DeNeui D. Be a Fit Kid: nutrition and physical activity for the fourth grade. Health Promot Pract. 2010. 11:522-9. doi:10.1177/1524839908328992. | Intervention/exposure
766 | Slusser WM, Sharif MZ, Erausquin JT, Kinsler JJ, Collin D, Prelip ML. Improving overweight among at-risk minority youth: results of a pilot intervention in after-school programs. J Health Care Poor Underserved. 2013. 24:12-24. doi:10.1353/hpu.2013.0111. | Intervention/exposure
767 | Smith CA, Corriveau N, Aaronson S, Fitzgerald C, Heeres A, Eagle KA, DuRussel-Weston J. School intervention incorporates farm to school programs to highlight healthy eating: a report from Project Healthy Schools. Child Obes. 2012. 8:584-7. doi:10.1089/chi.2012.0042. | Study design
768 | Smith E, Wells K, Stluka S, McCormack L. The Impact of a Fruit and Vegetable Intervention on Children and Caregivers. Am J Health Educ. 2015. 46:316-322. doi:10.1080/19325037.2015.1077487. | Study design
769 | Smith JJ, Morgan PJ, Plotnikoff RC, Dally KA, Salmon J, Okely AD, Finn TL, Lubans DR. Smart-phone obesity prevention trial for adolescent boys in low-income communities: the ATLAS RCT. Pediatrics. 2014. 134:e723-31. doi:10.1542/peds.2014-1012. | Intervention/exposure
770 | Smith LH, Holloman C. Comparing the effects of teen mentors to adult teachers on child lifestyle behaviors and health outcomes in Appalachia. J Sch Nurs. 2013. 29:386-96. doi:10.1177/1059840512472708. | Intervention/exposure
771 | Smith LH, Holloman C. Piloting “sodabriety”: a school-based intervention to impact sugar-sweetened beverage consumption in rural Appalachian high schools. J Sch Health. 2014. 84:177-84. doi:10.1111/josh.12134. | Study design
772 | Smith LH. Piloting the use of teen mentors to promote a healthy diet and physical activity among children in Appalachia. J Spec Pediatr Nurs. 2011. 16:16-26. doi:10.1111/j.1744-6155.2010.00264.x. | Intervention/exposure
773 | Somerset S, Markwell K. Impact of a school-based food garden on attitudes and identification skills regarding vegetables and fruit: a 12-month intervention trial. Public Health Nutr. 2009. 12:214-21. doi:10.1017/s1368980008003327. | Outcome
774 | Song HJ, Grutzmacher S, Munger AL. Project ReFresh: Testing the Efficacy of a School-Based Classroom and Cafeteria Intervention in Elementary School Children. J Sch Health. 2016. 86:543-51. doi:10.1111/josh.12404. | Comparator
775 | Sousa P, Martinho R, Reis CI, Dias SS, Gaspar PJS, Dixe MDA, Luis LS, Ferreira R. Controlled trial of an mHealth intervention to promote healthy behaviours in adolescence (TeenPower): Effectiveness analysis. J Adv Nurs. 2020. 76:1057-1068. doi:10.1111/jan.14301. | Intervention/exposure
776 | Souza VR, Ferreira AB, São José, JFB, Silva Emmd Silva DA. Influence of intervention on the menu’s nutritional and sensory qualities and on the food waste of children’s education center. Cien Saude Colet. 2019. 24:411-418. doi:10.1590/1413-81232018242.02362017. | Study design,Age at intervention/exposure
777 | Spears-Lanoix EC, McKyer EL, Evans A, McIntosh WA, Ory M, Whittlesey L, Kirk A, Hoelscher DM, Warren JL. Using Family-Focused Garden, Nutrition, and Physical Activity Programs To Reduce Childhood Obesity: The Texas! Go! Eat! Grow! Pilot Study. Child Obes. 2015. 11:707-14. doi:10.1089/chi.2015.0032. | Study design
778 | Speroni KG, Earley C, Atherton M. Evaluating the effectiveness of the Kids Living Fit program: a comparative study. J Sch Nurs. 2007. 23:329-36. doi:10.1177/10598405070230060501. | Intervention/exposure
779 | Spiegel SA, Foulk, D. Reducing overweight through a multidisciplinary school-based intervention. Obesity (Silver Spring). 2006. 14:88-96. doi:10.1038/oby.2006.11. | Intervention/exposure
780 | Springer AE, Kelder SH, Ranjit N, Hochberg-Garrett H, Crow S, Delk J. Promoting physical activity and fruit and vegetable consumption through a community-school partnership: the effects of Marathon Kids® on low-income elementary school children in Texas. J Phys Act Health. 2012. 9:739-53. doi:10.1123/jpah.9.5.739. | Intervention/exposure
781 | Staudigel M, Lingl C, Roosen J. Preferences versus the Environment: How Do School Fruit and Vegetable Programs Affect Children’s Fresh Produce Consumption?. Appl Econ Perspect Pol. 2019. 41:742-763. doi:10.1093/aepp/ppy031. | Study design
782 | Stea TH, Hovdenak IM, Rønnestad J, Rennestraum K, Vik FN, Klepp KI, Bere E. Effects of 1 y of free school fruit on intake of fruits, vegetables, and unhealthy snacks: 14 y later. Am J Clin Nutr. 2018. 108:1309-1315. doi:10.1093/ajcn/nqy243. | Study design
783 | Stea TH, Tveter ET, Te Velde SJ, Vik FN, Klepp KI, Bere E. The effect of an extra piece of fruit or vegetables at school on weight status in two generations - 14 years follow-up of the Fruit and Vegetables Makes the Marks study. PLoS One. 2018. 13:e0205498. doi:10.1371/journal.pone.0205498. | Outcome
784 | Stevens J, Story M, Ring K, Murray DM, Cornell CE, Juhaeri, Gittelsohn J. The impact of the Pathways intervention on psychosocial variables related to diet and physical activity in American Indian schoolchildren. Prev Med. 2003. 37:S70-9. doi:10.1016/j.ypmed.2003.08.012. | Intervention/exposure, Outcome
785 | Stock S, Miranda C, Evans S, Plessis S, Ridley J, Yeh S, Chanoine JP. Healthy Buddies: a novel, peer-led health promotion program for the prevention of obesity and eating disorders in children in elementary school. Pediatrics. 2007. 120:e1059-68. doi:10.1542/peds.2006-3003. | Intervention/exposure
786 | Stone EJ, Norman JE, Davis SM, Stewart D, Clay TE, Caballero B, Lohman TG, Murray, DM. Design, implementation, and quality control in the Pathways American-Indian multicenter trial. Prev Med. 2003. 37:S13-23. doi:10.1016/j.ypmed.2003.08.006. | Intervention/exposure, Outcome
787 | Story M, Hannan, PJ, Fulkerson JA, Rock BH, Smyth M, Arcan C, Himes JH. Bright Start: Description and main outcomes from a group-randomized obesity prevention trial in American Indian children. Obesity (Silver Spring). 2012. 20:2241-9. doi:10.1038/oby.2012.89. | Intervention/exposure
788 | Story M, Sherwood NE, Himes JH, Davis M, Jacobs DR, Jr Cartwright, Y, Smyth M, Rochon J. An after-school obesity prevention program for African-American girls: the Minnesota GEMS pilot study. Ethn Dis. 2003. 13:S54-64. | Intervention/exposure
789 | Story M, Snyder MP, Anliker J, Weber JL, Cunningham-Sabo L, Stone EJ, Chamberlain A, Ethelbah, B, Suchindran C, Ring K. Changes in the nutrient content of school lunches: results from the Pathways study. Prev Med. 2003. 37:S35-45. doi:10.1016/j.ypmed.2003.08.009. | Intervention/exposure, Outcome
790 | Stuewe R. All about lunch!. NASN Sch Nurse. 2011. 26:300. doi:10.1177/1942602x11416514. | Study design
791 | Suarez-Balcazar Y, Kouba J, Jones LM, Lukyanova VV. A university--school collaboration to enhance healthy choices among children. J Prev Interv Community. 2014. 42:140-51. doi:10.1080/10852352.2014.881193. | Study design
792 | Sundborn G, Ni Mhurchu C, Ness C, Latu H, Jackson R. Kelston Beverages Pilot Study: Rationale, design and implementation of a community and school based intervention to reduce sugary drink consumption among children and youth. Pac Health Dialog. 2014. 20(1):89-94. | Study design, Other: rationale and design (no results)
793 | Sundgot-Borgen C, Friborg O, Kolle E, Torstveit MK, Sundgot-Borgen J, Engen KME, Rosenvinge JH, Pettersen G, Bratland-Sanda S. Does the Healthy Body Image program improve lifestyle habits among high school students? A randomized controlled trial with 12-month follow-up. J Int Med Res. 2019. 48:300060519889453. doi:10.1177/0300060519889453. | Intervention/exposure
794 | Sutherland R, Nathan N, Brown A, Yoong S, Finch M, Lecathelinais C, Reynolds R, Walton A, Janssen L, Desmet C, Gillham K, Herrmann, V, Hall A, Wiggers J, Wolfenden L. A randomized controlled trial to assess the potential efficacy, feasibility and acceptability of an m-health intervention targeting parents of school aged children to improve the nutritional quality of foods packed in the lunchbox ‘SWAP IT’. Int J Behav Nutr Phys Act. 2019. 16:54. doi:10.1186/s12966-019-0812-7. | Intervention/exposure
795 | Swanson M, Branscum A, Nakayima PJ. Promoting consumption of fruit in elementary school cafeterias. The effects of slicing apples and oranges. Appetite. 2009. 53:264-7. doi:10.1016/j.appet.2009.07.015. | Study design
796 | Swanson RB, Perry JM, Carden LA. Acceptability of reduced-fat brownies by school-aged children. J Am Diet Assoc. 2002. 102:856-9. doi:10.1016/s0002-8223(02)90193-8. | Study design
797 | Sweat V, Bruzzese JM, Fierman A, Mangone A, Siegel C, Laska E, Convit A. Outcomes of The BODY Project: A Program to Halt Obesity and Its Medical Consequences in High School Students. J Community Health. 2015. 40:1149-54. doi:10.1007/s10900-015-0041-1. | Study design
798 | Swinburn B, Malakellis M, Moodie M, Waters E, Gibbs L, Millar L, Herbert J, Virgo-Milton M, Mavoa H, Kremer P, de Silva-Sanigorski A. Large reductions in child overweight and obesity in intervention and comparison communities 3 years after a community project. Pediatr Obes. 2014. 9:455-62. doi:10.1111/j.2047-6310.2013.00201.x. | Intervention/exposure
799 | Tak NI, Te Velde SJ, Brug J. Ethnic differences in 1-year follow-up effect of the Dutch Schoolgruiten Project - promoting fruit and vegetable consumption among primary-school children. Public Health Nutr. 2007. 10:1497-507. doi:10.1017/s1368980007000456. | Study design
800 | Tak NI, Te Velde SJ, Brug J. Long-term effects of the Dutch Schoolgruiten Project--promoting fruit and vegetable consumption among primary-school children. Public Health Nutr. 2009. 12:1213-23. doi:10.1017/s1368980008003777. | Study design
801 | Tak NI, Te Velde SJ, Singh AS, Brug J. The effects of a fruit and vegetable promotion intervention on unhealthy snacks during mid-morning school breaks: results of the Dutch Schoolgruiten Project. J Hum Nutr Diet. 2010. 23:609-15. doi:10.1111/j.1365-277X.2010.01090.x. | Study design
802 | Tallon JM, Dias RS, Costa AM, Narciso J, Barros A, Silva AJ. Pilot evaluation of an interactive multimedia platform to provide nutrition education to Portuguese adolescents. Eur J Public Health. 2020. 30:353-357. doi:10.1093/eurpub/ckz231. | Study design
803 | Tamiru D, Argaw A, Gerbaba M, Nigussie A, Ayana G, Belachew, T. Improving dietary diversity of school adolescents through school based nutrition education and home gardening in Jimma Zone: Quasi-experimental design. Eat Behav. 2016. 23:180-186. doi:10.1016/j.eatbeh.2016.10.009. | Country
804 | Tarp J, Jespersen E, Moller NC, Klakk H, Wessner B, Wedderkopp N, Bugge A. Long-term follow-up on biological risk factors, adiposity, and cardiorespiratory fitness development in a physical education intervention: a natural experiment (CHAMPS-study DK). BMC Public Health. 2018. 18(1):605. doi:10.1186/s12889-018-5524-4. | Intervention/exposure
805 | Tavassoli E, Reisi M, Javadzad SH, Gharli Pour Z, Gilasi HR, Ghasemi S, Hafez AA. The effect of education on the improvement of fruits and vegetables consumption aiming to preventing colorectal cancer. Gastroenterol Hepatol Bed Bench. 2014. 7(2):94-100. | Intervention/exposure
806 | Tavassoli E, Reisi M, Javadzade SH, Gharlipour Z, Gilasi HR, Ashrafi Hafez A. The effect of education on improvement of intake of fruits and vegetables aiming at preventing cardiovascular diseases. Med J Islam Repub Iran. 2015. 29:183. | Intervention/exposure
807 | Taylor C, Darby H, Upton P, Upton D. Can a school-based intervention increase children’s fruit and vegetable consumption in the home setting?. Perspect Public Health. 2013. 133:330-6. doi:10.1177/1757913913506575. | Study design
808 | Taylor R. Salad bars in schools. Interview by Jamie Devereaux. Child Obes. 2012. 8:290-3. doi:10.1089/chi.2012.0084.tayl. | Study design
809 | Taylor RW, McAuley KA, Barbezat W, Farmer VL, Williams SM, Mann JI. Two-year follow-up of an obesity prevention initiative in children: the APPLE project. Am J Clin Nutr. 2008. 88:1371-7. doi:10.3945/ajcn.2007.25749. | Intervention/exposure
810 | Taylor RW, McAuley KA, Barbezat W, Strong A, Williams SM, Mann JI. APPLE Project: 2-y findings of a community-based obesity prevention program in primary school age children. Am J Clin Nutr. 2007. 86:735-42. doi:10.1093/ajcn/86.3.735. | Intervention/exposure
811 | Templeton SB, Marlette MA, Panemangalore M. Competitive foods increase the intake of energy and decrease the intake of certain nutrients by adolescents consuming school lunch. J Am Diet Assoc. 2005. 105:215-20. doi:10.1016/j.jada.2004.11.027. | Study design
812 | Teng CY, Chin YS, Taib MNM, Chan YM. Evaluation of the Effectiveness of a 3-Year, Teacher-Led Healthy Lifestyle Program on Eating Behaviors Among Adolescents Living in Day School Hostels in Malaysia. Food Nutr Bull. 2018. 39:595-607. doi:10.1177/0379572118795358. | Intervention/exposure
813 | Tester JM, Yen IH, Laraia B. Using mobile fruit vendors to increase access to fresh fruit and vegetables for schoolchildren. Prev Chronic Dis. 2012. 9:E102. doi:10.5888/pcd9.110222. | Study design, Intervention/exposure
814 | Thompson D. Chef of the Week. Sci Child. 2012. 50(1):38-41. | Study design
815 | Thompson E, Johnson DC, Leite-Bennett A, Ding Y, Mehrotra K. The Impact of Multiple Strategies to Encourage Fruit and Vegetable Consumption During School Lunch. J Sch Health. 2017. 87:616-622. doi:10.1111/josh.12533. | Study design
816 | Thompson HR, Gosliner W, Ritchie L, Wobbekind K, Reed AL, O’Keefe O, Madsen KA. The Impact of a Multipronged Intervention to Increase School Lunch Participation among Secondary School Students in an Urban Public School District. Child Obes. 2020. 16:S14-s22. doi:10.1089/chi.2019.0233. | Outcome
817 | Thornburg R, Hill K. Using Internet Assessment Tools for Health and Physical Education Instruction. TechTrends. 2004. 48:53. | Study design
818 | Toruner EK, Savaser S. A Controlled Evaluation of a School-Based Obesity Prevention in Turkish School Children. J Sch Nurs. 2010. 26:473-482. doi:10.1177/1059840510383987. | Intervention/exposure
819 | Toulabi T, Khosh Niyat Nikoo M, Amini F, Nazari H, Mardani M. The influence of a behavior modification interventional program on body mass index in obese adolescents. J Formos Med Assoc. 2012. 111:153-9. doi:10.1016/j.jfma.2011.05.007. | Country
820 | Tran BX, Ohinmaa A, Kuhle S, Johnson JA, Veugelers PJ. Life course impact of school-based promotion of healthy eating and active living to prevent childhood obesity. PLoS One. 2014. 9:e102242. doi:10.1371/journal.pone.0102242. | Study design, Outcome
821 | Treviño RP, Yin Z, Hernandez A, Hale DE, Garcia OA, Mobley C. Impact of the Bienestar school-based diabetes mellitus prevention program on fasting capillary glucose levels: a randomized controlled trial. Arch Pediatr Adolesc Med. 2004. 158:911-7. doi:10.1001/archpedi.158.9.911. | Intervention/exposure
822 | Triador L, Farmer A, Maximova K, Willows N, Kootenay J. A school gardening and healthy snack program increased Aboriginal First Nations children’s preferences toward vegetables and fruit. J Nutr Educ Behav. 2015. 47:176-80. doi:10.1016/j.jneb.2014.09.002. | Study design
823 | Truman E, Elliott C. Health-promoting skills for children: Evaluating the influence of a media literacy and food marketing intervention. Health EducJ. 2020. 79:431-445. doi:10.1177/0017896919889647. | Study design
824 | Tse MM, Yuen DT. Effects of providing a nutrition education program for teenagers: dietary and physical activity patterns. Nurs Health Sci. 2009. 11:160-5. doi:10.1111/j.1442-2018.2009.00443.x. | Study design
825 | Tsorbatzoudis H. Evaluation of a planned behavior theory-based intervention programme to promote healthy eating. Percept Mot Skills. 2005. 101:587-604. doi:10.2466/pms.101.2.587-604. | Outcome
826 | Tucker S, Lanningham-Foster L, Murphy J, Olsen G, Orth K, Voss J, Aleman M, Lohse C. A school based community partnership for promoting healthy habits for life. J Community Health. 2011. 36:414-22. doi:10.1007/s10900-010-9323-9. | Intervention/exposure
827 | Tucker S, Lanningham-Foster LM. Nurse-Led School-Based Child Obesity Prevention. J Sch Nurs. 2015. 31:450-66. doi:10.1177/1059840515574002. | Study design, Intervention/exposure
828 | Tumolo J. Safe school zone? To stay healthy, students must stay smart. Adv Nurse Pract. 2001. 9(9):67-8. | Study design
829 | Turnin MC, Buisson JC, Ahluwalia N, Cazals L, Bolzonella-Pene C, Fouquet-Martineau C, Martini P, Tauber M, Hanaire H. Effect of Nutritional Intervention on Food Choices of French Students in Middle School Cafeterias, Using an Interactive Educational Software Program (Nutri-Advice). J Nutr Educ Behav. 2016. 48:131-7.e1. doi:10.1016/j.jneb.2015.09.011. | Study design
830 | Tuuri G, Zanovec M, Silverman L, Geaghan J, Solmon M, Holston D, Guarino A, Roy H, Murphy E. “Smart Bodies” school wellness program increased children’s knowledge of healthy nutrition practices and self-efficacy to consume fruit and vegetables. Appetite. 2009. 52:445-51. doi:10.1016/j.appet.2008.12.007. | Outcome
831 | Upton D, Upton P, Taylor C. Increasing children’s lunchtime consumption of fruit and vegetables: an evaluation of the Food Dudes programme. Public Health Nutr. 2013. 16:1066-72. doi:10.1017/s1368980012004612. | Study design
832 | Upton P, Taylor C, Upton D. The effects of the Food Dudes Programme on children’s intake of unhealthy foods at lunchtime. Perspect Public Health. 2015. 135:152-9. doi:10.1177/1757913914526163. | Study design
833 | Utter J, Scragg R, Robinson E, Warbrick J, Faeamani G, Foroughian S, Dewes O, Moodie M, Swinburn BA. Evaluation of the Living 4 Life project: a youth-led, school-based obesity prevention study. Obes Rev. 2011. 12 Suppl 2:51-60. doi:10.1111/j.1467-789X.2011.00905.x. | Intervention/exposure
834 | Utter J, Warbrick J, Scragg R, Denny S, Schaaf, D. Design, development, and achievements of a youth-led nutrition and physical activity intervention in a Pacific community in New Zealand. J Am Diet Assoc. 2010. 110:1634-7. doi:10.1016/j.jada.2010.08.014. | Study design, Intervention/exposure, Other: no results
835 | van de Gaar VM, Jansen W, van Grieken A, Borsboom G, Kremers S, Raat H. Effects of an intervention aimed at reducing the intake of sugar-sweetened beverages in primary school children: a controlled trial. Int J Behav Nutr Phys Act. 2014. 11:98. doi:10.1186/s12966-014-0098-8. | Intervention/exposure
836 | Van Lippevelde W, van Stralen M, Verloigne M, De Bourdeaudhuij I, Deforche B, Brug J, Maes L, Haerens L. Mediating effects of home-related factors on fat intake from snacks in a school-based nutrition intervention among adolescents. Health Educ Res. 2012. 27:36-45. doi:10.1093/her/cyr110. | Study design, Intervention/exposure, Outcome
837 | van Nassau F, Singh AS, Cerin E, Salmon J, van Mechelen W, Brug J, Chinapaw MJ. The Dutch Obesity Intervention in Teenagers (DOiT) cluster controlled implementation trial: intervention effects and mediators and moderators of adiposity and energy balance-related behaviours. Int J Behav Nutr Phys Act. 2014. 11:158. doi:10.1186/s12966-014-0158-0. | Intervention/exposure
838 | van Nassau F, Singh AS, van Mechelen W, Brug J, Chinapaw MJ. Implementation evaluation of school-based obesity prevention programmes in youth; how, what and why?. Public Health Nutr. 2015. 18:1531-4. doi:10.1017/s1368980014002778. | Study design, Other: commentary
839 | Van Offelen SJ, Schroeder MM, Leines DR, Roth-Yousey Lori Reicks MM. Go Wild with Fruits and Veggies: Engaging Children in Nutrition Education and Physical Activity with Animal Characters. J Ext. 2011. 49(2). | Study design
840 | Vander Ploeg KA, McGavock J, Maximova K, Veugelers PJ. School-based health promotion and physical activity during and after school hours. Pediatrics. 2014. 133:e371-8. doi:10.1542/peds.2013-2383. | Intervention/exposure, Outcome
841 | Vanelli M, Monti G, Volta E, Finestrella V, Gkliati D, Cangelosi M, Caragnulo R, Vitale M, Ingrosso L, Scazzina F. “GIOCAMPUS” - An effective school-based intervention for breakfast promotion and overweight risk reduction. Acta Biomed. 2014. 84(3):181-8. | Intervention/exposure
842 | Vanhelst J, Béghin L, Fardy PS, Bui-Xuan G, Mikulovic J. A conative educational model for an intervention program in obese youth. BMC Public Health. 2012. 12:416. doi:10.1186/1471-2458-12-416. | Study design, Intervention/exposure
843 | Vargas IC, Sichieri R, Sandre-Pereira G, da Veiga GV. Evaluation of an obesity prevention program in adolescents of public schools. Rev Saude Publica. 2011. 45:59-68. doi:10.1590/s0034-89102011000100007. | Intervention/exposure
844 | Veitch J, Singh A, van Stralen MM, van Mechelen W, Brug J, Chinapaw MJ. Reduction in sugar-sweetened beverages is not associated with more water or diet drinks. Public Health Nutr. 2011. 14:1388-93. doi:10.1017/s1368980010002727. | Intervention/exposure
845 | Vereecken C, Huybrechts I, van Houte H, Martens V, Wittebroodt I, Maes L. Results from a dietary intervention study in preschools “Beastly Healthy at School”. Int J Public Health. 2009. 54:142-9. doi:10.1007/s00038-009-8028-2. | Age at intervention/exposure
846 | Vericker TC, Gearing ME, Kim SD. Updated Nutrition Standards for School Meals Associated With Improved Weight Outcomes for Boys in Elementary School. J Sch Health. 2019. 89:907-915. doi:10.1111/josh.12828. | Study design, Intervention/exposure
847 | Verloigne M, Ahrens W, De Henauw S, Verbestel V, Mårild S, Pigeot I, De Bourdeaudhuij I. Process evaluation of the IDEFICS school intervention: putting the evaluation of the effect on children’s objectively measured physical activity and sedentary time in context. Obes Rev. 2015. 16 Suppl 2:89-102. doi:10.1111/obr.12353. | Study design, Intervention/exposure
848 | Veugelers PJ, Fitzgerald AL. Effectiveness of school programs in preventing childhood obesity: a multilevel comparison. Am J Public Health. 2005. 95:432-5. doi:10.2105/ajph.2004.045898. | Study design, Comparator
849 | Vicari RM, Bramlet D, Olivera B, Barber L, Alexander L, Parker L, Howard M. Atherosclerosis and teen eating study. J Clin Lipidol. 2007. 1:194-7. doi:10.1016/j.jacl.2007.04.005. | Study design
850 | Vieira M, Carvalho GS. Costs and benefits of a school-based health intervention in Portugal. Health Promot Int. 2019. 34:1141-1148. doi:10.1093/heapro/day085. | Intervention/exposure
851 | Vierregger A, Hall J, Sehi N, Abbott M, Wobig K, Albrecht JA, Anderson-Knott M, Koszewski, W. Growing Healthy Kids: A School Enrichment Nutrition Education Program to Promote Healthy Behaviors for Children. J Ext. 2015. 53(5). | Study design, Outcome
852 | Vik FN, Næss IK, Heslien KEP, Øverby NC. Possible effects of a free, healthy school meal on overall meal frequency among 10-12-year-olds in Norway: the School Meal Project. BMC Res Notes. 2019. 12:382. doi:10.1186/s13104-019-4418-6. | Intervention/exposure
853 | Vik FN, Van Lippevelde W, Øverby NC. Free school meals as an approach to reduce health inequalities among 10-12-year-old Norwegian children. BMC Public Health. 2019. 19:951. doi:10.1186/s12889-019-7286-z. | Intervention/exposure
854 | Vilchis-Gil J, Klünder-Klünder M, Duque X, Flores-Huerta S. Decreased Body Mass Index in Schoolchildren After Yearlong Information Sessions With Parents Reinforced With Web and Mobile Phone Resources: Community Trial. J Med Internet Res. 2016. 18:e174. doi:10.2196/jmir.5584. | Intervention/exposure
855 | Villalba JA, Amirehsani K, Lewis TF. Increasing healthy behaviors in adolescents of Mexican heritage in rural emerging Latino communities: results from a school-based health intervention pilot study. J Immigr Minor Health. 2011. 13:629-32. doi:10.1007/s10903-010-9385-x. | Study design
856 | Vinsel D. Shedding old habits to create a new future. Interactive program targets childhood obesity by teaching healthy lifestyle choices. Healthc Exec. 2010. 25(3):70, 72. | Study design
857 | Visscher TL, van Hal WC, Blokdijk L, Seidell JC, Renders CM, Bemelmans WJ. Feasibility and impact of placing water coolers on sales of sugar-sweetened beverages in Dutch secondary school canteens. Obes Facts. 2010. 3:109-15. doi:10.1159/000300848. | Intervention/exposure
858 | Vogeltanz-Holm N, Holm J. Changes in Body Mass Index during a 3-Year Elementary School-Based Obesity Prevention Program for American Indian and White Rural Students. Health Educ Behav. 2018. 45:277-285. doi:10.1177/1090198117714825. | Intervention/exposure
859 | von Germeten JP, Hirsch S. Pre-sliced or do it yourself? - Determinants of schoolchildren’s acceptance of convenience fruits and vegetables. Food Qual Prefer. 2015. 44:1-11. doi:10.1016/j.foodqual.2015.03.006. | Outcome
860 | Voorhees J, Goto K, Bianco-Simeral S, Wolff C. Impact of the Harvest of the Month program on low-income Hmong and white middle school students. J Nutr Educ Behav. 2011. 43:S152-4. doi:10.1016/j.jneb.2011.01.011. | Study design
861 | Wadolowska L, Hamulka J, Kowalkowska J, Ulewicz, N, Hoffmann M, Gornicka M, Bronkowska M, Leszczynska T, Glibowski P, Korzeniowska-Ginter R. Changes in Sedentary and Active Lifestyle, Diet Quality and Body Composition Nine Months after an Education Program in Polish Students Aged 11⁻12 Years: Report from the ABC of Healthy Eating Study. Nutrients. 2019. 11:331. doi:10.3390/nu11020331. | Study design
862 | Wall DE, Least C, Gromis J, Lohse B. Nutrition education intervention improves vegetable-related attitude, self-efficacy, preference, and knowledge of fourth-grade students. J Sch Health. 2012. 82:37-43. doi:10.1111/j.1746-1561.2011.00665.x. | Outcome
863 | Wang JJ, Baranowski T, Lau PWC, Buday R, Gao Y. Story Immersion May Be Effective in Promoting Diet and Physical Activity in Chinese Children. J Nutr Educ Behav. 2017. 49:321-329.e1. doi:10.1016/j.jneb.2017.01.001. | Intervention/exposure, Outcome
864 | Wang JJ, Lau WC, Wang HJ, Ma J. Evaluation of a comprehensive intervention with a behavioural modification strategy for childhood obesity prevention: a nonrandomized cluster controlled trial. BMC Public Health. 2015. 15:1206. doi:10.1186/s12889-015-2535-2. | Intervention/exposure, Country
865 | Wang M, Struthers A. Health buzz at school: Evaluations of a statewide teen health campaign. Health Mark Q. 2018. 35:151-166. doi:10.1080/07359683.2018.1490544. | Study design, Intervention/exposure
866 | Wang MC, Rauzon S, Studer N, Martin AC, Craig L, Merlo C, Fung K, Kursunoglu D, Shannguan M, Crawford P. Exposure to a comprehensive school intervention increases vegetable consumption. J Adolesc Health. 2010. 47:74-82. doi:10.1016/j.jadohealth.2009.12.014. | Study design
867 | Wardle J, Herrera ML, Cooke L, Gibson EL. Modifying children’s food preferences: the effects of exposure and reward on acceptance of an unfamiliar vegetable. Eur J Clin Nutr. 2003. 57:341-8. doi:10.1038/sj.ejcn.1601541. | Intervention/exposure
868 | Warren JM, Henry CJ, Simonite V. Low glycemic index breakfasts and reduced food intake in preadolescent children. Pediatrics. 2003. 112:e414. doi:10.1542/peds.112.5.e414. | Intervention/exposure, Outcome
869 | Waters E, Gibbs L, Tadic, M, Ukoumunne OC, Magarey A, Okely AD, de Silva A, Armit C, Green J, O’Connor T, Johnson B, Swinburn B, Carpenter L, Moore G, Littlecott, H, Gold L. Cluster randomised trial of a school-community child health promotion and obesity prevention intervention: findings from the evaluation of fun ’n healthy in Moreland!. BMC Public Health. 2017. 18:92. doi:10.1186/s12889-017-4625-9. | Intervention/exposure
870 | Weaver RG, Moore JB, Huberty J, Freedman D, Turner-McGrievy B, Beighle A, Ward D, Pate R, Saunders R, Brazendale K, Chandler J, Ajja R, Kyryliuk B, Beets MW. Process Evaluation of Making HEPA Policy Practice: A Group Randomized Trial. Health Promot Pract. 2016. 17:631-47. doi:10.1177/1524839916647331. | Intervention/exposure
871 | Weber KS, Spörkel, O, Mertens M, Freese A, Strassburger K, Kemper B, Bachmann C, Diehlmann K, Stemper T, Buyken AE, Ketelhut K, Müssig K. Positive Effects of Promoting Physical Activity and Balanced Diets in a Primary School Setting with a High Proportion of Migrant School Children. Exp Clin Endocrinol Diabetes. 2017. 125:554-562. doi:10.1055/s-0043-101918. | Intervention/exposure
872 | Wehling Weepie AK, McCarthy AM. A healthy lifestyle program: promoting child health in schools. J Sch Nurs. 2002. 18:322-8. doi:10.1177/10598405020180060401. | Study design
873 | Wells NM, Meyers BM, Todd LE, Henderson CR, Jr Barale K, Gaolach B, Ferenz G, Aitken M, Tse CC, Pattison KO, Hendrix, L, Carson JB, Taylor C, Franz, NK. The carry-over effects of school gardens on fruit and vegetable availability at home: A randomized controlled trial with low-income elementary schools. Prev Med. 2018. 112:152-159. doi:10.1016/j.ypmed.2018.03.022. | Outcome
874 | Wells NM, Myers BM, Henderson CR. School gardens and physical activity: A randomized controlled trial of low-income elementary schools. Prev Med. 2014. 69:S27-S33. doi:10.1016/j.ypmed.2014.10.012. | Outcome
875 | Wells NM, Myers BM, Todd LE, Barale K, Gaolach B, Ferenz G, Aitken M, Henderson CR, Tse C, Pattison KO, Taylor C, Connerly L, Carson JB, Gensemer AZ, Franz NK, Falk E. The Effects of School Gardens on Children’s Science Knowledge: A randomized controlled trial of low-income elementary schools. Int J Sci Educ. 2015. 37:2858-2878. doi:10.1080/09500693.2015.1112048. | Outcome
876 | Werch CE, Bian H, Carlson JM, Moore MJ, Diclemente CC, Huang IC, Ames SC, Thombs D, Weiler RM, Pokorny SB. Brief integrative multiple behavior intervention effects and mediators for adolescents. J Behav Med. 2011. 34:3-12. doi:10.1007/s10865-010-9281-9. | Intervention/exposure
877 | Werner D, Teufel J, Holtgrave PL, Brown SL. Active generations: an intergenerational approach to preventing childhood obesity. J Sch Health. 2012. 82:380-6. doi:10.1111/j.1746-1561.2012.00713.x. | Study design
878 | Whatley Blum JE, Davee AM, Devore RL, Beaudoin CM, Jenkins PL, Kaley LA, Wigand DA. Implementation of low-fat, low-sugar, and portion-controlled nutrition guidelines in competitive food venues of Maine public high schools. J Sch Health. 2007. 77:687-93. doi:10.1111/j.1746-1561.2007.00252.x. | Outcome
879 | Whetstone LM, Kolasa KM, Collier DN. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. 2012. 27:10-6. doi:10.4278/ajhp.100415-QUAN-117. | Study design
880 | Whiteley C, Matwiejczyk L. Preschool Program Improves Young Children’s Food Literacy and Attitudes to Vegetables. J Nutr Educ Behav. 2015. 47:397-8.e1. doi:10.1016/j.jneb.2015.04.002. | Study design, Outcome
881 | Whittemore R, Jeon S, Grey M. An internet obesity prevention program for adolescents. J Adolesc Health. 2013. 52:439-47. doi:10.1016/j.jadohealth.2012.07.014. | Intervention/exposure
882 | Widhalm K, Helk O, Pachinger O. The Viennese EDDY Study as a Role Model for Obesity: Prevention by Means of Nutritional and Lifestyle Interventions. Obes Facts. 2018. 11:247-256. doi:10.1159/000481140. | Intervention/exposure
883 | Willi SM, Hirst K, Jago R, Buse J, Kaufman F, El Ghormli L, Bassin S, Elliot D, Hale DE. Cardiovascular risk factors in multi-ethnic middle school students: the HEALTHY primary prevention trial. Pediatr Obes. 2012. 7:230-9. doi:10.1111/j.2047-6310.2011.00042.x. | Intervention/exposure
884 | Williamson DA, Champagne CM, Harsha DW, Han H, Martin CK, Newton RL, Jr Sothern MS, Stewart TM, Webber LS, Ryan DH. Effect of an environmental school-based obesity prevention program on changes in body fat and body weight: a randomized trial. Obesity (Silver Spring). 2012. 20:1653-61. doi:10.1038/oby.2012.60. | Intervention/exposure
885 | Williamson DA, Copeland AL, Anton SD, Champagne C, Han H, Lewis L, Martin C, Newton RL, Jr Sothern M, Stewart T, Ryan D. Wise Mind project: a school-based environmental approach for preventing weight gain in children. Obesity (Silver Spring). 2007. 15:906-17. doi:10.1038/oby.2007.597. | Intervention/exposure
886 | Williamson DA, Han H, Johnson WD, Martin CK, Newton RL, Jr. Modification of the school cafeteria environment can impact childhood nutrition. Results from the Wise Mind and LA Health studies. Appetite. 2013. 61:77-84. doi:10.1016/j.appet.2012.11.002. | Intervention/exposure
887 | Wilson DB, Jones RM, McClish D, Westerberg AL, Danish S. Fruit and vegetable intake among rural youth following a school-based randomized controlled trial. Prev Med. 2012. 54:150-6. doi:10.1016/j.ypmed.2011.11.005. | Intervention/exposure
888 | Winter EM, Stluka S, Wells K, Wey H, Kemmer TM. Fun with Foodella: A Pilot Study for Determining the Efficacy of a 2nd Grade Nutrition and Physical Activity Curriculum. J Ext. 2012. 50(4). | Outcome
889 | Winterfeld A. Nutrition rules: making healthy food choices available to school kids is a priority for many lawmakers. State Legis. 2008. 34(5):22-4. | Study design
890 | Wofford L, Froeber D, Clinton B, Ruchman E. Free afterschool program for at-risk African American children: findings and lessons. Fam Community Health. 2013. 36:299-310. doi:10.1097/FCH.0b013e31829d2497. | Study design, Intervention/exposure
891 | Wolfe WS. Choose Health: Food, Fun and Fitness, an Experiential Youth Curriculum That Promotes Healthy Eating and Active Play. J Nutr Educ Behav. 2018. 50:1053-1055. doi:10.1016/j.jneb.2017.09.011. | Study design
892 | Wolfenden L, Nathan N, Reilly K, Delaney T, Janssen LM, Reynolds R, Sutherland R, Hollis J, Lecathelinais C, Williams CM, Wyse R, Wiggers J, Yoong S. Two-year follow-up of a randomised controlled trial to assess the sustainability of a school intervention to improve the implementation of a school-based nutrition policy. Health Promot J Austr. 2019. 30 Suppl 1:26-33. doi:10.1002/hpja.238. | Outcome
893 | Woo T, Lee KH. Effects of sensory education based on classroom activities for lower grade school children. Nutr Res Pract. 2013. 7:336-41. doi:10.4162/nrp.2013.7.4.336. | Outcome
894 | Wordell D, Daratha K, Mandal B, Bindler R, Butkus SN. Changes in a middle school food environment affect food behavior and food choices. J Acad Nutr Diet. 2012. 112:137-41. doi:10.1016/j.jada.2011.09.008. | Study design
895 | Wright K, Norris K, Newman Giger J, Suro Z. Improving healthy dietary behaviors, nutrition knowledge, and self-efficacy among underserved school children with parent and community involvement. Child Obes. 2012. 8:347-56. doi:10.1089/chi.2012.0045. | Intervention/exposure
896 | Wright ND, Wylie-Rosett J, Lukoscheck P, Moadel AB, Soroudi N. The School Yard Kids: a puppet show to promote a healthful lifestyle. J Nutr Educ Behav. 2007. 39:290-1. doi:10.1016/j.jneb.2007.06.001. | Study design
897 | Wyatt KM, Lloyd JJ, Creanor S, Logan S. The development, feasibility and acceptability of a school-based obesity prevention programme: results from three phases of piloting. BMJ Open. 2011. 1:e000026. doi:10.1136/bmjopen-2010-000026. | Intervention/exposure, Comparator
898 | Xu F, Wang X, Ware RS, Tse LA, Wang Z, Hong X, Chan EY, Li J, Wang Y. A school-based comprehensive lifestyle intervention among Chinese kids against Obesity (CLICK-Obesity) in Nanjing City, China: the baseline data. Asia Pac J Clin Nutr. 2014. 23:48-54. doi:10.6133/apjcn.2014.23.1.04. | Other: Baseline data and participant characteristics
899 | Xu F, Ware RS, Leslie E, Tse LA, Wang Z, Li J, Wang Y. Effectiveness of a randomized controlled lifestyle intervention to prevent obesity among Chinese primary school students: CLICK-Obesity Study. PLoS One. 2015. 10:e0141421. doi:10.1371/journal.pone.0141421. | Intervention/exposure
900 | Xu H, Ecker O, Zhang Q, Du S, Liu A, Li Y, Hu X, Li T, Guo H, Li Y, Xu G, Liu W, Ma J, Sun J, Chen K, Ma G. The effect of comprehensive intervention for childhood obesity on dietary diversity among younger children: Evidence from a school-based randomized controlled trial in China. PLoS One. 2020. 15:e0235951. doi:10.1371/journal.pone.0235951. | Country
901 | Xu H, Li Y, Zhang Q, Hu XL, Liu A, Du S, Li T, Guo H, Li Y, Xu G, Liu W, Ma J, Ma G. Comprehensive school-based intervention to control overweight and obesity in China: a cluster randomized controlled trial. Asia Pac J Clin Nutr. 2017. 26:1139-1151. doi:10.6133/apjcn.112016.05. | Country
902 | Yang Y, Kang, B, Lee EY, Yang HK, Kim HS, Lim SY, Lee JH, Lee SS, Suh BK, Yoon KH. Effect of an obesity prevention program focused on motivating environments in childhood: a school-based prospective study. Int J Obes (Lond). 2017. 41:1027-1034. doi:10.1038/ijo.2017.47. | Intervention/exposure
903 | Yeom MY, Cho YO. Nutrition education discouraging sugar intake results in higher nutrient density in diets of pre-school children. Nutr Res Pract. 2019. 13:434-443. doi:10.4162/nrp.2019.13.5.434. | Study design
904 | Yon BA, Johnson RK, Stickle TR. School children’s consumption of lower-calorie flavored milk: a plate waste study. J Acad Nutr Diet. 2012. 112:132-6. doi:10.1016/j.jada.2011.09.011. | Study design
905 | Yoshida T, Kouda K, Nakamura H, Nishio N. Taste development from health education among schoolchildren: a two-year intervention study. J Physiol Anthropol. 2008. 27:1-5. doi:10.2114/jpa2.27.1. | Study design, Outcome
906 | Yu HJ, Li F, Hu YF, Li CF, Yuan S, Song Y, Zheng M, Gong J, He QQ. Improving the metabolic and mental health of children with obesity: a school-based nutrition education and physical activity intervention in Wuhan, China. Nutrients. 2020. 12:194. doi:10.3390/nu12010194. | Intervention/exposure
907 | Zahr R, Sibeko L. Influence of a school-based cooking course on students’ food preferences, cooking skills, and confidence. Can J Diet Pract Res. 2017. 78:37-41. doi:10.3148/cjdpr-2016-030. | Outcome
908 | Zammit N, Maatoug J, Ghammam R, Raoudha K, Lamia B, Mustafa A, Harry L, Ghannem H. Sustainability of the results of a non communicable diseases prevention program among youth in the region of Sousse, Tunisia. Int J Adolesc Med Health. 2016. 30. doi:10.1515/ijamh-2016-0065. | Intervention/exposure
909 | Zask A, Adams JK, Brooks LO, Hughes DF. Tooty Fruity Vegie: an obesity prevention intervention evaluation in Australian preschools. Health Promot J Austr. 2012. 23:10-5. doi:10.1071/he12010. | Intervention/exposure, Age at intervention/exposure
910 | Zeinstra GG, Vingerhoeds MH, Vrijhof M, van Mourik S, Houtzager RN, van Kleef E. Changing the behaviour of children living in Dutch disadvantaged neighbourhoods to improve breakfast quality: Comparing the efficacy of three school-based strategies. Appetite. 2019. 137:163-173. doi:10.1016/j.appet.2019.02.011. | Study design
911 | Zenner DA, Cobuzzi JL. Eat your veggies: A chef-prepared, family style school lunch increases vegetable liking and consumption in elementary school students. Food Qual Prefer. 2017. 55:8-15. doi:10.1016/j.foodqual.2016.08.007. | Study design
912 | Zhao SR, Cao S, Lin PS, Yenor J, Lam R, Chang E, Liu R, Liu J. Interprofessional and interdisciplinary approach from undergraduate health and pre-medical students in children’s health educational initiative. J Community Med Health Educ. 2013. 4:266. doi:10.4172/2161-0711.1000266. | Study design, Outcome
913 | Zhou J. Results from a quasi-experimental study of a training intervention for healthy eating behaviors of students. Neuroquantology. 2018. 16:19-24. doi:10.14704/nq.2018.16.2.1165. | Study design
914 | Zhou WJ, Xu XL, Li G, Sharma M, Qie YL, Zhao Y. Effectiveness of a school-based nutrition and food safety education program among primary and junior high school students in Chongqing, China. Glob Health Promot. 2016. 23:37-49. doi:10.1177/1757975914552914. | Outcome
915 | Zive MM, Pelletier RL, Sallis JF, Elder JP. An environmental intervention to improve a la carte foods at middle schools. J Am Diet Assoc. 2002. 102:S76-8. doi:10.1016/s0002-8223(02)90427-x. | Study design, Outcome