# Appendix 3 NESR grading rubric

Table A 2 NESR grading rubric

Elements | Strong | Moderate | Limited | Grade Not Assignable
Risk of bias | Across the body of evidence, there is a strong likelihood that the design and conduct of the studies has prevented or minimized bias such that the reported results are the true effects of the intervention/ exposure, and plausible bias and/or potential limitations are unlikely to alter the results | Across the body of evidence, there is a moderate likelihood that the design and conduct of the studies has prevented or minimized bias such that the reported results are the true effects of the intervention/ exposure, and plausible bias and/or potential limitations are unlikely to alter the results | Across the body of evidence, there is a limited likelihood that the design and conduct of the studies has prevented or minimized bias such that the reported results may not be the true effects of the intervention/ exposure, and plausible bias and/or potential limitations may have altered the results | A [underlined: grade is not assignable] for this element because it cannot be adequately assessed
Consistency | The body of evidence demonstrates findings with [underlined: strong] consistency in direction and magnitude of effect; or, any inconsistencies in findings can be explained by methodological differences | The body of evidence demonstrates findings with [underlined: moderate] consistency in direction and magnitude of effect; some of the inconsistencies in findings can be explained by methodological differences | The body of evidence demonstrates findings with [underlined: limited] consistency in direction and magnitude of effect; few of the inconsistencies in findings can be explained by methodological differences | A [underlined: grade is not assignable] for this element because it cannot be adequately assessed
Directness | The body of evidence demonstrates [underlined: strong] directness, such that studies are designed to directly examine the relationships among intervention/exposure, comparator, and outcomes of primary interest in the systematic review question | The body of evidence demonstrates [underlined: moderate] directness, such that some studies are designed to directly examine the relationships among intervention/exposure, comparator, and/or outcomes of primary interest in the systematic review question | The body of evidence demonstrates [underlined: limited] directness, such that few studies are designed to directly examine the relationships among intervention/exposure, comparator, and/or outcomes of primary interest in the systematic review question | A [underlined: grade is not assignable] for this element because it cannot be adequately assessed
Precision | The body of evidence demonstrates [underlined: strong] precision based on a substantial number of sufficiently-powered studies with a narrow assessment of variance | The body of evidence demonstrates [underlined: moderate] precision based on an adequate number of sufficiently-powered studies with a narrow assessment of variance | The body of evidence demonstrates [underlined: limited] precision based on an inadequate number of sufficiently-powered studies with a narrow assessment of variance | A [underlined: grade is not assignable] for this element because it cannot be adequately assessed
Generalizability | The body of evidence demonstrates [underlined: strong] generalizability to the U.S. population of interest with regard to:; a) the participant characteristics; b) the intervention/exposure and outcomes studied | The body of evidence demonstrates [underlined: moderate] generalizability to the U.S. population of interest with regard to:; a) the participant characteristics; b) the intervention/exposure and outcomes studied | The body of evidence demonstrates [underlined: limited] generalizability to the U.S. population of interest with regard to the:; a) participant characteristics; b) intervention/ exposure and outcomes studied | A [underlined: grade is not assignable] for this element because it cannot be adequately assessed