# Appendix 2 Literature search strategy

PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: September 18, 2020
- Date range searched: January 1, 2000-September 18, 2020
- Results: 6,981

- #1- “Diet”[Mesh] OR “dietary pattern*”[tiab] OR “dietary habit*”[tiab] OR “eating pattern*”[tiab] OR “eating habit*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “healthy eat*”[tiab] OR “eating health*”[tiab] OR “eat health*”[tiab] OR “healthy food*”[tiab] OR “dietary guideline*”[tiab] OR “Meals”[Mesh] OR “meal*”[tiab] OR “breakfast*”[tiab] OR “break fast*”[tiab] OR “lunch*”[tiab] OR “snack*”[tiab] OR “food”[tiab] OR “foods”[tiab] OR “Beverages” [MeSH] OR “beverage*”[tiab] OR “soda*”[tiab] OR “dairy”[tiab] OR “milk”[tiab] OR “Fruit”[Mesh] OR “fruits”[tiab] OR “fruit”[tiab] OR “Vegetables”[Mesh] OR “vegetable*”[tiab] OR “Meat”[Mesh] OR “meat”[tiab] OR “meats”[tiab] OR “Whole Grains”[Mesh] OR “whole grain*”[tiab] OR “Sodium, Dietary”[Mesh] OR “sodium”[tiab] OR “salt”[tiab] OR “sugar”[tiab] OR “sugary”[tiab] OR “sweet*”[tiab] OR “saturated fat*”[tiab]
- #2- “Overweight”[Mesh] OR “overweight”[tiab] OR “obes*”[tiab] OR “body weight”[tiab] OR “weight gain*”[tiab] OR “weight loss*”[tiab] OR “underweight”[tiab] OR “healthy weight”[tiab] OR “Body Mass Index”[Mesh] OR “body mass index”[tiab] OR “BMI”[tiab] OR “Body Composition”[Mesh] OR “body composition”[tiab] OR “body fat”[tiab] OR “fat mass”[tiab] OR “fat free mass”[tiab] OR “anthropometr*”[tiab] OR “adiposity”[tiab]
- #3 - #1 OR #2
- #4- “Schools”[Mesh] OR “school*”[tiab] OR “classroom*”[tiab] OR “School Health Services”[Mesh] OR “Teaching”[Mesh:NoExp] OR “teach*”[tiab] OR “Curriculum”[Mesh] OR “curricul*”[tiab]
- #5- “Consumer Behavior”[Mesh] OR “food program*”[tiab] OR “feeding program*”[tiab] OR “food selection*”[tiab] OR “food choice*”[tiab] OR “food polic*”[tiab] OR “fruit program*”[tiab] OR “vegetable program*”[tiab] OR “nutritional education*”[tiab] OR “nutrition education*”[tiab] OR “nutrition knowledge”[tiab] OR “nutrition standard*”[tiab] OR “nutrition program*”[tiab] OR “dietary Intervention*”[tiab] OR “dietary education*”[tiab] OR “Health Promotion”[Mesh] OR “health promotion*”[tiab] OR “Health Education”[Mesh:NoExp] OR “health education*”[tiab] OR “educational program*”[tiab] OR “healthy lifestyle*”[tiab] OR “Food Preferences”[Mesh] OR “food preference*”[tiab] OR “Choice Behavior”[Mesh:NoExp] OR “healthy choice*”[tiab] OR ((intervention*[tiab] OR program*[tiab] OR environment*[tiab]) AND (cafeteria*[tiab] OR garden*[tiab] OR “Food Services”[Mesh] OR “food service*”[tiab] OR “Nutrition Assessment”[Mesh] OR “diet quality”[tiab] OR “daily amount*”[tiab] OR “behavioral change*”[tiab] OR “behavioural change*”[tiab] OR “behavioral outcome*”[tiab] OR “behavioural outcome*”[tiab]))
- #6- “Child”[Mesh:NoExp] OR “child*”[tiab] OR “youth*”[tiab] OR “Adolescent”[Mesh] OR “adolescen*”[tiab] OR “teen*”[tiab] OR “preteen*”[tiab] OR “pre-teen*”[tiab] OR “pre-adolescen*”[tiab] OR “preadolescen*”[tiab] OR “boy”[tiab] OR “boys”[tiab] OR “girl*”[tiab] OR “schoolchild*”[tiab] OR “elementary school*”[tiab] OR “primary school*”[tiab] OR “secondary school*”[tiab] OR “middle school*”[tiab] OR “junior high*”[tiab] OR “high school*”[tiab] OR “juvenile*”[tiab]
- #7– (#3 AND #4 AND #5 AND #6) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2020/09/18; English

Web of Science (Core Collection)

- Provider: Clarivate
- Date Searched: September 21, 2020
- Date range searched: January 1, 2000-September 21, 2020
- Results: 4,367

- #5- (#4 AND #3 AND #2 AND #1 NOT (DT=(“Editorial Material” OR “News Item” OR Letter OR Review OR “Retracted Publication”) )) AND LANGUAGE: (English) AND DOCUMENT TYPES: (Article)
  Indexes=SCI-EXPANDED, SSCI Timespan=2000-2020
- #4- (TS=(child* OR youth* OR adolescen* OR teen* OR preteen* OR pre-teen* OR pre-adolescen* OR preadolescen* OR boy OR boys OR girl* OR schoolchild* OR “elementary school*” OR “primary school*” OR “secondary school*” OR “middle school*” OR “junior high*” OR “high school*” OR juvenile* )
- #3- (TS=( “consumer behavior” OR “food program*” OR “feeding program*” OR “food selection*” OR “food choice*” OR “food polic*” OR “fruit program*” OR “vegetable program*” OR “nutritional education*” OR “nutrition education*” OR “nutrition knowledge” OR “nutrition standard*” OR “nutrition program*” OR “dietary Intervention*” OR “dietary education*” OR “health promotion*” OR “health education*” OR “educational program*” OR “healthy lifestyle*” OR “food preference*” OR “healthy choice*” OR ((intervention* OR program* OR environment* ) NEAR/6 ( cafeteria* OR garden* OR “food service*” OR “nutrition assessment” OR “diet quality” OR “daily amount*” OR “behavioral change*” OR “behavioural change*” OR “behavioral outcome*” OR “behavioural outcome*” )
- #2- (TS=(school* OR classroom* OR teach* OR curricul*) )
- #1- (TS=(“dietary pattern*” OR “dietary habit*” OR “eating pattern*” OR “eating habit*” OR “healthy diet*” OR “healthy eat*” OR “eating health*” OR “eat health*” OR “healthy food*” OR “dietary guideline*” OR meal* OR breakfast* OR breakfast* OR lunch* OR snack* OR food OR foods OR beverage* OR soda* OR dairy OR milk OR fruits OR fruit OR vegetable* OR meat OR meats OR “whole grain*” OR sodium OR salt OR sugar OR sugary OR sweet* OR “saturated fat*” OR overweight OR obes* OR “body weight” OR “weight gain*” OR “weight loss*” OR underweight OR “healthy weight” OR “body mass index” OR “BMI” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR anthropometry* OR adiposity) )

Education Resources Information Center (ERIC)

- Provider: Institute of Education Sciences within the United States Department of Education
- Date Searched: September 21, 2020
- Date range searched: January 1, 2000-September 21, 2020
- Results: 1,458

(“dietary pattern*” OR “dietary habit*” OR “eating pattern*” OR “eating habit*” OR “healthy diet*” OR “healthy eat*” OR “eating health*” OR “eat health*” OR “healthy food*” OR “dietary guideline*” OR meal* OR breakfast* OR breakfast* OR lunch* OR snack* OR food OR foods OR beverage* OR soda* OR dairy OR milk OR fruits OR fruit OR vegetable* OR meat OR meats OR “whole grain*” OR sodium OR salt OR sugar OR sugary OR sweet* OR “saturated fat*” OR overweight OR obes* OR “body weight” OR “weight gain*” OR “weight loss*” OR underweight OR “healthy weight” OR “body mass index” OR “BMI” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR anthropometry* OR adiposity) AND (school* OR classroom* OR teach* OR curricul*) AND (“consumer behavior” OR “food program*” OR “feeding program*” OR “food selection*” OR “food choice*” OR “food polic*” OR “fruit program*” OR “vegetable program*” OR “nutritional education*” OR “nutrition education*” OR “nutrition knowledge” OR “nutrition standard*” OR “nutrition program*” OR “dietary Intervention*” OR “dietary education*” OR “health promotion*” OR “health education*” OR “educational program*” OR “healthy lifestyle*” OR “food preference*” OR “healthy choice*”) OR ((intervention* OR program* OR environment* ) AND ( cafeteria* OR garden* OR “food service*” OR “nutrition assessment” OR “diet quality” OR “daily amount*” OR “behavioral change*” OR “behavioural change*” OR “behavioral outcome*” OR “behavioural outcome*”))