# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BRFSS: Behavioral Risk Factor Surveillance System
CNPP: Center for Nutrition Policy and Promotion
ERIC: Education Resources Information Center
FFQ: Food frequency questionnaire
FNS: Food and Nutrition Services
HDI: Human Development Index
HPM: Health Promotion Model
kcal: Kilocalorie
LNED: Low-nutrient energy-dense
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
NSLP: National School Lunch Program
OPS: Office of Policy Support
RCT: Randomized controlled trial
SBP: School Breakfast Program
SCT: Social Cognitive Theory
SES: Socioeconomic status
SNAP-Ed: Supplemental Nutrition Assistance Program-Education
SNRAD: Special Nutrition Research and Analysis Division
SSB: Sugar-sweetened beverage
TEENS: Teens Eating for Energy and Nutrition at Schools
TPB: Theory of Planned Behavior
UK: United Kingdom
US: United States
USDA: United States Department of Agriculture
WHO: World Health Organization