# Executive summary

## Background

In a typical fiscal year, almost 91,000 schools served low-cost or free breakfasts through the U.S. School Breakfast Program (SBP) to about 15 million students daily.^a^ Involvement in the SBP can play an influential role in school-age children’s development of a healthy dietary pattern.^b^

a United States Department of Agriculture Food and Nutrition Service National Data Bank. Accessed April 25, 2022. https://afnazre3ws08/NDB8/Home/Signin2.aspx

b U.S. Department of Agriculture and U.S. Department of Health and Human Services. Dietary Guidelines for Americans, 2020-2025. 9th Edition. December 2020. Available at DietaryGuidelines.gov.

The USDA Nutrition Evidence Systematic Review (NESR) team conducted a rapid review for the USDA Food and Nutrition Service, Office of Policy Support to summarize evidence on the relationship between eating breakfast and school performance, weight-related and health outcomes, and on best practices in the SBP, including models of student costs and breakfast delivery.

## Key findings

- Eating breakfast may result in improved learning achievement later in the day, although long-term effects and impact on cognitive development is unclear.
- Increased breakfast frequency in childhood and adolescence may be associated with healthier weight status, though a large proportion of studies find no association.
- Eating breakfast may lead to health benefits throughout the morning, including lower hunger and appetite, higher satiety and glucose levels, and perhaps better mood, but long-term impacts on cardiometabolic and mental health outcomes are unclear.
- SBP universal-free breakfast and breakfast-after-the-bell delivery models, particularly breakfast in the classroom, significantly and substantially increases SBP participation and may increase rates of consuming a nutritionally substantive breakfast.

## Methods

A literature search using 4 databases (PubMed, Cochrane CENTRAL, Web of Science, CINAHL Plus) identified articles published from January 2005 through August 2021 that met pre-defined inclusion and exclusion criteria. Eligible interventions examined (a) the intervention or exposure of breakfast consumption, compared to breakfast skipping, in relation to measures of school performance, weight-related outcomes, and health outcomes, or (b) models of SBP delivery, compared to variations in SBP models, in relation to SBP participation, diet quality, breakfast skipping, school preformance and learning achievement, weight-related outcomes, student or teacher satisfaction with the SBP, and health outcomes.

Articles were partially dual screened by 2 NESR analysts based on pre-determined criteria, and a third analyst adjudicated disagreements. Eligible study designs included randomized controlled trials (RCT), non-randomized controlled trials (NRCT), prospective cohort studies (PCS), retrospecitve cohorts, pre-post studies with a control, case control studies, and for acute school preformance and health outcomes only, cross-sectional studies (CS). The SBP best practices review included CS and uncontrolled pre-post studies (UPP) to inform research recommendations. Studies were published in English in peer-reviewed journals, were conducted in countries with high or very high levels of human development, and enrolled children and adolescents (5 to 18 years). Studies on SBP best practices were conducted in the U.S. only. Data were extracted and risk of bias was assessed for each article. Evidence was qualitatively synthesized, with attention given to overarching themes, similarities and differences between studies, and factors that may affect results. Summary statements were developed and compared with findings from a previously published comprehensive review^a^.

a Murphy, JM. Breakfast and learning: an updated review. Current Nutrition & Food Science. 2007; 3(1):3–36. 10.2174/1573401310703010003

## Findings

Breakfast and school performance, 2 RCTs, 1 PCS and 1 CS (nested within a cluster RCT) examined the relationship between eating breakfast and learning achievement, and 12 RCTs, 1 NRCT, 1 cohort study and 3 CS examined breakfast and cognitive development.

- Eating breakfast may result in improved learning achievement later in the day in school-aged children. The evidence comes from four small well-conducted studies with marked heterogeneity. Additional studies are needed to assess acute and longitudinal effects of breakfast consumption in school-aged children.
- The effect of eating breakfast, compared to fasting, on measures of cognitive development in school-aged children is unclear. Despite a reasonable number of studies, the ability to draw conclusions was restricted by inconsistency in study findings, heterogeneity in cognitive tests, and small sample sizes.

Breakfast and weight-related outcomes, 1 RCT and 37 PCS examined the association between breakfast intake during childhood or adolescence and weight-related outcomes.

- Increased frequency of breakfast intake in childhood (5-9y) may be associated with healthier weight-related outcomes, though roughly half of the studies found no statistically significant association. No studies examining overall breakfast intake found an association with greater frequency and less healthy outcomes. These studies enrolled large cohorts of participants with substantial diversity in race/ethnicity and socioeconomic status, as well as long follow-up periods, but they were also limited by high attrition, inconsistent definitions of breakfast, and intake assessments at baseline only.
- Increased frequency of breakfast intake in early adolescence (10-12y) may be associated with healthier weight-related outcomes, particularly lower BMI and healthier weight status, though roughly half of the studies found no statistically significant association. No studies found an association between increased breakfast intake and less healthy BMI or weight status. These studies included long follow-up periods but were limited by high attrition, small sample sizes, greater age group overlap, inconsistent definitions of breakfast, and intake assessment at baseline only.
- Increased frequency of breakfast intake in later adolescence (13y+) showed a more consistent association with healthier weight-related outcomes than in younger populations, particularly for BMI and weight status, with eight of twelve studies supporting that finding. However, these eight studies came from only two cohorts, and the remaining four studies from other cohorts did not find statistically significant associations. No studies found an association between greater breakfast intake and less healthy BMI or weight status. These studies enrolled large cohorts of participants with substantial diversity in race/ethnicity and socioeconomic status, as well as long follow-up periods, but they were limited by high attrition and intake assessments at baseline only.

Breakfast and health, 19 articles, including 8 RCT, 1 NRCT, and 10 PCS examined the association between breakfast intake during childhood or adolescence and health outcomes.

- Eating breakfast, compared to no breakfast, results in lower hunger, lower appetite, and higher satiety, with effects measured as long as 4 hours after breakfast. The evidence, from three randomized controlled trials, is most generalizable to early adolescence (ages 12 to 14 years), as there is no evidence from other age groups. These findings are limited because participants could not be blinded, which could have had an impact on their subjective, self-reported outcomes.
- Eating breakfast may result in favorable mood outcomes throughout the morning. However, some of the available evidence suggests that these subjective, participant-reported outcomes may have been influenced by a lack of participant blinding.
- Eating breakfast results in higher glucose levels than fasting, with effects measured as long as 3 hours after breakfast. The evidence, from two well-conducted randomized controlled trials, was consistent in 9-year-olds with obesity and a sample of predominantly female 16-year-olds with a normal BMI.
- Some studies found that eating breakfast, compared with fasting, results in higher triglycerides, insulin, PYY, resting energy expenditure, and carbohydrate oxidation, and lower glucagon, ghrelin, and lipid oxidation during the morning. However, few studies examined these outcomes, and the evidence is limited in its generalizability.
- Associations between breakfast consumption during childhood and adolescence and long-term cardiometabolic and mental health outcomes are unclear. The evidence was inconclusive because it was from a small number of studies with inconsistent findings and limitations.

SBP best practices, 24 articles from 3 RCT, 8 NRCT, 6 CS, and 3 UPP studies examined SBP best practices, RCT and NRCT informed summary statements.

- U.S. School Breakfast Program universal-free breakfast and breakfast-after-the-bell delivery models, particularly breakfast in the classroom (or a combination of these models) compared to traditional School Breakfast Program delivery, significantly and substantially increases School Breakfast Program participation. Evidence is from large, well designed intervention studies conducted in diverse grades and socioeconomic student groups.
- Universal-free breakfast or breakfast in the classroom may increase rates of consuming a nutritionally substantive breakfast (e.g., consume food from at least two of five food groups and intake of greater than 10% of daily energy requirements). Evidence is from two large, rigorous intervention studies conducted in high-poverty, urban elementary and middle schools.
- The effect of universal-free breakfast in the classroom on weight-related outcomes is unclear due to insufficient evidence. However, one rigorous study conducted in high-poverty urban schools found breakfast in the classroom increased the incidence of obesity but found breakfast in the classroom had no significant effect on combined incidence of overweight and obesity at 2.5 years of intervention. Additional longitudinal research is needed on the impact of free breakfast in the classroom on weight-related outcomes and eating behaviors using research designs with sufficient power to explore the effect of baseline weight, socioeconomic status, and urbanicity.
- Breakfast in the classroom and universal-free School Breakfast Program have little effect on measures of attendance and academic achievement during the first year of implementation in elementary and middle school children. Additional longitudinal research is needed on universal-free breakfast and breakfast-after-the-bell models and measures of attendance, and chronic absenteeism, particularly among high school students.
- The relationship between the School Breakfast Program student cost and delivery models and breakfast skipping, student/teacher satisfaction, and health is unclear due to lack of evidence.

Recently published studies provide new evidence and confirms previous findings published by Murphy, 2007^a^ with more rigorous study designs and data exclusively from studies conducted in school-aged children and adolescents from high and very high development countries. There are several research recommendations that apply to evidence examining breakfast eating and SBP models in schoolchildren.

- Conduct experimental studies that examine a variety of breakfast interventions that more closely resemble students’ habitual breakfast consumption.
- Evaluate characteristics of the breakfast meal (e.g., location, timing, type of food, macronutrient composition, specific portion size, and calorie content) and other foods and beverages consumed through the day using well-controlled studies to enhance understanding of relationships identified.
- Explore the impact of BIC on weight-related outcomes using strong, longitudinal study designs that have sufficient power to evaluate the effect of baseline weight, school level, SES, and urbanicity.
- Enroll adequate samples of students with a range of demographic characteristics including more middle school and high school students, and students of varying weight status, and socioeconomic status to improve generalizability of results.
- Use valid measures consistently to build a body of evidence specifically for cognitive and health outcomes.