# Acknowledgments and funding

[underlined: Review team from NESR at the USDA Center for Nutrition Policy and Promotion]: analysts Brittany J. Kingshipp, PhD, Ramkripa Raghavan, DrPH, Darcy Güngör, MS, and Carol Dreibelbis, MPH (for the initial report of May 2019), librarian Gisela Butera, MLIS (for the initial report of May 2019), and project lead Joanne M. Spahn, MS, RDN.

[underlined: USDA Food and Nutrition Service Office of Policy Support]: Conor McGovern, MA (Social Science Research Analyst, Special Nutrition Evaluation Branch), Danielle Berman, PhD (Chief, Special Nutrition Evaluation Branch), and Kelley Scanlon, PhD, RD (Director, Special Nutrition Research and Analysis Division).

The review team and collaborators developed the initial rapid review protocol (September 2018). GB developed the literature search. BJK, RR, DG, CD, and JMS screened search results, identified articles for inclusion, extracted data from and assessed the risk of bias of the included studies, synthesized the evidence, and developed summary statements and research recommendations. RR, BJK, and DG led Key Questions 1a, 1b, and 1c, respectively. CD led Key Question 2 prior to May 2019, and JMS led the update of Key Question 2 in 2021. JMS provided oversight of the project and has primary responsibility for final content. The authors declare no conflict of interest.

The NESR team thanks the following members of the USDA Food and Nutrition Service for their time and expertise as peer reviewers of the initial rapid review protocol (September 2018) and interim report (May 2019): John Endahl, PhD (Senior Social Science Analyst, Office of Policy Support), Sara Olson, ScM, RD (Special Assistant to the Deputy Administrator, Child Nutrition Programs), and Farrah Buff, MGA (Senior Technical Advisor, Child Nutrition Programs) and the final report: Margaret Applebaum, PhD (Chief, Special Nutrition Analysis Branch, Office of Policy Support) and Marlana Bates, MPH, RD (Social Science Policy Analyst, Special Nutrition Analysis Branch, Office of Policy Support). We thank Molly Higgins, MLIS, for re-running the literature search and reviewing the literature search content of the report and Concetta LaPergola, MS, for her work on the initial report draft.