# Appendix 2 Excluded articles

The following tables list the articles excluded from the rapid reviews during full-text screening. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A2 1 Articles excluded during full-text screening of the initial literature search for Key Question 1a: What is the relationship between eating breakfast and school performance?

Article | Reason for exclusion
Mhurchu, C. N., Gorton, D., Turley, M., Jiang, Y., Michie, J., Maddison, R., & Hattie, J. (2013). Effects of a free school breakfast programme on children’s attendance, academic achievement, and short-term hunger: Results from a stepped-wedge, cluster randomised controlled trial. Journal of Epidemiology & Community Health, 67 (3), 257-264. http://doi.org/10.1136/jech-2012-201540 | Publication status
Pivik, R. T., Tennal, K. B., Chapman, S. D., & Gu, Y. (2012). Eating breakfast enhances the efficiency of neural networks engaged during mental arithmetic in school-aged children. Physiology & Behavior, 106 (4), 548-555. https://doi.org/10.1016/j.physbeh.2012.03.034 | Publication status
Effects of Breakfast on Cognitive Processes in Children. (2010). NCT01063894. Retrieved from https://clinicaltrials.gov/show/nct01063894 | Publication status
Nutrition Intervention to Measure Metabolic Response in Children. (2017). NCT03139773. Retrieved from https://clinicaltrials.gov/show/nct03139773 | Publication status
The Effects of Breakfast on Brain Function. (2008). NCT00621595. Retrieved from https://clinicaltrials.gov/ct2/show/nct00621595 | Publication status
The Influence of Breakfast on Hormone Responses and Cognitive Performance.(2016). NCT03005951. Retrieved from https://clinicaltrials.gov/show/nct03005951 | Publication status
Ahmadi, A., Sohrabi, Z., & Eftekhari, M. H. (2009). Evaluating the relationship between breakfast pattern and short-term memory in junior high school girls. Pakistan Journal of Biological Sciences, 12 (9), 712-715. http://doi.org/10.3923/pjbs.2009.742.745 | Intervention, exposure, or comparator
Anzman-Frasca, S., Djang, H. C., Halmo, M. M., Dolan, P. R., & Economos, C. D. (2015). Estimating impacts of a breakfast in the classroom program on school outcomes. JAMA Pediatrics, 169 (1), 71-77. http://doi.org/10.1001/jamapediatrics.2014.2042 | Intervention, exposure, or comparator
Benton, D., Maconie, A., & Williams, C. (2007). The influence of the glycaemic load of breakfast on the behaviour of children in school. Physiology & Behavior, 92 (4), 717-724. https://doi.org/10.1016/j.physbeh.2007.05.065 | Intervention, exposure, or comparator
Chaplin, K., & Smith, A. P. (2011). Breakfast and snacks: Associations with cognitive failures, minor injuries, accidents and stress. Nutrients, 3 (5), 515-528. https://doi.org/10.3390/nu3050515 | Intervention, exposure, or comparator
Corcoran, S. P., Elbel, B., & Schwartz, A. E. (2016). The effect of breakfast in the classroom on obesity and academic performance: Evidence from New York City. Journal of Policy Analysis and Management Volume, 35 (3), 509-532. https://doi.org/10.1002/pam.21909 | Intervention, exposure, or comparator
Faught, E. L., Gleddie, D., Storey, K. E., Davison, C. M., & Veugelers, P. J. (2017). Healthy lifestyle behaviours are positively and independently associated with academic achievement: An analysis of self-reported data from a nationally representative sample of Canadian early adolescents. PLoS One, 12 (7), e0181938-e0181952. https://doi.org/10.1371/journal.pone.0181938 | Intervention, exposure, or comparator
Frisvold, D. E. (2015). Nutrition and cognitive achievement: An evaluation of the School Breakfast Program. Journal of Public Economics, 124, 91-104. https://doi.org/10.1016/j.jpubeco.2014.12.003 | Intervention, exposure, or comparator
Leos-Urbel, J., Schwartz, A. E., Weinstein, M., & Corcoran, S. (2013). Not just for poor kids: The impact of universal free school breakfast on meal participation and student outcomes. Economics of Education Review, 36, 88-107. https://doi.org/10.1016/j.econedurev.2013.06.007 | Intervention, exposure, or comparator
Mhurchu, C. N., Gorton, D., Turley, M., Jiang, Y., Michie, J., Maddison, R., & Hattie, J. (2013). Effects of a free school breakfast programme on children’s attendance, academic achievement, and short-term hunger: Results from a stepped-wedge, cluster randomised controlled trial. Journal of Epidemiology & Community Health, 67 (3), 257-264. http://doi.org/10.1136/jech-2012-201540 | Intervention, exposure, or comparator
Micha, R., Rogers, P. J., Nelson, M. (2011). Glycaemic index and glycaemic load of breakfast predict cognitive function and mood in school children: A randomised controlled trial. British Journal of Nutrition, 106 (10), 1552-1561. https://doi.org/10.1017/S0007114511002303 | Intervention, exposure, or comparator
Skogheim, T. S., Vollrath, M. E. (2015). Associations of child temperament with child overweight and breakfast habits: A population study in five-year-olds. Nutrients, 7 (12), 10116-10128. http://doi.org/10.3390/nu7125522 | Intervention, exposure, or comparator
So W. Y. (2013). Association between frequency of breakfast consumption and academic performance in healthy Korean adolescents. Iranian Journal of Public Health, 42 (1), 25-32. PMID: 23514747 | Intervention, exposure, or comparator
Stea, T. H., & Torstveit, M. K. (2014). Association of lifestyle habits and academic achievement in Norwegian adolescents: A cross-sectional study. BMC Public Health, 14 (829). https://doi.org/10.1186/1471-2458-14-829 | Intervention, exposure, or comparator
Stroebele N, McNally J, Plog A, Siegfried S, Hill JO. (2013). The association of self-reported sleep, weight status, and academic performance in fifth-grade students. Journal of School Health, 83 (2), 77-84. https://doi.org/10.1111/josh.12001 | Intervention, exposure, or comparator
Tanihata, T., Kanda, H., Osaki, Y., Ohida, T., Minowa, M., Wada, K., … Hayashi, K. (2015). Unhealthy lifestyle, poor mental health, and its correlation among adolescents: A nationwide cross-sectional survey. Asia Pacific Journal of Public Health, 27 (2), NP1557–NP1565. https://doi.org/10.1177/1010539512452753 | Intervention, exposure, or comparator
Tapper, K., Murphy, S., Lynch, R., Clark, R., Moore, G. F., & Moore, L. (2007). Development of a scale to measure 9–11-year-olds’ attitudes towards breakfast. European Journal of Clinical Nutrition, 62 (4), 511-518. http://doi.org/10.1038/sj.ejcn.1602735 | Intervention, exposure, or comparator
Torres, M., Carmona, I., Campillo, C., Pérez, G., & Campillo, J. E. (2007). Breakfast, plasma glucose and β-hydroxybutyrate, body mass index and academic performance in children from Extremadura, Spain. Nutrición Hospitalaria, 22 (4), 487-490. PMID: 17650890 | Intervention, exposure, or comparator
Veldwijk, J. , Fries, M. C., Bemelmans, W. J., Haveman-Nies, A. , Smit, H. A., Koppelman, G. H. and Wijga, A. H. (2012). Overweight and school performance among primary school children: The PIAMA birth cohort study. Obesity, 20 (3): 590-596. http://doi.org/10.1038/oby.2011.327 | Intervention, exposure, or comparator
Amiri, F., Amani, R., Rashidkhani, B., Khajemogahi, N., Wesnes, K., & Saxby, B. (2008). Effect of breakfast composition on memory of primary school children in Ahwaz. Iranian Journal of Endocrinology & Metabolism, 10 (3), 247-256. | Publication language
Lozano, R. H., & Ballesteros, J. C. F. (2006). A study on breakfast and school performance in a group of adolescents. Nutricion Hospitalaria, 21 (3), 346-352. PMID: 16771116 | Publication language
Morales, I. F., Vilas, M. V. A., Vega, C. J. M., & Para, M. C. M. (2008). Relation between the breakfast quality and the academic performance in adolescents of Guadalajara (Castilla-La Mancha). Nutricion Hospitalaria, 23 (4), 383-387. PMID: 18604325 | Publication language
Ahadi, Z., Kelishadi, R., Qorbani, M., Zahedi, H., Aram, M., Motlagh, M. E., Ardalan, G., Shafiee, G., Arzaghi, S. M., Asayesh, H., & Heshmat, R. (2016). Association of breakfast intake with psychiatric distress and violent behaviors in Iranian children and adolescents: The CASPIAN- IV study. The Indian Journal of Pediatrics, 83 (9), 922-929. https://doi.org/10.1007/s12098-016-2049-7 | Outcome
Baldinger, N., Krebs, A., Muller, R., & Aeberli, I. (2012). Swiss children consuming breakfast regularly have better motor functional skills and are less overweight than breakfast skippers. Journal of the American College of Nutrition, 31 (2), 87-93. https://doi.org/10.1080/07315724.2012.10720013 | Outcome
Boschloo, A., Ouwehand, C., Dekker, S., Lee, N., de Groot, R., Krabbendam, L., Jolles, J. (2012). The relation between breakfast skipping and school performance in adolescents. Mind, Brain, and Education, 6 (2) 82-88. https://doi.org/10.1111/j.1751-228X.2012.01138.x | Outcome
Hashemi, F. S., Soltani, R., Hassanzadeh, A., & Eslami, A. A. (2017). Relationship between breakfast consumption and self-efficacy, outcome expectations, evaluation and knowledge in elementary students. International Journal of Pediatrics, 5 (1), 4163-4174. http://doi.org/10.22038/ijp.2016.7678 | Outcome
Lee, G., Han, K., & Kim, H. (2017). Risk of mental health problems in adolescents skipping meals: The Korean National Health and Nutrition Examination Survey 2010 to 2012. Nursing Outlook, 65 (4), 411-419. https://doi.org/10.1016/j.outlook.2017.01.007 | Outcome
Lien, L. (2007). Is breakfast consumption related to mental distress and academic performance in adolescents? Public Health Nutrition, 10 (4), 422-428. https://doi.org/10.1017/S1368980007258550 | Outcome
O’Sullivan, T. A., Robinson, M., Kendall, G. E., Miller, M., Jacoby, P., Silburn, S. R., Oddy, W. H. (2009). A good-quality breakfast is associated with better mental health in adolescence. Public Health Nutrition, 12 (2), 249-258. https://doi.org/10.1017/S1368980008003935 | Outcome
Richards, G., Smith, A. P. (2016). Breakfast and energy drink consumption in secondary school children: Breakfast omission, in isolation or in combination with frequent energy drink use, is associated with stress, anxiety, and depression cross-sectionally, but not at 6-month follow-up. Frontiers in Psychology, 7 (106), 1-10. https://doi.org/10.3389/fpsyg.2016.00106 | Outcome
Mhurchu, C. N., Turley, M., Gorton, D., Jiang, Y., Michie, J., Maddison, R., & Hattie, J. (2010). Effects of a free school breakfast programme on school attendance, achievement, psychosocial function, and nutrition: a stepped wedge cluster randomised trial. BMC Public Health, 10 (1), 738-743. http://doi.org/10.1186/1471-2458-10-738 | Study design
Adolphus, K., Lawton, C. L., & Dye, L. (2015). The Relationship between Habitual Breakfast Consumption Frequency and Academic Performance in British Adolescents. Frontiers in Public Health, 3 (68), 1-10. https://doi.org/10.3389/fpubh.2015.00068 | Study design
Edwards, J. U., Mauch, L., Winkelman, M. R. (2011). Relationship of nutrition and physical activity behaviors and fitness measures to academic performance for sixth graders in a midwest city school district. Journal of School Health, 81 (2), 65-73. https://doi.org/10.1111/j.1746-1561.2010.00562.x | Study design
Hjorth, M. F., Sorensen, L. B., Andersen, R., Dyssegaard, C. B., Ritz, C., Tetens, I., Michaelsen, K. F., Astrup, A., Egelund, N., & Sjodin, A. (2016). Normal weight children have higher cognitive performance - Independent of physical activity, sleep, and diet. Physiology & Behavior, 165 (2016), 398-404. https://doi.org/10.1016/j.physbeh.2016.08.021 | Study design
Ho, C. Y., Huang, Y. C., Lo, Y. T., Wahlqvist, M. L., & Lee, M. S. (2015). Breakfast is associated with the metabolic syndrome and school performance among Taiwanese children. Research in Developmental Disabilities, 43-44 (2015), 179-188. https://doi.org/10.1016/j.ridd.2015.07.003 | Study design
Sampasa-Kanyinga, H., Roumeliotis, P., Farrow, C. V., & Shi, Y. F. (2014). Breakfast skipping is associated with cyberbullying and school bullying victimization. A school-based cross-sectional study. Appetite, 79 (2014), 76-82, https://doi.org/10.1016/j.appet.2014.04.007 | Study design
Imberman, S. A., & Kugler, A. D. (2014). The effect of providing breakfast in class on student performance. Journal of Policy Analysis and Management, 33 (3), 669-699. https://doi.org/10.1002/pam.21759 | Study design
Kang, Y. W., & Park, J. H. (2016). Does skipping breakfast and being overweight influence academic achievement among Korean adolescents? Osong Public Health and Research Perspectives, 7 (4), 220-227. https://doi.org/10.1016/j.phrp.2016.05.004 | Study design
Kim, S. Y., Sim, S., Park, B., Kong, I. G., Kim, J. H., & Choi, H. G. (2017). Dietary habits are associated with school performance in adolescents. Medicine (Baltimore), 95 (12), e3096-e3045. http://doi.org/10.1097/MD.0000000000003096 | Study design
Kohyama, J. (2017). Self-reported academic performance and lifestyle habits of school children in Japan. International Journal of Child Health and Nutrition, 6 (3), 90-97. https://doi.org/10.6000/1929-4247.2017.06.03.1 | Study design
Liu, J., Hwang, W. T., Dickerman, B., & Compher, C. (2013). Regular breakfast consumption is associated with increased IQ in kindergarten children. Early Human Development, 89 (4), 257-262. https://doi.org/10.1016/j.earlhumdev.2013.01.006 | Study design
McIsaac, J. L., Kirk, S. F., Kuhle, S. (2015). The association between health behaviours and academic performance in Canadian elementary school students: A cross-sectional study. International Journal of Environmental Research and Public Health, 12 (11), 14857-14871. https://doi.org/10.3390/ijerph121114857 | Study design
Øverby, N., & Høigaard, R. (2012). Diet and behavioral problems at school in Norwegian adolescents. Food & Nutrition Research, 56 (1), 17231-17237. https://doi.org/10.3402/fnr.v56i0.17231 | Study design
Saeidi, Z., Vakili, R., Hashemi, A. G., & Saeidi, M. (2015). The effect of diet on learning of junior high school students in Mashhad, north-east of Iran. International Journal of Pediatrics, 3 (2.2), 517-526. http://doi.org/10.22038/ijp.2015.4139 | Study design
Sampasa-Kanyinga, H., & Hamilton, H. A. (2017). Eating breakfast regularly is related to higher school connectedness and academic performance in Canadian middle- and high-school students. Public Health, 145 (2017), 120-123. http://doi.org/10.1016/j.puhe.2016.12.027 | Study design

Table A2 2 Articles excluded during full-text screening of the initial literature search for Key Question 1b: What is the relationship between eating breakfast and weight-related outcomes?

Article | Reason for exclusion
Feeley, A. B., Musenge, E., Pettifor, J. M., & Norris, S. A. (2013). Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutrition, 16 (4), 693-703. http://doi.org/10.1017/S1368980012003308 | Study setting
Albertson, A. M., Thompson, D., Franko, D. L., Holschuh, N. M., Bauserman, R., & Barton, B. A. (2009). Prospective associations among cereal intake in childhood and adiposity, lipid levels, and physical activity during late adolescence. Journal of the American Dietetic Association, 109 (10), 1775-1780. https://doi.org/10.1016/j.jada.2009.07.004 | Intervention, exposure, or comparator
Ambrosini, G. L., Emmett, P. M., Northstone, K., & Jebb, S. A. (2014). Tracking a dietary pattern associated with increased adiposity in childhood and adolescence. Obesity (Silver Spring), 22 (2), 458-465. http://doi.org/10.1002/oby.20542 | Intervention, exposure, or comparator
Ask, A. S., Hernes, S., Aarek, I., & Vik, F. (2010). Serving of free school lunch to secondary-school pupils - a pilot study with health implications. Public Health Nutrition, 13 (2), 238-244. https://doi.org/10.1017/S1368980009990772 | Intervention, exposure, or comparator
Barbosa, M. I. D., de Oliveira, B. R., de Carvalho, N. A. et al. (2016). Food and Nutrition Education: Influence on students feeding behavior and nutritional status. Mundo Da Saude, 40, 399-409. PMID: 26400123 | Intervention, exposure, or comparator
Bruening, M., Larson, N., Story, M., Neumark-Sztainer, D., & Hannan, P. (2011). Predictors of adolescent breakfast consumption: longitudinal findings from Project EAT. Journal of Nutrition Education Behavior, 43 (5), 390-395. https://doi.org/10.1016/j.jneb.2011.02.016 | Intervention, exposure, or comparator
Campos Pastor, M. M., Serrano Pardo, M. D., Fernández Soto, M. L. Luna Del Castillo, J. D., & Escobar-Jiménez, F. (2012). Impact of a ‘school-based’ nutrition intervention on anthropometric parameters and the metabolic syndrome in Spanish adolescents. Annals of Nutrition & Metabolism, 61 (4), 281-288. http://doi.org/10.1159/000341495 | Intervention, exposure, or comparator
Capogrossi, K., & You, W. (2017). The influence of school nutrition programs on the weight of low-income children: A treatment effect analysis. Health Economics, 26 (8), 980-1000. https://doi.org/10.1002/hec.3378 | Intervention, exposure, or comparator
Chen, C. Y., & Hsiao, Y. C. (2018). Dual trajectories of breakfast eating and fruit and vegetable intake over a 5-year follow-up period among economically disadvantaged children: Gender differences. Appetite, 121 (2018), 41-49. https://doi.org/10.1016/j.appet.2017.10.027 | Intervention, exposure, or comparator
Corcoran, S. P., Elbel, B., & Schwartz, A. E. (2016). The effect of breakfast in the classroom on obesity and academic performance: Evidence from New York City. Journal of Policy Analysis and Management, 35 (3), 509-32. https://doi.org/10.1002/pam.21909 | Intervention, exposure, or comparator
Drenowatz, C., Kobel, S., Kettner, S. Kesztyüs, D., Wirt, T., Dreyhaupt, J., & Steinacker, J. M. (2013). Correlates of weight gain in German children attending elementary school. Preventative Medicine, 57 (4), 310-314. https://doi.org/10.1016/j.ypmed.2013.06.004 | Intervention, exposure, or comparator
Elinder, L. S., Heinemans, N., Zeebari, Z., & Patterson, E. (2014). Longitudinal changes in health behaviours and body weight among Swedish school children - Associations with age, gender and parental education - The SCIP school cohort. BMC Public Health, 14, 640-649. https://doi.org/10.1186/1471-2458-14-640 | Intervention, exposure, or comparator
Fairclough, S. J., Hackett, A. F., Davies, I. G. , Gobbi, R., Mackintosh, K. A., Warburton, G. L., Stratton, G., van Sluijs, E. M., & Boddy, L. M. (2013). Promoting healthy weight in primary school children through physical activity and nutrition education: A pragmatic evaluation of the CHANGE! randomised intervention study. BMC Public Health, 13, 626-640. https://doi.org/10.1186/1471-2458-13-626 | Intervention, exposure, or comparator
François, P., Guyomard, A., Baudet, D, Dubois-Fabing, D., Boussuges, S., Perrin, F., & Seigneurin, A. (2014). Evaluation of an obesity prevention program for school-aged children in deprived urban areas. Archives De Pédiatrie, 21 (7), 727-735. http://doi.org/10.1016/j.arcped.2014.04.026 | Intervention, exposure, or comparator
Franko, D. L., Albertson, A. M., Thompson, D. R., Barton, B. A. (2011). Cereal consumption and indicators of cardiovascular risk in adolescent girls. Public Health Nutrition, 14 (4), 584-590. https://doi.org/10.1017/S1368980010002016 | Intervention, exposure, or comparator
Heo, M., Jimenez, C. C., Lim, J. , Isasi, C. R., Blank, A. E., Lounsbury, D. W., Fredericks, L., Bouchard, M., Faith, M. S., & Wylie-Rosett, J. (2018). Effective nationwide school-based participatory extramural program on adolescent body mass index, health knowledge and behaviors. BMC Pediatrics, 18 (1), 7-17. https://doi.org/10.1186/s12887-017-0975-9 | Intervention, exposure, or comparator
Hollywood, E., Comiskey, C., Begley, T. Snel, A., O’Sullivan, K., Quirke, M., & Wynne, C. (2013). Measuring and modelling body mass index among a cohort of urban children living with disadvantage. Journal of Advanced Nursing, 69 (4), 851-861. https://doi.org/10.1111/j.1365-2648.2012.06071.x | Intervention, exposure, or comparator
Jääskeläinen, A., Schwab, U., Kolehmainen, M. Kaakinen, M., Savolainen, M. J., Froguel, P., Cauchi, S., Järvelin, M., & Laitinen, J. (2013). Meal frequencies modify the effect of common genetic variants on body mass index in adolescents of the northern Finland birth cohort 1986. PLoS One, 8 (9), e73802. https://doi.org/10.1371/journal.pone.0073802 | Intervention, exposure, or comparator
Kocken, P. L., Scholten, A., Westhoff, E., De Kok, B. P. H., Taal, E. M., & Goldbohm, R. A. (2016). Effects of a theory-based education program to prevent overweightness in primary school children. Nutrients, 8 (1), 12-29. https://doi.org/10.3390/nu8010012 | Intervention, exposure, or comparator
Leidy, H. J., Hoertel, H. A., Douglas, S. M., Higgins, K. A., & Shafer, R. S. (2015). A high-protein breakfast prevents body fat gain, through reductions in daily intake and hunger, in “Breakfast skipping” adolescents. Obesity (Silver Spring), 23 (9), 1761-1764. https://doi.org/10.1002/oby.21185 | Intervention, exposure, or comparator
Mihas, C., Mariolis, A., Manios, Y., Naska, A., Arapaki, A., Mariolis-Sapsakos, T., & Tountas, Y. (2010). Evaluation of a nutrition intervention in adolescents of an urban area in Greece: short- and long-term effects of the VYRONAS study. Public Health Nutrition, 13 (5), 712-719. https://doi.org/10.1017/S1368980009991625 | Intervention, exposure, or comparator
Neumark-Sztainer, D., Wall, M., Haines, J, Story, M., Eisenberg, M. E. (2007). Why does dieting predict weight gain in adolescents? Findings from Project EAT-II: A 5-year longitudinal study. Journal of the American Dietetic Association, 107 (3), 448-455. https://doi.org/10.1016/j.jada.2006.12.013 | Intervention, exposure, or comparator
Ochoa-Avilés, A., Verstraeten, R., Huybregts, L., Andrade, S., Van Camp, J., Donoso, S., Ramírez, P. L., Lachat, C., Maes, L., & Kolsteren, P. (2017). A school-based intervention improved dietary intake outcomes and reduced waist circumference in adolescents: a cluster randomized controlled trial. Nutrition Journal, 16, 79. https://doi.org/10.1186/s12937-017-0299-5 | Intervention, exposure, or comparator
Pablos, A., Nebot, V., Vañó-Vicent, V., Ceca, D., & Elvira, L. (2018). Effectiveness of a school-based program focusing on diet and health habits taught through physical exercise. Applied Physiology, Nutrition, and Metabolism, 43 (4), 331-337, https://doi.org/10.1139/apnm-2017-0348 | Intervention, exposure, or comparator
Powers, H. J., Stephens, M., Russell, J., & Hill, M. H. (2016). Fortified breakfast cereal consumed daily for 12 wk leads to a significant improvement in micronutrient intake and micronutrient status in adolescent girls: a randomised controlled trial. Nutrition Journal, 15, 69. https://doi.org/10.1186/s12937-016-0185-6 | Intervention, exposure, or comparator
Raffoul, A., Leatherdale, S. T., & Kirkpatrick, S. I. (2018). Dieting predicts engagement in multiple risky behaviours among adolescent Canadian girls: A longitudinal analysis. Canadian Journal of Public Health-Revue Canadienne De Sante Publique, 109 (1), 61-69. https://doi.org/10.17269/s41997-018-0025-x | Intervention, exposure, or comparator
Rodearmel, S. J., Wyatt, H. R., Barry, M. J., Dong, F., Pan, D., Israel, R. G., Cho, S. S., McBurney, M. I., & Hill, J. O. (2006). A family-based approach to preventing excessive weight gain. Obesity (Silver Spring), 14 (8), 1392-1401. https://doi.org/10.1038/oby.2006.158 | Intervention, exposure, or comparator
Sacchetti, R., Dallolio, L., Musti, M. A., Guberti, E., Garulli, A., Beltrami, P., Castellazzi, F., Centis, E., Zenesini, C., Coppini, C., Rizzoli, C., Sardocardalano, M., & Leoni, E. (2015). Effects of a school based intervention to promote healthy habits in children 8-11 years old, living in the lowland area of Bologna Local Health Unit. Annali di Igiene: Medicina Preventiva e di Comunità, 27, 432-446. http://doi.org/10.7416/ai.2015.2030 | Intervention, exposure, or comparator
van Grieken, A., Renders, C. M., Veldhuis, L., Looman, C. W. N., Hirasing, R. A., & Raat, H. (2014). Promotion of a healthy lifestyle among 5-year-old overweight children: Health behavior outcomes of the ‘Be active, eat right’ study. BMC Public Health, 14, 59. https://doi.org/10.1186/1471-2458-14-59 | Intervention, exposure, or comparator
van Nassau, F., Singh, A. S., Cerin, E., Salmon, J., van Mechelen, W., Brug, J., & Chinapaw, M. J. M. (2014). The Dutch Obesity Intervention in Teenagers (DOiT) cluster controlled implementation trial: intervention effects and mediators and moderators of adiposity and energy balance-related behaviours. International Journal of Behavioral Nutrition and Physical Activity, 11, 158. https://doi.org/10.1186/s12966-014-0158-0 | Intervention, exposure, or comparator
Watts, A. W., Mason, S. M., Loth, K., Larson, N., & Newmark-Sztainer, D. (2016). Socioeconomic differences in overweight and weight-related behaviors across adolescence and young adulthood: 10-year longitudinal findings from Project EAT. Preventative Medicine, 87 (2016), 194-199. https://doi.org/10.1016/j.ypmed.2016.03.007 | Intervention, exposure, or comparator
Westerberg-Jacobson, J., Edlund, B., & Ghaderi, A. (2010). A 5-year longitudinal study of the relationship between the wish to be thinner, lifestyle behaviours and disturbed eating in 9-20-year old girls. European Eating Disorders Review, 18 (3), 207-219. https://doi.org/10.1002/erv.983 | Intervention, exposure, or comparator
Wirt, T., Hundsdörfer, V., Schreiber, A., Kesztyüs, D., Steinacker, J. M., & The Komm mit in das gesunde Boot-Grundschule” - Research Group (2014). Associations between inhibitory control and body weight in German primary school children. Eating Behaviors, 15 (1), 9-12. https://doi.org/10.1016/j.eatbeh.2013.10.015 | Intervention, exposure, or comparator
Yamada, M., Sekine, M., & Tatsuse, T. (2018). Parental internet use and lifestyle factors as correlates of prolonged screen time of children in Japan: Results from the Super Shokuiku School Project. Journal of Epidemiology, 28 (10), 407-413. https://doi.org/10.2188/jea.JE20170100 | Intervention, exposure, or comparator
Yamaoka, K., Watanabe, M., Hida, E., & Tango, T. (2011). Impact of group-based dietary education on the dietary habits of female adolescents: A cluster randomized trial. Public Health Nutrition, 14 (4), 702-708. https://doi.org/10.1017/S1368980010002405 | Intervention, exposure, or comparator
Alwattar, A. Y., Thyfault, J. P., & Leidy, H. J. (2015). The effect of breakfast type and frequency of consumption on glycemic response in overweight/obese late adolescent girls. European Journal of Clinical Nutrition, 69 (2015), 885-890. http://doi.org/10.1038/ejcn.2015.12 | Outcome
Bellisle, F., Rolland-Cachera, M. F., & Kellogg Scientific Advisory Committee (2007). Three consecutive (1993, 1995, 1997) surveys of food intake, nutritional attitudes and knowledge, and lifestyle in 1000 French children, aged 9-11 years. Journal of Human Nutrition and Dietetics, 20 (3), 241-251. http://doi.org/10.1111/j.1365-277X.2007.00789.x | Outcome
Crepinsek, M. K., Singh, A., Bernstein, L. S., & McLaughlin, J. E. (2006). Dietary effects of universal-free school breakfast: findings from the evaluation of the school breakfast program pilot project. Journal of the American Dietetic Association, 106 (11), 1796-1803. https://doi.org/10.1016/j.jada.2006.08.013 | Outcome
Lipsky, L. M., Nansel, T. R., Haynie, D. L., Liu, D., Li, K., Pratt, C. A., Iannotti, R. J., & Dempster, K. W. (2017). Diet quality of US adolescents during the transition to adulthood: Changes and predictors. American Journal of Clinical Nutrition, 105 (6) 1424-1432. https://doi.org/10.3945/ajcn.116.150029 | Outcome
Meijerink, F. J., van Vuuren, C. L., Wijnhoven, H. A, & van Eijsden, M. (2016). Seven-year time trends in energy balance-related behaviours according to educational level and ethnic background among 14-year-old adolescents. Public Health Nutrition, 19 (5), 777-787. https://doi.org/10.1017/S1368980015001743 | Outcome
Pedersen, T. P., Holstein, B. E., Flachs, E. M., & Rasmussen, M. (2013). Meal frequencies in early adolescence predict meal frequencies in late adolescence and early adulthood. BMC Public Health, 13, 445. https://doi.org/10.1186/1471-2458-13-445 | Outcome
Roßbach, S., Diederichs, T., Bolzenius, K., Herder, C., Buyken, A. E., & Alexy, U. (2017). Age and time trends in eating frequency and duration of nightly fasting of German children and adolescents. European Journal of Nutrition, 56 (8), 2507-2517. http://doi.org/10.1007/s00394-016-1286-x | Outcome
Roßbach, S., Diederichs, T., Herder, C., Buyken, A. E., & Alexy, U. (2018). Time and age trends in morning and evening protein intakes of German children and adolescents. Journal of Nutritional Science, 7 (e9), 1-8. https://doi.org/10.1017/jns.2018.1 | Outcome
Sevindi, T. (2012). The effects of nutrition habits of secondary school students on their educational status. Energy Education Science and Technology Part B-Social and Educational Studies, 4, 2119-2128. | Outcome
Zaqout, M., Vyncke, K., Moreno, L. A., De Miguel-Etayo, P., Lauria, F., Molnar, D., Lissner, L., Hunsberger, M., Veidebaum, T., Tornaritis, M., Reisch, L. A., Bammann, K., Sprengeler, O., Ahrens, W., & Michels, N. (2016). Determinant factors of physical fitness in European children. International Journal of Public Health, 61 (5), 573-582. http://doi.org/10.1007/s00038-016-0811-2 | Outcome
Hollar, D., Heitz, C., & Zhou, W. (2015). Abstract MP30: More young children in an obesity prevention intervention in MS and LA Head Start centers improve/maintain BMI percentile and waist circumference compared to nonparticipants. Circulation, 131 (Supplement 1). | Study design
Küpers, L. K., de Pijper, J. J., Sauer, P. J., Stolk, R. P., & Corpeleijn, E. (2014). Skipping breakfast and overweight in 2- and 5-year-old Dutch children-the GECKO Drenthe cohort. International Journal of Obesity (London), 38, 569-571. http://doi.org/10.1038/ijo.2013.194 | Study design
Pbert, L., Druker, S., Barton, B., Schneider, K. L., Olendzki, B., Gapinski, M. A., Kurtz, S., & Stavroula, O. (2016). A school-based program for overweight and obese adolescents: A randomized controlled trial. Journal of School Health, 86 (10), 699-708. https://doi.org/10.1111/josh.12428 | Study design
Péneau, S., Thibault, H., Meless, D., Soulié, D., Carbonel, P., Roinsol, D., Longueville, E., Sérog, P., Deheeger, M., Bellisle, F., Maurice-Tison, S., & Rolland-Cachera, M. F. (2008). Anthropometric and behavioral patterns associated with weight maintenance after an obesity treatment in adolescents. Journal of Pediatrics, 152 (5), 678-684. https://doi.org/10.1016/j.jpeds.2007.09.053 | Study design
Serrano, M, Campos, M, Escobar, Gome-Villalba F et al. (2016). Variations in the states of prediabetes in adolescents after a school programme for nutritional and behavioural intervention. Diabetologia,59.(supplement 1)S331-S332. https://doi.org/10.1007/s00125-016-4046-9 | Study design
Albertson, A. M., Affenito, S. G., Bauserman, R., Holschuh, N. M., Eldridge, A. L., & Barton, B. A. (2009). The relationship of ready-to-eat cereal consumption to nutrient intake, blood lipids, and body mass index of children as they age through adolescence. Journal of the American Dietetic Association, 109 (9), 1557-1565. https://doi.org/10.1016/j.jada.2009.06.363 | Study design
Alsharairi, N. A., & Somerset, S. M. (2016). Skipping breakfast in early childhood and its associations with maternal and child BMI: A study of 2-5-year-old Australian children. European Journal of Clinical Nutrition, 70, 450-455. http://doi.org/10.1038/ejcn.2015.184 | Study design
Ask, A. S., Hernes, S., Aarek, I., Johannessen, G., & Haugen, M. (2006). Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast - a pilot study. Nutrition Journal, 5, 33. https://doi.org/10.1186/1475-2891-5-33 | Study design
Baxter, S. D., Paxton-Aiken, A. E., Tebbs, J. M., Royer, J. A., Guinn, C. H., & Finney, C. J. (2012). Secondary analyses of data from 4 studies with fourth-grade children show that sex, race, amounts eaten of standardized portions, and energy content given in trades explain the positive relationship between body mass index and energy intake at school-provided meals. Nutrition Research, 32 (9), 659-668. https://doi.org/10.1016/j.nutres.2012.07.001 | Study design
Isoldi, K. K., Calderon, O., & Dolar, V. (2014). Cooking up energy: Response to a youth-focused afterschool cooking and nutrition education program. Topics in Clinical Nutrition, 29 (2), 123-131. https://doi.org/10.1097/01.TIN.0000445896.52276.0e | Study design
Jääskeläinen, A., Schwab, U., Kolehmainen, M., Pirkola, J., Järvelin, M.-R., & Laitinen, J. (2013). Associations of meal frequency and breakfast with obesity and metabolic syndrome traits in adolescents of Northern Finland Birth Cohort 1986. Nutrition, Metabolism and Cardiovascular Diseases, 23, (10), 1002-1009. https://doi.org/10.1016/j.numecd.2012.07.006 | Study design
Kapantais, E., Chala, E., Kaklamanou, D., Lanaras L., Kaklamanou, M., & Tzotzas, T. (2010). Breakfast skipping and its relation to BMI and health-compromising behaviours among Greek adolescents. Public Health Nutrition, 14 (1), 101-108. https://doi.org/10.1017/S1368980010000765 | Study design
O’Dea, J. A., & Wagstaff, S. (2011). Increased breakfast frequency and nutritional quality among schoolchildren after a national breakfast promotion campaign in Australia between 2000 and 2006. Health Education Research, 26 (6), 1086-1096. https://doi.org/10.1093/her/cyr042 | Study design
Park, E. H., Oh, M. S., Kim, S., Lee, J., & Kang, K. S. (2018). The analysis of factors causing the high prevalence of child obesity in Jeju Island. Pediatric Gastroenterology, Hepatology & Nutrition, 21 (2), 127-133. https://doi.org/10.5223/pghn.2018.21.2.127 | Study design
Reeves, S., Huber, J. W., Halsey, L. G., Horabady-Farahani, Y., Ijadi, M., & Smith, T. (2014). Experimental manipulation of breakfast in normal and overweight/obese participants is associated with changes to nutrient and energy intake consumption patterns. Physiology & Behavior, 133, 130-135. https://doi.org/10.1016/j.physbeh.2014.05.015 | Study design
Trancoso, S. C., Cavalli, S. B., & Proença, R. P. D. (2010). Breakfast: characterization, consumption and importance for health. Revista De Nutricao-Brazilian Journal of Nutrition, 23 (5), 859-869. http://doi.org/10.1590/S1415-52732010000500016 | Study design
Vericker, T. C. (2014). Children’s school-related food and physical activity behaviors are associated with body mass index. Journal of the Academy of Nutrition and Dietetics, 114 (2), 250-256. https://doi.org/10.1016/j.jand.2013.07.046 | Study design
Zurriaga, O., Perez-Panades, J., Izquierdo, J. Q., Costa, M. G., Anes, Y., Quiñones, C., Margolles, M., Lopez-Maside, A., Vega-Alonso, A. T., Espí, M. T. M., & Recent OBICE Research Group. (2011). Factors associated with childhood obesity in Spain. The OBICE study: A case-control study based on sentinel networks. Public Health Nutrition, 14 (6), 1105-1113. https://doi.org/10.1017/S1368980010003770 | Study design

Table A2 3 Articles excluded during full-text screening of the initial literature search for Key Question 1c: What is the relationship between eating breakfast and health?

Article | Reason for exclusion
Albertson, A. M., Affenito, S. G., Bauserman, R., Holschuh, N. M., Eldridge, A. L., & Barton, B. A. (2009). The relationship of ready-to-eat cereal consumption to nutrient intake, blood lipids, and body mass index of children as they age through adolescence. Journal of the American Dietetic Association, 109(9), 1557-1565. http://doi.org/10.1016/j.jada.2009.06.363 | Intervention, exposure, or comparator
Bonnet, F., Lepicard, E. M., Cathrin, L., Letellier, C., Constant, F., Hawili, N., & Friedlander, G. (2012). French children start their school day with a hydration deficit. Annals of Nutrition & Metabolism, 60(4), 257-263. http://doi.org/10.1159/000337939 | Intervention, exposure, or comparator
Miller, D. P., Waldfogel, J., & Han, W. J. (2012). Family meals and child academic and behavioral outcomes. Child Development, 83(6), 2104-2120. http://doi.org/10.1111/j.1467-8624.2012.01825.x | Intervention, exposure, or comparator
Simetin, I. P., Kuzman, M., Franelic, I. P., Pristas, I., Benjak, T., & Dezeljin, J. D. (2011). Inequalities in Croatian pupils’ unhealthy behaviours and health outcomes: role of school, peers and family affluence. European Journal of Public Health, 21(1), 122-128. http://doi.org/10.1093/eurpub/ckq002 | Intervention, exposure, or comparator
Stookey, J. D., Brass, B., Holliday, A., & Arieff, A. (2012). What is the cell hydration status of healthy children in the USA? Preliminary data on urine osmolality and water intake. Public Health Nutrition, 15(11), 2148-2156. http://doi.org/10.1017/s1368980011003648 | Intervention, exposure, or comparator
Cordero, M. J. A., Jimenez, E. G., Perona, J. S., Lopez, C. A. P., Ferre, J. A., Villar, N. M., & Garcia, F. R. (2010). The Guadix Study of the effects of a Mediterranean-diet breakfast on the postprandial lipid parameters of overweight and obese pre-adolescents. Nutricion Hospitalaria, 25(6), 1025-1033. PMID: 21519776 | Publication language
Park, E. (2008). The influencing factors on suicide attempt among adolescents in South Korea. Journal of Korean Academy of Nursing, 38(3), 465-473. http://doi.org/10.4040/jkan.2008.38.3.465 | Publication language
Perez-Lancho, C., Ruiz-Prieto, I., Bolanos-Rios, P., & Jauregui-Lobera, I. (2013). Salivary cortisol as a measure of stress during a nutrition education program in adolescents. Nutricion Hospitalaria, 28(1), 211-216. http://doi.org/10.3305/nh.2013.28.1.6261 | Publication language
Quintero-Gutierrez, A. G., Gonzalez-Rosendo, G., Rodriguez-Murguia, N. A., Reyes-Navarrete, G. E., Puga-Diaz, R., & Villanueva-Sanchez, J. (2014). Skipping breakfast, nutritional state, and food habits of children and adolescents in public schools of Morelos, Mexico. CyTa-Journal of Food, 12(3), 256-262. http://doi.org/10.1080/19476337.2013.839006 | Publication language
Traub, M., Steinacker, J. M., Kesztyus, D., & Arbeitsgrp Komm Gesunde, Boot (2017). Avoiding breakfast for the primary school children cofactors as an important basis for targeted prevention measures. Ernahrungs Umschau, 64(9), M494. http://doi.org/10.4455/eu.2017.035 | Publication language
Eleftheriadou, M., Stefanidis, K., Lykeridou, K., Iliadis, I., & Michala, L. (2015). Dietary habits in adolescent girls with polycystic ovarian syndrome. Gynecological Endocrinology, 31(4), 269-271. http://doi.org/10.3109/09513590.2014.984677 | Outcome
Holmberg, L. I.,& Hellberg, D. (2008). Behavioral and other characteristics of relevance for health in adolescents with self-perceived sleeping problems. International Journal of Adolescent Medicine and Health, 20(3), 353-365. https://doi.org/10.1515/IJAMH.2008.20.3.353 | Outcome
Iovino, I., Stuff, J., Liu, Y., Brewton, C., Dovi, A., Kleinman, R., & Nicklas, T. (2016). Breakfast consumption has no effect on neuropsychological functioning in children: a repeated-measures clinical trial. American Journal of Clinical Nutrition, 104(3), 715-721. http://doi.org/10.3945/ajcn.116.132043 | Outcome
Kelly, Y., Patalay, P., Montgomery, S., & Sacker, A. (2016). BMI development and early adolescent psychosocial well-being: UK Millennium Cohort Study. Pediatrics, 138(6), e20160967. http://doi.org/10.1542/peds.2016-0967 | Outcome
Olafsdottir, A. S., Torfadottir, J. E., & Arngrimsson, S. A. (2016). Health behavior and metabolic risk factors associated with normal weight obesity in adolescents. PLoS One, 11(8), e0161451. http://doi.org/10.1371/journal.pone.0161451 | Outcome
Overby, N. C., Margeirsdottir, H. D., Brunborg, C., Dahl-Jorgensen, K., & Andersen, L. F. (2008). Sweets, snacking habits, and skipping meals in children and adolescents on intensive insulin treatment. Pediatric Diabetes, 9(4 Pt 2), 393-400. http://doi.org/10.1111/j.1399-5448.2008.00381.x | Outcome
Vierola, A., Suominen, A. L., Eloranta, A. M., Lintu, N., Ikavalko, T., Narhi, M., & Lakka, T. A. (2017). Determinants for craniofacial pains in children 6-8 years of age: The PANIC study. Acta Odontologica Scandinavica, 75(6), 453-460. http://doi.org/10.1080/00016357.2017.1339908 | Outcome
Vondrova, D., Kapsdorfer, D., Argalasova, L., Hirosova, K., Samohyl, M., & Sevcikova, L. (2017). The impact of selected environmental, behavioral and psychosocial factors on schoolchildren’s somatic and mental health. Reviews on Environmental Health, 32(1-2), 189-192. http://doi.org/10.1515/reveh-2016-0034 | Outcome
Benton, D., & Brock, H. (2010). Mood and the macro-nutrient composition of breakfast and the mid-day meal. Appetite, 55(3), 436-440. http://doi.org/10.1016/j.appet.2010.08.001 | Participant characteristics
Bougard, C., Moussay, S., Gauthier, A., Espie, S., & Davenne, D. (2009). Effects of waking time and breakfast intake prior to evaluation of psychomotor performance in the early morning. Chronobiology International, 26(2), 324-336. http://doi.org/10.1080/07420520902774540 | Participant characteristics
Brown, D., & Wyon, M. (2014). The effect of moderate glycemic energy bar consumption on blood glucose and mood in dancers. Medical Problems of Performing Artists, 29(1), 27-31. https://doi.org/10.21091/mppa.2014.1007 | Participant characteristics
Fernandez-Aranda, F., Krug, I., Granero, R., Ramon, J. M., Badia, A., Gimenez, L., Solano, R., Collier, D., Karwautz, A., & Treasure, J. (2007). Individual and family eating patterns during childhood and early adolescence: An analysis of associated eating disorder factors. Appetite, 49(2), 476-485. http://doi.org/10.1016/j.appet.2007.03.004 | Participant characteristics
Geliebter, A., Grillot, C. L., Aviram-Friedman, R., Haq, S., Yahav, E., & Hashim, S. A. (2015). Effects of oatmeal and corn flakes cereal breakfasts on satiety, gastric emptying, glucose, and appetite-related hormones. Annals of Nutrition & Metabolism, 66(2-3), 93-103. http://doi.org/10.1159/000365933 | Participant characteristics
Ishimoto, Y., Yoshida, M., Nagata, K., Yamada, H., Hashizume, H., & Yoshimura, N. (2013). Consuming breakfast and exercising longer during high school increases bone mineral density in young adult men. Journal of Bone and Mineral Metabolism, 31(3), 329-336. http://doi.org/10.1007/s00774-012-0415-8 | Participant characteristics
Jin, Y., He, L., Kang, Y., Chen, Y., Lu, W., Ren, X., Song, X., Wang, L., Nie, Z., Guo, D., & Yao, Y. (2014). Prevalence and risk factors of anxiety status among students aged 13-26 years. International Journal of Clinical and Experimental Medicine, 7(11), 4420-4426. PMID: 25550963 | Participant characteristics
Odegaard, A. O., Jacobs, D. R., Jr., Steffen, L. M., Van Horn, L., Ludwig, D. S., & Pereira, M. A. (2013). Breakfast frequency and development of metabolic risk. Diabetes Care, 36(10), 3100-3106. http://doi.org/10.2337/dc13-0316 | Participant characteristics
Smith, Andrew P. (2011). Breakfast cereal, digestive problems and well-being. Stress & Health, 27(5), 388-394. http://doi.org/10.1002/smi.1390 | Participant characteristics
Brindal, E., Hendrie, G., Noakes, M., Celander, M., & Brinkworth, G. (2011). A randomised controlled trial to compare the effect of breakfast cereals differing in fibre content on short-term appetite and mood in 8-12 year old children. Australasian Medical Journal, 4(12), 706. | Publication status
Ruxton, C. (2011). Breakfast clubs: The nutritional, social and health benefits. Nursing in Practice: The Journal for Today’s Primary Care Nurse(60), 5p-5p. | Publication status
Afifi, M. (2006). Positive health practices and depressive symptoms among high school adolescents in Oman. Singapore Medical Journal, 47(11), 960-966. PMID: 17075664 | Study design
Agostini, A., Hawkes, A., Lewkowicz, A., Lushington, K., & Dorrian, J. (2017). Are sleep, bullying, and breakfast and junk food consumption related to anxiety, sadness and health in late childhood and adolescence? Sleep Medicine, 40 (Supplement 1), e6. https://doi.org/10.1016/j.sleep.2017.11.010 | Study design
Ahadi, Z., Kelishadi, R., Qorbani, M., Zahedi, H., Aram, M., Motlagh, M. E., Ardalan, G., Shafiee, G., Arzaghi, S. M., Asayesh, H., & Heshmat, R. (2016). Association of breakfast intake with psychiatric distress and violent behaviors in Iranian children and adolescents: The CASPIAN- IV study. Indian Journal of Pediatrics, 83(9), 922-929. http://doi.org/10.1007/s12098-016-2049-7 | Study design
Ahadi, Z., Qorbani, M., Kelishadi, R., Ardalan, G., Motlagh, M. E., Asayesh, H., Zeynali, M., Chinian, M., Larijani, B., Shafiee, G., & Heshmat, R. (2015). Association between breakfast intake with anthropometric measurements, blood pressure and food consumption behaviors among Iranian children and adolescents: The CASPIAN-IV study. Public Health, 129(6), 740-747. http://doi.org/10.1016/j.puhe.2015.03.019 | Study design
ALBashtawy, M. (2015). Exploring the reasons why school students eat or skip breakfast. Nursing Children & Young People, 27(6), 16-22. http://doi.org/10.7748/ncyp.27.6.16.e622 | Study design
Alexander, K. E., Ventura, E. E., Spruijt-Metz, D., Weigensberg, M. J., Goran, M. I., & Davis, J. N. (2009). Association of breakfast skipping with visceral fat and insulin indices in overweight Latino youth. Obesity (Silver Spring), 17(8), 1528-1533. http://doi.org/10.1038/oby.2009.127 | Study design
Ansari, H., Kelishadi, R., Qorbani, M., Mansourian, M., Ahadi, Z., Motlagh, M. E., Ardalan, G., Safiri, S., Asayesh, H., Mohammadi, R., & Heshmat, R. (2016). Is meal frequency associated with mental distress and violent behaviors in children and adolescents? The CASPIAN IV study. International Journal of Pediatrics-Mashhad, 4(7), 2247-2255. https://doi.org/10.22038/ijp.2016.7177 | Study design
Arat, G. (2015). Emerging protective and risk factors of mental health in Asian American students: findings from the 2013 Youth Risk Behavior Survey. Vulnerable Children and Youth Studies, 10(3), 192-205. http://doi.org/10.1080/17450128.2015.1045437 | Study design
Arbour-Nicitopoulos, K. P., Faulkner, G. E., & Irving, H. M. (2012). Multiple health-risk behaviour and psychological distress in adolescence. Journal of the American Academy of Child and Adolescent Psychiatry, 21(3), 171-178. PMID: 22876262 | Study design
Barba, G., Troiano, E., Russo, P., Siani, A., & ARCA Project Study Group (2006). Total fat, fat distribution and blood pressure according to eating frequency in children living in southern Italy: The ARCA Project. International Journal of Obesity, 30(7), 1166-1169. http://doi.org/10.1038/sj.ijo.0803257 | Study design
Bel-Serrat, S., Mouratidou, T., Bornhorst, C., Peplies, J., De Henauw, S., Marild, S., Molnar, D., Siani, A., Tornaritis, M., Veidebaum, T., Krogh, V., & Moreno, L. A. (2013). Food consumption and cardiovascular risk factors in European children: The IDEFICS Study. Pediatric Obesity, 8(3), 225-236. http://doi.org/10.1111/j.2047-6310.2012.00107.x | Study design
Blank, M., Zhang, J., Lamers, F., Taylor, A. D., Hickie, I. B., & Merikangas, K. R. (2015). Health correlates of insomnia symptoms and comorbid mental disorders in a nationally representative sample of US adolescents. Sleep, 38(2), 197-204. http://doi.org/10.5665/sleep.4396 | Study design
Bolton, K. A., Jacka, F., Allender, S., Kremer, P., Gibbs, L., Waters, E., & de Silva, A. (2016). The association between self-reported diet quality and health-related quality of life in rural and urban Australian adolescents. Australian Journal of Rural Health, 24(5), 317-325. http://doi.org/10.1111/ajr.12275 | Study design
Campos Pastor, M. M., Serrano Pardo, M. D., Fernandez Soto, M. L., Luna Del Castillo, J. D., & Escobar-Jimenez, F. (2012). Impact of a ‘school-based’ nutrition intervention on anthropometric parameters and the metabolic syndrome in Spanish adolescents. Annals of Nutrition & Metabolism, 61(4), 281-288. http://doi.org/10.1159/000341495 | Study design
Cayres, S. U., Junior, I. F., Barbosa, M. F., Christofaro, D. G., & Fernandes, R. A. (2016). Breakfast frequency, adiposity, and cardiovascular risk factors as markers in adolescents. Cardiology in the Young, 26(2), 244-249. http://doi.org/10.1017/s1047951115000050 | Study design
Chen, X., Sekine, M., Hamanishi, S., Wang, H., Gaina, A., Yamagami, T., & Kagamimori, S. (2005). Lifestyles and health-related quality of life in Japanese school children: a cross-sectional study. Preventative Medicine, 40(6), 668-678. http://doi.org/10.1016/j.ypmed.2004.09.034 | Study design
Cuenca-Garcia, M., Ruiz, J. R., Ortega, F. B., Labayen, I., Gonzalez-Gross, M., Moreno, L. A., Gomez-Martinez, S., Ciarapica, D., Hallstrom, L., Wastlund, A., Molnar, D., Gottrand, F., Manios, Y., Widhalm, K., Kafatos, A., De Henauw, S., Sjostrom, M., & Castillo, M. J. (2014). Association of breakfast consumption with objectively measured and self-reported physical activity, sedentary time and physical fitness in European adolescents: The HELENA (Healthy Lifestyle in Europe by Nutrition in Adolescence) study. Public Health Nutrition, 17(10), 2226-2236. http://doi.org/10.1017/s1368980013002437 | Study design
Donin, A. S., Nightingale, C. M., Owen, C. G., Rudnicka, A. R., Perkin, M. R., Jebb, S. A., Stephen, A. M., Sattar, N., Cook, D. G., & Whincup, P. H. (2014). Regular breakfast consumption and type 2 diabetes risk markers in 9- to 10-year-old children in the child heart and health study in England (CHASE): A cross-sectional analysis. PLoS Med, 11(9), e1001703. http://doi.org/10.1371/journal.pmed.1001703 | Study design
Farajian, P., Panagiotakos, D. B., Risvas, G., Micha, R., Tsioufis, C., & Zampelas, A. (2015). Dietary and lifestyle patterns in relation to high blood pressure in children: The GRECO study. Journal of Hypertension, 33(6), 1174-1181. http://doi.org/10.1097/hjh.0000000000000536 | Study design
Freitas Junior, I. F., Christofaro, D. G., Codogno, J. S., Monteiro, P. A., Silveira, L. S., & Fernandes, R. A. (2012). The association between skipping breakfast and biochemical variables in sedentary obese children and adolescents. Journal of Pediatrics, 161(5), 871-874. http://doi.org/10.1016/j.jpeds.2012.04.055 | Study design
Gates, G., & Perera, T. (2013). Association between breakfast consumption and nutritional status in 9 to 13 year old children. Journal of Nutrition Education & Behavior, 45(4S), S31-S31. https://doi.org/10.1016/j.jneb.2013.04.084 | Study design
Gilardini, L., Croci, M., Pasqualinotto, L., Caffetto, K., & Invitti, C. (2015). Dietary habits and cardiometabolic health in obese children. Obesity Facts, 8(2), 101-109. http://doi.org/10.1159/000381157 | Study design
Guo, X., Zhang, X., Li, Y., Zhou, X., Yang, H., Ma, H., Wang, N., Liu, J., Zheng, L., & Sun, Y. (2012). Differences in healthy lifestyles between prehypertensive and normotensive children and adolescents in Northern China. Pediatric Cardiology, 33(2), 222-228. http://doi.org/10.1007/s00246-011-0112-8 | Study design
Hallstrom, L., Labayen, I., Ruiz, J. R., Patterson, E., Vereecken, C. A., Breidenassel, C., Gottrand, F., Huybrechts, I., Manios, Y., Mistura, L., Widhalm, K., Kondaki, K., Moreno, L. A., Sjostrom, M. (2013). Breakfast consumption and CVD risk factors in European adolescents: The HELENA (Healthy Lifestyle in Europe by Nutrition in Adolescence) study. Public Health Nutrition, 16(7), 1296-1305. https://doi.org/10.1017/S1368980012000973 | Study design
Hirschler, V., Maccallini, G., Aranda, C., & Molinari, C. (2012). Lifestyle behaviors and dyslipidemia in Argentinean native versus urban children. Clinical Biochemistry, 45(15), 1161-1166. http://doi.org/10.1016/j.clinbiochem.2012.04.020 | Study design
Ho, C. Y., Huang, Y. C., Lo, Y. T., Wahlqvist, M. L., & Lee, M. S. (2015). Breakfast is associated with the metabolic syndrome and school performance among Taiwanese children. Research in Developmental Disabilities, 43-44, 179-188. http://doi.org/10.1016/j.ridd.2015.07.003 | Study design
Hong, S. A., & Peltzer, K. (2017). Dietary behaviour, psychological well-being and mental distress among adolescents in Korea. Child and Adolescent Psychiatry and Mental Health, 11, 56. http://doi.org/10.1186/s13034-017-0194-z | Study design
Huang, C. J., Hu, H. T., Fan, Y. C., Liao, Y. M., & Tsai, P. S. (2010). Associations of breakfast skipping with obesity and health-related quality of life: evidence from a national survey in Taiwan. International Journal of Obesity (London), 34(4), 720-725. http://doi.org/10.1038/ijo.2009.285 | Study design
Itani, O., Kaneita, Y., Munezawa, T., Ikeda, M., Osaki, Y., Higuchi, S., Kanda, H., Nakagome, S., Suzuki, K., & Ohida, T. (2016). Anger and impulsivity among Japanese adolescents: A nationwide representative survey. Journal of Clinical Psychiatry, 77(7), e860-e866. http://doi.org/10.4088/JCP.15m10044 | Study design
Jaaskelainen, A., Schwab, U., Kolehmainen, M., Pirkola, J., Jarvelin, M. R., & Laitinen, J. (2013). Associations of meal frequency and breakfast with obesity and metabolic syndrome traits in adolescents of Northern Finland Birth Cohort 1986. Nutrition, Metabolism and Cardiovascular Diseases, 23(10), 1002-1009. http://doi.org/10.1016/j.numecd.2012.07.006 | Study design
Kennedy, S., Ryan, L., & Clegg, M. E. (2016). The effect of a breakfast containing multiple functional ingredients on glucose response, insulin response and cognitive performance in adolescents. Proceedings of the Nutrition Society, 75(OCE3), 1. http://doi.org/10.1017/S0029665116002196 | Study design
Kim, S. H., Song, Y. H., Park, S., & Park, M. J. (2016). Impact of lifestyle factors on trends in lipid profiles among Korean adolescents: The Korea National Health and Nutrition Examination Surveys study, 1998 and 2010. Korean Journal of Pediatrics, 59(2), 65-73. http://doi.org/10.3345/kjp.2016.59.2.65 | Study design
Kollias, A., Antonodimitrakis, P., Grammatikos, E., Chatziantonakis, N., Grammatikos, E. E., & Stergiou, G. S. (2009). Trends in high blood pressure prevalence in Greek adolescents. Journal of Human Hypertension, 23(6), 385-390. http://doi.org/10.1038/jhh.2008.166 | Study design
Kye, S. Y., Kwon, J. H., & Park, K. (2016). Happiness and health behaviors in South Korean adolescents: A cross-sectional study. Epidemiology & Health, 38, e2016022. http://doi.org/10.4178/epih.e2016022 | Study design
Lazzeri, G., Azzolini, E., Pammolli, A., Simi, R., Meoni, V., & Giacchi, M. V. (2014). Factors associated with unhealthy behaviours and health outcomes: A cross-sectional study among Tuscan adolescents (Italy). International Journal for Equity in Health, 13(1), 83. http://doi.org/10.1186/s12939-014-0083-5 | Study design
Lee, G., Han, K., & Kim, H. (2017). Risk of mental health problems in adolescents skipping meals: The Korean National Health and Nutrition Examination Survey 2010 to 2012. Nursing Outlook, 65(4), 411-419. http://doi.org/10.1016/j.outlook.2017.01.007 | Study design
Lepkowska, D. (2015). The importance of a healthy breakfast to start the school day. British Journal of School Nursing, 10(4), 171-174. https://doi.org/10.12968/bjsn.2015.10.4.171 | Study design
Li, W., Sekine, M., Yamada, M., Fujimura, Y., & Tatsuse, T. (2018). Lifestyle and overall health in high school children: Results from the Toyama birth cohort study, Japan Pediatrics International, 60(5), 467-473. http://doi.org/10.1111/ped.13548 | Study design
Lien, L. (2007). Is breakfast consumption related to mental distress and academic performance in adolescents? Public Health Nutrition, 10(4), 422-428. http://doi.org/10.1017/s1368980007258550 | Study design
Marlatt, K. L., Farbakhsh, K., Dengel, D. R., & Lytle, L. A. (2016). Breakfast and fast food consumption are associated with selected biomarkers in adolescents. Preventive Medicine Reports, 3, 49-52. http://doi.org/10.1016/j.pmedr.2015.11.014 | Study design
Mielgo-Ayuso, J., Valtuena, J., Cuenca-Garcia, M., Gottrand, F., Breidenassel, C., Ferrari, M., Manios, Y., De Henauw, S., Widhalm, K., Kafatos, A., Kersting, M., Huybrechts, I., Moreno, L. A., & Gonzalez-Gross, M. (2017). Regular breakfast consumption is associated with higher blood vitamin status in adolescents: The HELENA (Healthy Lifestyle in Europe by Nutrition in Adolescence) study. Public Health Nutrition, 20(8), 1393-1404. http://doi.org/10.1017/s1368980016003645 | Study design
Monzani, A., Rapa, A., Fuiano, N., Diddi, G., Prodam, F., Bellone, S., & Bona, G. (2014). Metabolic syndrome is strictly associated with parental obesity beginning from childhood. Clinical Endocrinology (Oxford), 81(1), 45-51. http://doi.org/10.1111/cen.12261 | Study design
Moreno, C., Garcia-Moya, I., Rivera, F., & Ramos, P. (2016). Characterization of vulnerable and resilient Spanish adolescents in their developmental contexts. Frontiers in Psychology, 7, 983. http://doi.org/10.3389/fpsyg.2016.00983 | Study design
Morioka, H., Itani, O., Kaneita, Y., Iwasa, H., Ikeda, M., Yamamoto, R., Osaki, Y., Kanda, H., Nakagome, S., & Ohida, T. (2014). Factors affecting unhappiness at school among Japanese adolescents: An epidemiological study. PLoS One, 9(11), e111844. http://doi.org/10.1371/journal.pone.0111844 | Study design
Moschiano, F., Messina, P., D’Amico, D., Grazzi, L., Frediani, F., Casucci, G., d’Onofrio, F., Demurtas, A., Beghi, E., & Bussone, G. (2012). Headache, eating and sleeping behaviors and lifestyle factors in preadolescents and adolescents: Preliminary results from an Italian population study. Neurological Sciences, 33 (Supplement 1), S87-S90. http://doi.org/10.1007/s10072-012-1048-3 | Study design
Oak, J. W., & Lee, H. S. (2012). Prevalence rate and factors associated with atopic dermatitis among Korean middle school students. Journal of Korean Academy of Nursing, 42(7), 992-1000. http://doi.org/10.4040/jkan.2012.42.7.992 | Study design
Olson, M. L., Maalouf, N. M., Oden, J. D., White, P. C., & Hutchison, M. R. (2012). Vitamin D deficiency in obese children and its relationship to glucose homeostasis. Journal of Clinical Endocrinology & Metabolism, 97(1), 279-285. http://doi.org/10.1210/jc.2011-1507 | Study design
Osawa, H., Sugihara, N., Ukiya, T., Ishizuka, Y., Birkhed, D., Hasegawa, M., & Matsukubo, T. (2015). Metabolic syndrome, lifestyle, and dental caries in Japanese school children. The Bulletin of Tokyo Dental College, 56(4), 233-241. http://doi.org/10.2209/tdcpublication.56.233 | Study design
Osera, T., Awai, M., Kobayashi, M., Tsutie, S., & Kurihara, N. (2017). Relationship between self-rated health and lifestyle and food habits in Japanese high school students. Behavioral Sciences, 7(4), 71-80. http://doi.org/10.3390/bs7040071 | Study design
O’Sullivan, T. A., Robinson, M., Kendall, G. E., Miller, M., Jacoby, P., Silburn, S. R., & Oddy, W. H. (2009). A good-quality breakfast is associated with better mental health in adolescence. Public Health Nutrition, 12(2), 249-258. http://doi.org/10.1017/s1368980008003935 | Study design
Overby, N. C., Margeirsdottir, H. D., Brunborg, C., Andersen, L. F., & Dahl-Jorgensen, K. (2007). The influence of dietary intake and meal pattern on blood glucose control in children and adolescents using intensive insulin treatment. Diabetologia, 50(10), 2044-2051. http://doi.org/10.1007/s00125-007-0775-0 | Study design
Overby, N., & Hoigaard, R. (2012). Diet and behavioral problems at school in Norwegian adolescents. Food & Nutrition Research, 56, 17231. http://doi.org/10.3402/fnr.v56i0.17231 | Study design
Page, R. M., Simonek, J., Ihasz, F., Hantiu, I., Uvacsek, M., Kalabiska, I., & Klarova, R. (2009). Self-rated health, psychosocial functioning, and other dimensions of adolescent health in Central and Eastern European adolescents. European Journal of Psychiatry, 23(2), 101-114. https://doi.org/10.4321/S0213-61632009000200004 | Study design
Page, R. M., & Suwanteerangkul, J. (2009). Self-rated health, psychosocial functioning, and health-related behavior among Thai adolescents. Pediatrics International, 51(1), 120-125. http://doi.org/10.1111/j.1442-200X.2008.02660.x | Study design
Papoutsou, S., Briassoulis, G., Hadjigeorgiou, C., Savva, S. C., Solea, T., Hebestreit, A., Pala, V., Sieri, S., Kourides, Y., Kafatos, A., & Tornaritis, M. (2014). The combination of daily breakfast consumption and optimal breakfast choices in childhood is an important public health message. International Journal of Food Science & Nutrition, 65(3), 273-279. http://doi.org/10.3109/09637486.2013.854750 | Study design
Papoutsou, S., Briassoulis, G., Wolters, M., Peplies, J., Iacoviello, L., Eiben, G., Veidebaum, T., Molnar, D., Russo, P., Michels, N., Moreno, L. A., & Tornaritis, M. (2014). No breakfast at home: Association with cardiovascular disease risk factors in childhood. European Journal of Clinical Nutrition, 68(7), 829-834. http://doi.org/10.1038/ejcn.2014.88 | Study design
Pasic, M. D., Colantonio, D. A., Chan, M. K., Venner, A. A., Brinc, D., & Adeli, K. (2012). Influence of fasting and sample collection time on 38 biochemical markers in healthy children: A CALIPER substudy. Clinical Biochemistry, 45(15), 1125-1130. http://doi.org/10.1016/j.clinbiochem.2012.07.089 | Study design
Richards, G., & Smith, A. P. (2016). Breakfast and energy drink consumption in secondary school children: Breakfast omission, in isolation or in combination with frequent energy drink use, is associated with stress, anxiety, and depression cross-sectionally, but not at 6-month follow-up. Frontiers in Psychology, 7 (106). http://doi.org/10.3389/fpsyg.2016.00106 | Study design
Richter, M., Erhart, M., Vereecken, C. A., Zambon, A., Boyce, W., & Nic Gabhainn, S. (2009). The role of behavioural factors in explaining socio-economic differences in adolescent health: A multilevel study in 33 countries. Social Science & Medicine, 69(3), 396-403. http://doi.org/10.1016/j.socscimed.2009.05.023 | Study design
Sakaguchi, K., Yagi, T., Maeda, A., Nagayama, K., Uehara, S., Saito-Sakoguchi, Y., Kanematsu, K., & Miyawaki, S. (2014). Association of problem behavior with sleep problems and gastroesophageal reflux symptoms. Pediatrics International, 56(1), 24-30. http://doi.org/10.1111/ped.12201 | Study design
Sampasa-Kanyinga, H., & Hamilton, H. A. (2017). Eating breakfast regularly is related to higher school connectedness and academic performance in Canadian middle- and high-school students. Public Health, 145, 120-123. http://doi.org/10.1016/j.puhe.2016.12.027 | Study design
Sandercock, G. R. H., Cramer, F., & Voss, C. (2010). Associations between school-day breakfast consumption, BMI, physical activity and cardiorespiratory fitness in English schoolchildren. Proceedings of the Nutrition Society, 69(OCE1), E55. http://doi.org/10.1017/s0029665109992436 | Study design
Sandercock, G. R., Voss, C., & Dye, L. (2010). Associations between habitual school-day breakfast consumption, body mass index, physical activity and cardiorespiratory fitness in English schoolchildren. European Journal of Clinical Nutrition, 64(10), 1086-1092. http://doi.org/10.1038/ejcn.2010.145 | Study design
Schenker, S. (2008). Eating breakfast is cereally good for your health. Nursing in Practice (43), 64-67. Retrieved at: https://www.nursinginpractice.com/article/eating-breakfast-cereally-good-your-health | Study design
Shafiee, G., Kelishadi, R., Qorbani, M., Motlagh, M. E., Taheri, M., Ardalan, G., Taslimi, M., Poursafa, P., Heshmat, R., & Larijani, B. (2013). Association of breakfast intake with cardiometabolic risk factors. Jornal de Pediatria, 89(6), 575-582. http://doi.org/10.1016/j.jped.2013.03.020 | Study design
Tajik, E., Latiffah, A. L., Awang, H., Siti Nur’Asyura, A., Chin, Y. S., Azrin Shah, A. B., Patricia Koh, C. H., & Mohd Izudin Hariz, C. G. (2016). Unhealthy diet practice and symptoms of stress and depression among adolescents in Pasir Gudang, Malaysia. Obesity Research & Clinical Practice, 10(2), 114-123. http://doi.org/10.1016/j.orcp.2015.06.001 | Study design
Takasaki, Y. (2005). Serum lipid levels and factors affecting atherogenic index in Japanese children. Journal of Physiological Anthropology and Applied Human Science, 24(4), 511-515. http://doi.org/10.2114/jpa.24.511 | Study design
Tanihata, T., Kanda, H., Osaki, Y., Ohida, T., Minowa, M., Wada, K., Suzuki, K., & Hayashi, K. (2015). Unhealthy lifestyle, poor mental health, and its correlation among adolescents: A nationwide cross-sectional survey. Asia Pacific Journal of Public Health, 27(2), NP1557-NP1565. http://doi.org/10.1177/1010539512452753 | Study design
Thivel, D., Aucouturier, J., Isacco, L., Lazaar, N., Ratel, S., Dore, E., Meyer, M., & Duche, P. (2013). Are eating habits associated with physical fitness in primary school children? Eating Behaviors, 14(1), 83-86. http://doi.org/10.1016/j.eatbeh.2012.11.002 | Study design
Torres-Ferrus, M., Vila-Sala, C., Quintana, M., Ajanovic, S., Gallardo, V. J., Gomez, J. B., Alvarez-Sabin, J., Macaya, A., & Pozo-Rosich, P. (2018). Headache, comorbidities and lifestyle in an adolescent population (The TEENs Study). Cephalalgia, 39(1), 91-99. http://doi.org/10.1177/0333102418777509 | Study design
Walter, S. (2014). Lifestyle behaviors and illness-related factors as predictors of recurrent headache in U.S. adolescents. Journal of Neuroscience Nursing, 46(6), 337-350. http://doi.org/10.1097/jnn.0000000000000095 | Study design
Walther, J., Aldrian, U., Stuger, H. P., Kiefer, I., & Ekmekcioglu, C. (2014). Nutrition, lifestyle factors, and mental health in adolescents and young adults living in Austria. International Journal of Adolescent Medicine & Health, 26(3), 377-386. http://doi.org/10.1515/ijamh-2013-0310 | Study design
Wisting, L., Reas, D. L., Bang, L., Skrivarhaug, T., Dahl-Jorgensen, K., & Ro, O. (2017). Eating patterns in adolescents with type 1 diabetes: Associations with metabolic control, insulin omission, and eating disorder pathology. Appetite, 114, 226-231. http://doi.org/10.1016/j.appet.2017.03.035 | Study design
Yoshinaga, M., Hatake, S., Tachikawa, T., Shinomiya, M., Miyazaki, A., & Takahashi, H. (2011). Impact of lifestyles of adolescents and their parents on cardiovascular risk factors in adolescents. Journal of Atherosclerosis and Thrombosis, 18(11), 981-990. https://doi.org/10.5551/jat.9514 | Study design
Zhang, F., Zhao, L., Feng, X., & Hu, X. (2016). An investigation on self-rated health of adolescent students and influencing factors from Sichuan, China. American Journal of Therapeutics, 23(5), e1143-e1150. http://doi.org/10.1097/mjt.0000000000000425 | Study design

Table A2 4 Articles excluded during full-text screening of the initial literature search for Key Question 2: What best practices exist in the U.S. School Breakfast Program, including models of student costs and breakfast delivery?

Article | Reason for exclusion
Morris, C. T., Courtney, A., Bryant, C. A., McDermott, R. J. (2010). Grab N’ Go breakfast at school: Observations from a pilot program. Journal of Nutrition Education and Behavior, 42(3), 208-209. http://doi.org/10.1016/j.jneb.2009.10.003 | Study design
Ask, A. S., Hernes, S., Aarek, I., Johannessen, G., & Haugen, M. (2006). Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast - A pilot study. Nutrition Journal, 5(33). https://doi.org/10.1186/1475-2891-5-33 | Study setting
Ask, A. S., Hernes, S., Aarek, I., Vik, F., Brodahl, C., & Haugen, M. (2010). Serving of free school lunch to secondary-school pupils - A pilot study with health implications. Public Health Nutrition, 13(2): 238-244. https://doi.org/10.1017/S1368980009990772 | Study setting
Briggs, L., & Menger, B. (2011). Improving nutrition at breakfast and after school clubs. Journal of Human Nutrition & Dietetics, 24(4): 379-379. https://doi.org/10.1111/j.1365-277X.2011.01177_6.x | Study setting
Defeyter, M. A., Graham, P. L., & Russo, R. (2015). More than just a meal: Breakfast club attendance and children’s social relationships. Frontiers in Public Health, 3(183). http://doi.org/10.3389/fpubh.2015.00183 | Study setting
Mhurchu, C. N., Turley, M., Gorton, D., Jiang, Y., Michie, J. Maddison, R., & Hattie, J. (2010). Effects of a free school breakfast programme on school attendance, achievement, psychosocial function, and nutrition: A stepped wedge cluster randomised trial. BMC Public Health, 10, 738. http://doi.org/10.1186/1471-2458-10-738 | Study setting
Muthayya, S., Thomas, T., Srinivasan, K., Rao K., Kurpad, A. V., van Klinken, J. W., Owen, G., & de Bruin, E. A. (2007). Consumption of a mid-morning snack improves memory but not attention in school children. Physiology & Behavior, 90(1), 142-150. https://doi.org/10.1016/j.physbeh.2006.09.025 | Study setting
Watanabe, J., Watanabe, M., Koga, M., Yamaoka, K., Yokotsuka, M., Adachi, M., Hashimoto, Y., & Tango, T. (2013). Effects of dietary lifestyle education program for adolescents in middle schools: Study design of a cluster randomized controlled trial. Annals of Nutrition and Metabolism, 63, 726-727. https://doi.org/10.1371/journal.pone.0165285 | Study setting
Askelson, N. M., Golembiewski, E. H., Ghattas, A., Williams, S., Delger, P. J., & Scheidel, C. A. (2017). Exploring the parents’ attitudes and perceptions about school breakfast to understand why participation is low in a rural midwest state. Journal of Nutrition Education and Behavior, 49(2), 107-116.e1. http://doi.org/10.1016/j.jneb.2016.10.011 | Intervention, exposure, or comparator
Au, L. E., Gurzo, K., Gosliner, W., Webb, K. L., Crawford, P. B., & Ritchie, L. D. (2018). Eating school meals daily is associated with healthier dietary intakes: The Healthy Communities Study. Journal of the Academy of Nutrition and Dietetics, 118(8), 1474-1481.e1. http://doi.org/10.1016/j.jand.2018.01.010 | Intervention, exposure, or comparator
Bartfeld, J. S., & Ahn, H. M. (2011). The School Breakfast Program strengthens household food security among low-income households with elementary school children. Journal of Nutrition, 141(3), 470-475. http://doi.org/10.3945/jn.110.130823 | Intervention, exposure, or comparator
Bartfeld, J. S., & Ryu, J. H. (2011). The School Breakfast Program and breakfast-skipping among Wisconsin elementary school children. Social Service Review, 85(4), 619-634. https://doi.org/10.1086/663635 | Intervention, exposure, or comparator
Baxter, S. D., Paxton-Aiken, A. E., Tebbs, J. M., Royer, J. A., Guinn, C. H., & Finney, C. J. (2012). Secondary analyses of data from 4 studies with fourth-grade children show that sex, race, amounts eaten of standardized portions, and energy content given in trades explain the positive relationship between body mass index and energy intake at school-provided meals. Nutrition Research, 32(9), 659-668. http://doi.org/10.1016/j.nutres.2012.07.001 | Intervention, exposure, or comparator
Baxter, S. D., Royer, J. A., Hardin, J. W., Guinn, C. H., & Smith, A. F. (2007). Fourth-grade children are less accurate in reporting school breakfast than school lunch during 24-hour dietary recalls. Journal of Nutrition Education and Behavior, 39(3), 126-133. http://doi.org/10.1016/j.jneb.2006.12.014 | Intervention, exposure, or comparator
Bhattacharya, J., Currie, J., & Haider, S. J. (2006). Breakfast of champions? The school breakfast program and the nutrition of children and families. Journal of Human Resources, 41(3), 445-466. http://doi.org/10.3368/jhr.XLI.3.445 | Intervention, exposure, or comparator
Bruening, M., Larson, N., Story, M., Neumark-Sztainer, D., & Hannan, P. (2011). Predictors of adolescent breakfast consumption: Longitudinal findings from Project EAT. Journal of Nutrition Education and Behavior, 43(5), 390-395. http://doi.org/10.1016/j.jneb.2011.02.016 | Intervention, exposure, or comparator
Centeio, E. E., Somers, C. L., Moore, E. W. G., Kulik, N., Garn, A., Martin, J., McCaughtry, N. (2018). Relationship between academic achievement and healthy school transformations in urban elementary schools in the United States. Physical Education and Sport Pedagogy, 23(4), 402-417. https://doi.org/10.1080/17408989.2018.1441395 | Intervention, exposure, or comparator
Clark, M. A., & Fox, M. K. (2009). Nutritional quality of the diets of US public school children and the role of the school meal programs. Journal of the American Dietetic Association, 109 (2 Supplement), S44-S56. http://doi.org/10.1016/j.jada.2008.10.060 | Intervention, exposure, or comparator
Condon, E. M., Crepinsek, M. K., & Fox, M. K. (2009). School meals: types of foods offered to and consumed by children at lunch and breakfast. Journal of the American Dietetic Association, 109 (2 Supplement), S67-S78. http://doi.org/10.1016/j.jada.2008.10.062 | Intervention, exposure, or comparator
Crawford, P. B., Woodward-Lopez, G., Gosliner, W., & Webb, K. (2013). Lessons of Fresh Start can guide schools seeking to boost student fruit consumption. California Agriculture, 67(1) 21-29. https://doi.org/10.3733/ca.v067n01p21 | Intervention, exposure, or comparator
Cullen, K. W., & Chen, T. A. (2016). The contribution of the USDA school breakfast and lunch program meals to student daily dietary intake. Preventive Medicine Reports, 5, 82-85. https://doi.org/10.1016/j.pmedr.2016.11.016 | Intervention, exposure, or comparator
Dave, J. M., Chen, T. A., Oceguera, A., M., Cullen, K. W., & Thompson, D. I. (2015). Outcome evaluation of a pilot study using nudges. International Journal of Child Health and Nutrition, 4(1), 33-39. https://doi.org/10.6000/1929-4247.2015.04.01.3 | Intervention, exposure, or comparator
Dykstra, H., Davey, A., Fisher, J. O., Polonsky, H., Sherman, S., Abel, M. L., Dale, L. C., Foster, G. D., & Bauer, K. W. (2016). Breakfast-skipping and selecting low-nutritional-quality foods for breakfast are common among low-income urban children, regardless of food security status. Journal of Nutrition, 146(3), 630-636. http://doi.org/10.3945/jn.115.225516 | Intervention, exposure, or comparator
Fletcher, J. M., & Frisvold, D. E. (2017). The relationship between the School Breakfast Program and food insecurity. Journal of Consumer Affairs, 51(), 481-500. https://doi.org/10.1111/joca.12163 | Intervention, exposure, or comparator
Frisvold, D. E. (2015). Nutrition and cognitive achievement: An evaluation of the school breakfast program. Journal of Public Economics, 124, 91-104. http://doi.org/10.1016/j.jpubeco.2014.12.003 | Intervention, exposure, or comparator
Gu, X., & Tucker, K. L. (2017). Dietary quality of the US child and adolescent population: Trends from 1999 to 2012 and associations with the use of federal nutrition assistance programs. American Journal of Clinical Nutrition, 105(1), 194-202. http://doi.org/10.3945/ajcn.116.135095 | Intervention, exposure, or comparator
Guinn, C. H., Baxter, S. D., Royer, J. A., Hitchcock, D. B. (2013). Explaining the positive relationship between fourth-grade children’s body mass index and energy intake at school-provided meals (breakfast and lunch). Journal of School Health, 83(5) 328-334. http://doi.org/10.1111/josh.12035 | Intervention, exposure, or comparator
HEALTHY Study Group, Mobley, C. C., Stadler, D. D., Staten, M. A., El Ghormli, L., Gillis, B., Hartstein, J., Siega-Riz, A. M., & Virus, A. (2012). Effect of nutrition changes on foods selected by students in a middle school-based diabetes prevention intervention program: The HEALTHY experience. Journal of School Health, 82(2), 82-90. http://doi.org/10.1111/j.1746-1561.2011.00670.x | Intervention, exposure, or comparator
Hearst, M. O., Shanafelt, A., Wang, Q., Leduc, R., & Nanney, M. S. (2016). Barriers, benefits, and behaviors related to breakfast consumption among rural adolescents. Journal of School Health, 86(3), 187-194. http://doi.org/10.1111/josh.12367 | Intervention, exposure, or comparator
Heo, M., Irvin, E., Ostrovsky, N., Isasi, C., Blank, A. E., Lounsbury, D. W., Fredericks, L., Yom, T., Ginsberg, M., Hayes, S., & Wylie-Rosett, J. (2016). Behaviors and knowledge of Healthcorps New York City high school students: Nutrition, mental health, and physical activity. Journal of School Health, 86(2), 84-95. http://doi.org/10.1111/josh.12355 | Intervention, exposure, or comparator
Hoelscher, D. M., Moag-Stahlberg, A., Ellis, K., Vandewater, E. A., & Malkani, R. (2016). Evaluation of a student participatory, low-intensity program to improve school wellness environment and students’ eating and activity behaviors. International Journal of Behavioral Nutrition and Physical Activity, 13, 13-59. http://doi.org/10.1186/s12966-016-0379-5 | Intervention, exposure, or comparator
Hofferth, S. L., & Curtin, S. (2005). Poverty, food programs, and childhood obesity. Journal of Policy Analysis and Management, 24(4), 703-726. https://doi.org/10.1002/pam.20134 | Intervention, exposure, or comparator
Irwin, C., Irwin, R., Richey, P., Miller, M., Boddie, J., & Dickerson, T (2012). Get fit with the Grizzlies: A community-school-home initiative to fight childhood obesity led by a professional sports organization. Studies in Health Technology and Informatics, 172, 163-167. http://doi.org/10.3233/978-1-61499-088-8-163 | Intervention, exposure, or comparator
Ishdorj, A., Crepinsek, M. K., & Jensen, H. H. (2013). Children’s consumption of fruits and vegetables: Do school environment and policies affect choices at school and away from school? Applied Economic Perspectives and Policy, 35(2), 341-359. https://doi.org/10.1093/aepp/ppt003 | Intervention, exposure, or comparator
Kim, N., Seo, D. C., King, M. H., Lederer, A. M., & Sovinski, D. (2014). Long-term predictors of blood pressure among adolescents during an 18-month school-based obesity prevention intervention. Journal of Adolescent Health, 55(4), 521-527. http://doi.org/10.1016/j.jadohealth.2014.04.011 | Intervention, exposure, or comparator
Kimbro, R. T., & Rigby, E. (2010). Federal food policy and childhood obesity: A solution or part of the problem? Health Affairs, 29(3), 411-418. https://doi.org/10.1377/hlthaff.2009.0731 | Intervention, exposure, or comparator
Larsen, A. L., Liao, Y., Alberts, J., Huh, J., Robertson, T., & Dunton, G. F. (2017). RE-AIM Analysis of a school-based nutrition education intervention in kindergarteners. Journal of School Health, 87(1), 36-46. http://doi.org/10.1111/josh.12466 | Intervention, exposure, or comparator
Lawman, H. G., Polonsky, H. M., Vander Veur, S. S., Abel, M. L., Sherman, S., Bauer, K. W., Sanders, T., Fisher, J. O., Bailey-Davis, L., Ng, J., Van Wye, G., & Foster, G. D. (2014). Breakfast patterns among lowincome, ethnically-diverse 4th-6th grade children in an urban area. BMC Public Health, 14, 604. http://doi.org/10.1186/1471-2458-14-604 | Intervention, exposure, or comparator
Miller, D. P. (2011). Associations between the home and school environments and child body mass index. Social Science & Medicine, 72(5), 677-684. http://doi.org/10.1016/j.socscimed.2010.12.003 | Intervention, exposure, or comparator
Millimet, D. L., Tchernis, R., & Husain, M. (2010). School nutrition programs and the incidence of childhood obesity. Journal of Human Resources, 45, 640-654. https://doi.org/10.3386/w14297 | Intervention, exposure, or comparator
Millimet, D. L., & Tchernis, R. (2013). Estimation of treatment effects without an exclusion restriction: With an application to the analysis of the School Breakfast Program. Journal of Applied Econometrics, 28(), 982-1017. https://doi.org/10.3386/w15539 | Intervention, exposure, or comparator
Montgomery-Reagan, K., Bianco, J. A., Heh, V., Rettos, J., & Huston, R. S. (2009). Prevalence and correlates of high body mass index in rural Appalachian children aged 6-11 years. Rural Remote Health, 9(4), 1234. PMID: 19848443 | Intervention, exposure, or comparator
Peart, T., Kao, J., Crawford, P. B., Samuels, S. E., Craypo, L., & Woodward-Lopez, G. (2012). Does competitive food and beverage legislation hurt meal participation or revenues in high schools? Child Obesity, 8(4), 339-346. http://doi.org/10.1089/chi.2012.0009 | Intervention, exposure, or comparator
Polonsky, H. M., Davey, A., Bauer, K. W., Foster, G. D., Sherman, S., Abel, M. L., Dale, L. C., & Fisher, J. O (2018). Breakfast quality varies by location among low-income ethnically diverse children in public urban schools. Journal of Nutrition Education and Behavior, 50(2), 190-197.e1. http://doi.org/10.1016/j.jneb.2017.09.009 | Intervention, exposure, or comparator
Quick, V., Wall, M., Larson, N., Haines, J., & Neumark-Sztainer, D. (2013). Personal, behavioral and socio-environmental predictors of overweight incidence in young adults: 10-yr longitudinal findings. International Journal of Behavioral Nutrition and Physical Activity, 10, 37. http://doi.org/10.1186/1479-5868-10-37 | Intervention, exposure, or comparator
Reich, S. M., Kay, J. S., & Lin, G. C. (2015). Nourishing a partnership to improve middle school lunch options a community-based participatory research project. Family & Community Health, 38(1), 77-86. https://doi.org/10.1097/fch.0000000000000055 | Intervention, exposure, or comparator
Robinson-O’Brien, R., Burgess-Champoux, T., Haines, J., Hannan, P. J., & Neumark-Sztainer, D. (2010). Associations between school meals offered through the National School Lunch Program and the School Breakfast Program and fruit and vegetable intake among ethnically diverse, low-income children. Journal of School Health, 80(10), 487-492. http://doi.org/10.1111/j.1746-1561.2010.00532.x | Intervention, exposure, or comparator
Rosas, S., Case, J., & Tholstrup, L. (2009). A retrospective examination of the relationship between implementation quality of the coordinated school health program model and school-level academic indicators over time. Journal of School Health, 79(3), 108-115. https://doi.org/10.1111/j.1746-1561.2008.00394.x | Intervention, exposure, or comparator
Smith, T. A. (2017). Do school food programs improve child dietary quality? American Journal of Agricultural Economics, 99(2), 339-356. https://doi.org/10.1093/ajae/aaw091 | Intervention, exposure, or comparator
Sweeney, N. M., & Horishita, N. (2005). The breakfast-eating habits of inner city high school students. Journal of School Nursing, 21(2), 100-105. http://doi.org/10.1177/10598405050210020701 | Intervention, exposure, or comparator
Trude, A. C., Kharmats, A. Y., Hurley, K. M., Anderson Steeves, E., Talegawkar, S. A., & Gittelsohn, J. (2016). Household, psychosocial, and individual-level factors associated with fruit, vegetable, and fiber intake among low-income urban African American youth. BMC Public Health, 16(1), 872. http://doi.org/10.1186/s12889-016-3499-6 | Intervention, exposure, or comparator
Vericker, T. C. (2014). Children’s school-related food and physical activity behaviors are associated with body mass index. Journal of the Academy of Nutrition and Dietetics, 114(2), 250-256. http://doi.org/10.1016/j.jand.2013.07.046 | Intervention, exposure, or comparator
Wang, S., Schwartz, M. B., Shebl, F. M., Read, M., Henderson, K. E., & Ickovics, J. R. (2017). School breakfast and body mass index: A longitudinal observational study of middle school students. Pediatric Obesity, 12(3), 213-220. http://doi.org/10.1111/ijpo.12127 | Intervention, exposure, or comparator
Williams, B. M., O’Neil, C. E., Keast, D. R., Cho, S., & Nicklas, T. A. (2009). Are breakfast consumption patterns associated with weight status and nutrient adequacy in African-American children? Public Health Nutrition, 12(4), 489-496. http://doi.org/10.1017/S1368980008002760 | Intervention, exposure, or comparator
Williamson, D. A., Han, H., Johnson, W. D., Martin, C. K., & Newton, R. L., Jr. (2013). Modification of the school cafeteria environment can impact childhood nutrition. Results from the Wise Mind and LA Health studies. Appetite, 61(1), 77-84. http://doi.org/10.1016/j.appet.2012.11.002 | Intervention, exposure, or comparator
Diaz, T., Ficapal-Cusi, P., & Aguilar-Martinez, A. (2016). Breakfast habits in primary and secondary schoolchildren: Options for nutritional education in schools. Nutricion Hospitalaria, 33(4), 909-914. https://doi.org/10.20960/nh.391 | Language of publication
Amaya, Lauren, Gates, G. (2015). Evaluation of the promotion of free school breakfast on consumption and perceptions of school breakfast in a rural district. Journal of Nutrition Education & Behavior, 47(4), S75. https://doi.org/10.1016/j.jneb.2015.04.198 | Study design
Ask, A. S., Hernes, S., Aarek, I., Johannessen, G., & Haugen, M. (2006). Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast--a pilot study. Nutrition Journal, 5, 33. http://doi.org/10.1186/1475-2891-5-33 | Study design
Baxter, S., Hitchcock, D. B., Smith, A. F., Finney, C. J., Guinn, C. H., & Royer, J. A. (2016). As children’s body mass index percentile increased, they ate more kilocalories at school-provided breakfast and lunch, but did not report more kilocalories at the same rate. Journal of the Academy of Nutrition & Dietetics, 116(9 Supplement), A72. https://doi.org/10.1016/j.jand.2016.06.250 | Outcome
Cubero, J., Franco-Reynolds, L., Calderon, M. A., Caro, B., Rodrigo, M., & Ruiz, C. (2017). School breakfast, an educative intervention in healthy food and nutrition. Didactica De Las Ciencias Experimentales Y Sociales, (32), 171-182. | Study design
Fernandez, A. C., Weigand, C. M., Pomar, M. D. B., Casariego, A. V., Gómez, J. J. L., Rodríguez, I. C., Arias, M. T. G., & Fernández, M. C. G. (2011). Changes on dietary habits of the late-breakfast in a school population. Nutricion Hospitalaria, 26(3), 560-565. http://doi.org/10.1590/S0212-16112011000300019 | Intervention, exposure, or comparator
Fisher, J. O., Polonsky, H., Bauer, K., Sherman, S., Abel, M., Vander Veur, S., & Foster, G. (2015). Increasing breakfast consumption and decreasing childhood obesity in low-income, ethnically diverse youth. Journal of Nutrition Education & Behavior, 47(4 Supplement), S99. https://doi.org/10.1016/j.jneb.2015.04.266 | Publication status
Gates, G., & Perera, T. (2013). Association between breakfast consumption and nutritional status in 9 to 13 year old children. Journal of Nutrition Education & Behavior, 45(4 Supplement), S31. https://doi.org/10.1016/j.jneb.2013.04.084 | Publication status
Hearst, M. O., Shanafelt, A., Wang, Q., Leduc, R., & Nanney, M. S. (2018). Altering the school breakfast environment reduces barriers to school breakfast participation among diverse rural youth. Journal of School Health, 88(1), 3-8. http://doi.org/10.1111/josh.12575 | Outcomes
Krueger, E. B., Eggett, D. L., & Stokes, N. (2018). Teacher perceptions and preferences for 5 school breakfast program models. Journal of Nutrition Education and Behavior, 50(8), 788-794. http://doi.org/10.1016/j.jneb.2018.01.006 | Outcomes
Rives, F. M., Marin, F. M., Rives, L. V. M., & Garralda, G. M. Á. (2015). Pharmaceutical care for healthy breakfast promotion in community pharmacies. Nutricion Hospitalaria, 32(3), 1267-1272. http://doi.org/10.3305/nh.2015.32.3.9390 | Intervention, exposure, or comparator
Traub, M., Steinacker, J. M., Kesztyus, D., & Arbeitsgrp Komm Gesunde Boot. (2017). Avoiding breakfast for the primary school children cofactors as an important basis for targeted prevention measures. Ernahrungs Umschau, 64, 9. https://doi.org/10.4455/eu.2017.035 | Intervention, exposure, or comparator
Wixom, N., Walther, C., Urbach, K., & Yussman, S. M. (2018). 242 - Introduction of a breakfast in the classroom program in an urban middle school. Journal of Adolescent Health, 62(2), S123. https://doi.org/10.1016/j.jadohealth.2017.11.250 | Study design
Baxter, S. D., Guinn, C. H., Royer, J. A., Hardin, J. W., Mackelprang, A. J., & Smith, A. F. (2009). Accuracy of children’s school-breakfast reports and school-lunch reports (in 24-h dietary recalls) differs by retention interval. European Journal of Clinical Nutrition, 63(12), 1394-1403. http://doi.org/10.1038/ejcn.2009.107 | Outcome
Baxter, S. D., Guinn, C. H., Smith, A. F., Hitchcock, D. B., Royer, J. A., Puryear, M. P., Collins, K. L., & Smith, A. L. (2016). Children’s school-breakfast reports and school-lunch reports (in 24-h dietary recalls): Conventional and reporting-error-sensitive measures show inconsistent accuracy results for retention interval and breakfast location. British Journal of Nutrition, 115(7), 1301-1315. http://doi.org/10.1017/S0007114515005413 | Outcome
Nanney, M. S., Shanafelt, A., Wang, Q., Leduc, R., Dodds, E., Hearst, M., Kubik, M. Y., Grannon, K., & Harnack, L. (2016). Project BreakFAST: Rationale, design, and recruitment and enrollment methods of a randomized controlled trial to evaluate an intervention to improve School Breakfast Program participation in rural high schools. Contemporary Clinical Trials Communications, 3, 12-22. http://doi.org/10.1016/j.conctc.2015.12.009 | Outcome
Ollinger, M., Ralston, K., & Guthrie, J. (2012). Location, school characteristics, and the cost of school meals. Journal of Agricultural and Resource Economics, 37(3), 379-397. https://www.jstor.org/stable/23496723 | Outcome
Poblacion, A., Cook, J., de Cuba, S. E., Bovell, A., Sheward, R., Pasquariello, J., & Cutts, D. (2017). Can food insecurity be reduced in the United States by improving SNAP, WIC, and the Community Eligibility Provision? World Medical & Health Policy, 9(4), 435-455. https://doi.org/10.1002/wmh3.248 | Outcome
Askelson, N. M., Golembiewski, E. H., Bobst, A., Delger, P. J., & Scheidel, C. A. (2017). Understanding perceptions of school administrators related to school breakfast in a low school breakfast participation state. Journal of School Health, 87(6), 427-434. http://doi.org/10.1111/josh.12511 | Study setting
Khodabocus, R., Tran, K., Broom, T., & Razaq, A. (2015). Breakfast club: a simple, reproducible, student education initiative. Medical Education, 49(11), 1143-1144. http://doi.org/10.1111/medu.12879 | Study setting
Knoblock-Hahn, A., Brown, K., Medrow, L., & Murphy, A. (2016). How community food banks support school breakfast: Strategies used and lessons learned. Journal of the Academy of Nutrition & Dietetics, 116(7), 1187-1192. https://doi.org/10.1016/j.jand.2016.01.013 | Population
Spruance, L. A., Harrison, C., Brady, P., Woolford, M., & LeBlanc, H. (2018). Who eats school breakfast? Parent perceptions of school breakfast in a state with very low participation. Journal of School Health, 88(2), 139-149. http://doi.org/10.1111/josh.12597 | Study design
Access to breakfast clubs vital for parents.(2014). British Journal of School Nursing,9: 59-59. https://doi.org/10.12968/bjsn.2014.9.2.57. | Study design
Breakfast in the Classroom: An Investment Today for our Kid’s Future.(2010). New York Family Medicine News, 4-4. | Study design
Breakfast in the Classroom: An investment today for our kids’ future. (2012). New York Family Medicine News, 7-7. | Study design
Conjuring up breakfast for children. (2008). Practice Nurse, 4-4. | Study design
Askelson, N. M., Golembiewski, E. H., DePriest, A. M., O’Neill, P., Delger, P. J., Scheidel, C. A. (2015). The answer isn’t always a poster: Using social marketing principles and concept mapping with high school students to improve participation in school breakfast. Social Marketing Quarterly, 21(3), 119-134. https://doi.org/10.1177/1524500415589591 | Study design
Cowbrough, K. (2014). Early breakfast challenges. Journal of Family Health Care, 24(7), 23-24. PMID: 25668970 | Study design
Creighton, L. S. (2012). Stakeholder engagement for successful breakfast in the classroom implementation. Journal of School Health, 82(11), 496-498. http://doi.org/10.1111/j.1746-1561.2012.00728.x | Study design
Egner, R., Oza-Frank, R., & Cunningham, S. A. (2014). The school breakfast program: A view of the present and preparing for the future-a commentary. Journal of School Health, 84(7), 417-420. http://doi.org/10.1111/josh.12164 | Study design
French, S. A., & Story, M. (2013). Commentary on nutrition standards in the national school lunch and breakfast programs. JAMA Pediatrics, 167(1), 8-9. http://doi.org/10.1001/jamapediatrics.2013.639 | Study design
Gundersen, C. (2015). Food assistance programs and child health. Future of Children, 25(1), 91-109. https://doi.org/10.1353/foc.2015.0004 | Study design
Heller, E., & Johnson, T. (2016). Healthy foods in schools. National Conference of State Legislature Legisbrief, 24(22), 1-2. | Study design
Lepkowska, D. (2015). The importance of a healthy breakfast to start the school day. British Journal of School Nursing, 10(4), 171-174. https://doi.org/10.12968/bjsn.2015.10.4.171 | Study design
Marcason, W. (2012). What are the new national school lunch and breakfast program nutrition standards? Journal of the Academy of Nutrition and Dietetics, 112(7), 1112. https://doi.org/10.1016/j.jand.2012.05.017 | Study design
Marcason, W. (2008). Where can I find information and resources for the School Breakfast Program?. Journal of the American Dietetic Association, 108(9), 1580. http://doi.org/10.1016/j.jada.2008.07.032 | Study design
Ohr, L. M. (2016). Ingredients for Healthy Adolescents. Food Technology, 70(8). | Study design
Precht, T. E., Strassner, C., & Kral, T. V. E. (2014). School breakfast - what can Germany learn from the US experience? Ernahrungs Umschau, 61(2), 20-26. http://doi.org/10.4455/eu.2014.004 | Study design
Ruxton, C. (2011). Breakfast clubs: The nutritional, social and health benefits. Nursing in Practice. Retrieved at: https://www.nursinginpractice.com/article/breakfast-clubs-nutritional-social-and-health-benefits | Study design
Schwaab, B., Fettweis, C., & Caplon, M. (2012). Increasing student breakfast consumption: An established model in Maryland. Interview by Jodi R. Godfrey. Child Obesity, 8(2), 162-166. http://doi.org/10.1089/chi.2012.0082.godf | Study design
Story, M., Kaphingst, K. M., & French, S. (2006). The role of schools in obesity prevention. The Future of Children, 16(1), 109-142. http://doi.org/10.1353/foc.2006.0007 | Study design
Zilberter, T., & Zilberter, E. Y. (2013). Breakfast and cognition: Sixteen effects in nine populations, no single recipe. Frontiers in Human Neuroscience, 7(631). http://doi.org/10.3389/fnhum.2013.00631 | Study design

Table A2 5 Articles excluded during full-text screening of the [underlined: updated literature search] for all rapid review questions

Article | Reason for exclusion
Morgenmadsklubben (the breakfast club). ISRCTN11265280 2018. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01949949/full | Publication status
School children’s breakfast consumption: An educational intervention based on social cognitive theory. Annals of tropical medicine and public health. 2018;(11 ):SP36. | Outcome
A training intervention based on the social marketing model in promoting healthy breakfast and snack. IRCT20170201032347N1. 2018. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01951001/full | Publication status
Acute effects of breakfast compared with no breakfast on cognitive function and subjective state in 11-13 year old children. NCT03979027. 2019. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01945391/full | Publication status
Nutrition education potentially improves breakfast quality of adolescents from low-mid socioeconomic background. Ann Nutr Metab. 2019;75(3):186. | Publication status
Erratum: Effect of a breakfast in the classroom initiative on obesity in urban school-aged children: A cluster randomized clinical trial (JAMA Pediatr (2019) DOI: 10.1001/jamapediatrics.2018.5531). JAMA Pediatr. 2019;173(7):704. | Study design
The 3 Healthy Study for obesity prevention among vulnerable children. ISRCTN11347525. 2019. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01974155/full | Publication status
Metabolic responses to breakfast in adolescent girls. NCT04476693. 2020. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-02145352/full | Publication status
Breakfast omission and energy balance in girls. NCT04481776. 2020. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-02145467/full | Publication status
Study on the effects of dietary education on the basis of breakfast intake of schoolchildren for different subjects. JPRN-UMIN000040336. 2020. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-02172953/full | Publication status, Outcome
Dietary Habits and Metabolic Response in Obese Children Whose Mothers Received an Intervention to Promote Healthy Eating. NCT04374292. 2020. https://clinicaltrials.gov/ct2/show/NCT04374292 | Publication status
Adolphus K, Lawton CL, Dye L. Associations between habitual school-day breakfast consumption frequency and academic performance in British adolescents. Front Public Health. 2019;7:283. doi:10.3389/fpubh.2019.00283 | Study design
Agostini A, Lushington K, Kohler M, Dorrian J. Associations between self-reported sleep measures and dietary behaviours in a large sample of Australian school students (n = 28,010). J Sleep Res. Oct 2018;27(5):e12682. doi:10.1111/jsr.12682 | Intervention/exposure
Al-Hazzaa HM, Al-Rasheedi AA, Alsulaimani RA, Jabri L. Anthropometric, familial- and lifestyle-related characteristics of school children skipping breakfast in Jeddah, Saudi Arabia. Nutrients. Nov 29 2020;12(12)doi:10.3390/nu12123668 | Study design
Al-Hazzaa HM, Alhowikan AM, Alhussain MH, Obeid OA. Breakfast consumption among Saudi primary-school children relative to sex and socio-demographic factors. BMC Public Health. Apr 6 2020;20(1):448. doi:10.1186/s12889-020-8418-1 | Study design
Allara E, Angelini P, Gorini G, et al. Effects of a prevention program on multiple health-compromising behaviours in adolescence: A cluster randomized controlled trial. Prev Med. Jul 2019;124:1-10. doi:10.1016/j.ypmed.2019.04.001 | Outcome
Alsharairi NA, Somerset S. Parental work status and children’s dietary consumption: Australian evidence. International Journal of Consumer Studies. Sep 2018;42(5):522-532. doi:10.1111/ijcs.12463 | Intervention/exposure, Outcome
Altay N, Toruner EK, Akgun-Citak E. Determine the BMI levels, self-concept and healthy life behaviours of children during a school based obesity training programme. AIMS Public Health. 2020;7(3):535-547. doi:10.3934/publichealth.2020043 | Design, Intervention/exposure
Arenaza L, Medrano M, Oses M, et al. The effect of a family-based lifestyle education program on dietary habits, hepatic fat and adiposity markers in 8-12-year-old children with overweight/obesity. Nutrients. May 16 2020;12(5)doi:10.3390/nu12051443 | Study design
Arenaza L, Munoz-Hernandez V, Medrano M, et al. Association of breakfast quality and energy density with cardiometabolic risk factors in overweight/obese children: Role of physical activity. Nutrients. Aug 10 2018;10(8)doi:10.3390/nu10081066 | Study design
Bani-Issa W, Dennis CL, Brown HK, et al. The influence of parents and schools on adolescents’ perceived diet and exercise self-efficacy: A school-based sample from the United Arab Emirates. J Transcult Nurs. Sep 2020;31(5):479-491. doi:10.1177/1043659619876686 | Outcome
Bardin S, Gola AA. Analyzing the association between student weight status and school meal participation: Evidence from the School Nutrition and Meal Cost Study. Nutrients. Dec 23 2020;13(1)doi:10.3390/nu13010017 | Intervention/exposure
Barstad LH, Juliusson PB, Johnson LK, Hertel JK, Lekhal S, Hjelmesaeth J. Gender-related differences in cardiometabolic risk factors and lifestyle behaviors in treatment-seeking adolescents with severe obesity. BMC Pediatr. Feb 14 2018;18(1):61. doi:10.1186/s12887-018-1057-3 | Study design
Bartfeld JS, Berger L, Men F. Universal access to free school meals through the community eligibility provision is associated with better attendance for low-income elementary school students in Wisconsin. J Acad Nutr Diet. Feb 2020;120(2):210-218. doi:10.1016/j.jand.2019.07.022 | Intervention/exposure
Bastami F, Arash A, Fereshteh Z-A, Mostafavi F. Explaining the dimensions of social support for breakfast and healthy snacks in students: A qualitative study. Int J Adolesc Med Health. Nov 2 2020;34(2):59-66. doi:10.1515/ijamh-2019-0249 | Study design
Bernabe-Ortiz A, Carrillo-Larco RM. Longitudinal association between food frequency and changes in body mass index: A prospective cohort study. BMJ Open. 2020;10(9)doi:10.1136/bmjopen-2020-037057 | Intervention/exposure
Blasetti A, Franchini S, Castorani V, et al. Skipping breakfast is associated with an atherogenic lipid profile in overweight and obese prepubertal children. Int J Endocrinol. 2020;2020:1849274. doi:10.1155/2020/1849274 | Study design
Blaszczyk-Bebenek E, Piorecka B, Plonka M, et al. Risk factors and prevalence of abdominal obesity among upper-secondary students. Int J Environ Res Public Health. May 17 2019;16(10)doi:10.3390/ijerph16101750 | Study design
Bleiweiss-Sande R, Chui K, Wright C, Amin S, Anzman-Frasca S, Sacheck JM. Associations between food group intake, cognition, and academic achievement in elementary schoolchildren. Nutrients. Nov 2019;11(11):2722. doi:10.3390/nu11112722 | Intervention/exposure
Boutelle KN, Manzano MA, Strong DR, Rhee KE. Evaluating the acceptability and feasibility of providing egg or cereal breakfast during a family-based treatment for children with overweight/obesity: The Families and Breakfast Pilot Trial. Child Obes. Dec 2019;15(8):502-509. doi:10.1089/chi.2018.0331 | Design, Comparator
Cao R, Gao T, Ren H, et al. Unique and cumulative effects of lifestyle-related behaviors on depressive symptoms among Chinese adolescents. Int J Soc Psychiatry. Mar 2022;68(2):354-364. doi:10.1177/0020764021996739 | Study design
Centeio EE, Somers CL, Moore EWG, et al. Relationship between academic achievement and healthy school transformations in urban elementary schools in the United States. Phys Educ Sport Peda. 2018;23(4):402-417. doi:10.1080/17408989.2018.1441395 | Intervention/exposure
Chen CY, Hsiao YC. Dual trajectories of breakfast eating and fruit and vegetable intake over a 5-year follow-up period among economically disadvantaged children: Gender differences. Appetite. Feb 1 2018;121:41-49. doi:10.1016/j.appet.2017.10.027 | Outcome
Christensen CB, Mikkelsen BE, Toft U. The effect of introducing a free breakfast club on eating habits among students at vocational schools. BMC Public Health. Apr 3 2019;19(1):369. doi:10.1186/s12889-019-6701-9 | Outcome
Cohen TR, Hazell TJ, Vanstone CA, Rodd C, Weiler HA. Changes in eating behavior and plasma leptin in children with obesity participating in a family-centered lifestyle intervention. Appetite. Jun 1 2018;125:81-89. doi:10.1016/j.appet.2018.01.017 | Study design
Critch JN. School nutrition: Support for providing healthy food and beverage choices in schools. Paediatr Child Health. Feb 2020;25(1):33-46. doi:10.1093/pch/pxz102 | Study design
De Cnop ML, Monteiro LS, Rodrigues PRM, Estima CCP, Veiga GV, Pereira RA. Meal habits and anthropometric indicators in adolescents from public and private schools of the metropolitan region of Rio de Janeiro. Revista De Nutricao-Brazilian Journal of Nutrition. Jan-Feb 2018;31(1):35-47. | Study design
de Souza MR, Neves MEA, Souza AM, et al. Skipping breakfast is associated with the presence of cardiometabolic risk factors in adolescents: Study of Cardiovascular Risks in Adolescents - ERICA. Br J Nutr. Jul 28 2021;126(2):276-284. doi:10.1017/S0007114520003992 | Study design
Deavin N, McMahon AT, Walton K, Charlton K. ‘Breaking barriers, breaking bread’: Pilot study to evaluate acceptability of a school breakfast program utilising donated food. Nutr Diet. Nov 2018;75(5):500-508. doi:10.1111/1747-0080.12478 | Study design
Deger VB, Arslan N, Dag I, CifCi S. Relationship between school performance and breakfast quality in refugee children: Case study of Mardin Region. Iran J Pediatr. Jun 2021;31(3)doi:10.5812/ijp.109584 | Study design
Deniz S, Oguzoncul AF. The prevalence of obesity and related factors among primary and secondary school students. Niger J Clin Pract. Dec 2019;22(12):1685-1692. doi:10.4103/njcp.njcp_173_19 | Setting
Douglas SM, Byers AW, Leidy HJ. Habitual breakfast patterns do not influence appetite and satiety responses in normal vs. high-protein breakfasts in overweight adolescent girls. Nutrients. May 29 2019;11(6)doi:10.3390/nu11061223 | Age
Dubuc MM, Aubertin-Leheudre M, Karelis AD. Lifestyle habits predict academic performance in high school students: The Adolescent Student Academic Performance Longitudinal Study (ASAP). Int J Env Res Pub He. Jan 2020;17(1)doi:10.3390/ijerph17010243 | Intervention/exposure
Farris AR, Roy M, Serrano EL, Misyak S. Impact of breakfast in the classroom on participation and food waste. J Nutr Educ Behav. Jul - Aug 2019;51(7):893-898. doi:10.1016/j.jneb.2019.04.015 | Design, Outcome
Ferrari GLD, Sole D, Pires C, Matsudo V, Katzmarzyk PT, Fisberg M. Correlates of body fat and waist circumference in children from Sao Caetano do Sul, Brazil. Cienc Saude Coletiva. Nov 2019;24(11):4019-4029. doi:10.1590/1413-812320182411.30182017 | Study design
Fisberg M, Kovalskys I, Previdelli AN, et al. Breakfast consumption habit and its nutritional contribution in Latin America: Results from the ELANS Study. Nutrients. Aug 10 2020;12(8)doi:10.3390/nu12082397 | Outcome
Flores YN, Contreras ZA, Ramirez-Palacios P, et al. Increased prevalence of psychosocial, behavioral, and socio-environmental risk factors among overweight and obese youths in Mexico and the United States. Int J Environ Res Public Health. Apr 30 2019;16(9)doi:10.3390/ijerph16091534 | Study design
Forkert ECO, Moraes ACF, Carvalho HB, et al. Skipping breakfast is associated with adiposity markers especially when sleep time is adequate in adolescents. Sci Rep. Apr 23 2019;9(1):6380. doi:10.1038/s41598-019-42859-7 | Study design
Foster GD. Error in statistical code in cluster randomized trial on the effect of a breakfast in the classroom initiative on obesity in urban, school-aged children. JAMA Pediatr. Jul 1 2019;173(7):703-704. doi:10.1001/jamapediatrics.2019.1589 | Study design
Grammatikopoulou MG, Maraki MI, Giannopoulou D, Poulimeneas D, Sidossis LS, Tsigga M. Similar Mediterranean diet adherence but greater central adiposity is observed among Greek diaspora adolescents living in Istanbul, compared to Athens. Ethnic Health. 2018;23(2):221-232. doi:10.1080/13557858.2016.1258043 | Outcome
Habib-Mourad C, Ghandour LA, Maliha C, Awada N, Dagher M, Hwalla N. Impact of a one-year school-based teacher-implemented nutrition and physical activity intervention: Main findings and future recommendations. BMC Public Health. Feb 19 2020;20(1):256. doi:10.1186/s12889-020-8351-3 | Intervention/exposure
Hacioglu DO, Simsek H. The effect of healthy life approaches applied to families of children in preschool on obesity and healthy life behaviour. Progress in Nutrition. Mar 2019;21(1):34-45. doi:10.23751/pn.v21i1.6141 | Age
Hassan BK, Cunha DB, da Veiga GV, Pereira RA, Sichieri R. Changes in breakfast frequency and composition during adolescence: The Adolescent Nutritional Assessment Longitudinal Study, a cohort from Brazil. PLoS One. 2018;13(7):e0200587. doi:10.1371/journal.pone.0200587 | Outcome
Hayes JF, Giles GE, Mahoney CR, Kanarek RB. Breakfast food health and acute exercise: Effects on state body image. Eat Behav. Aug 2018;30:22-27. doi:10.1016/j.eatbeh.2018.05.006 | Age, Intervention/exposure
Hearst MO, Shanafelt A, Wang Q, Leduc R, Nanney MS. Altering the school breakfast environment reduces barriers to school breakfast participation among diverse rural youth. J School Health. Jan 2018;88(1):3-8. doi:10.1111/josh.12575 | Outcome
Hu J, Li Z, Li S, et al. Skipping breakfast and physical fitness among school-aged adolescents. Clinics. 2020;75:e1599. doi:10.6061/clinics/2020/e1599 | Outcome
Huey TC, Siew CY, Ying LP, Bin Masrom SA, Shariff ZBM. Impact of a school nutrition program (SNP) in Malaysia. Ann Nutr Metab. 2019;75(3):366-367. | Outcome
Ichumar SO, Dahlberg EE, Paynter EB, et al. Looking through the keyhole: Exploring realities and possibilities for school breakfast programs in rural Western Australia. Nutrients. Mar 2018;10(3)doi:10.3390/nu10030371 | Study design
Ikeda N, Nishi N. First incidence and associated factors of overweight and obesity from preschool to primary school: Longitudinal analysis of a national cohort in Japan. Int J Obes. Apr 2019;43(4):751-760. doi:10.1038/s41366-018-0307-7 | Study design
Jankowska A, Brzezinski M, Romanowicz-Soltyszewska A, Szlagatys Sidorkiewicz A. Metabolic syndrome in obese children-clinical prevalence and risk factors. Int J Environ Res Public Health. Jan 25 2021;18(3)doi:10.3390/ijerph18031060 | Study design
Jeans MR, Asigbee FM, Landry MJ, et al. Breakfast consumption in low-income Hispanic elementary school-aged children: Associations with anthropometric, metabolic, and dietary parameters. Nutrients. Jul 9 2020;12(7)doi:10.3390/nu12072038 | Study design
Jose K, MacDonald F, Vandenberg M, et al. School breakfast club programs in Australian primary schools, not just addressing food insecurity: A qualitative study. Health Educ Behav. Aug 2020;47(4):619-630. doi:10.1177/1090198120920193 | Setting
Jose K, Vandenberg M, Williams J, Abbott-Chapman J, Venn A, Smith KJ. The changing role of Australian primary schools in providing breakfast to students: A qualitative study. Health Promot J Austr. Jan 2020;31(1):58-67. doi:10.1002/hpja.259 | Study design
Justamente I, Raudeniece J, Ozolina-Moll L, Guadalupe-Grau A, Reihmane D. Comparative analysis of the effects of daily eating habits and physical activity on anthropometric parameters in elementary school children in Latvia: Pach Study. Nutrients. Dec 14 2020;12(12)doi:10.3390/nu12123818 | Study design
Kavezade S, Mozaffari-Khosravi H, Aflatoonian M, Asemi M, Mehrabani S, Salehi-Abargouei A. The effects of whole milk compared to skim milk and apple juice consumption in breakfast on appetite and energy intake in obese children: A three-way randomized crossover clinical trial. BMC Nutr. 2018;4:44. doi:10.1186/s40795-018-0253-8 | Comparator
Kral TVE, Moore RH, Chittams J, et al. Caloric compensation and appetite control in children of different weight status and predisposition to obesity. Appetite. Aug 1 2020;151:104701. doi:10.1016/j.appet.2020.104701 | Comparator
Larson N, Laska MN, Neumark-Sztainer D. Food insecurity, diet quality, home food availability, and health risk behaviors among emerging adults: Findings from the EAT 2010-2018 Study. Am J Public Health. Sep 2020;110(9):1422-1428. doi:10.2105/AJPH.2020.305783 | Outcome
Larson N, Wang Q, Grannon K, Wei S, Nanney MS, Caspi C. A low-cost, grab-and-go breakfast intervention for rural high school students: Changes in school breakfast program participation among at-risk students in Minnesota. J Nutr Educ Behav. Feb 2018;50(2):125-132. doi:10.1016/j.jneb.2017.08.001 | Duplicate
Lee HJ, Kim CH, Han I, Kim SH. Emotional state according to breakfast consumption in 62276 South Korean adolescents. Iran J Pediatr. Dec 2019;29(6)doi:10.5812/ijp.92193 | Study design
Lee I, Bang KS, Moon H, Kim J. Risk factors for obesity among children aged 24 to 80 months in Korea: A decision tree analysis. J Pediatr Nurs. May - Jun 2019;46:e15-e23. doi:10.1016/j.pedn.2019.02.004 | Study design
Lee JJ, Brett NR, Chang JT, de Zepetnek JOT, Bellissimo N. Effects of white potatoes consumed with eggs on satiety, food intake, and glycemic response in children and adolescents. J Am Coll Nutr. Feb 2020;39(2):147-154. doi:10.1080/07315724.2019.1620659 | Intervention/exposure
Lee JJ, Brett NR, Wong VCH, Totosy de Zepetnek JO, Fiocco AJ, Bellissimo N. Effect of potatoes and other carbohydrate-containing foods on cognitive performance, glycemic response, and satiety in children. Appl Physiol Nutr Metab. Sep 2019;44(9):1012-1019. doi:10.1139/apnm-2018-0792 | Intervention/exposure
Lee JY, Ban D, Kim H, et al. Sociodemographic and clinical factors associated with breakfast skipping among high school students. Nutr Diet. Sep 2021;78(4):442-448. doi:10.1111/1747-0080.12642 | Study design
Long MW, Marple K, Andreyeva T. Universal free meals associated with lower meal costs while maintaining nutritional quality. Nutrients. Feb 19 2021;13(2)doi:10.3390/nu13020670 | Outcome
Martinez Arroyo A, Corvalan Aguilar C, Palma Molina X, Ceballos Sanchez X, Fisberg RM. Dietary patterns of adolescents from the Chilean Growth and Obesity Cohort Study indicate poor dietary quality. Nutrients. Jul 14 2020;12(7)doi:10.3390/nu12072083 | Design, Intervention/exposure
Masoomi H, Taheri M, Irandoust K, H’Mida C, Chtourou H. The relationship of breakfast and snack foods with cognitive and academic performance and physical activity levels of adolescent students. Biol Rhythm Res. Apr 2 2020;51(3):481-488. doi:10.1080/09291016.2019.1566994 | Study design
McKeon GP, Shukaitis J, Cuite CL. Teachers’ perceptions and attitudes toward breakfast in the classroom: The importance of health. J Sch Health. Sep 2021;91(9):741-749. doi:10.1111/josh.13064 | Design, Comparator
Merlo CL, Jones SE, Michael SL, et al. Dietary and physical activity behaviors among high school students - Youth Risk Behavior Survey, United States, 2019. MMWR Suppl. Aug 21 2020;69(1):64-76. doi:10.15585/mmwr.su6901a8 | Intervention/exposure, Outcome
Metro D, Papa M, Manasseri L, et al. Mediterranean diet in a Sicilian student population. Second part: breakfast and its nutritional profile. Nat Prod Res. Aug 2020;34(16):2255-2261. doi:10.1080/14786419.2018.1452016 | Study design
Nicklas TA. Summary on importance of breakfast for children’s health and development. Nestle Nutr Inst Workshop Ser. 2019;91:179. doi:10.1159/000493711 | Study design
Ober P, Sobek C, Stein N, et al. And yet again: Having breakfast is positively associated with lower BMI and healthier general eating behavior in schoolchildren. Nutrients. Apr 18 2021;13(4)doi:10.3390/nu13041351 | Study design
Onnerfalt J, Erlanson-Albertsson C, Montelius C, Thorngren-Jerneck K. Obese children aged 4-6 displayed decreased fasting and postprandial ghrelin levels in response to a test meal. Acta Paediatr. Mar 2018;107(3):523-528. doi:10.1111/apa.14165 | Design, Comparator
Pablos A, Nebot V, Vano-Vicent V, Ceca D, Elvira L. Effectiveness of a school-based program focusing on diet and health habits taught through physical exercise. Controlled Clinical Trial; Journal Article; Multicenter Study. Appl Physiol Nutr Me. Apr 2018;43(4):331-337. doi:10.1139/apnm-2017-0348 | Design, Intervention/exposure
Palla L, Almoosawi S. Diurnal patterns of energy intake derived via principal component analysis and their relationship with adiposity measures in adolescents: Results from the National Diet and Nutrition Survey RP (2008(-)2012). Nutrients. Feb 17 2019;11(2)doi:10.3390/nu11020422 | Intervention/exposure
Pasman WJ, Hendriks HFJ, Minekus MM, et al. Subjective feelings of appetite of wholegrain breakfasts evaluated under controlled, laboratory and ‘at home’ conditions. Physiol Behav. Oct 1 2018;194:285-291. doi:10.1016/j.physbeh.2018.06.024 | Age
Peña-Jorquera H, Campos-Núñez V, Sadarangani KP, et al. Breakfast: A crucial meal for adolescents’ cognitive performance according to their nutritional status. The Cogni-Action Project. Nutrients. 2021;13(4):1320. doi:10.3390/nu13041320 | Duplicate article
Rito AI, Dinis A, Rascoa C, et al. Improving breakfast patterns of portuguese children-an evaluation of ready-to-eat cereals according to the European nutrient profile model. Eur J Clin Nutr. Mar 2019;73(3):465-473. doi:10.1038/s41430-018-0235-6 | Outcome
Sevil J, Garcia-Gonzalez L, Abos A, Generelo E, Aibar A. Can high schools be an effective setting to promote healthy lifestyles? Effects of a multiple behavior change intervention in adolescents. J Adolesc Health. Apr 2019;64(4):478-486. doi:10.1016/j.jadohealth.2018.09.027 | Intervention/exposure
Shirazi MG, Kazemi A, Kelishadi R, Mostafavi F. The improvement of dietary behaviors among Iranian adolescent girls: a theory-based randomized controlled trial. Health Education Research. Apr 2019;34(2):159-172. doi:10.1093/her/cyz004 | Intervention/exposure
Sila S, Ilic A, Misigoj-Durakovic M, Soric M, Radman I, Satalic Z. Obesity in adolescents who skip breakfast is not associated with physical activity. Nutrients. Oct 18 2019;11(10)doi:10.3390/nu11102511 | Study design
Smith AP, Richards G. Energy drinks, caffeine, junk food, breakfast, depression and academic attainment of secondary school students. J Psychopharmacol. Aug 2018;32(8):893-899. doi:10.1177/0269881118783314 | Intervention/exposure
Stennett M, Blokland A, Watt RG, Heilmann A. Mid-adolescent ethnic variations in overweight prevalence in the UK Millennium Cohort Study. Eur J Public Health. Apr 24 2021;31(2):396-402. doi:10.1093/eurpub/ckab023 | Study design
Stokes N, Spruance L, Patten EV, Lybbert EK. Teachers’ experience and perspectives of traditional breakfast and breakfast in the classroom. J Nutr Educ Behav. Sep 2019;51(8):936-945. doi:10.1016/j.jneb.2019.04.004 | Duplicate article
Tan ML, Laraia B, Madsen KA, Johnson RC, Ritchie L. Community eligibility provision and school meal participation among student subgroups. J Sch Health. Oct 2020;90(10):802-811. doi:10.1111/josh.12942 | Study design
Teng CY, Chin YS, Taib MNM, Chan YM. Evaluation of the effectiveness of a 3-year, teacher-led healthy lifestyle program on eating behaviors among adolescents living in day school hostels in Malaysia. Food Nutr Bull. Dec 2018;39(4):595-607. doi:10.1177/0379572118795358 | Outcome
Teo CH, Chin YS, Lim PY, Masrom SAH, Shariff ZM. Impacts of a school-based intervention that incorporates nutrition education and a supportive healthy school canteen environment among primary school children in Malaysia. Nutrients. May 18 2021;13(5)doi:10.3390/nu13051712 | Intervention/exposure
Terry AL, Wambogo E, Ansai N, Ahluwalia N. Breakfast intake among children and adolescents: United States, 2015-2018. NCHS Data Brief. Oct 2020;(386):1-8. | Publication status
Tilles-Tirkkonen T, Nuutinen O, Sinikallio S, Poutanen K, Karhunen L. Theory-informed nutrition education curriculum Tools For Feeling Good promotes healthy eating patterns among fifth grade pupils: Cross-sectional study. J Hum Nutr Diet. Oct 2018;31(5):647-657. doi:10.1111/jhn.12568 | Intervention/exposure
Troiano G, Simi R, Mercurio I, et al. “OKKIO alla salute 2014” results from the Tuscan sample. Ann Ig. Jul-Aug 2018;30(4):259-272. doi:10.7416/ai.2018.2218 | Study design
Turner L, Guthrie JF, Ralston K. Community eligibility and other provisions for universal free meals at school: Impact on student breakfast and lunch participation in California public schools. Transl Behav Med. Oct 1 2019;9(5):931-941. doi:10.1093/tbm/ibz090 | Intervention/exposure
Vaidehi U, Shashikala S, Mirnalini K. Association between food habits and nutritional status of secondary school students in Kuala Lumpur, Malaysia: Baseline findings from Nuteen project. J Nutr Sci Vitaminol. 2020;66:S256-S261. doi:10.3177/jnsv.66.S256 | Study design
Valizadeh P, Ng SW. The New school food standards and nutrition of school children: Direct and indirect effect analysis. Econ Hum Biol. Dec 2020;39:100918. doi:10.1016/j.ehb.2020.100918 | Intervention/exposure, Outcome
Vaudrin N, Lloyd K, Yedidia MJ, Todd M, Ohri-Vachaspati P. Impact of the 2010 US Healthy, Hunger-Free Kids Act on School Breakfast and Lunch Participation Rates Between 2008 and 2015. Am J Public Health. Jan 2018;108(1):84-86. doi:10.2105/Ajph.2017.304102 | Study design
Vik FN, Naess IK, Heslien KEP, Overby NC. Possible effects of a free, healthy school meal on overall meal frequency among 10-12-year-olds in Norway: The School Meal Project. BMC Res Notes. Jul 5 2019;12(1):382. doi:10.1186/s13104-019-4418-6 | Outcome
Vilela S, Correia D, Severo M, et al. Eating frequency and weight status in Portuguese children aged 3-9 years: Results from the cross-sectional National Food, Nutrition and Physical Activity Survey 2015-2016. Public Health Nutr. Oct 2019;22(15):2793-2802. doi:10.1017/S1368980019000661 | Study design
Vilela S, Oliveira A, Severo M, Lopes C. Chrono-nutrition: The relationship between time-of-day energy and macronutrient intake and children’s body weight status. J Biol Rhythms. Jun 2019;34(3):332-342. doi:10.1177/0748730419838908 | Age
Wadolowska L, Hamulka J, Kowalkowska J, et al. Changes in sedentary and active lifestyle, diet quality and body composition nine months after an education program in polish students aged 11-12 years: Report from the ABC of Healthy Eating Study. Nutrients. Feb 2019;11(2)doi:10.3390/nu11020331 | Design, Intervention/exposure
Weng CB, Sheu JJ, Chen HS. Factors associated with unhealthy weight control behaviors among a representative sample of U.S. high school students. J Sch Nurs. Oct 19 2020;doi:10.1177/1059840520965497 | Outcome
Whisner CM, Angadi SS, Weltman NY, et al. Effects of low-fat and high-fat meals, with and without dietary fiber, on postprandial endothelial function, triglyceridemia, and glycemia in adolescents. Nutrients. Nov 2 2019;11(11)doi:10.3390/nu11112626 | Comparator
Wu CH, Lin CY, Hsieh YP, et al. Dietary behaviors mediate the association between food insecurity and obesity among socioeconomically disadvantaged youth. Appetite. Jan 1 2019;132:275-281. doi:10.1016/j.appet.2018.10.013 | Study design
Xu H, Ecker O, Zhang Q, et al. The effect of comprehensive intervention for childhood obesity on dietary diversity among younger children: Evidence from a school-based randomized controlled trial in China. PLoS One. 2020;15(7):e0235951. doi:10.1371/journal.pone.0235951 | Intervention/exposure
Yaguchi-Tanaka Y, Tabuchi T. Skipping breakfast and subsequent overweight/obesity in children: A nationwide prospective study of 2.5- to 13-year-old children in Japan. J Epidemiol. Jul 5 2021;31(7):417-425. doi:10.2188/jea.JE20200266 | Age
Yao J, Liu Y, Zhou S. Effect of eating breakfast on cognitive development of elementary and middle school students: An empirical study using large-scale provincial survey data. Med Sci Monit. Nov 22 2019;25:8843-8853. doi:10.12659/MSM.920459 | Study design
Yasuda J, Gomi T, Kotemori A, et al. Breakfast before resistance exercise lessens urinary markers of muscle protein breakdown in young men: A crossover trial. Nutrition. Mar 2021;83doi:10.1016/j.nut.2020.111088 | Age, Intervention/exposure
Yilmazbas P, Gokcay G. Assesment of obesogenic factors in school-age children. Turk J Pediatr. 2021;63(2):185-192. doi:10.24953/turkjped.2021.02.001 | Study design
You Y, Zhang F, Han J, et al. Breakfast preferences and consumption location among children at a median age of 7 in Shenzhen: Implications for managing overweight and obesity. Appetite. Jan 1 2021;156:104851. doi:10.1016/j.appet.2020.104851 | Intervention/exposure
Zakrzewski-Fruer JK, Wells EK, Crawford NSG, Afeef SMO, Tolfrey K. Physical activity duration but not energy expenditure differs between daily and intermittent breakfast consumption in adolescent girls: A randomized crossover trial. J Nutr. 2018;148(2):236-244. doi:10.1093/jn/nxx055 | Outcome
Zeinstra GG, Vingerhoeds MH, Vrijhof M, van Mourik S, Houtzager RN, van Kleef E. Changing the behaviour of children living in Dutch disadvantaged neighbourhoods to improve breakfast quality: Comparing the efficacy of three school-based strategies. Appetite. Jun 1 2019;137:163-173. doi:10.1016/j.appet.2019.02.011 | Outcome