# Appendix 1 Abbreviations

Table A1 1 Abbreviations from Key Question 1a: What is the relationship between eating breakfast and school performance?

Abbreviation | Meaning
BMI | Body Mass index
CHO | Carbohydrate
CPT | Continuous Performance Test
DSM-5 | Diagnostic and Statistical Manual of Mental Disorders, fifth edition
FSM | Free School Meal
GI | Glycemic Index
HDI | Human Development Index
IQ | Intelligence Quotient
LGT3 | Lern- und Gedaechtnistest
RCT | Randomized controlled trial
RTEC | Ready-to-eat-cereal
SES | Socio-economic status
TOMAL | The Test of Memory and Learning
USDA | U.S. Department of Agriculture
WIAT | Wechsler Individual Achievement Test
WISC | Wechsler Intelligence Scale for Children
WRAT | Wide Range Achievement Test
WRAML | Wide Range Assessment of Memory and Learning

Table A1 2 Abbreviations from Key Question 1b: What is the relationship between eating breakfast and weight-related outcomes?

Abbreviation | Meaning
BMI | Body Mass Index
kcal | Kilocalories
NESR | Nutrition Evidence Systematic Review
SES | Socioeconomic status

Table A1 3 Abbreviationsfrom Key Question 1c: What is the relationship between eating breakfast and health?

Abbreviation | Meaning
AUC | Area under the curve
BMI | Body mass index
cm | Centimeters
g | Grams
GLP-1 | Glucagon-like peptide-1
HDL | High-density lipoprotein
HOMA-IR | Homeostasis model of insulin resistance
kcal | Kilocalories
kj | Kilojoules
LDL | Low-density lipoprotein
m | Meters
mL | Milliliters
mm | Millimeters
mmHg | Millimeters of mercury
mmol/L | Millimoles per liter
PYY | Peptide YY
SES | Socioeconomic status
VO_2max_ | Maximal oxygen consumption

Table A1 4 Abbreviations from Key Question 2: What best practices exist in the U.S. School Breakfast Program, including models of student costs and breakfast delivery?

Abbreviation | Meaning
BAB | Breakfast-after-the-bell
BIC | Breakfast in the classroom
BMI | Body Mass index
CEP | Community Eligibility Provision
ES | Elementary school
FRP | Free- or reduced-price
GPA | Grade point average
HEI | Healthy Eating Index
HS | High school
K | Kindergarten
MS | Middle school
NESR | Nutrition Evidence Synthesis Review
NRCT | Randomized controlled trial
RCT | Non-randomized controlled trial
SCB | Second chance breakfast
SES | Socioeconomic status
SNAP-Ed | Supplemental Nutrition Assistance Program Education
UFB | Universal free breakfast