# ACKNOWLEDGEMENTS

Flavor exposure & Feeding practices Technical Expert Collaborative (TEC):

- Sara Benjamin-Neelon, PhD, MPH, RD, Johns Hopkins University
- Leann Birch, PhD, University of Georgia
- Maureen Black, PhD, University of Maryland School of Medicine and RTI International
- Ronette Briefel, DrPH, MPH, RD, Mathematica Policy Institute
- John Cook, PhD, MAEd, Boston Medical Center
- Myles Faith, PhD, University at Buffalo
- Julie Mennella, PhD, Monell Chemical Senses Center

Nutrition Evidence Systematic Review (NESR) Team:

- Maureen Spill^i^, PhD, Panum Group, Lead analyst
- Emily Gower^i^, MS, Panum Group, Analyst (from 11/2016)
- Kirsten Johns^i^, MS, Panum Group, Analyst (until 01/2017)
- Myra Shapiro^i^, PhD, Panum Group, Analyst (from 01/2017)
- Joanne Spahn, MS, USDA, Analyst
- Yat Ping Wong, MLS, MPH, USDA, Librarian
- Nancy Terry, MLS, NIH, Librarian

Project Leads:

- Kellie Casavale, PhD, RD, HHS
- Joanne Spahn, MS, RD, FADA, USDA
- Eve Essery Stoody, PhD, USDA

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) Liaisons:

- Andrea Farmer, MS, RD, LD, USDA (until 05/2016)
- Heather Hamner, PhD, MS, MPH, CDC (from 05/2016)
- Cria Perrine, PhD, CDC (from 10/2016)

All TEC and NESR team members, Project leads, and FEG-TEC liaisons participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. MKS and KJ facilitated and conducted the review. YPW searched the databases. LB, MMB, RB, JTC, MSF, JAM, and SBN substantial input in all levels of the review including development of protocol, evidence synthesis, conclusion statement, grade, research recommendations. KOC provided project oversight. All authors critically reviewed and approved the final report. The authors declare no conflicts of interest.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.