# List of abbreviations

Abbreviation: Full name
COI: Conflict of interest
HDI: Human Development Index
NEL: Nutrition Evidence Library
P/B-24 project: Pregnancy and Birth to 24 Months Project
SR: Systematic review
USDA: United States Department of Agriculture
TEC: Technical Expert Collaborative
COI: Conflict of interest