# List of abbreviations

Abbreviation: Full name
AHEI: Alternative Healthy Eating Index
AMDR: Acceptable Macronutrient Distribution Range
DASH: Dietary Approaches to Stop Hypertension
DII: Dietary Inflammatory Index
DP: Dietary pattern
EVOO: Extra virgin olive oil
FFQ: Food frequency questionnaire
GDM: Gestational diabetes mellitus
GWG: Gestational weight gain
HDI: Human Development Index
HEI: Healthy Eating Index
HFII: Healthy Food Intake Index
HHS: Department of Health and Human Services
IOM: Institute of Medicine
MDA: Mediterranean Diet Adherence
MDQS: Maternal Diet Quality Score
MED: Mediterranean
NESR: Nutrition Evidence Systematic Review
NFFD: Norwegian Fit for Delivery Diet
NND: New Nordic Diet
PCA: Principal component analysis
PPWL: Postpartum weight loss
PUFA: Polyunsaturated fatty acid
RCT: Randomized controlled trial
rMED: Relative Mediterranean Diet
RoB: Risk of bias
SES: Socioeconomic status
USDA: United States Department of Agriculture