# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED DURING PREGNANCY AND GESTATIONAL WEIGHT GAIN?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed during pregnancy and gestational weight gain?

### What is the answer to the question?

- Limited evidence suggests that certain dietary patterns during pregnancy are associated with a lower risk of excessive gestational weight gain during pregnancy. These patterns are higher in vegetables, fruits, nuts, legumes, fish, and lower in added sugar, and red and processed meat.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Pregnancy and Lactation Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- The population of interest is generally healthy, pregnant women.

### What evidence was found?

- This review includes 26 articles published between 2009 and 2019.
- Many studies showed that “beneficial” dietary patterns were related to less weight gain during pregnancy.
- Dietary patterns that were consistently related to less weight gain during pregnancy were:
  ○ higher in vegetables, fruits, nuts, legumes, fish, and
  ○ lower in added sugar, red and processed meat.
- The body of evidence is limited in several ways:
  ○ Studies were mostly observational and cause-effect relationships between diet and weight gain during pregnancy were therefore difficult to determine.
  ○ There was little racial/ethnic, socioeconomic, and age diversity in these studies.
  ○ It was difficult to compare studies due to inconsistencies in how diets were measured.
  ○ There were concerns about potential bias of the studies.
  ○ Many studies were not designed to study the relationship between dietary patterns and weight gain during pregnancy.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to November 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed during pregnancy and gestational weight gain?

### Conclusion statement and grade

Limited evidence suggests that certain dietary patterns during pregnancy are associated with a lower risk of excessive gestational weight gain during pregnancy. These patterns are higher in vegetables, fruits, nuts, legumes, fish, and lower in added sugar, and red and processed meat. (Grade: Limited)

### Summary of the evidence

- This systematic review includes 26 articles,^1–26^ including five articles from four randomized controlled trials (RCTs) and 21 articles from 19 prospective cohort studies published between 2009 and 2019.
- Articles included in this review assessed one of the following interventions/exposures during pregnancy:
  ○ Dietary patterns (DP) (24 studies).
  ○ Diets based on macronutrient distributions outside of the acceptable macronutrient distribution range (AMDR) (2 studies).
- Eight of the 15 articles that assessed maternal DPs using an index/score method showed an association with gestational weight gain (GWG):
  ○ Five of the eight articles showed that greater adherence to a DP (identified as beneficial by the study) was associated with lower GWG.
  ○ Three articles showed that greater adherence to a DP (identified as beneficial by the study) was associated with greater GWG in all participants or only women with obesity.
- Four of the five articles that assessed maternal DPs using a factor or cluster analysis showed one or more associations between adherence to DPs and GWG.
  ○ One article showed that greater adherence to a DP (identified as beneficial by the study) was associated with lower GWG.
  ○ Four articles showed that greater adherence to a DP (identified as detrimental by the study) was associated with higher GWG.
- One study that assessed maternal DPs using reduced rank regression showed that greater adherence to a DP was associated with higher GWG.
- Two RCTs showed that participants randomized to a DP (identified as beneficial by the study) had lower GWG
- One RCT and one prospective cohort study showed no association between maternal consumption of a diet higher in fat (i.e., >35 percent of total energy from fat, which is greater than the AMDR) and GWG
- Although the DPs examined were characterized by combinations of different foods and beverages, the patterns that were consistently shown to be associated with lower risk of excessive GWG were: higher in vegetables, fruits, nuts, legumes, and fish and lower in added sugar and red and processed meat.
  ○ Not all foods were part of the same DP. The evidence did not show a consistent association between grains or dairy and GWG.
- The ability to draw strong conclusions was limited by the following issues:
  ○ There were few RCTs and thus data were primarily observational in nature, limiting the ability to determine causal effects of DPs on GWG.
  ○ Key confounders were not consistently controlled for in most of the studies.
  ○ Studies had risk-of-bias issues, including exposure misclassification, self-reported outcomes, and selection bias.
  ○ Most of the studies were not designed to assess the association between DPs and GWG.
  ○ People with lower SES, adolescents, and racially and ethnically diverse populations were underrepresented in the body of evidence.

### Description of the evidence

This systematic review included articles that address the relationship between dietary patterns and/or diets based on macronutrient distributions outside of the AMDR during pregnancy and gestational weight gain (GWG). The search included articles from high and very high Human Development Index^ii^ countries and the search time frame spanned between January 2000 and November 2019. Studies considered in this body of evidence included pregnant women who were generally healthy. The following study designs were included: randomized controlled trials (RCTs), non-randomized controlled trials, prospective and retrospective cohort studies, and nested case-control studies.

This body of evidence includes 26 articles, including five from four RCTs^22–26^ and 21 from 19 prospective cohort studies.^1–21^ A total of 23 distinct trials/cohort studies are represented in this body of evidence. References are included for each study in Table 1 with trial/cohort names or locations when names were unavailable. Six studies were conducted in the U.S.^6,7,9,11–13,16,25^ In addition, three studies were conducted in Spain,^1,2,23,26^ two each in the U.K.,^22,24^ Norway,^5,21^ and Japan^3,4^; and one each in Mexico,^18^ Italy,^19^ Poland,^17^ Iceland,^14^ Finland,^10^ the Netherlands,^8^ China,^15^ and Malaysia.^20^

Table 1 Included trials and cohorts

Trial/Cohort name | Reference number(s)
Randomized Controlled Trials
Effect of Simple, Targeted Diet in Pregnant Women With Metabolic Risk Factors on Pregnancy Outcomes (ESTEEM) trial | ^22^
St. Carlos GDM prevention study | ^23^ ^,^ ^26^
Maternal Offspring Metabolics Family Intervention Trial (MOMFIT) | ^25^
U.K. Pregnancies Better Eating and Activity Trial (UPBEAT) | ^24^
Prospective Cohort Studies
Mamma & Bambino | ^19^
Osaka Maternal and Child Health Study (OMCHS) | ^3^
Generation R Study | ^8^
Born in Guangzhou Cohort Study (BIGCS) | ^15^
Polish Mother and Child Cohort | ^17^
Pregnancy Research on Inflammation, Nutrition and City Environments: Systematic Analyses (PRINCESA) | ^18^
New Hampshire Birth Cohort Study (NHBCS) | ^13^
INfancia y Medio Ambiente (INMA) | ^1^
Project Viva | ^6^ ^,^ ^9^ ^,^ ^12^
Mérida Cohort | ^2^
Norwegian Fit for Delivery (NFFD) | ^21^
Norwegian Mother and Child Cohort Study (MoBa) | ^5^
PREgnant Women of Iceland (PREWICE) | ^14^
Control arm of RADIEL trial | ^10^
Infant Feeding Practices Study II (IFPSII) | ^7^
Seremben Cohort Study (SECOST) | ^20^
Pregnancy Environment and Lifestyle Study (PETALS) | ^16^
Healthy Start | ^11^
Tokyo (Japan) | ^4^

Subject characteristics:

- Sample sizes of the studies ranged from 35^2^ to 66,597^5^ participants.
- Almost all of the studies were conducted in adult women (18-45 y) who had singleton pregnancies. Of note, Fulay et al^12^ and Wedolowska et al^17^ enrolled mothers as young as 15 y and 17 y, respectively.
- Health characteristics:
  ○ [underlined: Prepregnancy BMI]: Seven studies enrolled predominantly or exclusively overweight or obese women.^7,10,11,16,18,24,25^ In addition, Al Wattar et al enrolled women with metabolic risk factors, including women with obesity.^22^
  ○ [underlined: Diabetes]: 10 studies excluded women with a previous diagnosis of type 1 and/or 2 diabetes mellitus (as defined by the studies).^5,9–12,16,17,19,21,22,25^ Two studies excluded women with one or more of the following conditions: gestational diabetes, hypertension, and preeclampsia.^18,19^ In an RCT conducted in Spain, the authors noted that approximately 25 percent of the participants had a family history of type 2 diabetes mellitus.^23,26^
- Race/ethnicity: Thirteen of the 26 articles noted that the participants were predominantly or exclusively White (defined as ≥50 percent of the participants).^2,6–9,11–13,21,23–26^ Nine studies did not report race/ethnicity.^1,3,5,10,14,15,17–19^ Yong et al^20^ reported that 89 percent of the participants were Malay and Tajima et al^4^ noted that 100 percent of their participants were Japanese. Zhu et al^16^ reported that the participants were predominantly Hispanic (approximately 41.3 percent) and Al Wattar et al^22^ noted that the participants were predominantly Asian (approximately 43.7 percent).
- Socio-economic status:
  ○ [underlined: Maternal education]:
    ■ A majority of the studies reported that the participants had some college education.^6–9,11–16,23,25,26^ When studies reported the years of education, most noted that a majority of the participants had ≥12 y of education.^3,17,20,21^ Maugeri et al^19^ noted that < 20 percent of the participants had low-medium education (defined as ≤ 8 y of education), but did not give other details. Similarly, Gesteiro et al^2^ reported that 83 percent of the participants had medium or high education (but did not categorize education further).
    ■ However, the following were exceptions: Ancira-Moreno et al noted that >50 percent of the participants had < 9 y of education.^18^ Fernandez-Barres et al^1^ reported that 63.6 percent of the participants had secondary education or less.
    ■ Four studies did not report maternal education.^4,5,22,24^
      (Note: Fulay et al,^12^ who used Project Viva data, reported that approximately 32 percent of their participants had a college education, whereas Rifas-Shiman et al^6^ and Sen et al,^9^ who also used Project Viva data with a similar sample size as Fulay et al, reported that approximately 69 percent had college degrees).
  ○ [underlined: Income]: In the 17 articles that reported household income and/or participant employment status, the majority of women were employed and/or from middle-to-high income households.^1,3,6–9,12,15–17,19,21,23,25,26^ Two studies^20,24^ reported that the majority of participants were from low SES backgrounds.

#### Interventions/Exposures

##### Dietary Patterns

Dietary pattern (DP) was defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they were habitually consumed. At minimum, there had to be a description of the foods and beverages in the pattern. Dietary patterns may have been measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.

Dietary patterns were assessed using 1) index/score analysis, 2) factor analysis and principal component analysis (PCA), 3) experimental diet, and 4) reduced rank regression. A description of the studies categorized by the method used to measure dietary patterns is included below:

###### Index/Score Analysis

Fifteen articles included in this review used one or more of the following indices/scores summarized below:

- Maternal Diet Quality Score (MDQS)^18^
- Alternative Healthy Eating Index (AHEI) and its modifications^6,7,13^
- Healthy Eating Index (HEI)^2,16,20^
- relative Mediterranean Diet (rMED) score^1^
- Dietary Approaches to Stop Hypertension (DASH) and its modifications^12^
- Mediterranean Diet Adherence (MDA)^2^
- New Nordic Diet (NND)^5^
- Norwegian Fit for Delivery (NFFD) Diet^21^
- Dietary risk scores^14^
- Healthy Food Intake Index (HFII)^10^
- Dietary Inflammatory Index (DII)^9^
- Dutch Healthy Diet Index^8^

###### Factor analysis and PCA

Five studies included in this review assessed dietary patterns using factor analysis or PCA.^3,8,15,17,19^

###### Experimental Diet

Three RCTs^22,23,25,26^ in this review assigned participants to an experimental diet (i.e. Mediterranean diet, DASH diet) or a control diet.

###### Reduced Rank Regression

One study^11^ assessed adherence to DPs (patterns 1 and 2) derived using reduced rank regression.

Table 2 Dietary pattern components^iii^

Reference | Dietary pattern | Dietary components
Index/Score Analysis
Ancira-Moreno et al^18^ | MDQS | Vegetables and fruits; legumes; low-fat dairy products; PUFAs (positive); Red meat; added sugars; foods high in saturated fat or added sugar (negative)
Emond et al^13^ | AHEI-2010 | Vegetables; fruits; whole grains; nuts and legumes; long-chain (n-3) fats; PUFAs (positive); Red and processed meats; sugar-sweetened beverages and fruit juice; trans fats; sodium (negative); Alcohol component excluded
Fernández-Barrés et al^1^ | rMED | Vegetables; fruits and nuts; cereals; legumes; fish; olive oil (positive); Meat; dairy (negative); Alcohol component excluded
Fulay et al^12^ | DASH | Vegetables; fruits; whole grains; nuts and legumes; low-fat dairy (positive); Red and processed meat; sugar-sweetened beverages; sodium (negative)
Fulay et al^12^ | DASH OMNI | Vegetables; fruits; whole grains; nuts and legumes; low-fat dairy; PUFAs; MUFAs (positive); Red and processed meat; sugar-sweetened beverages; sodium (negative)
Gesteiro et al^2^ | HEI | Vegetables; fruits; cereals, grains, and legumes; meat, eggs, and fish; milk and dairy products; dietary variety; Total fats; SFAs; cholesterol; sodium
Gesteiro et al^2^ | MDA | Total vegetables; raw vegetables; fruits (including natural fruit juices); legumes; nuts (including peanuts); chicken, turkey, or rabbit meat; fish or shellfish; olive oil; dishes seasoned with sofrito (positive); Red meat, veal, hamburger, or sausage; butter, margarine or cream; sweet or carbonated beverages; commercial sweets or pastries (negative); Alcohol component excluded
Hillesund et al 2014^5^ | NND | Root vegetables; cabbages; potatoes relative to rice and pasta; Nordic fruits; foods from the wild countryside (game, fish, seafood, and native berries); whole grain breads relative to refined breads; oatmeal porridge; unsweetened milk relative to fruit juice; water relative to sweetened beverages; meal frequency (positive)
Hillesund et al 2018^21^ | NFFD diet | Vegetables with dinner; fruits or vegetables as snacks; water relative to other beverages; small portion size of one or more unhealthy food items (soda, salty crisps, or chocolate); meal frequency; never eating sweets and snacks without appreciation; reading nutrition labels (positive); Sugar-rich food items; fast-foods, snacks, or other salty food; eating beyond satiety (negative)
Hrolfsdottir et al^14^ | Dietary risk score (13 risk factors) | Low intake of vegetables and fruits; whole grains; beans, nuts, and seeds; dairy; fish; vitamin D; Low dietary variety; High intake of processed meat; french fries and fried potatoes; dairy; sweets, ice cream, cakes, and cookies; sugar and artificially sweetened beverages; butter relative to oil
Hrolfsdottir et al^14^ | Dietary risk score (6 risk factors) | Low intake of vegetables and fruits; whole grains; dairy; Low dietary variety; High intake of dairy; sugar and artificially sweetened beverages
Hrolfsdottir et al^14^ | Dietary risk score (4 risk factors) | Low intake of whole grains; dairy; High intake of dairy; sugar and artificially sweetened beverages
Meinila et al^10^ | HFII | Vegetables; fruits and berries; high-fiber grains; fish; low-fat milk; low-fat cheese; vegetable oils as cooking fat; oil-based fat spreads (positive); Sugar-sweetened beverages (including juice); fast food; snacks with added sugar or salt (negative)
Poon et al^7^ | AHEI-P | Vegetables; whole fruit; whole grains; nuts and legumes; long-chain (n-3) fats; PUFAs; calcium; folate; iron (positive); Red and processed meats; sugar-sweetened beverages; trans fats; sodium (negative); Alcohol component excluded
Rifas-Shiman et al^6^ | AHEI-P | Vegetables (includes tofu and soybeans); fruits; ratio of white (poultry, fish) to red meat (beef, pork, lamb, processed); ratio of PUFAs to SFAs; fiber; calcium; folate; iron (positive); Trans fats (negative); Alcohol and nut components excluded
Sen et al^9^ | DII | Vegetables; fruits; whole grains; fish and seafood; whole eggs (positive); Red and processed meat; sugar-sweetened soda (negative)
Tielemans et al^8^ | Dutch Healthy Diet Index | Vegetables; fruits; fish; fiber (positive); SFAs; sodium (negative); Alcohol, acidic food and drink, and trans fat components excluded
Yong et al^20^ | Modified HEI for Malaysians | Vegetables; fruits; cereals and grains; legumes; poultry, meat, and eggs; fish and seafood; milk and milk products; total fats; sodium (negative)
Zhu et al^16^ | HEI-2010 | Total vegetables; beans and greens; total fruit; whole fruit; whole grains; total protein foods; seafood and plant proteins; dairy; ratio of PUFAs and MUFAs to SFAs (positive); Refined grains; calories from solid fats and added sugars; sodium (negative); Alcohol component excluded
Factor Analysis and PCA^iv^
Maugeri et al^19^ | Western | High intake of red meat, fries, dipping sauces, salty snacks and alcoholic drinks
Maugeri et al^19^ | Prudent | High intake of boiled potatoes, cooked vegetables, legumes, pizza and soup
Okubo et al^3^ | Meat and eggs | High intake of beef and pork, processed meat, chicken, eggs, butter, and dairy products
Okubo et al^3^ | Wheat products | High intake of bread, confectioneries, fruit and vegetable juice, and soft drinks
Okubo et al^3^ | Rice, fish, and vegetables | High intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup, and salt-containing seasoning
Tielemans et al^8^ | Vegetable, Oil and Fish | High intake of vegetables, oil, and fish
Tielemans et al^8^ | Nuts, High-Fiber Cereals, and Soy | High intake of nuts, high-fiber cereals, and soy
Tielemans et al^8^ | Margarine, Sugar, and Snacks | High intake of margarine, sugar, and snacks
Wei et al^15^ | Cereals | Richer in cereals
Wei et al^15^ | Vegetables | Richer in vegetables
Wei et al^15^ | Meats | Richer in meats
Wei et al^15^ | Fruits | Richer in fruits
Wei et al^15^ | Fish, beans, nuts, and yogurt | Richer in fish, beans, nuts, and yogurt
Wei et al^15^ | Milk and milk powder | Richer in milk and milk powder
Wesolowska et al^17^ | Western | High intake of refined grains, processed meat, potatoes, and very low intake of whole grains
Wesolowska et al^17^ | Mixed | Intake between Western and Prudent
Wesolowska et al^17^ | Prudent | High intake of fruit, vegetables, legumes, whole grains, poultry, and low-fat dairy products
Experimental Diet
Al Wattar et al^22^ | MED-style Diet | High consumption of nuts, extra virgin olive oil, fruits, vegetables, non-refined grains, and legumes; moderate-to-high consumption of fish; low-to-moderate amounts of poultry and dairy products, such as yogurt and cheese; low consumption of red meat and processed meat; avoidance of sugary drinks, fast food, and foods rich in animal fat. Mixed nuts (walnuts, hazelnuts, and almonds) and EVOO provided by investigators.
Al Wattar et al^22^ | Control | Diet recommended as per U.K. national recommendations for antenatal care
Assaf-Balut et al^23,26^ | Control | Mediterranean Diet: High consumption of vegetables, fruit (avoiding juices), skimmed dairy products, whole grain cereals, and legumes; moderate-to-high consumption of fish; low consumption of red and processed meat; avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods, and precooked meals; restriction of dietary fat, including EVOO and nuts
Assaf-Balut et al^23,26^ | Intervention | Mediterranean Diet plus EVOO and pistachios provided by investigators
Van Horn et al^25^ | Mama-DASH | Encouraged consumption of low-fat dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes; discouraged consumption of sugar-sweetened beverages, sweets, and non-nutrient-dense snack foods; avoidance of fish considered higher in mercury; inclusion of calcium-rich, vitamin D–enriched dairy, or calcium-fortified non-dairy products
Van Horn et al^25^ | Control | Usual care, including bi-weekly newsletters and publicly available maternity website links
Reduced Rank Regression^v^
Starling et al^11^ | Pattern 1 | Higher consumption of poultry, nuts, cheese, fruits, whole grains, added sugars, and solid fats
Starling et al^11^ | Pattern 2 | Higher consumption of eggs, starchy vegetables, solid fats, fruits, and non-whole grains and a lower consumption of dairy foods, dark-green vegetables, and whole grains

##### Diets based on Macronutrient Distribution

Studies assessing diets based on macronutrient distributions outside of the acceptable macronutrient distribution range (AMDR) had to specify the distribution of carbohydrate, fat, and protein in the diet to be considered for this review. Macronutrient proportions outside of the AMDR are as follows:

- Carbohydrate for all age groups: < 45 or > 65 percent of energy;
- Protein for ≥ 19 years: < 10 or > 35 percent of energy;
- Fat for ≥ 19 years: < 20 or > 35 percent of energy

One RCT and one prospective cohort study^4,24^ in this review assessed macronutrient proportions and reported the percentage of total energy from fat was higher than the AMDR for one of the groups.

###### Time point of exposure

The RCTs^22–26^ randomized women during the late first trimester^23,26^ or early second trimester^22,24,25^ and followed them to the end of the second trimester.^22–26^

Most of the cohort studies administered food frequency questionnaires (FFQ) or 24 hour recalls toward the end of the first trimester or early in the second.^2,6,8–10,12,14,16,19–21^ Investigators typically collected retrospective dietary data reflecting early pregnancy intake (i.e. first trimester). In a few studies, maternal dietary data were collected in the second trimester^3,5,13,15,17^ or third trimester,^1,7^ reflecting intake in the past week,^15^ month,^3,7^ or the entire pregnancy until that point.^13,17^ In a few cohorts, dietary data were collected at multiple time points and assessed at individual time points (e.g. by trimester) or combined in the analysis.^6,9,11,20^

###### Outcome

The outcome considered in this review was gestational weight gain (GWG), reported in a number of ways, including total GWG,^2,3,7,11,12,15,16,19,22,25^ GWG for a specified time period^23,24,26^ or trimester,^10^ GWG rate,^1,4,8,15,18,20^ and GWG adequacy.^5,6,8,9,13–15,17–21,23,25^ The studies that assessed GWG adequacy classified GWG as inadequate, adequate, or excessive according to the Institute of Medicine (2009) guidelines^vi^, with the exception of Rifas-Shiman et al,^6^ who used Institute of Medicine (1990) guidelines^vii^, Hrolfsdottir et al,^14^ who used Icelandic recommendations (no reference provided), and Assaf-Balut et al,^23^ who had cited a previous publication^viii^.

### Evidence synthesis

With 26 articles, there is a substantial body of evidence available to examine the association between DPs during pregnancy and GWG (Table 3, Table 4). However, there is heterogeneity in the methods used to define and assess DPs and how outcomes were reported, which made it difficult to compare results across studies. Furthermore, the time period of dietary assessment and the duration of the recall also varied across studies.

#### Dietary patterns assessed via index/score

Fifteen articles used indices/scores to assess DPs and the findings are described below:

- Ancira-Moreno et al^18^ assessed the association between adherence to the Maternal Diet Quality Score (MDQS) and GWG trajectories (baseline n=660) in Mexican participants. The MDQS was based on the Mexican Dietary Guidelines and international recommendations for specific foods and was characterized by higher intake of PUFAs, fruits and vegetables, legumes, and low-fat dairy products; lower in foods higher in saturated fat, added sugars, and red meat. The study accounted for key confounders including age, SES, physical activity, prepregnancy BMI, GDM, hypertension, and parity. Anciro-Moreno et al also adjusted for energy intake (kilocalories per day) in the model when assessing whether diet quality was independent of total energy. The study noted the following findings:
  ○ Medium and high adherence throughout pregnancy were associated with lower risk of inadequate weight gain, but only high adherence was associated with lower risk of excessive weight gain.
  ○ When the investigators assessed specific time periods during pregnancy they noted that:
    ■ Medium adherence to the MDQS was associated with significantly lower rate of weight gain during middle pregnancy (20-30 weeks).
    ■ In late pregnancy (30-40 weeks), medium and higher adherence were positively associated with the rate of GWG.
    ■ When looking at weight gain beyond 40 weeks (defined by authors as prolonged pregnancy), higher adherence was associated with lower rate of weight gain.
- Emond et al^13^ examined maternal adherence to the Alternative Healthy Eating Index-2010 (AHEI) and GWG in a U.S.-based cohort (baseline n=1,140). The AHEI-2010 was characterized by higher intake of six ‘healthful’ components, including: fruits, vegetables, whole grains, nuts and legumes, long-chain n–3 fatty acids from foods and supplements, and PUFAs; and lower intake of four components, including: sugar-sweetened beverages and fruit juice, red and processed meats, trans fatty acids, and sodium. The primary objective of this study was to assess the association between the AHEI-2010 and infant outcomes. The study reported that there were no significant differences in GWG adequacy (i.e., insufficient, adequate, excessive) based on different levels of adherence to the AHEI-2010. None of the key confounders were accounted for in the analysis.
- In a Spain-based cohort study with a baseline sample size of 2,195 participants, Fernandez-Barres et al^1^ assessed maternal adherence to the relative Mediterranean Diet (rMED) score, which was constructed by taking into account the consumption of vegetables, fruits and nuts, cereals, legumes, fish, olive oil, meat, and dairy products. The scoring for meat and dairy products was reversed. Although GWG was assessed, the study was designed to examine the association between the rMED and the child’s longitudinal BMI and cardiometabolic risk. The study reported that highest adherence to the rMED DP was associated with significantly lower mean GWG (kilogram per week). The study did not account for any of the key confounders.
- In the U.S.-based Project Viva study (baseline n=2,128), Fulay et al^12^ examined the association between the DASH diet and GWG, in addition to other pregnancy outcomes. The authors noted that the DASH diet was similar to the Mediterranean diet in that both are rich in fruits, vegetables, legumes, whole grains, and healthy fats, with limited amounts of poultry, red meat, and dairy. In addition, the DASH diet emphasized reduced intake of sodium, saturated fat, total fat, and cholesterol, and higher intake of fiber and protein. As a variation of DASH, the authors also assessed the association between the DASH OMNI (supplemented by higher unsaturated fat intake) and GWG. After adjusting for total energy intake and key confounders (including age, race/ethnicity, SES, prepregnancy BMI, smoking and parity) in a statistical model, the authors reported that greater adherence to the DASH and DASH OMNI diets was associated with greater subsequent GWG. This was primarily observed among women who were obese during prepregnancy (≥ 30 kg/m^2^) and not in those who were overweight, normal weight or underweight.
- Gesteiro et al^2^ examined the association between maternal Mediterranean Diet Adherence (MDA), the Healthy Eating Index (HEI), and GWG, in a Spanish cohort study (baseline n=35).
  ○ High MDA (≥ 7) was characterized by the use of olive oil as the main dietary fat, higher intakes of vegetables, raw vegetables, fruits, fish or shellfish, nuts (including peanuts), legumes, chicken, turkey or rabbit meat, and dishes seasoned with sofrito, sauce made with tomato, onion, leek or garlic, and simmered with olive oil, and lower intakes of red meat, veal, pork, hamburger or sausage, butter, margarine or cream, sweet or carbonated beverages, and commercial sweets or pastries.
  ○ The HEI was characterized by intake of cereals, grains and legumes, vegetables, fruits, milk and dairy products, meat, eggs and fish, total fat, saturated fat, cholesterol (milligrams per day), and sodium (grams per day). HEI also accounted for the intake of total fat, saturated fat, sodium and dietary variety.
  The primary objective of this study was to assess the association between first trimester diet quality, measured by the HEI and MDA, and insulin sensitivity/resistance biomarkers at birth. The study accounted for key confounders, including race/ethnicity, smoking, and GDM. The investigators noted that women with higher MDA (≥ 7) had significantly higher total GWG, when compared to those with lower MDA (< 7). There were no significant differences in GWG between women with adequate vs. inadequate HEI adherence.
- Hillesund et al^5^ examined the association between the New Nordic Diet (NND) and GWG and fetal growth in this Norwegian cohort study (baseline n=66,597). The NND measured the frequency of eating of the following foods: Nordic fruits (apples, pears, plums, strawberries), root vegetables (carrots, rutabaga and various types of onions), cabbages (kale, cauliflower, broccoli and Brussels sprouts), potatoes, whole grain breads, oatmeal porridge, foods from the wild countryside (wild fish, seafood, game and wild berries), milk, and water. There were significant differences in GWG adequacy between groups, depending on the extent of NND adherence. Specifically, the proportion of women with excessive GWG was higher in the low adherence group compared to the medium or high adherence groups. When stratified by prepregnancy BMI, these results were consistent for women with a healthy prepregnancy BMI (BMI < 25.0 kg/m^2^), and marginally significant for those who were overweight or obese (BMI ≥ 25 kg/m^2^) prior to pregnancy (p=0.076). None of the key confounders were adjusted for in the analysis.
- Hillesund et al^21^ assessed maternal adherence to the Norwegian Fit for Delivery (NFFD) Diet in this Norwegian cohort study (based on the Norwegian Fit for Delivery trial) with a baseline sample size of 606. The NFFD diet was characterized by ≥ 24 main meals per week, water for ≥ 44 percent of drinking events, vegetables with dinner ≥ 5 per week, fruits or vegetables as snacks ≥ 3 per week, < 1 per day sugar-rich food items, <1 per day fast-foods, snacks, or other salty food, never eating sweets and snacks without appreciation, buying small portion size of ≥ 1 unhealthy food items, eating beyond satiety < 1 per week, and reading nutrition labels on foods sometimes or often. The main objective of the study was to assess the association between the NFFD diet and a number of maternal and neonatal outcomes, including GWG. After accounting for the key confounders, including age, SES, prepregnancy BMI, smoking and parity, there was a statistically significant inverse association between early pregnancy NFFD diet score and the odds of excessive GWG. This association remained significant even after adjusting for physical activity, in addition to other key confounders. There was no association between diet scores and inadequate GWG.
- Hrolsdottir et al,^14^ an Icelandic cohort study (baseline n=1,326), assessed the association between dietary risk scores and excessive GWG. A high dietary risk score was characterized by a non-varied diet, non-adequate frequency of consumption of fruits/vegetables, dairy, and whole grain intake, and excessive intake of sugar/artificially sweetened beverages and dairy. After accounting for the key confounders, including age, SES, prepregnancy BMI, smoking, parity and GDM (only in a sub-analysis), the study showed that a higher dietary risk score (which included 6 dietary risk factors - a non-varied diet, vegetables and fruits < 5 times per day, dairy intake < 2 times per day, whole grain products < 2 times per day, sugar- and artificially sweetened beverages ≥ 5 times per week, dairy intake ≥ 5 times per day) was associated with excessive GWG. Similarly higher dietary risk score with three foods (sugar- and artificially sweetened beverages ≥ 5 times per week, whole grain products < 2 times per day and dairy intake ≥ 5 times per day) was associated with the risk of excessive GWG; however, there was no association between dietary risk score when 13 foods were considered (not eating a varied diet, vegetables and fruits < 5 times per day, fish intake < 2 times per day, dairy intake < 2 times per day, whole grain products < 2 times per day, beans, nuts, seeds < 3.5 times per week, D-vitamin < 5 times per week, quality of fat - using butter rather than oil (≥ 50%) French fries and fried potatoes ≥ 1 times per week, sweets, ice cream, cakes, cookies ≥ 2.5 times per week, sugar- and artificially sweetened beverages ≥ 5 times per week, dairy intake ≥ 5 times per day, processed meat products ≥ 1 times per week).
- Meinila et al,^10^ a Finnish prospective cohort study (based on the control arm of the RADIEL trial), assessed the association between the Healthy Food Intake Index (HFII) and GWG (baseline n=137). The primary objective of this study, however, was to assess the association between the HFII and GDM. A higher HFII score was indicative of higher adherence to the Nordic Nutrition Recommendations (NNR), characterized by the following: 1) increased consumption of vegetables, fruits, fish and seafood, nuts and seeds; 2) substituting whole grains for refined grains, vegetable oils for butter, oil-based fat instead of butter-based spread and low-fat dairy instead of full-fat dairy; and 3) limiting beverages and foods with added sugar or salt, including snacks, sugar-sweetened drinks/juice, fast foods, and red and processed meat. Adherence to the HFII was not associated with GWG from the first to the second trimester. None of the key confounders were accounted for in the analysis.
- Poon et al^7^ assessed adherence to the Alternate Healthy Eating Index for Pregnancy (AHEI-P) and its association with GWG in a U.S.-based cohort study (baseline n=893). The primary objective of this study was to examine the impact of the maternal DP on the incidence of SGA and LGA. The AHEI-P was characterized by higher intake of vegetables, whole fruit, whole grains, nuts and legumes, long-chain (n-3) fatty acids, PUFAs, folate, calcium, and iron, and lower intake of sugar-sweetened beverages, red and processed meat, trans fat, and sodium. The authors reported no significant difference in GWG across different levels of adherence to the AHEI-P. None of the key confounders were accounted for in the analysis.
- Rifas-Shiman et al^6^ also used a modified AHEI called AHEI-P, characterized by the intake of vegetables (including tofu or soybean), fruit, ratio of white-to-red meat, fiber, trans fat, ratio of polyunsaturated-to-saturated fatty acids, and folate, calcium, and iron from foods. The authors made some changes to the AHEI by excluding alcohol and nuts and including folate, calcium and iron intake. Although the AHEI-P indices assessed by Poon et al^7^ and Rifas-Shiman et al^6^ are similar, they are not the same. The main objective of this U.S.-based study (baseline n=1,777), which used Project Viva data, was to assess the maternal characteristics associated with the AHEI-P score, with GWG measured as a secondary outcome. After adjusting for the key confounders, including age, race/ethnicity, SES and prepregnancy BMI, the study found that greater adherence to the AHEI-P was not associated with altered risk for inadequate or excessive GWG.
- Sen et al^9^ also used Project Viva data to assess the association between prenatal Dietary Inflammatory Index (DII) and a number of perinatal outcomes, including GWG (baseline n=1,808). Lower DII is characterized by higher intakes of vegetables, fruit, whole-grain foods, fish/seafood, and whole eggs, and lower intakes of red or processed meats and sugar-sweetened soda. After accounting for the key confounders, including age, race/ethnicity, SES, prepregnancy BMI, smoking and parity, the study found no association between consuming a lower DII diet and GWG.
- Tielemans et al^8^ used the Netherlands-based Generation R study data to assess the association between an a priori and an a posteriori DP and GWG (baseline n=4,097). The latter findings are discussed in the next section. The Dutch Healthy Diet Index (a priori DP) consisted of 6 components, including vegetables, fruit, dietary fiber, fish, saturated fatty acids, and sodium. After accounting for the key confounders, including, age, race/ethnicity, SES, prepregnancy BMI, smoking, GDM, hypertension and parity, the study found no significant association between the Dutch Health Diet Index and GWG.
- Yong et al^20^ examined the association between diet quality and GWG in a Malaysia-based Seremben Cohort Study (baseline n=480). Specifically, the study used a modified HEI for Malaysians, which measured adherence to the seven food groups, including 1) cereals and grains, 2) vegetables, 3) fruits, 4) milk and milk products, 5) poultry, meat and egg, 6) fish and seafood, and 7) legumes. After adjusting for the key confounders, including, age, SES, physical activity, prepregnancy BMI and parity, the authors reported that a higher HEI score in the third trimester was associated with excessive GWG, irrespective of prepregnancy BMI. However, during the second trimester, the association between the HEI and GWG varied based on prepregnancy BMI. In women with a prepregnancy BMI (18.50–24.99 kg/m^2^), higher HEI was associated with lower odds of inadequate GWG. In women who were overweight or obese during prepregnancy, higher HEI was associated with increased odds of excessive GWG.
- Zhu et al,^16^ using the U.S.-based PETALS cohort, investigated the association between the HEI-2010 and GWG, although the primary objective of this study was to investigate whether maternal diet quality affected fetal growth (baseline n=2,269). The HEI-2010 included 12 components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids, refined grains, sodium, and empty calories from solid fats, alcohol and added sugars. However, for this study, alcohol intake was excluded from the empty calories component. The study reported that total GWG did not differ among women across different levels of adherence to the HEI-2010. None of the key confounders were accounted for in the analysis.

Summary: Of the 15 articles that assessed maternal DPs using an index/score method, eight showed an association with GWG.^1,2,5,12,14,18,20,21^ Four of the eight showed that greater adherence to a beneficial DP was either associated with a: 1) lower risk of excessive GWG,^5,21^ 2) lower rate of GWG,^18^ or 3) lower mean GWG.^1^ An additional study showed that greater adherence to a ‘detrimental’ DP was associated with excessive GWG.^14^ However, three studies showed that higher adherence to a beneficial DP (i.e. DASH, DASH OMNI, Mediterranean Diet, HEI) was associated with higher GWG, either in all participants^2^ or only in obese women.^12,20^ Six of the eight articles^2,12,14,18,20,21^ that showed an association adjusted for one or more of the key confounders.

Among the seven articles that did not show an association,^6–10,13,16^ four did not adjust for any of the key confounders, nor were they primarily designed to address the association between DP and GWG.^7,10,13,16^ In two of these, the timing of exposure assessment was also different, with one assessing maternal diet at the end of the second trimester^13^ and the other during the third trimester.^7^ Two other articles that did not show an association were both conducted with the same cohort (Project Viva).^6,9^

#### Dietary patterns assessed via factor or principal components analysis

Five studies^3,8,15,17,19^ used data-driven methods (i.e. PCA, exploratory factor analysis, and cluster analysis) to assess dietary patterns:

○ Maugeri et al^19^ used PCA to generate the following dietary patterns:
  ○ Western pattern characterized by high intake of red meat, fries, dipping sauces, salty snacks, and alcoholic drinks
  ○ Prudent pattern characterized by high intake of boiled potatoes, cooked vegetables, legumes, pizza, and soup

The primary objective of this Italian study (baseline n=232) was to assess the association between maternal DPs and total GWG. In a statistical model, the analysis adjusted for total energy intake and key confounders, including, age, SES, smoking, GDM, hypertension, and parity. The study reported a positive trend of GWG across tertiles of a Western DP and this was more prominent in women who were obese prior to pregnancy. On the other hand, adherence to a prudent DP was positively associated with GWG among women who were underweight before pregnancy and negatively associated with GWG among women who were overweight and obese women before pregnancy.

○ In a Japanese prospective cohort study (baseline n=803), Okubo et al^3^ used a cluster analysis to create the following dietary patterns:
  ○ Meat and eggs pattern characterized by high intake of beef and pork, processed meat, chicken, eggs, butter, and dairy products
  ○ Wheat products pattern characterized by high intake of bread, confectioneries, fruit and vegetable juice, and soft drinks
  ○ Rice, fish, and vegetables pattern characterized by high intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup, and salt-containing seasoning

The primary objective of the study was to assess the association between maternal diet and neonatal anthropometric measurements at birth. The study noted that greater adherence to the wheat products DP was associated with significantly higher mean GWG when compared to the rice, fish, and vegetable DP. None of the key confounders were adjusted for in the analysis.

○ In a Dutch cohort study with a baseline n=4,097, Tielemans et al^8^ used a PCA to generate the DPs described below:
  ○ Vegetable, Oil, and Fish pattern characterized by higher intake of vegetables, high fat dairy products, cereals (both low and high fiber), fish and shellfish, eggs and egg products, vegetable oils, coffee and tea, alcoholic beverages, and legumes
  ○ Nuts, High-Fiber Cereals, and Soy pattern characterized by higher intake of potatoes and other tubers, fruits, high and low fat dairy products, high fiber cereals, meat and meat products, fish and shellfish, coffee and tea, sugar-containing beverages, light soft drinks, nuts, seeds and olives, and soy products
  ○ Margarine, Sugar, and Snacks pattern characterized by higher intake of potatoes and other tubers, high fat dairy products, low and high fiber cereals, meat and meat products, margarine and butter, sugar and confectionary and cakes, snacks, sugar-containing beverages, condiments and sauces, nuts, seeds and olives

The primary objective of the study was to investigate the association between DPs and GWG. After accounting for the key confounders, including age, race/ethnicity, SES, prepregnancy BMI, smoking and parity, none of the DPs were associated with rate of GWG (grams per week) (mid- and late-pregnancy) in normal weight or overweight women. The findings were consistent after adjusting for total energy intake in a sensitivity analysis. Similarly, none of the DPs were associated with inadequate GWG. However, greater adherence to the margarine, sugar, and snacks DP was associated with increased odds of excessive GWG compared to the lowest adherence, although per standard deviation (SD) increase in DP score was not statistically significantly associated with GWG. Tielemans et al^8^ also assessed the association between the Dutch Healthy Diet Index and GWG and the results were discussed in the previous section.

○ In a Chinese prospective cohort study (baseline n=5,733), Wei et al^15^ used cluster analysis to generate the following DPs according to the food groups that were predominant in each cluster:
  ○ Richer in cereals characterized by higher intake of cereals (rice, pasta, porridge) and eggs (fresh and preserved)
  ○ Richer in vegetables characterized by higher intake of leafy and cruciferous vegetables (dark green leafy vegetables, white leafy vegetables, broccoli, cauliflower)
  ○ Richer in meats characterized by higher intake of meats (red meat, including pork, beef, and mutton, and processed meat)
  ○ Richer in fruits characterized by higher intake of fruits (cherry/grapefruit/plum/apple/pear/peach, banana/oranges/grape, Watermelon/pineapple/mango/litchi/longan/durian and others) and Cantonese desserts
  ○ Richer in fish, beans, nuts, and yogurt characterized by higher intake of cereals (noodles, bread), poultry, animal organ meat (animal liver, other animal innards, animal brain and animal blood), fish (freshwater fish, seawater fish, other seafood including prawn/crab, shell fish/squid, others), bean products (soybean, other dry beans, soybean milk and bean curd), nuts (oil nuts, starchy nuts, melon), vegetables (including pumpkin/tomato/capsicums/eggplant, root vegetables including carrot, potatoes/radishes/lotus root, bean vegetables, mushrooms, sea vegetables and processed vegetables), and yogurt (snack including biscuit, cornmeal, cake/fried dough twist, confectionaries including honey, candy/chocolate, other confectionaries, sweet beverage and puffed food)
  ○ Richer in milk and milk powder characterized by higher intake of fresh milk, pasteurized milk, formula milk powder, fat free milk powder, whole milk powder, and others

The primary objective of this Chinese study was to assess the association between maternal DPs and GWG. The study accounted for some of the key confounders, including age, SES, prepregnancy BMI and parity. Among Chinese pregnant women with a healthy prepregnancy BMI, a DP richer in fruits (compared to a DP richer in cereals) was positively associated with total GWG and GWG rate. A DP richer in fruits was also associated with an increased risk for excessive GWG. A DP richer in fish, beans, nuts and yogurt, compared to a DP richer in cereals, was positively associated with GWG rate in the second trimester and was associated with a reduced risk for inadequate GWG.

○ In a Polish prospective cohort study (baseline n=1,306), Wesolowska et al,^17^ used an exploratory factor analysis to generate three DPs:
  ○ Western pattern characterized by higher intake of refined grains, processed meat, potatoes, and low intake of whole grains
  ○ Mixed pattern characterized by intakes in between Western and Prudent patterns
  ○ Prudent pattern characterized by high consumption of fruits, vegetables, legumes, whole grains, poultry, and both low-fat and high-fat dairy products

The primary objective of the study was to evaluate sociodemographic, lifestyle, environmental, and pregnancy-related determinants of DPs during pregnancy. The study reported no significant differences between the proportions of participants that gained recommended vs. low vs. high GWG across the DPs. None of the key confounders were adjusted for in the analysis.

Summary: Of the five studies that assessed maternal DPs using factor analysis or PCA, four^3,8,15,19^ showed significant associations between a maternal DP and GWG. One study showed that greater adherence to a beneficial DP was associated with lower GWG,^19^ while the same study and three others showed that greater adherence to a non-beneficial DP was associated with higher GWG.^3,8,15,19^ Three of the four studies that showed an association adjusted for some of the key confounders.^8,15,19^ The only study^17^ that showed no association between DP and GWG did not adjust for any of the key confounders.

#### Dietary patterns assessed using an experimental diet in an RCT

Four articles from three RCTs assessed the relationship between an intervention and GWG:

- Al Wattar et al,^22^ in a multicenter U.K.-based trial (baseline n=1,252), randomized pregnant women with metabolic risk factors such as obesity, chronic hypertension, or hypertriglyceridemia to a Mediterranean-style diet or a control diet.
  ○ Those randomized to the Mediterranean-style diet were encouraged to consume higher amounts of nuts, extra virgin olive oil, fruits, vegetables, non-refined grains, and legumes; moderate-to-high amounts of fish; low-to-moderate amounts of poultry and dairy products, such as yogurt and cheese; low amounts of red meat and processed meat; and to avoid sugary drinks, fast food, and foods rich in animal fat. Investigators provided mixed nuts (30 grams per day walnuts, hazelnuts, and almonds) and EVOO (0.5 liter per week) to the participants.
  ○ The control group received usual care and antenatal advice as per U.K. national recommendations for antenatal care.
  The primary outcomes were: 1) a composite maternal outcome that combined GDM and preeclampsia, and 2) a composite infant outcome that combined stillbirth and SGA or admission to neonatal care unit. GWG was considered a secondary maternal outcome. The study showed that metabolically at-risk women randomized to a Mediterranean-style dietary pattern had lower GWG when compared to the control group.
- In a single center, clinic-based RCT in Spain (baseline n=1,000), Assaf-Balut et al^23,26^ randomized pregnant women to one of the following groups:
  ○ The control group was advised to follow a Mediterranean Diet with ≥ 2 servings vegetables per day, ≥ 3 servings of fruits per day (avoiding juices), 3 servings skimmed dairy products per day, 3 servings wholegrain cereals per day, and 2-3 servings of legumes per week, moderate-to-high consumption of fish, low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods, and precooked meals. However, they were advised to restrict the consumption of dietary fat, including EVOO and nuts.
  ○ The intervention group was advised to follow the same Mediterranean Diet as the control group, and were advised to also consume 40 mL per day of EVOO and 25-30 grams per day pistachios. Investigators provided 10 liters of EVOO and 2 kilograms of roasted pistachios to the participants.
  The primary outcome of this RCT^26^ was to assess the effect of the intervention diet on GDM incidence, with GWG as a secondary outcome. When compared to the control group, the intervention DP resulted in lower GWG between 12 to 24-28 weeks gestation in women with a prepregnancy BMI < 25 kg/m^2^ (p=0.052) and overweight women (BMI ≥ 25 to ≤ 29.9 kg/m^2^) (p=0.076). These findings were marginally significant. However, no significant differences in GWG between the intervention and control groups were noted in women who were obese prior to pregnancy (≥ 30 kg/m^2^).
  When considering GWG from 12 to 36-38 weeks, the total GWG was not different between the intervention and control groups. Although non-significant, the directionality of the findings changed. In all women, the intervention group gained more total GWG than the control group between the beginning of the second trimester to the end of the third trimester (p=0.12). Among women with a prepregnancy BMI < 25 kg/m^2^, the intervention group tended to gain more weight than the control group (p=0.096), whereas among obese women there was no significant difference between groups (p=0.77), and among overweight women, those assigned to the control group tended to gain more weight than the intervention group (p=0.066).
  In a sub-analysis of the St. Carlos GDM Prevention Study^23^ with normoglycemic women, there were no significant differences in GWG from 12 weeks to 36-38 weeks between the control and intervention groups. Also, the study did not report significant differences in weight gain between the intervention and control groups after stratifying by adequacy of weight gain (i.e. excessive, adequate, inadequate).
- In a U.S.-based RCT (baseline n=281), Van Horn et al^25^ randomized women who were overweight or obese (prepregnancy BMI 25-40 kg/m^2^) to a DASH diet and lifestyle intervention or a usual-care group, as described below:
  ○ The intervention group was assigned to a slightly modified DASH diet (called Mama-DASH) and women were encouraged to consume a diet with low-fat dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes. They were also advised not to consume sugar-sweetened beverages, sweets, and non-nutrient-dense snack foods. Mama-DASH was designed to calorically suit the restricted weight gain recommendations (based on IOM) and to enable pregnant women to follow the nutrition guidelines specific for this population including avoidance of fish considered higher in mercury, and inclusion of calcium-rich, vitamin D–enriched dairy, or calcium-fortified non-dairy products.
  ○ The control group received the usual care that included bi-weekly newsletters and publicly available maternity website links.
  In addition to the diet, all participants were encouraged to engage in at least 30 minutes of activity or walking > 10,000 steps per day. The primary outcome of this study was GWG at 35 weeks. The study noted that pregnant women (with a prepregnancy BMI between 25-40 kg/m^2^) randomized to the intervention group gained significantly less weight when compared to their counterparts in the control group. Most participants in both groups exceeded the IOM’s recommended weight gain, although it was less common in the intervention group (69 percent) compared to the control group (85 percent) (p=0.004). Physical activity goals were not achieved by the majority of participants.

Summary: Of the three RCTs that assessed the relationship between Mediterranean (vs usual care),^22^ Mediterranean+EVOO (vs Mediterranean diet),^23,26^ or modified DASH (vs usual care)^25^ diets, two trials^22,25^ showed that the women in the intervention group had significantly lower GWG than their counterparts in the control groups. The third trial by Assaf-Balut et al^23,26^ showed that women assigned to the Mediterranean Diet+EVOO tended to have lower GWG only until the end of the second trimester (p=0.052). Both studies that showed an effect were conducted in either metabolically at-risk women^22^ or women who were overweight or obese prior to pregnancy.^25^ Consistent with these findings, Assaf-Balut et al^26^ showed that among overweight women, those in the intervention group tended to have lower GWG than those in the control group (p=0.076) from 12 to 24 weeks; however, this difference was not observed in women who were obese prepregnancy. When considering GWG from 12 to 36-38 weeks, the total GWG was not different between the intervention and control groups. Although non-significant, there was a change in directionality for certain sub-groups (i.e. normal weight, obese women) with women randomized to the intervention group gaining more weight than the control group from 12 to 36-38 weeks.^26^ As part of the same trial, a sub-analysis that was restricted only to normoglycemic women showed that there was no difference in GWG from 12 to 36-38 weeks between the intervention and control groups.^23^

#### Dietary patterns assessed via reduced rank regression

In a U.S.-based study (baseline n=764), Starling et al^11^ arrived at DPs by “entering the residual intakes from each food group into a reduced–rank regression model.” Two DPs were determined using this approach:

○ Pattern 1 was characterized by a higher consumption of poultry, nuts, cheese, fruits, whole grains, added sugars, and solid fats.
○ Pattern 2 was characterized by a higher consumption of eggs, starchy vegetables, solid fats, fruits, and non-whole grains and a lower consumption of dairy foods, dark-green vegetables, and whole grains.

The primary objective of this study was to assess the association between maternal DPs and newborn fat mass and adiposity, with maternal GWG as the intermediate variable. The study showed that women with greater adherence to pattern 1 (tertile 3) had significantly greater GWG (p for trend < 0.001). Similarly, women with greater adherence to pattern 2 (tertile 2 and tertile 3) had significantly greater GWG (p for trend=0.03). However, none of the key confounders were adjusted for in the analysis.

#### Diets based on macronutrient distributions

As described below, one RCT^24^ and one prospective cohort study^4^ assessed the association between diets based on macronutrient distributions and GWG.

○ In a U.K.-based RCT (baseline n=183), Poston et al^24^ randomized obese women (BMI ≥ 30 kg/m^2^) to an intervention of dietary advice and physical activity delivered by health trainers vs. standard care. The primary outcome of the study was to assess the impact of the intervention on maternal (GDM) and neonatal (LGA) outcomes, with GWG reported as a secondary outcome. The dietary advice in the intervention group focused on increasing the consumption of foods with a low dietary glycemic index (GI), including replacing sugar-sweetened beverages with low GI alternatives and reducing saturated fat consumption and replacing with mono- and polyunsaturated fatty acids. At the end of the intervention, there were significant differences in total fat intake between the groups, with the control group consuming an average of 35.9 percent of total energy from fat (which is outside of the AMDR), while the intervention group consumed an average of 32.5 percent of total energy from fat. The study reported that there was no significant difference in GWG between the intervention and control groups. Physical activity was a co-intervention in the study but the authors reported no difference in physical activity between the intervention and control groups.
○ Tajima et al,^4^ in a Japanese prospective cohort study (baseline n=325), assessed the association between tertiles of carbohydrate intake and glucose tolerance test. Based on 3-d dietary records collected from participants, the investigators assessed the average carbohydrate, protein, total fat, and saturated fatty acid intake, and calculated the percentage of total energy intake for each component. Carbohydrate intake was calculated by subtracting the percent total energy from fat and protein intake from 100 percent and participants were categorized into tertiles based on their carbohydrate intake. The study reported that women in different tertiles of carbohydrate intake also differed significantly on percent energy from total fat intake (p<0.001). That is, women in the ‘bottom’ tertile for carbohydrate had 35.1 percent energy from total fat (which is outside of the AMDR); those in the ‘middle’ and ‘top’ tertiles for carbohydrate intake had 30.3 percent and 24.6 percent energy from total fat intake, respectively. The study also reported GWG across tertiles of carbohydrate intake (i.e., ‘bottom’, ‘middle’ and ‘top’) and noted that the mean weight gain per week was not significantly different across the groups. None of the key confounders were adjusted for in the analysis.

Summary: Two studies included in this body of evidence reported no significant difference in GWG^24^ or rate of GWG^4^ based on varying percentages of total energy intake from fat. Of note, neither the RCT nor the prospective cohort study manipulated percentage of energy from fat. Further, these studies were not designed to assess the relationship between macronutrient proportions and GWG. In the U.K. based trial, the control group consumed a greater percentage of total energy from fat (which was above the AMDR) when compared to the intervention group. GWG was measured as a secondary objective. While the U.K. trial did not deliberately manipulate percentage of energy from total fat, the investigators recommended replacing saturated fats with mono- and poly-unsaturated fatty acids for the intervention group, whereas routine care was recommended for the control group. The Japanese cohort study presented tertiles of carbohydrate intake and stratified GWG into categories. Women with ‘bottom’, ‘middle’ and ‘top’ carbohydrate intake also differed on percentage of total energy from fat. The study reported no difference in rate of GWG among these tertiles.

#### Assessment of the evidence^ix^

The following conclusion statement was supported by three RCTs and 19 prospective cohort studies and was graded “limited.” The individual grading elements are discussed below and summarized in Table 5 and Table 6.

“Limited evidence suggests that certain dietary patterns during pregnancy are associated with a lower risk of excessive gestational weight gain during pregnancy. These patterns are higher in vegetables, fruits, nuts, legumes, fish, and lower in added sugar, and red and processed meat”

The DPs examined were characterized by combinations of different foods and beverages. The patterns that were consistently shown to be associated with lower risk of excessive GWG commonly included the foods highlighted in the conclusion statement (i.e. higher in vegetables, fruits, nuts, legumes, fish and lower in added sugar, red and processed meat), although not all foods were part of the same pattern.

Grains and dairy products were included in a number of studies; however, the association between these foods and GWG was inconsistent. Specifically, in the 10 articles that included dairy products in a DP, some recommended consuming low-fat dairy products, while others recommended dairy consumption in moderation (without specifying percent fat), and a few other articles reverse coded it as they considered it to be detrimental. Similarly, five articles included whole/non-refined grains in a DP, of which four included it as part of a beneficial DP (meaning the DP that included whole grains was associated with a lower risk of excessive GWG). One additional article noted that avoidance of refined grains was beneficial. In three articles, it was unclear whether the participants consumed whole or refined grains and two other articles reported that participants consumed both whole and refined grains. Because of these inconsistencies, it was difficult to determine the relationship between grains or dairy and GWG.

Risk of bias was graded as limited for both RCTs and cohort studies.

- Most of the RCTs included in this body of evidence had notable flaws, as described below:
  ○ In a RCT conducted in Spain,^23,26^ women randomized to both intervention and control groups received nutritional guidance to reduce the calorie content of their diet, individualized based on GWG in the first trimester BMI. In addition, women diagnosed with GDM in both the intervention and control group received treatment with insulin and/or diet. However, significantly more women in the control group were diagnosed with GDM. In the sub-analysis,^23^ the investigators excluded participants with gestational diabetes and assessed the effect of the diet on GWG only in normoglycemic women. Since the selection of participants into this sub-analysis was based on post intervention status, this sub-analysis was treated as a “per-protocol analysis,” rather than an “intention-to-treat analysis.”
  ○ In the U.S.-based RCT,^25^ there were issues with adherence, which was different between the intervention and control groups.
  ○ Outcome assessment methods were not specified in at least one RCT.
- Similar to the RCTs, the cohort studies had serious flaws in the design and conduct of the studies:
  ○ No studies accounted for all the key confounders. Seven studies had potentially critical bias as none of the key confounders were accounted for.
  ○ More than half of the studies had selection bias issues because selection of the participants was related to characteristics observed after the start of the exposure.
  ○ Dietary data reflected dietary intake at a single time point during pregnancy. The exposure data were self-reported (typically collected around the end of the first trimester or later), and thus it is possible that classification of exposure status may have been impacted by the knowledge of the outcome.
  ○ Many studies reported co-exposures which were unbalanced across treatment groups.
  ○ Outcome data were self-reported and in a few studies reporting of outcome data may have been influenced by the knowledge of the exposure received.
  ○ None of the studies reported having a pre-registered data analysis plan.

Consistency was graded limited for both RCTs and cohort studies.

- Among the articles that assessed DPs using an index/score method, five showed that greater adherence to a beneficial DP was associated with a lower risk of excessive GWG.^1,5,14,18,21^ However, three other articles showed that greater adherence to a beneficial DP was associated with excessive GWG.^2,12,20^ Seven other articles showed no association between DPs and GWG.^6–10,13,16^
- Four of the five cohort studies^3,8,15,19^ that assessed DPs using factor/cluster analysis showed an association with GWG, whereas one other study found no association between DPs and GWG.^17^
- One of the studies that assessed DP using reduced rank regression was associated with GWG.^11^
- Two RCTs showed that the intervention diet resulted in lower GWG.^22,25^
- Neither of the studies that assessed the relationship between a maternal high-fat diet (>35 percent total energy from fat) and GWG showed an association.^4,24^

Even among studies that found similar associations, the strength of the association could not be adequately assessed because of differences in study methods, including exposure and outcome assessment methodology.

The inconsistency in findings may be explained by the following:

- Key confounders: Many of the studies that reported null findings did not adjust for any of the key confounders. This can at least partly be attributed to the fact that the studies were not designed to assess the association, but rather presented the data because they assessed GWG as a secondary outcome or a mediator in the study.
- Exposure assessment: There was heterogeneity in exposure assessment methods. Studies used different approaches to generate DPs. The foods included in each DP were also different, thus making it difficult to compare exposures across studies.
- The inconsistencies in findings between RCTs may have been due to differences in study populations. The two RCTs that found an effect only included overweight/obese women, or metabolically at-risk women. On the other hand, the RCT that showed no effect recruited healthy women, which might partly explain the inconsistency in study findings.

Directness was graded as limited for both RCTs and prospective cohort studies. Only half of the studies in this body of evidence were designed to assess the association between DPs and GWG. For the rest, GWG was a secondary measure and thus the objectives of these studies did not necessarily align with the systematic review question. Often this also meant that most or all of the key confounders were not accounted for in the analysis.

Precision was graded as limited for both RCTs and prospective cohort studies. Most of the studies, except RCTs, did not report power analyses or sample size calculations. Even among the RCTs, two trials conducted power calculations for outcomes other than GWG and thus precision with respect to the present review is difficult to evaluate. Studies included in this body of evidence generally had moderate analytic sample sizes to investigate the relationship between maternal DPs and GWG. None of the studies unduly influenced the findings of this systematic review and removing a single study from this body of evidence would not likely change the conclusions.

Generalizability was graded as limited for both RCTs and prospective cohort studies. About one-fourth of the included studies (n=6), including only one RCT, were conducted in the U.S. Minority women were generally underrepresented in this body of evidence. Thirteen articles reported that their participants were predominantly White and nine others did not report race/ethnicity of the participants. With regard to SES, most women in the studies had at least some college education and participants were generally from mid-high income households. Participants were primarily adult women and none of the studies focused on adolescent mothers. Two RCTs recruited only women who were overweight/obese or had other metabolic risk factors. For the reasons stated above, it is unclear if the findings from this systematic review would be applicable to a more diverse U.S. population.

Publication bias is definitely a consideration for the systematic reviews. However, it may not be a serious concern for this body of evidence because at least a third of the studies reported non-significant findings while the others report significant findings or a mix of significant and non-significant findings.

### Research recommendations

- Include diverse populations with varying age groups and different racial/ethnic and socioeconomic backgrounds.
- Foster collaborative efforts to score dietary patterns consistently, so that they can be compared and reproduced across studies.
- Adjust for key confounding factors in observational studies, including age, race/ethnicity, SES, physical activity, anthropometry (prepregnancy BMI), smoking, history/diagnosis of gestational diabetes and gestational hypertension, and parity.
- Develop a standardized recommendation of what constitutes a ‘high-fat’ or ‘low-carbohydrate’ dietary pattern.

### Included articles

1 Fernandez-Barres S, Vrijheid M, Manzano-Salgado CB, . The association of Mediterranean diet during pregnancy with longitudinal body mass index trajectories and cardiometabolic risk in early childhood. J Pediatr. 2019;206:119–127 e116. doi:10.1016/j.jpeds.2018.10.005 30429079
2 Gesteiro E, Rodriguez Bernal B, Bastida S, Sanchez-Muniz FJ. Maternal diets with low healthy eating index or Mediterranean diet adherence scores are associated with high cord-blood insulin levels and insulin resistance markers at birth. Eur J Clin Nutr. 2012;66(9):1008–1015. doi:10.1038/ejcn.2012.92 22828732
3 Okubo H, Miyake Y, Sasaki S, . Maternal dietary patterns in pregnancy and fetal growth in Japan: the Osaka Maternal and Child Health Study. Br J Nutr. 2012;107(10):1526–1533. doi:10.1017/S0007114511004636 21929833
4 Tajima R, Yachi Y, Tanaka Y, . Carbohydrate intake during early pregnancy is inversely associated with abnormal glucose challenge test results in Japanese pregnant women. Diabetes Metab Res Rev. 2017;33(6). doi:10.1002/dmrr.2898
5 Hillesund ER, Bere E, Haugen M, Overby NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr. 2014;17(9):1909–1918. doi:10.1017/S1368980014000421 24685309
6 Rifas-Shiman SL, Rich-Edwards JW, Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. 2009;109(6):1004–1011. doi:10.1016/j.jada.2009.03.001 19465182
7 Poon AK, Yeung E, Boghossian N, Albert PS, Zhang C. Maternal dietary patterns during third trimester in association with birthweight characteristics and early infant growth. Scientifica (Cairo). 2013;2013:786409. doi:10.1155/2013/786409 24490111
8 Tielemans MJ, Erler NS, Leermakers ET, . A priori and a posteriori dietary patterns during pregnancy and gestational weight gain: The Generation R study. Nutrients. 2015;7(11):9383–9399. doi:10.3390/nu7115476 26569303
9 Sen S, Rifas-Shiman SL, Shivappa N, . Dietary inflammatory potential during pregnancy is associated with lower fetal growth and breastfeeding failure: results from Project Viva. J Nutr. 2016;146(4):728–736. doi:10.3945/jn.115.225581 26936137
10 Meinila J, Valkama A, Koivusalo SB, . Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Eur J Clin Nutr. 2017;71(4):555–557. doi:10.1038/ejcn.2016.275 28145421
11 Starling AP, Sauder KA, Kaar JL, Shapiro AL, Siega-Riz AM, Dabelea D. Maternal dietary patterns during pregnancy are associated with newborn body composition. J Nutr. 2017;147(7):1334–1339. doi:10.3945/jn.117.248948 28539412
12 Fulay AP, Rifas-Shiman SL, Oken E, Perng W. Associations of the dietary approaches to stop hypertension (DASH) diet with pregnancy complications in Project Viva. Eur J Clin Nutr. 2018;72(10):1385–1395. doi:10.1038/s41430-017-0068-8 29339829
13 Emond JA, Karagas MR, Baker ER, Gilbert-Diamond D. Better diet quality during pregnancy is associated with a reduced likelihood of an infant born small for gestational age: an analysis of the prospective New Hampshire birth cohort study. J Nutr. 2018;148(1):22–30. doi:10.1093/jn/nxx005 29378041
14 Hrolfsdottir L, Halldorsson TI, Birgisdottir BE, Hreidarsdottir IT, Hardardottir H, Gunnarsdottir I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. 2019;15(1):e12639. doi:10.1111/mcn.12639 30033533
15 Wei X, He JR, Lin Y, . The influence of maternal dietary patterns on gestational weight gain: A large prospective cohort study in China. Nutrition. 2019;59:90–95. doi:10.1016/j.nut.2018.07.113 30471529
16 Zhu Y, Hedderson MM, Sridhar S, Xu F, Feng J, Ferrara A. Poor diet quality in pregnancy is associated with increased risk of excess fetal growth: a prospective multi-racial/ethnic cohort study. Int J Epidemiol. 2019;48(2):423–432. doi:10.1093/ije/dyy285 30590563
17 Wesolowska E, Jankowska A, Trafalska E, . Sociodemographic, lifestyle, environmental and pregnancy-related determinants of dietary patterns during pregnancy. Int J Environ Res Public Health. 2019;16(5). doi:10.3390/ijerph16050754
18 Ancira-Moreno M, Vadillo-Ortega F, Rivera-Dommarco JA, . Gestational weight gain trajectories over pregnancy and their association with maternal diet quality: Results from the PRINCESA cohort. Nutrition. 2019;65:158–166. doi:10.1016/j.nut.2019.02.002 31132630
19 Maugeri A, Barchitta M, Favara G, . Maternal dietary patterns are associated with pre-pregnancy body mass index and gestational weight gain: results from the “Mamma & Bambino” cohort. Nutrients. 2019;11(6). doi:10.3390/nu11061308
20 Yong HY, Mohd Shariff Z, Mohd Yusof BN, . Pre-Pregnancy BMI influences the association of dietary quality and gestational weight gain: The SECOST study. Int J Environ Res Public Health. 2019;16(19). doi:10.3390/ijerph16193735
21 Hillesund ER, Bere E, Sagedal LR, . Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62. doi:10.29219/fnr.v62.1273
22 Al Wattar BH, Dodds J, Placzek A, . Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 31335871
23 Assaf-Balut C, Garcia de la Torre N, Duran A, . A Mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: a sub-analysis of the St. Carlos gestational diabetes mellitus prevention study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
24 Poston L, Briley AL, Barr S, . Developing a complex intervention for diet and activity behaviour change in obese pregnant women (the UPBEAT trial); assessment of behavioural change and process evaluation in a pilot randomised controlled trial. BMC Pregnancy Childbirth. 2013;13:148. doi:10.1186/1471-2393-13-148 23855708
25 Van Horn L, Peaceman A, Kwasny M, . Dietary approaches to stop hypertension diet and activity to limit gestational weight: maternal offspring metabolics family intervention trial, a technology enhanced randomized trial. Am J Prev Med. 2018;55(5):603–614. doi:10.1016/j.amepre.2018.06.015 30262148
26 Assaf-Balut C, Garcia de la Torre N, Duran A, . A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): A randomized controlled trial: The St. Carlos GDM prevention study. PLoS One. 2017;12(10):e0185873. doi:10.1371/journal.pone.0185873 29049303
27 Meinila J, Valkama A, Koivusalo SB, . Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Eur J Clin Nutr. 2017;71(7):913. doi:10.1038/ejcn.2017.66 28685775

Table 3 Description of evidence on the relationship between dietary patterns during pregnancy and gestational weight gain^x^

Study and Participant Characteristics^xi^ | Intervention/Exposure and Outcomes | Results | Confounding, Study Limitations, and Summary of Findings
Randomized Controlled Trials
Index/Score
Al Wattar, 2019 ^22^ ; U.K.; RCT, ESTEEM trial; Baseline N=1252 Analytic N=468 (Attrition: 63%); n=~1190 for all participant characteristics; - Age: ~31.1y; - Race/Ethnicity:; ○ White: ~36.0%; ○ Asian: ~43.7%; ○ Black: ~16.8%; ○ Other: ~3.5%; - Physical Activity (n=1205): MET: ~2,584 min/wk; - Anthropometry:; ○ Normal BMI: ~13.9%; ○ Overweight: ~16.7%; ○ Obese: ~69.4%; - GDM: History: ~3.2%; - Gestational HTN: History of PE: ~4.3%; - Parity:; ○ Primigravida: ~27.4%; ○ Multigravida: ~72.6% | Dietary Pattern(s):; - Control: Received usual care and antenatal dietary advice as per U.K. national recommendations (Ref, n=625); - Intervention:; ○ High intake of nuts, EVOO, fruit, vegetables, nonrefined grains, and legumes; ○ Moderate to high consumption of fish; ○ Low to moderate intake of poultry and dairy products; ○ Low consumption of red meat and processed meat; ○ Avoidance of sugary drinks, fast food, and food rich in animal fat; ○ Participants provided with 30 g/d of mixed nuts and 0.5 L/wk of EVOO (n=627); at ~18 wk gestation; Dietary assessment methods:; 24-hr recall used to identify changes needed in the intervention group to follow a Mediterranean-style pattern. Validated short questionnaire (ESTEEM Q) used to assess dietary intake at 20, 24, 28, 32, and 36wk; Outcome & assessment methods:; GWG: Methods NR | Significant:; GWG (kg), P=0.03; - Control: 8.3± 6.4; - Intervention: 6.8± 5.6; - aOR: −1.2, 95% CI=(−2.2, −0.2); Non-significant: | Key confounders accounted for:; Age Race/ethnicity, Prepregnancy BMI, GDM, Parity; Limitations:; - Self-reported adherence; - Dietary intake info for ~40% of participants; change in diet based on intervention reported only for a sub-set of the women that were originally recruited; - Unclear how gestational weight gain was assessed and the window in which it was assessed; - Metabolically at risk participants, so the findings may not be generalizable; - Weight gain was collapsed into one group and was not stratified by prepregnancy BMI; Summary:; A simple, individualized, Mediterranean-style DP supplemented with mixed nuts and EVOO moderately reduced GWG in metabolically at risk women.
Assaf-Balut, 2017 ^26^ ; Spain; RCT; Baseline N=1000 Analytic N=874 (Attrition: 13%); - Age: ~33.0 y; - Race/Ethnicity:; ○ Caucasian: 68.4%; ○ Hispanic: 28.5%; ○ Other: 3.1%; - SES:; - Education:; ■ Elementary: 8.8%; ■ Secondary: 39.8%; ■ University degree: 50.3%; - Employed: 76.6%; - Physical Activity: Score (Walking >5d/wk: Score 0: ≥30 min/d, +1: >60 min/d, −1: <30 min/d; Climbing stairs >5d/wk: Score 0: 4-16 floors/d, +1: >16 floors/d, −1: <4 floors/d): −1.4; - Anthropometry: Prepregnancy BMI: 23.1; - Smoking status: Current: 8.3%; - GDM:; ○ GDM history: 2.8%; ○ Family history of Type 2 DM: 25.2%; - Parity:; ○ Primiparous: 44.3%; ○ Second pregnancy: 32%; ○ >2: 23.7% | Dietary Pattern(s):; - MedDiet: Recommended diet (servings) (Ref, n=440):; ○ ≥2/d vegetables, ≥3/d fruit (avoiding juices), 3/d skimmed dairy products, 3/d wholegrain cereals, and 2-3/wk legumes; ○ Moderate to high consumption of fish; ○ Low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods, and precooked meals; ○ Recommended to walk ≥30 min/d for both groups; ○ Advised to restrict consumption of dietary fat, including EVOO and nuts; - MedDiet + EVOO and Pistachios (n=434):; ○ In addition to MedDiet, recommended 40 mL/d EVOO and 25-30g/d pistachios; study provided 1L/wk EVOO and 150g/wk roasted pistachios throughout the pregnancy.; at 12-14 wks; Dietary assessment methods:; Participants randomized to either MedDiet or MedDiet + EVOO and Pistachios at 8-12wk gestation; Outcome & assessment methods:; Pregestational body weight was self-reported and registered at 12-14 wks (Visit 1). Weight measured at each visit (1,2 and 3). GWG evaluated at 24–28 and 36–38wk gestation (in relation to weight at Visit 1). | Significant:; GWG (kg) 12wk to 24–28wk gestation; - Women with prepregnancy BMI <25, P=0.003; ○ MedDiet (n=330): 5.8± 2.7; ○ MedDiet + EVOO and Pistachios (n=329): 5.4± 2.2; - **Authors write: Overall GWG was significantly lower in EVOO and Pistachio group vs controls at 24–28 GW and at 36–38 GW (P = 0.022 and 0.037, respectively). At 24–28 GW, the GWG was significantly lower in all the three groups of women stratified by BMI (<25, 25–29.9 and ≥30).; Non-significant:; GWG (kg) 12wk to 24–28wk gestation; - Total Sample, P=0.052; ○ MedDiet: 5.6± 2.8; ○ MedDiet + EVOO and Pistachios: 5.2± 2.5; - Women with prepregnancy BMI 25–29.9, P=0.076; ○ MedDiet (n=88): 5.1± 3.0; ○ MedDiet + EVOO and Pistachios (n=85): 4.7 ± 3.4; - Women with prepregnancy BMI ≥30,P= NS; GWG (kg) 12wk to 36–38wk gestation; - Total Sample, P=NS; - Women with prepregnancy BMI <25, P=0.096; ○ MedDiet (n=300): 9.9± 3.9; ○ MedDiet + EVOO and Pistachios (n=329): 10.6± 4.0; - Women with prepregnancy BMI 25–29.9, P=0.066; ○ MedDiet (n=88): 8.8± 4.5; ○ MedDiet + EVOO and Pistachios (n=85): 8.3± 6.5; Women with prepregnancy BMI ≥30, P=NS | Key confounders accounted for:; Age, Race/ethnicity, SES, PA, Prepregnancy BMI, Smoking, GDM, HTN, Parity; Limitations:; - The findings reported in the table are inconsistent with what is reported in the text.; - After GDM diagnosis (24-28wks), women in both intervention and control groups received treatment with insulin and/or diet. Thus, women in the control group diagnosed with GDM (103/440 (23.4%)) may have changed their diet post GDM-diagnosis. Note: there was increased olive oil intake in the control group (P-trend: 0.02).; - Women in both groups received individualized recommendations based on their first trimester BMI to reduce calorie content, when GWG goal is exceeded.; Summary:; Consuming a MedDiet with EVOO and Pistachios vs MedDiet alone resulted in less GWG at 24-28wk, particularly among women with prepregnancy BMI <25. There were no statistically signficant differences in GWG between groups at 36-38wk.
Assaf-Balut, 2019 ^23^ ; Spain; RCT; Baseline N=1000 Analytic N=697; - Age: ~33.0y; - Race/Ethnicity:; ○ Caucasian: 67.5%; ○ Hispanic: 29.7%; ○ Other: 2.8%; - SES:; - Education:; ■ University degree: 50.8%; - Employed: 77.3%; - Physical Activity Score >0 (Walking >5d/wk: Score 0: ≥30 min/d, +1: >60 min/d, −1: <30 min/d; Climbing stairs >5d/wk: Score 0: 4-16 floors/d, +1: >16 floors/d, −1: <4 floors/d): 11.6%; - Anthropometry: Prepregnancy BMI: 22.6; - Smoking status: Current: 7.9%; - GDM:; ○ GDM history: 2.2%; ○ Family history of Type 2 DM: 4.2%; ○ 0% GDM; - Parity:; ○ Primiparous: 43.2%; ○ Second pregnancy: 32.3%; ○ >2: 24.5% | Dietary Pattern(s):; - MedDiet: Recommended diet (servings) (Ref, n=337):; ○ ≥2/d vegetables, ≥3/d fruit (avoiding juices), 3/d skimmed dairy products, 3/d wholegrain cereals, and 2-3/wk legumes; ○ Moderate to high consumption of fish; ○ Low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods, and precooked meals; ○ Recommended to walk ≥30 min/d for both groups; ○ Advised to restrict consumption of dietary fat, including EVOO and nuts; - MedDiet + EVOO and Pistachios (n=360):; ○ In addition to MedDiet, recommended 40 mL/d EVOO and 25-30g/d pistachios; study provided 1L/wk EVOO and 150g/wk roasted pistachios throughout the pregnancy.; at 12-14 wks; Dietary assessment methods:; Participants randomized to either MedDiet or MedDiet + EVOO and Pistachios at 8-12wk gestation; Outcome & assessment methods:; Prepregnancy weight self-reported at baseline (12-14wk gestation). Weight evaluated at 12–14, 24–28 and 36–38wks (or last weight recorded before delivery). GWG reported at 36-38wk in relation to baseline. Adequate GWG defined according to prepregnancy BMI: <25: 9 kg, 25–29: 9.6 kg, 30–34.9: 3 kg, and ≥35: 0 kg. Weight gain 3 kg below designated target categorized as insufficient. Weight gain 3 kg above designated target categorized as excessive. | Significant:; Non-significant:; GWG (kg) 12wk to 36–38wk gestation, P=NS; - MedDiet (n=337): 10.29± 3.97; - MedDiet + EVOO and Pistachios (n=360): 10.68± 4.63; GWG adequacy, P=NS; - Excessive; ○ MedDiet (n=337): 26.7%; ○ MedDiet + EVOO and Pistachios (n=360): 27.5%; - Adequate; ○ MedDiet (n=337): 70.9%; ○ MedDiet + EVOO and Pistachios (n=360): 69.2%; - Inadequate; ○ MedDiet (n=337): 2.4%; ○ MedDiet + EVOO and Pistachios (n=360): 3.3% | Key confounders accounted for:; Age, Race/ethnicity, SES, PA, Prepregnancy BMI, Smoking, GDM, Parity; Limitations:; - Women in both groups received individualized recommendations based on their first trimester BMI to reduce calorie content, when GWG goal is exceeded.; - Risk of selective reporting; Summary:; Consuming a MedDiet with EVOO and Pistachios vs MedDiet alone resulted in no difference in GWG or GWG adequacy, particularly among normoglycemic women.
Van Horn, 2018 ^25^ ; U.S.; RCT, MOMFIT; Baseline N=281 Analytic N=280 (Attrition: 0%); - Age: ~33.6y; - Race/Ethnicity:; ○ Hispanic: ~21.4%; ○ White: ~63.3%; ○ Black/African American: ~19.2%; ○ Other: ~17.4%; - SES:; ○ Education:; ■ ≤High school diploma/GED: ~4.6%; ■ 1–3 years’ college: ~15.7%; ■ College degree: ~39.1%; ■ Postgraduate work: ~40.2%; ○ Marital status:; ■ Married: ~83.3%; ■ Living with significant other: 9.6%; ■ Not married: ~7.1%; ○ Total family income:; ■ <$20,000: ~4.6%; ■ ≥$200,000: ~17.4%; - Physical Activity (Median time/wk):; ○ Moderate activities (3-6 METs): ~4.5 hr; ○ Vigorous activities (7-12 METs): ~0.55 hr; - Anthropometry:; ○ Prepregnancy BMI: ~31; ○ Prepregnancy obesity: ~54.8%; - Smoking status: 0%; - Parity: Nulliparous: 47.0%; - Sleep duration >7 hrs: ~50.5% | Dietary Pattern(s):; - Control: Received usual-care, including biweekly newsletters and publicly available maternity website links via email (Ref, n=140); - Intervention: Mama-DASH diet; ○ Encouraged low-fat dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes; ○ Discouraged sugar-sweetened beverages, sweets, and non-nutrient-dense snack foods; ○ Calorically suited to restricted GWG recommendations and followed nutrition guidelines for pregnant women, including avoidance of fish considered higher in mercury, inclusion of calcium-rich, vitamin D–enriched dairy, or calcium-fortified non-dairy products; ○ Received 3 individual and 6 group diet and physical activity counseling sessions by phone and webinar (n=140); at 15wk gestation; Dietary assessment methods:; Two self-reported 24-hour recalls collected prior to randomization and at 35wks using the ASA24 system. Nutrient and food group intakes averaged at each time point with and without vitamin/mineral supplements, and then further averaged for group means by randomization status. Adherence to DASH diet scored 0-9 and 8-40 using different methodologies. Diet quality also assessed using the HEI-2010, with scores ranging from 0-100.; All participants received the 2008 Physical Activity Guidelines for Americans and recommendations from the ACOG.; Outcome & assessment methods:; GWG calculated as difference between self-reported prepregnancy weight and weight measured by blinded, trained staff at 35wk (weight closest to this time extracted from clinic charts or taken from previous study visits if no 35wk measure available). GWG adequcy determined by IOM 2009 recommendations. | Significant:; GWG (kg), P=0.02; - Control: 12± 6; - Intervention: 10± 6; Exceeded GWG guidelines, P=0.004; - Control: 84.4%; - Intervention: 68.6%; GWG (kg), P=0.01; - Prepregnancy BMI >30; ○ Control: 26± 14; ○ Intervention: 20± 12; Exceeded GWG guidelines, P=0.001; - Prepregnancy BMI >30; ○ Control: 83%; ○ Intervention: 60%; Non-significant:; GWG (kg), stratified by prepregnancy BMI, Median (IQR), P=0.49; - Prepregnancy BMI >25-30, P=NS; Exceeded GWG guidelines, Median (IQR), P=0.33; Prepregnancy BMI Overweight, P=NS | Key confounders accounted for:; Age, Race/ethnicity, Prepregnancy BMI; Limitations:; - Self-reported diet and exercise; - Lower adherence to intervention than expected; - Analyses differ between protocol and publication; Summary:; The MOMFIT intervention, including adherence to the Mama-DASH DP, significantly reduced GWG in obese women.
Prospective Cohort Studies
Factor Analysis and PCA
Maugeri, 2019 ^19^ ; Italy; PCS, Mamma & Bambino; Baseline N=232 Analytic N=232 (Attrition: 0%); - Median Age: ~37.3y; - Race/Ethnicity: NR; - SES:; ○ ≤8y of school: ~19.4%; ○ Working: ~58.3%; - Anthropometry: Prepregnancy BMI: ~22.6; - Smoking status: ~18.1%; - GDM: 0%; - Gestational HTN: 0% | Dietary Pattern(s):; - Prudent dietary pattern characterized by a high intake of boiled potatoes, cooked vegetables, legumes, pizza and soup; - Western dietary pattern characterized by high intake of red meat, fries, dipping sauces, salty snacks and alcoholic drinks.; at ~16wk gestation; Dietary assessment methods:; Dietary assessment performed at ~16wk gestation using a validated 95-item semi-quantitative FFQ, which referred to the previous month. Items from the FFQ were classified into 39 predefined food groups using PCA; Outcome & assessment methods:; GWG (kg) calculated by subtracting self-reported prepregnancy weight from weight measured at delivery | Significant:; GWG (kg), All women:; - Western Diet; ○ T1: Ref; ○ Trend T1 to T3: β=1.217, SE=0.487, P=0.013; GWG (kg), Prepregnancy BMI Underweight; - Prudent Diet; ○ Trend T1 to T3: β= 4.127, SE=1.722, P=0.048; GWG (kg), Prepregnancy BMI Overweight; - Prudent Diet; ○ T1: Ref; ○ T2: β= −7.975, SE=2.672, P=0.010; ○ T3: β= −9.736, SE=4.302, P=0.037; ○ Trend T1 to T3: β= −4.209, SE=1.635, P=0.016; GWG (kg), Prepregnancy BMI Obese; - Prudent Diet; ○ Trend T1 to T3: β= −7.356, SE=2.304, P=0.031; - Western Diet; ○ T1: Ref; ○ T3: β=13.701, SE=0.887, P=0.041; ○ Trend T1 to T3: β=7.363, SE=1.808, P=0.005; Non-significant:; GWG (kg), All women, P=0.830; - Prudent Diet, P=NS; - Western Diet, Median (IQR), P=0.056; ○ T1: 11.5 (7.2); ○ T2: 13.0 (7.0); ○ T3: 13.0 (9.0); GWG Adequacy; - Prudent Diet, P=0.823; ○ No difference in the prevalence of inadequate, adequate, and excessive GWG among tertiles of adherence; - Western Diet, P=0.162; ○ No difference in the prevalence of inadequate, adequate, and excessive GWG among tertiles of adherence; GWG (kg) among all women, and those with Prepregnancy underweight or normal weight:; - Prudent Diet; ○ No association with T2 or T3 (vs T1) adherence and GWG, and no significant trend.; - Western Diet; ○ No association with T2 or T3 (vs T1) adherence and GWG, and no significant trend.; GWG (kg), Prepregnancy BMI Overweight; - Western Diet; ○ No association with T2 or T3 (vs T1) adherence and GWG, and no significant trend.; GWG (kg), Prepregnancy BMI Obese; - Prudent Diet; ○ T1: Ref; ○ T2 vs T1, P=NS; ○ T3: β= −10.730, SE=4.156, P=0.061; - Western Diet; ○ T1: Ref; ○ T2 vs T1, P=NS | Key confounders accounted for:; Age, SES, Smoking, GDM, HTN, Parity; Limitations:; - Accounted for total energy intake; - Could not investigate the effect of DP on GWG trajectories; - Limited sample size in underweight and obese groups; - PCA-derived dietary patterns only explained 15.55% of total variance among food groups; - Selection into the analysis was related to exposure and outcome and not adjusted for in the analysis; Start of follow up and exposure did not coincide and a potentially important amount of follow-up time is missing from analyses; - Dietary data reflected first trimester intake, when mothers may have been prone to morning sickness; - Outcome measure was subjective and assessed by participants; - No pre-registered data analysis plan; Summary:; Adherence to a Western DP is positively associated with GWG, especially among obese women. Adherence to a prudent DP is positively associated with GWG among underweight women and negatively associated with GWG among overweight and obese women.
Okubo, 2012 ^3^ ; Japan; PCS, OMCHS; Baseline N=803 Analytic N=803 (Attrition: 0%); - Age:; ○ <29y: ~37.1%; ○ 29-31y: ~30.4%; ○ ≥32y: ~32.5%; - Race/Ethnicity: NR; - SES:; ○ Education:; ■ <13y: ~28.8%; ■ 13-14y: ~42.8%; ■ ≥15y: ~28.4%; ○ Household income (yen/y):; ■ <4,000,000: ~28.6%; ■ ≥6,000,000: ~31.1%; - Anthropometry: Prepregnancy BMI: ~20.2; - Parity: ≥1: ~51.7%; - Smoking:; ○ Never: ~71.6%; ○ Former: ~12.2%; ○ Current: ~16.2%; - Physical Activity:; ○ Low: ~58.9%; ○ Moderate or High: ~41.1% | Dietary Pattern(s):; - Meat and eggs pattern: high intake of beef and pork, processed meat, chicken, eggs, butter and dairy products (n=326); - Wheat products pattern: high intake of bread, confectioneries, fruit and vegetable juice, and soft drinks (n=303); - Rice, fish, and vegetables pattern: high intake of rice, potatoes, nuts, pulses, fruits, green and yellow vegetables, white vegetables, mushrooms, seaweeds, Japanese and Chinese tea, fish, shellfish, sea products, miso soup and salt-containing seasoning (n=174); at ~18.0wk, Range: 5 to 39wk gestation; Dietary assessment methods:; Self-administered, comprehensive, 150-item diet history questionnaire (DHQ), validated in Japanese men and women (not specifically pregnant women) (see Sasaki, 2000 and Sasaki, 1998); Patterns identified by K-means cluster analysis; Outcome & assessment methods:; Maternal weight gain was obtained using a survey collected 2-9 mo postpartum | Significant:; GWG (kg), Mean (95% CI), P=0.01; - Meat and eggs: 10.0 (9.7, 10.3); - Wheat products: 10.2 (9.8, 10.6); - Rice, fish and vegetables: 9.3 (8.8, 9.7); ○ Meat and eggs vs. wheat products: NS; ○ Meat and eggs vs. rice, fish and veg.: NS; ○ Wheat vs. rice, fish and veg: P<0.05; Non-significant: | Key confounders accounted for:; None; Limitations:; - Questionnaire not validated in pregnant women and may not reflect total food and nutrient intake; - Self-administered questionnaire used to assess potential confounders were developed for this study not validated; - Self-reported outcome data collected 2-9 mo postpartum; - Supplement intake: Sig higher in rice, fish and vegetables (~29% vs. ~19% in other groups); - Follow-up time varied (potentially widely) across participants; - Important co-exposures imbalanced across groups and could have likely to impacted the outcome; - Missingness by exposure NR; - No pre-registered data analysis plan; Summary:; Adherence to a wheat products dietary patterns was associated with significantly greater weight gain when compared to rice, fish, and vegetables DPs
Tielemans, 2015 ^8^ ; Netherlands; PCS, Generation R Study; Baseline N=3374 Analytic N=2748 (Attrition: 33%); Women excluded due to missing diet data (n = 538), weight data (n=5), multiple pregnancy (n=53), induced abortion (n=8), intrauterine fetal death (n=16), loss-to-follow up (n=3), prepregnancy underweight (n = 100), leaving 3374 women for the current analysis.; n=3374 for participant characteristics; - Age: ~31.3y; - Race/Ethnicity: 100% of Dutch ancestry; - SES:; ○ Education:; ■ Low and midlow: ~18.2%; ■ Midhigh: ~51.5%; ■ High: ~30.4%; ○ Household income <2200 Euro/mo: ~28.3%; - Anthropometry: Prepregnancy BMI: ~24.7; - Smoking status:; ○ Never in pregnancy: ~74.4%; ○ Until pregnancy known: ~8.3%; ○ During pregnancy: ~17.4%; - Parity:; ○ 0: ~59.8%; ○ ≥1: ~40.2%; - Alcohol:; ○ Never in pregnancy: ~36.6%; ○ Until pregnancy known: ~16.5%; ○ During pregnancy: ~46.9% | Dietary Pattern(s):; - Vegetable, Oil and Fish Pattern: higher intake of vegetables, high fat dairy products, cereals (both low and high fiber), fish and shellfish, eggs and egg products, vegetable oils, coffee and tea, alcoholic beverages and legumes; - Nuts, High-Fiber Cereals and Soy Pattern: higher intake of potatoes and other tubers, fruits, high and low fat dairy products, high fiber cereals, meat and meat products, fish and shellfish, coffee and tea, sugar-containing beverages, light soft drinks, nuts, seeds and olives, and soy products; - Margarine, Sugar and Snacks Pattern: higher intake of potatoes and other tubers, high fat dairy products, low and high fiber cereals, meat and meat products, margarine and butter, sugar and confectionary and cakes, snacks, sugar-containing beverages, condiments and sauces, nuts, seeds and olives; at ~13.4wk gestation; Higher adherence to each pattern indicates a diet characterized by higher intake of those food groups.; Dietary assessment methods:; Dietary intake assessed at ~13.4wk gestation using a validated, 293-item FFQ that covered dietary intake over the previous 3 months. A posteriori-derived dietary patterns identified using PCA with Varimax rotation. Adherence scores for each participant and each pattern calculated by individual sum of the intake of the 23 food groups, weighted with their factor loadings and standardizing those weighted sums to have mean zero and standard deviation one.; Outcome & assessment methods:; Self-reported prepregnancy weight collected at enrollment. Staff measured weight at 3 study visits: ~12.9wk (first visit), ~20.4wk (second visit), and ~30.2wk (third visit). At 6wk postpartum, women self-reported maximum weight during pregnancy.; GWG in different phases of pregnancy was calculated mid-pregnancy GWG (weight at the second visit minus weight the first visit, divided by follow-up duration (g/week), n = 2748), late-pregnancy GWG (weight at the third visit minus weight at the second visit, divided by follow-up duration (g/week), n = 3158), and GWG until early-third trimester (weight at the third visit minus prepregnancy weight, divided by follow up duration (g/week), n = 2815).; Women’s total GWG (maximum pregnancy weight minus prepregnancy weight, n = 1917) and GWG rate between visits 1 and 3 was used to classify their GWG into inadequate, adequate, or excessive GWG according to IOM (2009) recommendations. | Significant:; Weekly GWG adequacy; - Inadequate (n=437, Ref: Adequate, n=753); ○ Margarine, Sugar, and Snacks Pattern Q4 vs Q1: OR=1.49, 95% CI=(1.05, 2.11); - Excessive (n=1555, Ref: Adequate, n=753); ○ Margarine, Sugar, and Snacks Pattern Q4 vs Q1: OR=1.32, 95% CI=(1.01, 1.720; Non-significant:; Mid-Pregnancy Weight Gain (g/wk); - Prepregnancy Normal Weight (n=2079); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; - Prepregnancy Overweight Women (n=669); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; Late-Pregnancy Weight Gain (g/wk); - Prepregnancy Normal Weight Women (n=2384); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; - Prepregnancy Overweight Women (n=774); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; GWG adequacy:; - Inadequate GWG (n=459, Ref: Adequate, n=632); ○ Vegetable, Oil and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; - Excessive GWG (n=826, Ref: Adequate, n=632); ○ Vegetable, Oil and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS; Weekly GWG adequacy; - Inadequate (n=437, Ref: Adequate, n=753); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar, and Snacks Pattern, P=NS; - Excessive (n=1555, Ref: Adequate. N=753); ○ Vegetable, Oil, and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; Margarine, Sugar, and Snacks Pattern, P=NS | Key confounders accounted for:; Age, Race/ethnicity, SES, Prepregnancy BMI, Smoking, Parity; Limitations:; - Accounted for total energy intake; - Start of follow up and start of exposure did not coincide; - Self-reported diet, prepregnancy weight, and maximum pregnancy weight; - No pre-registered data analysis plan; Summary:; None of the a posteriori-derived DPs were associated with GWG.
Tielemans, 2015 continued | | Significant:; [underlined: Sensitivity Analysis (excludes women with GDM or hypertensive disorders of pregnancy)]; GWG until early-third trimester (g/wk); - Prepregnancy Normal Weight Women (n=1937); ○ Vegetable, Oil and Fish Pattern, P<0.01 per SD increase in DP score; ■ Q1: Ref; ■ Q2: β=20, 95% CI: (3, 36), P<0.05; ■ Q3: β=7, 95% CI: (−10, 23); ■ Q4: β=27, 95% CI: (11, 44), P<0.05; Non-significant:; [underlined: Sensitivity Analysis (excludes women with GDM or hypertensive disorders of pregnancy)]; GWG until early-third trimester (g/wk); - Prepregnancy Normal Weight Women (n=1937); ○ Nuts, High-Fiber Cereals and Soy, P=NS per SD increase in DP score; ○ Margarine, Sugar, and Snacks, P=NS; - Prepregnancy Overweight Women (n=532); ○ Vegetable, Oil and Fish Pattern, P=NS per SD increase in DP score; ○ Nuts, High-Fiber Cereals and Soy Pattern, P=NS; ○ Margarine, Sugar and Snacks Pattern, P=NS | Key confounders accounted for:; Age, Race/ethnicity, SES, Prepregnancy BMI, Smoking, GDM, HTN, Parity; Summary:; Among women with normal prepregnancy weight, higher adherence to the Vegetable, Oil and Fish Pattern was associated with greater GWG.
Wei, 2019 ^15^ ; China; PCS, BIGCS; Baseline N=5,733 Analytic N=5,733; - Age: ~29.1y; - Race/Ethnicity: NR; - SES:; ○ Educational level:; ■ High school or below: 8.0%; ■ Vocational/technical college: 23.6%; ■ Undergraduate: 55.5%; ■ Postgraduate: 12.9%; ○ Income (Yuan/mo; n=5605):; ■ ≤1500: 9.3%; ■ ≥9001: 16.9%; - Anthropometry: Prepregnancy BMI: 20.4± 2.6; - Smoker: 29.7%; - Parity: Primiparous: 88.2% | Dietary Pattern(s):; Six dietary patterns were generated according to the food groups predominant in each cluster.; - Cereals (n=872); - Vegetables (n=1147); - Meats (n=927); - Fruits (n=640); - Fish, beans, nuts, and yogurt (n=1130); - Milk and milk powder (n=817); at 24-27wk gestation; Dietary assessment methods:; A validated, 64-item FFQ used to assess diet Individual food items were combined into 30 groups by similar nutrient profile or culinary use. Contribution (%) of every food group was calculated for each participant. Cluster analysis with K-means method was conducted to generate six dietary patterns based on foods highly consumed and distribution of foods within clusters.; Outcome & assessment methods:; Prepregnancy weight self-reported, while weight during pregnancy extracted from medical records. Total GWG (kg) calculated as difference in weight between prepregnancy and delivery. Total GWG rate (kg/wk) calculated by dividing total GWG by total gestational wks. Second trimester GWG rate (kg/wk) calculated as difference in weight before 28wk and weight after 13wk, divided by wks between the two measures. Third trimester GWG rate (kg/wk) calculated as difference between pre-delivery weight and weight at 28wk, divided by wks between the two measures. | Significant:; GWG (kg), P=0.007; - Cereals: Ref; - Fruits: β=0.592, 95% CI: (0.166, 1.018); GWG rate (kg/wk), P=0.007; - Cereals: Ref; - Fruits: β=0.015, 95% CI: (0.004, 0.026); Second Trimester GWG rate (kg/wk), P<0.05; - Cereals: Ref, n=821; - Fish, beans, nuts, and yogurt: β=0.024, 95% CI: (0.001, 0.048), n=658; GWG adequacy; - Inadequate GWG; ○ Cereals: Ref; ○ Fish, beans, nuts, and yogurt: OR=0.797, 95% CI: (0.638, 0.997); - Excessive GWG; ○ Cereals: Ref; ○ Fruits: OR=1.393, 95% CI: (1.101, 1.763); Non-significant:; GWG (kg), P=NS; - Cereals: Ref; - Vegetables; - Meats; - Fish, beans, nuts, and yogurt: β=0.341, 95% CI: (−0.017, 0.699), P=0.062; - Milk and milk powder; GWG rate (kg/wk), P=NS; - Cereals: Ref; - Vegetables:; - Meats:; - Fish, beans, nuts, and yogurt: β=0.009, 95% CI: (0.000, 0.018), P=0.060; - Milk and milk powder; Second Trimester GWG rate (kg/wk), P=NS; - Cereals: Ref, n=821; - Vegetables: n=682; - Meats: n=493; - Fruits: n=968; - Milk and milk powder: n=645; Third Trimester GWG rate (kg/wk), P=NS; - Cereals: Ref, n=830; - Vegetables: n=708; - Meats: n=517; - Fruits: n=993; - Fish, beans, nuts, and yogurt: n=679; - Milk and milk powder: n=669; GWG adequacy (Ref: Adequate GWG, Cereals DP), P=NS; - Inadequate; - Excessive | Key confounders accounted for:; Age, SES, Prepregnancy BMI, Parity; Limitations:; - Food quantity and portion size not documented in the FFQ; - Adjusted for post-exposure variables; - Selection into analysis related to outcome; - Start of follow up and exposure did not coincide and a potentially important amount of follow-up time is missing from analyses; - Proportions of missing participants differed substantially across exposure groups and was not accounted for in the analyses; - No pre-registered data analysis plan; - High risk of selective reporting from among multiple analyses; Summary:; Among Chinese pregnant women with healthy BMI, the dietary pattern richer in fruits was positively associated with total GWG, GWG rate, and an increased risk for excessive GWG. The richer in fish, beans, nuts and yogurt pattern was positively associated with GWG rate in the second trimester and related to a reduced risk for inadequate GWG.
Wei, 2019 continued | | Significant:; GWG (kg), P<0.01; - Cereals: 14.5± 4.3; - Vegetables: 14.5± 4.4; - Meats: 14.3± 4.3; - Fruits: 15.1± 4.4; - Fish, beans, nuts, and yogurt: 14.7± 4.1; - Milk and milk powder: 14.6 ± 4.4; GWG rate (kg/wk), P=0.01; - Cereals: 0.37± 0.11; - Vegetables: 0.37± 0.1; - Meats: 0.39± 0.11; - Fruits: 0.38± 0.10; - Fish, beans, nuts, and yogurt: 0.38± 0.11; - Milk and milk powder: 0.37± 0.11; GWG Adequacy, P<0.01; - Cereals:; ○ Inadequate: 23.5%; ○ Adequate: 47.6%; ○ Excessive: 28.9%; - Vegetables:; ○ Inadequate: 23.6%; ○ Adequate: 44.9%; ○ Excessive: 31.5%; - Meats:; ○ Inadequate: 22.4%; ○ Adequate: 49.9%; ○ Excessive: 27.6%; - Fruits:; ○ Inadequate: 19.2%; ○ Adequate: 43.6%; ○ Excessive: 37.2%; - Fish, beans, nuts, and yogurt:; ○ Inadequate: 19.6%; ○ Adequate: 48.9%; ○ Excessive: 31.5%; - Milk and milk powder:; ○ Inadequate: 20.2%; ○ Adequate: 46.9%; ○ Excessive: 32.9% | Key confounders accounted for:; None; Summary:; Among Chinese pregnant women with healthy BMI, the dietary pattern richer in fruits was positively associated with total GWG, GWG rate, and an increased risk for excessive GWG. The richer in fish, beans, nuts and yogurt pattern was positively associated with GWG rate in the second trimester and related to a reduced risk for inadequate GWG.
Wesolowska, 2019 ^17^ ; Poland; PCS; Baseline N=1306 Analytic N=1158 (Attrition: 34%); N=1306 for participant characteristics; - Age: 17-30y: ~65.2%, >30y: ~34.8%; - Race/Ethnicity: NR; - SES:; ○ Marital Status: Married: ~80.0%; ○ Education:; ■ ≤9y: ~2.3%; ■ 10-12y: ~27.9%; ■ >12y: ~69.8%; ○ SES:; ■ Low: ~7.4%; ■ Middle: ~67.9%; ■ High: ~24.7%; - Physical Activity: Yes: ~68.8%; - Anthropometry: Prepregnancy BMI:; ○ <18.5: ~8.9%; ○ 18.5-24.99: ~72.6%; ○ ≥25: ~18.6%; - Smoking status: Cotinine level >10 ng/mL: ~11.1%; - Parity:; ○ 0: ~52.0%; ○ ≥1: ~48.0%; - Alcohol consumption: ~6.4%; - Perceived Stress Scale (0-38 pts): ≥17 points (higher stress): ~52.6% | Dietary Pattern(s):; - Western: High intake of refined grains, processed meat, potatoes, and low intake of whole grains; - Mixed: Intakes in between Western and Prudent; - Prudent: High consumption of fruits, vegetables, legumes, whole grains, poultry, and low-fat and high-fat dairy products; at 20-24wk gestation; Dietary assessment methods:; Modified version of validated FFQ administered by trained personnel at 20-24wks gestation. Food items grouped into 14 predefined food groups: Refined grains, Whole grains, Low–fat dairy, High–fat dairy, Butter, Red meat, Poultry, Processed meat, Fish/Seafood, Fruits, Vegetables, Potatoes, Legumes, Sweets. 3 dietary patterns derived using exploratory factor analysis.; Outcome & assessment methods:; GWG calculated as difference between latest weight before delivery and prepregnancy weight. GWG adequacy determined by IOM 2009 recommendations. | Significant:; Non-significant:; GWG Adequacy (Pearson’s chi squared test across all GWG and diet categories), P=NS | Key confounders accounted for:; None; Limitations:; - Selection into the study related to exposure and outcome; - Some missing outcome data, reasons NR; - Unclear if outcome was self-reported or assessed objectively. Start of follow up and exposure did not coincide and a potentially important amount of follow-up time was missing from analyses; - Important co-exposures not balanced across groups that were likely to impact the outcome, and no adjustment techniques were used to correct for the issues; - No information on how weight was measured; - No pre-registered data analysis plan; Summary:; No association was found between GWG and Western, Mixed, or Prudent dietary patterns during pregnancy.
Index/Score
Ancira-Moreno, 2019 ^18^ ; Mexico; PCS, PRINCESA; Baseline N=660 Analytic N=660 (Attrition: 0%); - Age: ~24.9y; - Race/Ethnicity: NR; - SES:; ○ Married/partnered: ~73.9%; ○ >9y education: ~14.2%; - Anthropometry: Prepregnancy BMI: ~25.7; - GDM: 0%; - Gestational HTN: 0%; - Parity:; ○ Nulliparous: ~48.0%; ○ 1-2: ~28.3%; ○ ≥3: ~23.3%; - Term birth: ~88.0% | Dietary Pattern(s):; Maternal Diet Quality Score (MDQS) based on Mexican Dietary Guidelines and international recommendations for specific foods and nutrients.; - Low adherence (Score 0-2); - Medium adherence (Score 3-4); - High adherence (Score ≥5); Higher adherence characterized by:; - PUFAS >6% of energy intake; - Added sugars <10% of energy intake; - Fruits and vegetables >400 g/d; - Red meat <500 g/wk; - 2 servings/d low fat dairy products; - 2 servings/d legumes; - Foods high in SFAs or added sugar <10% of energy intake; early-mid pregnancy (0-20 wk), middle pregnancy (≥20 and <30wk), late pregnancy (30-40wk), and prolonged pregnancy (≥40wk); Dietary assessment methods:; Dietitian collected data on maternal diet via a multiple-step 24-h dietary recall at each prenatal visit.; Value of 1 assigned if recommendation met and 0 if recommendation not met. Values summed with maximum score of 7 and minimum score of 0. Three categories of adherence defined: low (0-2 points), medium (3-4 points), and high (≥5 points).; Outcome & assessment methods:; Weight measured at first and consecutive visits by trained staff using standardized methods. Prepregnancy weight self-reported. Rate of GWG (kg/wk) calculated as weight at current visit minus weight from previous visit, divided by follow-up duration. First GWG rate estimated using prepregnancy weight. Adequacy of GWG rate based on IOM (2009) recommendations. | Significant:; GWG rate (kg/wk); - Middle pregnancy (≥20 and <30wk); ○ Low: Ref; ○ Medium: β= −0.0266, 95% CI: (−0.0496, −0.0037), P=0.023; - Late pregnancy (30-40wk); ○ Low: Ref; ○ Medium: β=0.0256, 95% CI: (0.0077, 0.0436), P=0.005; ○ High: β=0.0472, 95% CI: (0.0222, 0.0723), P<0.001; - Prolonged pregnancy (≥40wk); - Low: Ref; - High: β=−0.182, 95% CI: (−0.360, −0.00450), P=0.044; GWG rate adequacy; - Inadequate; ○ Low: Ref; ○ Medium: OR=0.742, 95% CI: (0.555, 0.991), P=0.044; ○ High: OR=0.630, 95% CI: (0.417, 0.953), P=0.031; - Excessive; ○ Low: Ref; ○ High: OR=0.623, 95% CI: (0.411, 0.942), P=0.025; GWG rate adequacy, Prepregnancy BMI <25; - Inadequate; ○ Low: Ref; ○ Medium: OR=0.426, 95% CI: (0.184, 0.985), P=0.046; ○ High: OR=0.295, 95% CI: (0.092, 0.946), P=0.040; - Excessive; ○ Low: Ref; ○ Medium: OR=0.347, 95% CI: (0.126, 0.952), P=0.040; ○ High: OR=0.242, 95% CI: (0.059, 0.989), P=0.048; GWG rate adequacy, Prepregnancy BMI ≥25; - Inadequate; ○ Low: Ref; ○ Medium: OR=0.095, 95% CI: (0.010, 0.906), P=0.044; ○ High: OR= 0.033, 95% CI: (0.002, 0.442), P=0.010; - Excessive; ○ Low: Ref; ○ Medium: OR= 0.084, 95% CI: (0.126, 0.918), P=0.042; ○ High: OR=0.077, 95% CI: (0.059, 0.999), P=0.05; Non-significant:; GWG rate (kg/wk); - Early-mid pregnancy (0-20wk); ○ Low: Ref; ○ Medium: β=0.0162, 95% CI: (−0.0005, 0.0333), P=0.058; ○ High, P=NS; - Middle pregnancy (≥20 and <30wk); ○ Low: Ref; ○ High: β= −0.0363, 95% CI: (−0.076, 0.0037), P=0.076; - Prolonged pregnancy (≥40wk); ○ Low: Ref; ○ Medium, P=NS; GWG rate adequacy:; - Excessive; ○ Low: Ref; ○ Medium: OR=0.773, 95% CI: (0.572, 1.044), P=0.094 | Key confounders accounted for:; Age, SES, PA, Prepregnancy BMI, GDM, HTN, Parity; Limitations:; - Accounted for total energy intake; - Lack of weight measurement at each visit; - Recall bias and other biases related to a priori DP; could not capture day-to-day variability in dietary intake; - Participants who developed HTN or GDM excluded from final analysis; - Selection into analysis related to exposure and outcome and not adjusted for; - Start of follow up and exposure do not coincide and a potentially important amount of follow-up time missing from analyses; - Multiple 24HR recalls collected, but unclear if analysis was cross-sectional; - No pre-registered data analysis plan; - High risk of selective reporting from among multiple analyses; - Baseline differences in maternal age and education; Summary:; Higher adherence to maternal dietary quality recommendations was protective against inadequate and excessive GWG throughout pregnancy, associated with slower GWG in middle and prolonged late pregnancy, and associated with a faster GWG in early and late pregnancy.
Emond, 2018 ^13^ ; U.S.; PCS, NHBCS; Baseline N=1140 Analytic N=862; Participants excluded due to unrealistic/missing dietary data (n=64), missing key covariates (n=89), underweight prepregnancy BMI (n=20), incomplete/ unrealistic infant birth data (n=62), or missing urinary arsenic data (n=43); N=862 for all participant characteristics; - Age: ~31.2y; - Race/Ethnicity: White, non-Hispanic: 96.8%; - SES:; ○ High school graduate or less: 26.8%; ○ Some college: 24.1%; ○ College graduate or more: 49.1%; - Physical Activity: Regular exercise during pregnancy: 60.6%; - Anthropometry: Prepregnancy BMI:; ○ 18.5-24.9: 54.5%; ○ 25.0-29.9: 26.3%; ○ ≥30: 19.3%; - Smoking status: Smoker: 5.5%; - GDM: 7.1%; ○ History of DM: 5.9%; - Gestational HTN: PE: 6.7%; ○ History of HTN: 1.9%; - Parity: Nulliparous: 41.0% | Dietary Pattern(s):; Adherence to AHEI-2010 diet, by quartile; - Q1: n=215; - Q2: n=215; - Q3: n=216; - Q4: Highest intake of fruits, vegetables, whole grains, nuts and legumes, long-chain n–3 FAs, and PUFAs; Lowest intake of sugar-sweetened beverages and fruit juice, red and processed meats, trans fatty acids, and sodium (n=216); at 24-28wk gestation; Dietary assessment methods:; Women completed a validated FFQ at 24–28wk gestation), reflecting usual dietary intake during pregnancy.; Diet quality assessed as adherence to a modified AHEI-2010 for pregnant women, including 10 dietary components: 6 healthful components to encourage (vegetables, fruits, whole grains, nuts/legumes, long-chain n–3 FAs from foods and supplements, polyunsaturated fats) and 4 components to reduce (sugary beverages, red and processed meats, trans fatty acids, and sodium). All components are scored from 0 to 10 for a total score of 0-100 such that a higher score indicates a healthier intake.; Outcome & assessment methods:; GWG computed using self-reported prepregnancy weight and the last recorded prenatal weight from prenatal medical records. Adequacy of GWG defined according to IOM 2009 recommendations. | Significant:; Non-significant:; - GWG Adequacy, P=NS; ○ Insufficient GWG; ○ Adequate GWG; ○ Excessive GWG | Key confounders accounted for:; None; Limitations:; - Power analysis NR for this secondary analysis; - Selection into study may have been related to exposure and outcome, without adjustment; - Self-reported exposure & prepregnancy BMI; - Unclear sample size at enrollment; - No preregistered data analysis plan; - Baseline imbalances in multiple key confounders; - No correction for multiple comparisons; Summary:; Adherence to the AHEI-2010 diet at 24-28wk gestation was not associated with GWG.
Fernández-Barrés, 2019 ^1^ ; Spain; PCS, INMA; Baseline N=2195 Analytic N=2127; Participants excluded from analysis if no dietary data at 3rd trimester (n = 319) or no BMI measured (n = 248); Those lost to follow-up were younger, smoked more, and had lower socioeconomic and education levels.; - Age: 30.9y; - Race/Ethnicity: NR; - SES:; ○ Social class:; ■ I+II: ~23.2%; ■ III: ~27.1%; ■ IV+V: ~49.7%; ○ Education level:; ■ Primary or less: ~22.1%; ■ Secondary: ~41.5%; ■ University: ~36.4%; - Physical Activity: METs(hr/d): ~37.4; - Anthropometry: Prepregnancy BMI: ~23.5; - Smoking status: During pregnancy: ~16.6%; - GDM: ~4.1%; ○ History of GDM: ~0.3%; - Parity:; ○ Primiparous: ~57.0%; ○ Multiparous: ~43.0% | Dietary Pattern(s):; - Adherence to Relative Mediterranean Diet (rMED) score: consumption of vegetables, fruits and nuts, cereals, legumes, fish, olive oil, meat, and dairy products. Alcohol not scored.; - T1: low rMED (Score 0-7), n=925; - T2: medium rMED (Score 8-9), n=631; - T3: high rMED (Score 10-15), n=639; - *highest score differs btw 15 and 16 throughout the paper; at 12wk and 32wk gestation; Dietary assessment methods:; 101-item validated FFQ at 12 and 32wk gestation measured diet in the first trimester and 12-32wk. Adherence to the Mediterranean diet assessed using the rMED. Values of 0, 1, and 2 assigned to intake tertiles, positively scoring higher intakes for the 6 components that fit into the Mediterranean diet (vegetables, fruits and nuts, cereals, legumes, fish, olive oil). Scoring reversed for meat and dairy. Scores summed for each component, for a total score ranging from 0 to 16.; Outcome & assessment methods:; GWG extracted from prenatal visit records; timing NR | Significant:; GWG (kg/wk), P=0.017; - T1: 0.35± 0.13; - T2: 0.35± 0.12; - T3: 0.34± 0.13; Non-significant: | Key confounders accounted for:; None; Limitations:; - Start of follow up and exposure did not coincide and potentially important amount of follow-up time was missing from analyses; - Important co-exposures were not balanced across groups that were likely to impact the outcome, and no adjustment techniques were used to correct for the issues; - No pre-registered data analysis plan; Summary:; Higher adherence to the Mediterranean diet during pregnancy is associated with lower GWG.
Fulay, 2018 ^12^ ; U.S.; PCS, Project Viva; Baseline N=2128 Analytic N=1756 (Attrition: 17%); Participants excluded due to Type 1 or 2 Diabetes Mellitus (n=16), missing outcomes data (n=7) or dietary data (n=345); n=~1760 for all participant characteristics; - Age:; ○ 15-24y: 7.4%; ○ 25-34y: 63.9%; ○ 35-44y: 28.8%; - Race/Ethnicity:; ○ Black: 12.3%; ○ Hispanic: 6.5%; ○ White: 72%; ○ Asian: 5.6%; ○ Other: 3.6%; - SES:; ○ Annual household income; ■ <$20,000: 2.9%; ■ >$70,000: 59.6%; ○ Married/cohabiting: 93.3%; ○ Education; ■ Primary: 9.4%; ■ Secondary: 58.6%; ■ ≥College: 32.0%; - Anthropometry: Prepregnancy BMI:; ○ <18.5: 3.9%; ○ 18.5-24.9: 60.7%; ○ 25.0-29.9: 21.4%; ○ ≥30: 12.7%; - Smoking status: During pregnancy: 10.9%; - GDM: 5.2%; - Gestational HTN: History before pregnancy: 4.5%; - Parity:; ○ 0: 49.3%; ○ 1: 35.3%; ○ ≥2: 15.4% | Dietary Pattern(s):; - Adherence to DASH diet; ○ Higher adherence characterized by higher intakes of fruits, vegetables, whole grains, nuts/legumes, and low-fat dairy, and lower intakes of sodium, sugar-sweetened beverages, and red and/or processed meats.; - Adherence to DASH OMNI diet at 11wk gestation.; ○ Higher adherence characterized by higher intakes of fruits, vegetables, whole grains, nuts/legumes, low-fat dairy, and MUFAs and PUFAs, and lower intakes of sodium, sugar-sweetened beverages, and red and/or processed meats.; at 11wk gestation; Dietary assessment methods:; Semi-quantitative, validated, 140-item FFQ based on NHS, administered at enrollment (11.1wk gestation).DASH score calculated as weighted sum of frequency of intake/day for the following components, with increasingly postitive scores for higher quintiles of intake for fruits, vegetables, whole grains, nuts/legumes, and low-fat dairy, and for lower quintiles of intake for sodium, sugars-weetened beverages, and red and/or processed meats. Total score range: 8-40.The DASH diet is rich in fruits, vegetables, legumes, whole grains, and healthy fats, with limited amounts of poultry, red meat, and dairy. The DASH diet also focuses on intake of foods high in macro- and micronutrients that have been specifically demonstrated to be effective in reducing risk of hypertension: reduced amounts of saturated fat, total fat, and cholesterol; and high levels of potassium, magnesium, calcium, fiber, and protein, with ≤3 g/d sodium.; DASH OMNI score calculated similarly to DASH score, with the additional component of increasingly postitive scores for higher quintiles of intake of MUFAs and PUFAs. Total score range: 9-45.; Outcome & assessment methods:; GWG from time of FFQ in first trimester to delivery. Derived via linear interpolation between the two measures of weight assessed in closest temporal proximity to the date of FFQ administration and calculated the difference between the last clinicallymeasured weight prior to self-reported prepregnancy weight. | Significant:; Subsequent GWG (kg) per unit 1st trimester DASH score; - Prepregnancy obese (n=244); ○ β=0.31, 95% CI: 0.08, 0.53; Subsequent GWG (kg) per unit 1st trimester DASH OMNI score; - Prepregnancy obese (n=244); ○ β=0.34, 95% CI: (0.09, 0.58); Non-significant:; Subsequent GWG (kg) per unit 1st trimester DASH score, P=NS; - Prepregnancy underweight (n=68); - Prepregnancy normal weight (n=1068); - Prepregnancy overweight (n=376); Subsequent GWG (kg) per unit 1st trimester DASH OMNI score, P=NS; - Prepregnancy underweight (n=68); - Prepregnancy normal weight (n=1068); - Prepregnancy overweight (n=376) | Key confounders accounted for:; Age, Race/ethnicity, SES, Pre-preg BMI, Smoking, Parity; Limitations:; - Accounted for total energy intake; - Power analysis NR for this exploratory study based on secondary analysis of existing data; - Adjusted for potential mediator (early GWG); - Start of follow up and start of exposure did not coincide; - Unclear proportions/reasons for missing exposure data; - Self-reported diet and prepregnancy weight; - No pre-registered data analysis plan; Summary:; Among women with prepregnancy obesity, higher adherence to a DASH or DASH OMNI diet is associated with higher GWG from 1st trimester through delivery. This association was not statistically significant among women with prepregnancy BMI <30.
Gesteiro, 2012 ^2^ ; Spain; PCS, Mérida Cohort; Baseline N=35 Analytic N=35; n=35 for all participant characteristics; - Age:; ○ Mean± SE: 30.4± 0.9y; ○ <35y: 54%; ○ ≥35y: 46%; - Race/Ethnicity: All infants were Caucasian; - SES:; ○ Education degree:; ■ Low: 17%; ■ Medium: 63%; ■ High: 20%; - Anthropometry: Prepregnancy BMI: 23.0± 0.6; - Smoking status: 0%; - GDM: 0%; ○ Positive O’Sullivan glucose tolerance test at 24-28wk gestation: 77%; - Parity:; ○ Primiparous: 37%; ○ Multiparous: 63%; - Full-term: 100%; - Alcohol consumption: 0% | Dietary Pattern(s):; Mediterranean Diet Adherence (MDA); - Low MDA (n=13); - High MDA: olive oil as main culinary fat, higher intakes of vegetables, raw vegetables, fruits, fish or shellfish, nuts (including peanuts), legumes, chicken, turkey or rabbit meat, and dishes seasoned with sofrito, sauce made with tomato, onion, leek or garlic and simmered with olive oil, and lower intakes of red meat, veal, pork, hamburger or sausage, butter, margarine or cream, sweet or carbonated beverages, and commercial sweets or pastries (n=22); at 12-15wk gestation; Dietary assessment methods:; Dietary intake assessed via a validated, 169-item FFQ, conducted by a trained dietician, and included photographs of sample portions to estimate the serving size and volumes consumed.; Dietary pattern adherence assessed with the Mediterranean Diet, modified to remove red wine consumption (PERIMED study). 1pt awarded for each of the following 13 components: Use of olive oil as main culinary fat; ≥4 TBSP/d olive oil; ≥2 servings/d vegetables, including ≥1 raw or as salad; ≥3 units of fruits, including juices; <1 serving/d red meat; <1 serving/d butter, margarine or cream; <1 sweet or carbonated beverage/d; ≥3 servings/wk legumes; ≥3 servings/wk fish or shellfish; <3 commercial (not home-made) sweets or pastries; ≥3 servings/wk nuts (including peanuts); Consumption of chicken, turkey or rabbit meat instead of veal, pork, hamburger or sausage; 2 servings/wk vegetables, pasta, rice or dishes seasoned with sofrito, sauce made with tomato, onion, leek or garlic and simmered with olive oil; Low Mediterranean Diet adherence (MDA) defined as score <7, and high MDA defined as scores ≥7.; Outcome & assessment methods:; Anthropometrical measurements were taken by trained personnel following hospital’s standard procedures. GWG data obtained from hospital records | Significant:; GWG (kg), Mean± SE (95% CI), P= 0.017; - Low MDA: 7.9± 1.8 (4.1, 11.8); - High MDA: 11.5± 0.6 (10.1, 12.8); Non-significant: | Key confounders accounted for:; Race/ethnicity, Smoking, GDM; Limitations:; - Study powered to detect differences in insulin resistance in infants.; - No information on group differences in exclusion due to GDM (a potential mediator); - No pre-registered data analysis plan; Summary:; Higher vs lower adherence to a Mediterranean diet at 12-15wk gestation was associated with greater GWG.
Gesteiro, 2012 continued | Dietary Pattern(s):; Adherence to Healthy Eating Index; - Inadequate HEI (n=19); - Adequate HEI (n=16); - Perfect HEI adherence encourages 6-10 servings/d Cereals, grains, and legumes; 3-5 servings/d Vegetables; 2-4 servings/d Fruits; 2-3 serving/d Milk and dairy products; 2-3 servings/d Meat, eggs and fish; ≤30% FAT; ≤10% SFA; <300mg/d Cholesterol; <2,400 mg/d Sodium; 16 different food items diet variety over 3d; at 12-15 wk gestation; Dietary assessment methods:; Dietary pattern assessed with the Healthy Eating Index (HEI), modified for the Spanish population (Kennedy et al), based on a 10-component, 100-point scale, taking into account recommended energy intakes of for 1600, 2200 and 2800 kcal and the required servings. Diets with HEI scores of ≤70 were labelled ‘inadequate’, vs ‘adequate’ (scores >70).; Dietary components included 10 groups (by 1600, 2200 and 2800 kcal/d recommendations): Cereals, grains, and legumes (0=0 servings, 10=6, 8, 10 servings); Vegetables (0=0 servings, 10=3, 4, 5 servings); Fruits (0=0 servings, 10=2, 3, 4 servings); Milk and dairy products (0=0 servings, 10=2-3 servings) ; Meat, eggs and fish (0=0 servings, 10=2-3 servings); % FAT (0=≥45%, 10=≤30%); % SFA (0=≥15%, 10=≤10%); Cholesterol (0=≥450mg/d, 10= <300mg/d); Sodium (0=≥ 4,800 mg/d, 10=<2,400 mg/d); Diet variety over 3d (0=≤6 different food items, 10=16 different food items) | Significant:; Non-significant:; GWG (kg), Mean, P=NS | Key confounders accounted for:; Race/ethnicity, Smoking, GDM; Summary:; Adequate vs inadequate adherence to a Healthy Eating Index was not associated with differential GWG.
Hillesund, 2018 ^21^ ; Norway; PCS, NFFD; Baseline N=606 Analytic N=524 Twelve women withdrew due to miscarriage (n=6), twin pregnancy (n=2), and moving away (n=4), very low BMI (n=1), and personal reasons (n=2), leaving 591 eligible for the present analyses.; n=~591 for participant characteristics; - Age: 28.0± 4.4 y (range 18–44y); ○ <25y: 25.2%,; ○ 25-29y: 46.2%; ○ 30-34y: 21.8%; ○ ≥35y: 6.8%; - Race/Ethnicity: “predominantly White, European”; - SES: Education:; ○ ≤12y: 31.8%; ○ 13-15y: 32.7%; ○ ≥16y: 35.5%; - Occupation:; ○ Work outside home: 84.2%; ○ Student: 8.7%; ○ Unempoyed: 3.9%; ○ Sick leave/disabled: 1.9%; ○ Homemaker: 1.4%; - Income (NOK):; ○ ≤400,000: 31.2%; ○ >700,000: 34.4%; ○ Refrain from response: 6.6%; - Marital Status:; ○ Married/boyfriend/partner: 96.2%; - PA: The intervention also included supervised exercise classes (2/wk), including strength training and cardiovascular exercise at moderate intensity; - PA level in early pregnancy:; ○ Low activity: 26.4%; ○ Medium activity: 58.2%; ○ High activity: 15.4%; - Anthropometry: Pre-preg BMI: 23.7± 3.9; ○ <19: 0%; ○ <25: 72.2 %; ○ 25-29.9: 20.2 %; ○ ≥30: 7.6%; - Smoking status: Current: 3.9%; - GDM: ~9.1%; - Gestational HTN: PE: ~4.3%; - Parity: Nulliparous: 100% | Dietary Pattern(s):; - Adherence to the Norwegian Fit for Delivery (NFFD) diet,; - Low (Score 0-3), n=151; - Medium (Score 4-5), n=204; - High (Score 6-10), n=236; - Higher scores characterized by eating/drinking: ≥24 main meals/wk, water for ≥44% of drinking events, vegetables with dinner ≥5x/wk, fruits or vegetables as snacks ≥3x/wk, <1x/d sugar-rich food items, <1x/d fast-foods, snacks, or other salty food, never eating sweets and snacks without appreciation, buying small portion size of ≥1 unhealthy food items, eating beyond satiety <1/wk, and reading nutrition labels on foods sometimes or often.; at 15 wk gestation; Dietary assessment methods:; 43-item FFQ, including questions about selected aspects of current diet and dietary behavior, mainly those targeted in NFFD.; The subscales could be single variables or sum scores constructed from relevant questionnaire responses. Each subscale was dichotomized with the sample median as cutoff, and participants with the healthier behavior were assigned ‘1’ in each subscale, whereas the other half of the sample was assigned ‘0’. Individual diet scoring ranged from 0 to 10, with higher score indicating healthier behavior.; Outcome & assessment methods:; GWG calculated as final measured weight within 2wk of delivery among women at term (≥37wk gestation) minus self-reported prepregnancy weight. GWG adequacy defined by 2009 IOM recommendations. | Significant:; GWG Adequacy, per 1pt NFFD score; - Excessive (Ref: Optimal GWG), n=528, P=0.024; ○ aOR=0.90, 95% CI: (0.83, 0.99); [underlined: Subanalysis additionally adjusting for PA]; GWG Adequacy, per 1pt NFFD score; - Excessive (Ref: Optimal GWG, Low adherence), n=418, P=0.009; - aOR=0.88, 95% CI: (0.79, 0.97); Non-significant:; GWG Adequacy, per 1pt NFFD score; - Inadequate (Ref: Optimal GWG, Low adherence), n=524, P=NS; [underlined: Sub-analysis additionally adjusting for PA]; GWG Adequacy, per 1pt NFFD score; Inadequate (Ref: Optimal GWG, Low adherence), (n=414), P=NS | Key confounders accounted for:; Age, SES, PA (subanalyses), Pre-preg BMI, Smoking, Parity; Limitations:; - Models adjusted for randomization assignment, but residual confounding could remain; - The study was restricted to nulliparous women, so the findings may not be generalizable; - Diet score showed test–retest reproducibility but this was not validated against other methods of operationalizing dietary behavior; - Not all participants who would have been eligible for the target trial were included in the study; - Single FFQ did not address full diet; - Smoking status varied by diet score, but included in models; - May not have accounted for all effects of co-exposures across groups; - Total missingness similar across groups, but unclear proportions for different reasons for missingness; - The outcome measure may be influenced by knowledge of the exposure received by study participants; - No pre-registered data analysis plan; Summary:; Higher adherence to NFFD diet at 15wk gestation is associated with lower odds of excessive GWG at term, regardless of dietary and exercise intervention.
Hillesund, 2014 ^5^ ; Norway; PCS, MoBa; Baseline N=66,597 Analytic N=56629 (Attrition: 15%); - Age: 30.1± 4.6y; - Race/Ethnicity: NR; - SES:; ○ Education; ■ ≤12y: ~33.3%; ■ 13-16y: ~33.3%; ■ ≥17y: ~33.3%; - Anthropometry: Prepregnancy BMI: 24.0± 4.2; - Smoking: During pregnancy: ~7.2%; - Physical Activity: Exercise:; ○ Rarely: ~37.4%; ○ 1-2 times/wk: ~32.1%; ○ ≥3 times/wk: ~30.5%; - GDM: History of DM: 0%; - Parity:; ○ 0: ~52.7%; ○ 1: ~30.2%; ○ 2: ~13.4%; ○ ≥3: ~3.7% | Dietary Pattern(s):; Adherence to New Nordic Diet (NND); - Low, n=17802; - Medium, n=23558; - High, n=25237; - Higher scores characterized by eating/drinking: ≥24 main meals/wk, Nordic fruits ≥5/wk, root vegetables ≥5/wk, cabbage ≥2/wk, potatoes at least one-third of total occasions of eating potatoes, rice or pasta, whole grain bread more often than refined bread, oatmeal ≥1/mo, fish/game/berries ~2/wk, milk more often than juice, ≥6 times as much water as sugar-sweetened beverages; at 22wk gestation; Dietary assessment methods:; Self-administered, semi-quantitative FFQ validated for use in MoBa (see Brantsaeter, 2008); Outcome & assessment methods:; GWG, difference between prepregnancy body weight and body weight at birth, as reported in questionnaires at 17wk gestation and 6 mo postpartum.; GWG categorized into inadequate, optimal and excessive (2009 IOM recommendations) | Significant:; GWG (kg); - Overall: 15.0± 5.9; - Inadequate: 6.8± 3.9; - Optimal: 12.8± 2.5; - Excessive: 19.3± 4.7; GWG adequacy (%); - All Women, P<0.001; ○ Low:; ■ Inadequate: 18.7; ■ Optimal: 33.0; ■ Excessive: 48.3; ○ Medium:; ■ Inadequate: 18.4; ■ Optimal: 34.6; ■ Excessive: 47.1; ○ High:; ■ Inadequate: 18.6; ■ Optimal: 35.9; ■ Excessive: 45.4; - Prepregnancy BMI <25, P=0.008; ○ Low:; ■ Inadequate: 21.8; ■ Optimal: 39.1; ■ Excessive: 39.1; ○ Medium:; ■ Inadequate: 21.7; ■ Optimal: 40.2; ■ Excessive: 38.1; ○ High:; ■ Inadequate: 21.8; ■ Optimal: 41.6; ■ Excessive: 36.6; Non-significant:; GWG adequacy (%); - Prepregnancy BMI ≥25, P=0.07; ○ Low:; ■ Inadequate: 12.7; ■ Optimal: 21.4; ■ Excessive: 65.9; ○ Medium:; ■ Inadequate: 10.8; ■ Optimal: 21.9; ■ Excessive: 67.2; ○ High:; ■ Inadequate: 10.2; ■ Optimal: 20.8; ■ Excessive: 69.0 | Key confounders accounted for:; None; Limitations:; - Limited generalizability due to homogenous sample; - Potential selection bias because of excluding preterm and post-term infants; - Start of follow up and start of exposure did not coincide; - Self-reported outcome; - Unclear why the sample size in table 4 was smaller than other tables; - Energy intake was potentially on the causal pathway, but was still adjusted for in the multivariable regression model; Summary:; Greater adherence to the NND during pregnancy may facilitate optimal GWG, especially among with healthy prepregnancy BMI
Hillesund, 2014 continued | | Significant:; Inadequate GWG (Ref: Optimal GWG, Low NND), aOR (95% CI); - Prepregnancy BMI ≥25; ○ Medium: 0.86 (0.74, 0.99), P=0.038; Excessive GWG (Ref: Optimal GWG, Low NND), aOR (95% CI); - Prepregnancy BMI <25; ○ High: 0.93 (0.87, 0.99), P=0.024; Non-significant:; Inadequate GWG (Ref: Optimal GWG, Low NND), aOR (95% CI); - Prepregnancy BMI <25; ○ Medium, P=NS; ○ High, P=NS; - Prepregnancy BMI ≥25; ○ High, P=NS; Excessive GWG (Ref: Optimal GWG, Low NND), aOR (95% CI); - Prepregnancy BMI <25; ○ Medium, P=NS; - Prepregnancy BMI ≥25; Medium, P=NS | Key confounders accounted for:; Age, SES, Pre-preg BMI, Smoking, PA, GDM, Parity; Summary:; Greater adherence to the NND during pregnancy may facilitate optimal GWG, especially among with healthy prepregnancy BMI
Hrolfsdottir, 2019 ^14^ ; Iceland; PCS, PREWICE; Baseline N=1326 Analytic N=1326; n=1326 for all participant characteristics; - Age: 30.2± 5.2y; - Race/Ethnicity: NR; - SES:; ○ Married status: Single: 6%; ○ Education:; ■ Elementary: 13%; ■ High & technical school: 29%; ■ University: 35%; ■ Higher academic: 24%; - Anthropometry: Pre-preg BMI: 24.1± 6.5; ○ <18.5: 4%; ○ 18.5–24.9: 55%; ○ ≥25.0–30.0: 24%; ○ ≥30.0: 18%; - Smoking status:; ○ Before preg: 16%; ○ During preg: 7%; - GDM: 19.9%; - Parity: Nulliparous: 39% | Dietary Pattern(s):; - Low risk diet score (≤2 pt), n=305; - Medium risk diet score (3 pt), n=632; - High risk diet score (≥4 pt), n=389; - Higher risk score (out of 5) characterized by: Not eating a varied diet, <5/d fruits/vegetable, <2/d dairy, <2/d whole grain products, ≥5/wk sugar/artificially sweetened beverages, and ≥5/d dairy.; at 11-14wk gestation; Dietary assessment methods:; Risk factors for inadequate diet assessed from 40-item FFQ. Women reported diet in the previous 4wk, corresponding to the first trimester (enrolled in 11–14 week of pregnancy). This information was converted to frequency/wk for all food groups, which was then transformed into 13 predefined dietary risk factors for inadequate diet, based on the Icelandic Food-Based Dietary Recommendations, which are based on the Nordic Nutrition Recommendations (2014). If the women excluded/avoided any of the main food groups (cereal, vegetables/ fruits, fish, meat, eggs, high-fat foods, or dairy), they were categorized to the group not eating a varied diet.; After logistic regression modeling to predict excessive GWG, the six dietary risk factors (predictors) were included in the final model. To construct a total dietary risk score, each participant got 1 for fulfilling the risk criteria and 0 for not fulfilling the risk criteria. The scores of the six dietary risk factors were then summed up, ranging from scores of 0 to 5 as it was not possible to be in both milk risk groups (too low/too high).; Outcome & assessment methods:; Excessive GWG: >18 kg in women with normal pre-pregnant weight and >12 kg in women with pre-pregnant overweight and obesity; GWG retrieved from the maternal hospital records as women were weighed in antenatal visits. Total GWG calculated as the difference between the highest recorded weight (≥36wk) and prepregnancy weight. | Significant:; Excessive GWG; - Per unit increase in score: aRR: 1.10 (1.01, 1.19); - Per SD increase in score: aRR: 1.08, 95% CI: (1.01, 1.15), P<0.05; - Low risk diet score: Cases=99 (32%); - High risk diet score: Cases n=160 (41%); ○ aRR vs Low risk scores: 1.23, 95% CI: (1.002, 1.50), P<0.05; Non-significant:; Excessive GWG; - Low risk diet score: Cases n=99 (32%); - Medium risk diet score: Cases n=217 (34%); ○ aRR vs Low scores: 1.04, 95% CI: (0.86, 1.26), P=NS; [underlined: Analyses excluding 264 GDM cases:]; Excessive GWG; - Per one unit increase in score: aRR: 1.09, 95% CI: (1.00, 1.19), P=NS; - Low risk diet score: Cases n=89/266 (34%); - Medium risk diet score: Cases n=184/533 (35%); ○ aRR vs Low scores: 1.01, 95% CI: (0.82, 1.23), P=NS; - High risk diet score: Cases n=136/326 (42%); ○ aRR vs Low scores: 1.19, 95% CI: (0.96, 1.47), P=NS | Key confounders accounted for: Age, SES, Pre-preg BMI, Smoking, GDM (in subanalyses), Parity; Limitations:; - Power analysis NR; - Self-reported diet, prepregnancy weight and height; - Potential differential exposure time between groups; - Unclear whether analyses accounted for group differences in missing data; - Unclear systematic errors in outcome measurement by exposure; - No pre-registered data analyses; Summary:; A higher dietary risk score, including a nonvaried diet, a nonadequate intake of fruits/vegetables, dairy, and whole grain, as well as an excessive intake of sugar/artificially sweetened beverages and dairy, was associated with a higher risk of excessive GWG, but the association disappeared after removing GDM cases.
Hrolfsdottir, 2019 continued | Dietary Pattern(s):; - Score based on three dietary risk factors most strongly associated with excessive GWG in the multivariable model. Higher dietary risk scores characterized by ≥ 5/wk sugar- and artificially sweetened beverages, <2/d whole grain products, and ≥5/d dairy; at 11-14wk gestation | Significant:; Excessive GWG; Per SD increase in score; aRR: 1.08, 95% CI: (1.002, 1.15), P<0.05; Non-significant: | Key confounders accounted for:; Pre-preg BMI, Smoking, GDM (in subanalyses), Parity; Summary:; A higher dietary risk score, including excessive intake of sugar- and artificially sweetened beverages, inadequate intake of whole grains, and nonadequate intake of dairy was associated with a higher risk of excessive GWD.
Hrolfsdottir, 2019 continued | Dietary Pattern(s):; - Diet score based on 13 dietary risk factors. Higher dietary risk scores characterized by: not eating a varied diet, <5/d vegetables and fruits, <2/d fish, <2/d dairy, <2/d whole grain products, <3.5/wk beans, nuts, seeds, <5/wk D-vitamin, using butter rather than oil (≥50%), ≥ 1/wk french fries and fried potatoes, ≥ 2.5/wk sweets, ice cream, cakes, cookies, ≥ 5/wk sugar- and artificially sweetened beverages, ≥ 5/d dairy intake, ≥1/wk processed meat products; at 11-14wk gestation | Significant:; Non-significant:; Excessive GWG:; Per SD increase in score, P=NS | Key confounders accounted for:; Pre-preg BMI, Smoking, GDM (in subanalyses), Parity; Summary:; A higher dietary risk score including 13 dietary risk factors (as described in the exposure) was not associated with the risk of excessive GWG.
Meinila, 2017 ^27^ ; Finland; PCS, Control arm of RADIEL trial; Baseline N=137 Analytic N=137; - Age: ~32y; - Race/Ethnicity: NR; - SES: Education: ~14.3y; - PA: Leisure-time physical activity: ~78.3 min/wk; - Anthropometry: BMI at 12.0-14.6wk: ~31.7; - 100% ≥30 BMI [underlined: or] with history of GDM; - GDM: ~40.1%; - Parity: Nulliparous: ~37.2% | Dietary Pattern(s):; Healthy Food Intake Index (HFII) adherence; - HFII score 0-7 (n=24); - HFII score 8-12 (n=84); - HFII score 13-17 (n=29); - Higher scores are indicative of higher adherence to the Nordic Nutrition Recommendations (NNR), characterized by higher consumption of fruits, vegetables, whole-grains, and fish and poultry, and lower intakes of red and processed meat, and refined grains.; at first trimester (~13wk); Dietary assessment methods:; Diet assessed during the first trimester via FFQ. The HFII comprised the following components: snacks, low-fat cheese, fish, low-fat milk, vegetables, fruits and berries, sugar-sweetened beverages, high-fiber grains, fast food, fat spread, and cooking fat.; The HFII scores were divided into three categories by setting z cut-off limits at ± 1 SD from the mean.; Outcome & assessment methods:; Weight measured by a study nurse. GWG from 12.0-14.6wk through 22.4-24.1wk gestation. | Significant:; Non-significant:; GWG from first to second trimester (kg), P=NS | Key confounders accounted for:; None; Limitations:; - The study enrolled only those women who were at risk of GDM (i.e. women with a history of GDM and/or prepregnancy BMI ≥30). The findings, therefore, may not be generalizable; - Potential selection bias due to exclusion after first trimester OGTT; - Women diagnosed with GDM may have altered their diet in an unbalanced way; - Potential differential exposure time between groups; - Reasons for/characteristics of women with missing outcome data NR; - Total GWG not measured; - No pre-registered data analysis plan.; Summary:; Adherence to the Healthy Food Intake Index during the first trimester was not associated with GWG from first to second trimester.
Poon, 2013 ^7^ ; U.S.; PCS, IFPSII; Baseline N=893 Analytic N=893 (Attrition: 0%); - Age: 29.1± 5.4y; - Race/Ethnicity: White: 87.4%; - SES:; ○ Education:; ■ High school or less: 18.0%; ■ Some college: 39.3%; ■ Associate or BA: 31.7%; ■ Master or more: 10.9%; ○ Poverty index ratio:; ■ <185%: 37.5%; ■ ≥350%: 23.7%; - Anthropometry: Prepregnancy BMI: 26.1± 6.4; - Smoking Status: Yes: 8.3% | Dietary Pattern(s):; Alternative Healthy Eating Index for Pregnancy (AHEI-P):; - T1: (n=285); - T2: (n=286); - T3: (n=282); Based on a 130-point scale with 0–10 points awarded for optimal intake of 13 types of foods and nutrients; - Positively-scored components: vegetables, whole fruit, whole grains, nuts and legumes, long-chain (n-3) fats, PUFAs, folate, calcium, and iron; - Negatively-scored components: sugar-sweetened beverages, red and processed meat, trans fat, and sodium; at 28-36wk gestation; Dietary assessment methods:; Modified version of the Diet History Questionnaire (DHQ) previously developed and validated by the National Cancer Institute (see Subar, 2001a; Subar, 2001b; Thompson, 2002a; Thompson, 2002b); Outcome & assessment methods:; GWG at postpartum using neonatal questionnaire | Significant:; Non-significant:; GWG (kg), P=NS; T1: 13.4± 6.4; T2: 14± 6.1; T3: 14.4± 5.8 | Key confounders accounted for:; None; Limitations:; - Baseline differences in BMI between groups and it is possible that the rate of weight gain might have differed based on their baseline BMI, but not discussed or accounted for; - GWG is self-reported; Summary:; There was no association between adherence to the AHEI-P and GWG
Rifas-Shiman, 2009 ^6^ ; U.S.; PCS, Project Viva; Baseline N=1777 Analytic N=1666 2,670 enrolled, then excluded 329 due to subsequent ineligibility. Additional women withdrew (n=195), or were lost to follow-up (n=18). 1777 completed first FFQ, 1666 completed second FFQ; - Age: 32.4± 4.9y; - Race/Ethnicity:; ○ White: 72%; ○ Black/African American: 12%; ○ Other, > 1 race: 16%; - SES:; ○ Education:; ■ ≤High school diploma: 9%; ■ Some college/tech school: 21%; ■ College graduate: 69%; ○ Household income <$40,000/y: 13%; - Anthropometry: Prepregnancy BMI: 24.6± 5.3; - Parity; ○ Nulliparous: 49%; ○ 1: 36%; ○ ≥2: 15% | Dietary Pattern(s):; Adherence to Alternate Healthy Eating Index for Pregnancy (AHEI-P); - Based on 9 components: vegetables; fruit; ratio of white to red meat; fiber; trans fat; ratio of polyunsaturated to saturated fatty acids; and folate, calcium, and iron from foods (each 10 points, with a total of 90 points); - Changes made to original AHEI: Alcohol, nuts excluded; folate, calcium and iron included; at first trimester (~11wk) and second trimester (~26-28wk); Dietary assessment methods:; 166-item validated semiquantitative FFQ, slightly modified for use in pregnancy (Based on extensively validated Willett FFQ used in the Nurses’ Health Study and calibrated against blood levels) (see Fawzi, 2004); Outcome & assessment methods:; Self-reported prepregnancy weight at baseline.; Last clinical prenatal weight recorded - self-reported prepregnancy weight; GWG adequacy based on IOM 1990 recommendations | Significant:; Non-significant:; 50% experienced excessive weight gain; GWG Adequacy for each 5 point increase in AHEI-P score (Ref: Adequate); - First trimester (n=1,777); ○ Inadequate, P=NS; ○ Excessive, P=NS; - Second trimester (n=1,666); ○ Inadequate, P=NS; Excessive, P=NS | Key confounders accounted for:; Age, Race/Ethnicity, SES, Pre-preg BMI; Limitations:; - Unclear whether those who did not complete FFQ in round 2 were different from those that completed first FFQ.; - Follow-up time varied across participants; - Reasons for exposure missingness NR; - Pre-registered data analysis plan NR; Summary:; AHEI-P is not associated with pregnancy weight gain
Sen, 2016 ^9^ ; U.S.; PCS, Project Viva; Baseline N=1808 Analytic N=1808; n=~1808 for most participant characteristics; - Age: 32.2± 5.0y; - Race/Ethnicity:; ○ Black: 13.9%; ○ Hispanic: 6.8%; ○ Asian: 5.0%; ○ White: 70.6%; ○ Other: 3.8%; - SES:; ○ Graduated college: 68.6%; ○ Household income ≤$70,000: 36.5%; - Anthropometry: Prepregnancy BMI: 24.9± 5.2; ○ 18.5-<25: 63.1%; ○ 25-<30: 22.5%; ○ ≥30: 14.4%; - Smoking status:; ○ Never: 67.8%; ○ Former: 21.0%; ○ During pregnancy: 11.2%; - GDM: 5.4%; - Gestational HTN: 6.9%; ○ Chronic HTN: 1.4%; ○ PE: 3.5%; - Parity: Nulliparous: 48.6% | Dietary Pattern(s):; Dietary inflammatory index (DII) score:; - Lower scores indicate lower dietary inflammation, characterized by higher intakes of vegetables, fruit, whole-grain foods, fish/seafood, and whole eggs, and lower intakes of red or processed meats and sugar-sweetened soda.; mean score from ~9.9wk and ~27.9wk gestation; Dietary assessment methods:; Mothers completed self-administered FFQs at median 9.9wk and 27.9wk gestation., assessing diet intake during the first and second trimesters.; Dietary data used to estimate a standard global mean for the 28 food parameters included in the DII, then converted to a centered percentile score, multiplied by the literature-derived respective food parameter effect score to obtain a food parameter–specific DII score, which were all summed to create the overall DII score for each participant. A higher DII score indicates a more proinflammatory diet, whereas a more negative score represents a more antiinflammatory diet.; Outcome & assessment methods:; GWG (kg) calculated as the difference between the last recorded clinical weight before delivery and self-reported prepregnancy weight reported at the first study visit (9,9wk gestation). GWG adequacy categorized by IOM (2009) recommendations. | Significant:; Non-significant:; GWG adequacy per unit of DII (Ref: Adequate):; - All women (n=1808); ○ Inadequate, P=NS; ○ Excessive, P=NS; - Prepregnancy BMI 18.5-<25 (n=1141); ○ Inadequate, P=NS; ○ Excessive, P=NS; - Prepregnancy BMI 25-<30 (n=406); ○ Inadequate, P=NS; ○ Excessive, P=NS; - Prepregnancy BMI ≥30 (n=261); ○ Inadequate, P=NS; ○ Excessive, P=NS | Key confounders accounted for:; Age, Race/ethnicity, SES, Pre-preg BMI, Smoking, Parity; Limitations:; - Data collected at the end of 2^nd^ trimester may be influenced by GDM knowledge; - Start of follow up and start of exposure may not coincide; - Self-reported diet and prepregnancy weight; - Important co-exposures were not balanced across groups, and adjustment techniques were used to correct for the issues.; - No information on reasons for missingness or proportions across groups; - Any error in measuring the outcome is only minimally related to exposure status; - No pre-registered data analysis plan; Summary:; Consumption of a low DII diet during the first and second trimesters was not associated with GWG.
Tielemans, 2015 ^8^ ; Netherlands; PCS, Generation R Study; Baseline N=4097 Analytic N=2748 (Attrition: 33%); - Age: ~31.3y; - Race/Ethnicity: 100% of Dutch ancestry; - SES:; ○ Education:; ■ Low and midlow: ~18.2; ■ Midhigh: ~51.5; ■ High: ~30.4; ○ Household income <2200 Euro/mo: ~28.3; - Anthropometry: Prepregnancy BMI: ~24.7; - Smoking status:; ○ Never in pregnancy: ~74.4; ○ Until pregnancy known: ~8.3; ○ During pregnancy: ~17.4; - Alcohol:; ○ Never in pregnancy: ~36.6; ○ Until pregnancy known: ~16.5; ○ During pregnancy: ~46.9 | Dietary Pattern(s):; - Adherence to standardized Dutch Healthy Diet Index. Higher scores indicate better adherence and higher intake of vegetables, fruits, fiber, and fish, and lower intake of saturated fat and sodium.; at ~13.4wk; Dietary assessment methods:; The Dutch HDI was modified to align with pregnancy recommendations and available data, and consisted of 6 components: vegetable, fruit, dietary fiber, fish, saturated fatty acids, and sodium. The score of each component ranged between 0 and 10 points, resulting in a total score ranging from 0 to 60 points.; Outcome & assessment methods:; Self-reported prepregnancy weight collected at enrollment. Staff measured weight at 3 study visits: ~12.9wk (first visit), ~20.4wk (second visit), and ~30.2wk (third visit). At 6wk postpartum, women self-reported maximum weight during pregnancy.; GWG in different phases of pregnancy was calculated mid-pregnancy GWG (weight at the second visit minus weight the first visit, divided by follow-up duration (g/week), n = 2748), late-pregnancy GWG (weight at the third visit minus weight at the second visit, divided by follow-up duration (g/week), n = 3158), and GWG until early-third trimester (weight at the third visit minus prepregnancy weight, divided by follow up duration (g/week), n = 2815).; Women’s total GWG (maximum pregnancy weight minus prepregnancy weight, n = 1917) was used to classify their GWG into inadequate, adequate, or excessive GWG according to IOM (2009) recommendations. | Significant:; Non-significant:; Sensitivity Analysis (excludes women with GDM or hypertensive disorders of pregnancy); GWG until early-third trimester (g/wk); - Prepregnancy Normal Weight Women (n=1937); ○ Dutch HDI Pattern, P=0.06 per SD increase in DP score; ■ Q1: Ref; ■ Q2: β=−13, 95% CI: (−29, 3); ■ Q3: β=−4, 95% CI: (−20, 12); ■ Q4: β=−16, 95% CI: (−33, 1); - Prepregnancy Overweight Women (n=532); Dutch HDI Pattern, P=NS per SD increase in DP score | Key confounders accounted for:; Age, Race/ethnicity, SES, Pre-preg BMI, Smoking, GDM, HTN, Parity; Limitations:; - Self-reported diet, prepregnancy weight, and maximum pregnancy weight; Summary:; Adherence to Dutch HDI the was not associated with GWG.
Tielemans, 2015 continued | | Significant:; Non-significant:; Mid-Pregnancy Weight Gain (g/wk); - Prepregnancy Normal Weight Women (n=2079); ○ Dutch HDI Pattern, P=0.76 per SD; - Prepregnancy Overweight Women (n=669); ○ Dutch HDI Pattern, P=0.88 per SD; Late-Pregnancy Weight Gain (g/wk); - Prepregnancy Normal Weight Women (n=2384); ○ Dutch HDI Pattern, P=0.57 per SD; - Prepregnancy Overweight Women (n=774); ○ Dutch HDI Pattern, P=0.58 per SD; GWG adequacy:; - Inadequate GWG (n=459, Ref: Adequate intake, n=632); Excessive GWG (n=826, Ref: Adequate intake, n=632) | Key confounders accounted for:; Age, Race/ethnicity, SES, Pre-preg BMI, Smoking, Parity; Summary:; Adherence to Dutch HDI the was not associated with GWG.
Yong, 2019 ^20^ ; Malaysia; PCS, SECOST; Baseline N=480 Analytic N=480 (Attrition: 0%); - Age: 30.16± 4.51y; - Race/Ethnicity:; ○ Malay: 89.0%; ○ Non-Malay: 11.0%; - SES:; ○ Education level: 12.95± 2.41y; ■ Secondary and lower: 46.0%; ■ STPM/matric/diploma/certificate: 32.7%; ■ Tertiary and above: 21.3%; ○ Occupation status: Employed: 69.2%; ○ Monthly household income: RM 3698.30± 2034.20; ■ Low: 63.5%; ■ Middle: 33.5%; ■ High: 2.9%; ○ Household size: 3.78± 1.63; ■ ≤2: 24.2%; ■ 3–4: 50.0%; ■ ≥5: 25.8%; - Physical Activity: MET hrs/week:; ○ 2nd trimester 264.58± 118.06; ○ 3rd trimester: 249.56± 107.36; - Anthropometry:; ○ Pre-preg weight (kg): 59.11± 13.57; ○ Pre-preg BMI: 24.10± 5.06; ○ Underweight: 10.2%; ○ Normal: 53.1%; ○ Overweight: 22.3%; ○ Obese: 14.4%; - GDM: History: 7.5%; - Parity: 1.22± 1.29; ○ 0: 36.7%; ○ 1–2: 47.7%; ○ ≥3: 15.6% | Dietary Pattern(s):; - Modified HEI for Malaysians comprised of 9 components, each with max score of 10 and min score of 0. Higher score indicates intake closer to recommended range.; ○ Adherence with the 7 major food groups recommended by Malaysian Dietary Guidelines 2010 (MDG):; ■ Cereals and grains; ■ Vegetables; ■ Fruits; ■ Milk and milk products; ■ Poultry, meat and egg,; ■ Fish and seafood; ■ Legumes; ○ Adherence with MDG recommendations for %E from fat and sodium intake.; once during each trimester; Dietary assessment methods:; 24-hr recall conducted each trimester. Dietary data analyzed using Nutritionist Pro Diet Analysis software: Version 1.5.; Score for each HEI component calculated using formula: (Actual serving consumed based on respondent’s diet recall/recommended serving size based on MDG) and multiplied by 10. If an individual consumed less than the recommended amount of servings, score was calculated with the formula: 10 × (the consumed amount of servings)/ (the lower limit of the recommended serving). If an individual consumed more than the recommended amount of servings, the score was calculated with the formula: 10–10 × [(the consumed servings) – (the upper limit of the recommended servings)]/(the upper limit of the recommended serving). Each score rounded off to nearest whole number. When calculation produced a negative score because of excess servings, score converted to 0.; Outcome & assessment methods:; Prepregnancy weight self-reported. Weight measured at 10–13wks, 24–32wks, and 34–38wks using standard instrument and procedures. GWG calculated as difference between measured weight at last visit and prepregnancy weight. | Significant:; GWG adequacy by HEI in each trimester; - All women; ○ 2nd trimester:; ■ Inadequate: OR=0.98, 95% CI=(0.96, 0.98), P=0.03; ○ 3rd trimester:; ■ Excessive: OR=1.04, 95% CI=(1.01, 1.06), P=0.01; - Non-oveweight/obese (n=304):; ○ 2nd trimester:; ■ Inadequate: OR=0.97, 95% CI=(0.95, 0.99), P=0.01; ○ 3rd trimester:; ■ Excessive: OR=1.04, 95% CI=(1.01, 1.07) P=0.03; - Overweight/obese (n=176):; ○ 2nd trimester:; ■ Excessive: OR=1.04, 95% CI=(1.01, 1.07), P=0.02; ○ 3rd trimester:; ■ Excessive: OR=1.04, 95% CI=(1.01–1.08), P=0.02; Non-significant:; GWG adequacy by HEI in each trimester; - All women; ○ 1st trimester:; ■ Inadequate, P=NS; ■ Excessive, P=NS; ○ 2nd trimester:; ■ Excessive, P=NS; ○ 3rd trimester:; ■ Inadequate, P=NS; - Non-oveweight/obese (n=304):; ○ 1st trimester:; ■ Inadequate, P=NS; ■ Excessive, P=NS; ○ 2nd trimester:; ■ Excessive, P=NS; ○ 3rd trimester:; ■ Inadequate, P=NS; - Overweight/obese (n=176):; ○ 1st trimester:; ■ Inadequate, P=NS; ■ Excessive, P=NS; ○ 2nd trimester:; ■ Inadequate, P=NS; ○ 3rd trimester:; Inadequate, P=NS | Key confounders accounted for:; Age, SES, PA, Pre-preg BMI, Parity; Limitations:; - Respondents were not representative of the general population of pregnant women in Malaysia.; - Self-reported dietary data; single 24-h dietary recall might not represent the usual intake; - Third trimester results may be cross-sectional—unclear timing of third FFQ; - Start of follow up and start of exposure did not coincide and a potentially important amount of follow-up time is missing from analyses; - Co-exposures and reasons for missingness between groups NR; - High risk of selective reporting from among multiple analyses; - Information on missingness NR; - No pre-registered data analysis plan; Summary:; Women who were not overweight or obese prepregnancy with a higher total HEI score in the second trimester were at a lower risk for inadequate GWG, while women who were overweight or obese prepregnancy with a higher total HEI score in the second trimester were at a higher risk for excessive GWG. Women with a higher total HEI score in the third trimester were at higher risk for excessive GWG, regardless of prepregnancy BMI.
Zhu, 2019 ^16^ ; U.S.; PCS, PETALS; Baseline N=2269 Analytic N=2269; Of 2525 enrolled, loss to follow-up due to pregnancy loss (n=37), moved (n=7) or excluded due to missing data on child BW (n=94), FFQ (n=87), >6000 kcal/d reported (n=23), or due to FFQ after GDM diagnosis (n=8); n=2269 for all participants characteristics; - Age:; ○ 18-24: ~16.1%; ○ 25-29: ~26.5%; ○ 30-34: ~35.8%; ○ ≥35: ~21.6%; - Race/Ethnicity:; ○ Non-Hispanic White: ~22.3%; ○ Hispanic: ~41.3%; ○ African American: ~9.4%; ○ Asian/Pacific Islander: ~23.6%; ○ Other: ~3.5%; - SES:; ○ Education:; ■ High School or less: ~13.8%; ■ Some college: ~38.4%; ■ College graduate or above: ~47.9%; ○ Household income ($):; ■ <50,000: ~32.7%; ■ ≥150,000: ~15.9%; - Physical Activity: ~152.1 METs/wk; - Anthropometry: Pre-preg BMI:; ○ <18.5: ~2.7%; ○ 18.5-24.9: ~40.3%; ○ 25.0-29.9: ~28.9%; ○ ≥30.0: ~28.1%; - Smoking status: 0.5%; - GDM: ~10.8%; - Gestational HTN: ~10.8%; - Parity: Nulliparity: ~44.1%; - Alcohol in pregnancy: ~15.0% | Dietary Pattern(s):; - Healthy Eating Index (HEI) index measures adherence to the USDA Dietary Guidelines for Americans. The HEI-2010 consists of 12 components (total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids, refined grains, sodium and empty calories from solid fats, alcohol and added sugars), with a maximum possible score of 100. Alcohol intake was excluded from the empty calories component.; - Q1: Score of 37.5-64.4 (n=567); - Q2: Score of 64.5-71.7 (n=567); - Q3: Score of 71.8-78.6 (n=568); - Q4: Score of 78.7-94.2 (n=567); at 10-13wk gestation; Dietary assessment methods:; Validated, 147 item Block FFQ administered at visit 1 (gestational wks 10–13). Nutrient intakes adjusted for total energy intake using the residual method. HEI-2010 score was calculated to assess diet quality.; Outcome & assessment methods:; NR | Significant:; Non-significant:; GWG (kg), P=0.69; - Q1: 13.2± 6.7; - Q2: 13.2± 6.2; - Q3: 12.9± 6.2; - Q4: 13.1± 6.0 | Key confounders accounted for:; None; Limitations:; - Participant characteristics not balanced across groups; - Selection into the study related to exposure and outcome and could not be adjusted for in the analyses; - Start of follow up and exposure did not coincide and a potentially important amount of follow-up time was missing from analyses; - Dietary intake self-reported from one FFQ; - Important co-exposures not balanced across groups that were likely to impact the outcome and no adjustment techniques were used to correct for the issues; - Outcome assessment methods NR; - No pre-registered data analysis plan; Summary:; Maternal diet quality as measured by the HEI-2010 in early pregnancy was not associated with GWG.
Reduced Rank Regression
Starling, 2017 ^11^ ; U.S.; PCS; Baseline N=764 Analytic N=764 (Attrition: 0%); - Age: ~28.6y; - Race/Ethnicity:; ○ Non-Hispanic White: 60%; ○ Hispanic: 21%; ○ Non-Hispanic Black: 12%; ○ Other: 6%; - SES:; ○ More than high school education: 75.3%; - Physical Activity: METs/wk: ~183; - Anthropometry: Prepregnancy BMI: 25.4± 5.9; - Smoking status: : ~5.5%; Parity: Multiparous: 62.8% | Dietary Pattern(s):; - Pattern 1: Higher consumption of healthy protein sources (poultry, nuts, and seeds), whole grains, cheese, citrus fruits, melons and berries, and other fruits, as well as added sugars and discretionary solid fat; - Pattern 2: Higher consumption of eggs, potatoes, other starchy vegetables, discretionary solid fat, citrus, melons and berries, and non-whole grains and yogurt, added sugars, soy products (tofu and meat analogs), dark-green vegetables, and whole grains; at 17wk gestation; Dietary assessment methods:; Dietary intake during pregnancy was assessed using the National Cancer Institute’s Automated Self-Administered (ASA) 24h Recall. Analysis was restricted to participants who completed ≥2 ASA24s; Outcome & assessment methods:; Maternal weight during pregnancy was measured at each in-person study visit, and all weights measured at clinic visits were abstracted from the prenatal medical record by study personnel. Maternal weight before pregnancy was obtained either from medical records (~90%) or from participant self-report at the first study visit (~10%). GWG was calculated by subtracting the prepregnancy weight from the last recorded maternal weight during pregnancy. Median number of days between the last recorded weight and delivery was 5 d (IQR 2–8 d). | Significant:; GWG (kg); - Pattern 1, Ptrend<0.001; ○ T1: 12.4± 6.6; ○ T2: 14.7± 5.6; ○ T3: 15.7± 5.7; - Pattern 2, Ptrend=0.03; ○ T1: 13.5± 6.1; ○ T2: 14.7± 5.6; ○ T3: 14.7± 6.5; - Pattern 1 correlated with greater GWG, P<0.01; ○ r=0.22; - Pattern 2 correlated with greater GWG, P=0.02; ○ r=0.09; Non-significant: | Key confounders accounted for:; None; Limitations:; - GWG was not stratified by prepregnancy BMI and the analysis did not stratify weight gain by inadequate, adequate and excess; - Co-exposures unbalanced between groups and likely to impact the outcome; - Missingness by exposure NR; - Unclear GDM prevalence; - No pre-registered data analysis plan; Summary:; Women with greater adherence to pattern 1 (tertile 3) had significantly greater GWG (ptrend<0.001). Similarly, women with greater adherence to pattern 2 (tertile 2 and tertile 3) had significantly greater GWG (ptrend=0.03)

Table 4 Description of evidence on the relationship between diets based on macronutrient distribution during pregnancy and gestational weight gain^xii^

Study and Participant Characteristics^xiii^ | Intervention/Exposure and Outcomes | Results | Confounding, Study Limitations, and Summary of findings
Poston, 2013 ^24^ ; U.K.; RCT, UPBEAT; Baseline N=183 Analytic N=140 (Attrition: 23%); - Age: ~30.5y; - Race/Ethnicity:; ○ White: ~56%; ○ Black: ~38%; ○ Asian: ~2%; ○ Other: ~4%; - SES:; ○ Most deprived: ~56%; ○ Single: ~46%; - Living arrangements (%):; ○ With partner: ~74; ○ With parents: ~11; - Housing (%):; ○ Owned: ~26; - Physical Activity (n=140):; ○ Sedentary (min/d): ~1169, Active: 221, Light: 181, MVPA: 41; - Anthropometry: BMI at ~17wk: ~36.3; - Smoking status: Never: 68%, Ex-smoker: 26%, Current: 7%,; - GDM: at 28wk: 30%; - Parity: 0: 44%, 1: 36%, ≥2: 21% | Macronutrient Proportions:; - Control: 35.9% FAT, 48.2% CHO, 15.5% PRO (n=69); - Intervention: 32.5% FAT, 50.0% CHO, 17.1% PRO (n=71), also received PA intervention, to no effect; from 17wk to 28wk gestation; Dietary assessment methods:; Women randomized to intervention of dietary and physical activity advice delivered by health trainers vs standard care.; Diet assessed via repeated, triple pass, interviewer-led 24 hr recall data obtained at baseline (randomization) and 28wk gestation. Diet evaluated twice, one week apart in both the intervention and control group.; Outcomes & assessment methods:; GWG: Weight measured at baseline and 28wk | Significant:; Non-significant:; - Weight at 17wk (kg), Mean± SD; ○ Control: 96.8± 16.2; ○ Intervention: 97.8± 12.7; - GWG at 28wk between groups, P=NS; ○ Data NR | Key confounders accounted for:; Age, Race/ethnicity, SES, PA, GDM, Parity; Limitations:; - Exploratory study, no power calculation for GWG; - Deviations from intended intervention unbalanced between groups and likely to have affected the outcome; - Unclear how weight was assessed and GWG was calculated; - No pre-registered data analysis plan; Summary:; Consuming a diet with >35% FAT versus a diet with <35% FAT during send trimester in obese women did not affect GWG.
Tajima, 2017 ^4^ ; Japan; PCS; Baseline N=325 Analytic N=325; - Age: ~33.5y; - Race/Ethnicity: 100% Japanese; - SES: NR; - Anthropometry: BMI at first prenatal visit: ~19.7; ○ <18.5: 28.9%; ○ ≥23: 5.5%; - GDM: 4% (n=540), Prepregnancy diabetes: 0%; - Parity: Primiparous: ~67.1% | Macronutrient Proportions:; - Bottom: 48.9% CHO, 35.1% FAT, 16.0% PRO (n=108); - Middle: 54.9% CHO, 30.3% FAT, 14.8% PRO (n=109); - Top: 61.5% CHO, 24.6% FAT, 13.9% PRO (n=108); at <16wk gestation; Dietary assessment methods:; Data grouped by tertile of CHO intake (bottom, middle, and top).; 3-d weighed dietary record on 2 weekdays and 1 weekend day, consecutive or nonconsecutive. Calories from each macronutrient calculated by multiplying g of macronutrients by calories/g (16.7 kJ/g for protein; 37.7 kJ/g for fat). Percentage of carbohydrate intake calculated by subtracting percentages of protein and fat intake from 100%.; Outcomes & assessment methods:; GWG: Weight measured by a registered nurse at the first prenatal visit and at 28wk. Rate of GWG/wk calculated from 1^st^ prenatal visit to 28 wks of gestation. | Significant:; Non-significant:; - GWG per week (kg), P=0.22; ○ Bottom: 0.3± 0.1; ○ Middle: 0.3± 0.1; ○ Top: 0.3± 0.1 | Key confounders accounted for:; Race/ethnicity; Limitations:; - Self-reported dietary assessments during first trimester, when women may be prone to nausea; - Start of follow up and exposure did not coincide and a potentially important amount of follow-up time is missing from analyses; - Methods used to define exposure status are not clearly described and likely to result in some degree of random misclassification; - GWG not stratified by prepregnancy BMI and unclear if it varied among underweight vs. healthy vs. overweight participants; - GWG available for a small window (~7-28 wks) and weight gain during first trimester may have been minimal; - Generalizability to U.S. population may be questionable given that ~1/3 of the participants were underwight; - No information on whether the proportion of participants and reasons for missing data are similar across exposure groups; Summary:; GWG per week is not significantly different between tertiles of %CHO among Japanese pregnant women.

Table 5 Risk of bias for randomized controlled trials examining dietary patterns during pregnancy and gestational weight gain^xiv^ ^xv^

| Randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Al Wattar, 2019^22^ | Low | Low | Low | Some concerns | Low
Assaf-Balut, 2017^26^ | Low | High | Low | Low | Low
Van Horn, 2018^25^ | Low | High | Low | Low | Low
Poston, 2013^24^ | Low | High | Low | Some concerns | Some concerns
Assaf-Balut, 2019^23^ | Low | High | Low | Low | High

Table 6 Risk of bias for observational studies examining dietary patterns during pregnancy and gestational weight gain^xvi^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Maugeri, 2019^19^ | Serious | Serious | Low | Low | Low | Moderate | Serious
Okubo, 2012^3^ | Serious | Serious | Serious | Serious | Moderate | Serious | Serious
Tielemans, 2015^8^ | Serious | Moderate | Moderate | Low | Low | Serious | Serious
Wei, 2019^15^ | Serious | Serious | Serious | No information | Serious | Moderate | Serious
Wesolowska, 2019^17^ | Critical | Serious | Moderate | Serious | Moderate | No information | Serious
Ancira-Moreno, 2019^18^ | Serious | Serious | Serious | Low | Moderate | Moderate | Serious
Emond, 2018^13^ | Serious | Serious | Moderate | Low | No information | Low | Serious
Fernández-Barrés, 2019^1^ | Critical | Serious | Serious | Serious | Moderate | Moderate | Serious
Fulay, 2018^12^ | Serious | Moderate | Moderate | Low | Moderate | Moderate | Serious
Gesteiro, 2012^2^ | Serious | Serious | Serious | Low | Moderate | Low | Serious
Hillesund, 2018^21^ | Serious | Moderate | Serious | Moderate | Serious | Moderate | Serious
Hillesund, 2014^5^ | Serious | Serious | Moderate | Moderate | Moderate | Serious | Serious
Hrolfsdottir, 2019^14^ | Serious | Moderate | Moderate | Low | Moderate | Moderate | Serious
Meinila, 2017^27^ | Critical | Serious | Moderate | Moderate | No information | Moderate | Serious
Poon, 2013^7^ | Critical | Serious | Serious | Serious | Moderate | Serious | Serious
Rifas-Shiman, 2009^6^ | Serious | Serious | Moderate | Moderate | Moderate | Moderate | Serious
Sen, 2016^9^ | Serious | Moderate | Moderate | Moderate | Moderate | Moderate | Serious
Yong, 2019^20^ | Serious | Serious | Moderate | No information | No information | Moderate | Serious
Zhu, 2019^16^ | Critical | Moderate | Moderate | Low | Low | No information | Serious
Starling, 2017^11^ | Critical | Moderate | Moderate | Moderate | Moderate | Moderate | Serious
Tajima, 2017^4^ | Critical | Moderate | Serious | Moderate | No information | Low | Serious

ii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

iii EVOO: extra virgin olive oil, MUFA: monounsaturated fatty acid, OMNI: optimal macronutrient intake, PCA: principal component analysis, PUFA: polyunsaturated fatty acid, SFA: saturated fatty acid

iv Author-derived dietary pattern

v Author-derived dietary pattern

vi Institute of Medicine (US) and National Research Council (US) Committee to Reexamine IOM Pregnancy Weight Guidelines. Weight Gain During Pregnancy: Reexamining the Guidelines. (Rasmussen KM, Yaktine AL, eds.). Washington (DC): National Academies Press (US); 2009

vii Institute of Medicine (US) Committee on Nutritional Status During Pregnancy and Lactation. Nutrition During Pregnancy: Part I Weight Gain. Washington (DC): National Academies Press (US); 1990

viii Hutcheon JA, Platt RW, Abrams B, Himes KP, Simhan HN, Bodnar LM. Pregnancy weight gain charts for obese and overweight women. Obesity. 2015; 23(3): 532–535. doi: 10.1002/oby.21011.25707378

ix A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC

x ACOG: American College of Obstetricians and Gynecologists, AHEI: alternative healthy eating index, aOR: adjustd odds ration, aRR: adjusted risk ratio, BIGCS: Born in Guangzhou Cohort Study, BMI: body mass index, BW: birth weight, CI: confidence interval, d: day, DASH: Dietary Approaches to Stop Hypertension, DHQ: diet history questionnaire, DII: Dietary Inflammation Index, DP: dietary pattern, ESTEEM: Effect of Simple, Targeted Diet in Pregnant Women With Metabolic Risk Factors on Pregnancy Outcomes, EVOO: extra virgin olive oil, FFQ: food frequency questionnaire, g: gram(s), GDM: gestational diabetes mellitus, GWG: gestational weight gain, HEI: Healthy Eating Index, HFII: Healthy Food Intake Index, hr: hour, HTN: hypertension, IFPSII: Infant Feeding Practices Study II, INMA: INfancia y Medio Ambiente, IOM: Institute of Medicine, IQR: interquartile range, kcal: kilocalories, kg: kilogram(s), MDA: Mediterranean Diet Adherence, MDQS: Maternal Diet Quality Score, Med: Mediterranean, MET: metabolic equivalent of task, mo: month, MOMFIT: Maternal Offspring Metabolics Family Intervention Trial, MoBa: Mothers and Babies cohort, MUFA: monounsaturated fatty acid, NFFD: Norwegian Fit for Delivery, NHBCS: New Hampshire Birth Cohort Study, NHS: National Health Service, NND: New Nordic Diet, NR: not reported, NS: non-significant, OMCHS: Osaka Maternal and Child Health Study, OMNI: optimal macronutrient intake, OR: odds ratio, PA: physical activity, PCA: principal component analysis, PCS: prospective cohort study, PE: preeclampsia, PETALS: Pregnancy Environment and Lifestyle Study, PRINCESA: Pregnancy Research on Inflammation, Nutrition and City Environments: Systematic Analyses, PREWICE: PREgnant Women of Iceland, PUFA: polyunsaturated fatty acid, Q#: quartile, Ref: reference, RCT: randomized controlled trial, rMED: relative Mediterranean Diet, SD: standard deviation, SE: standard error, SECOST: Seremben Cohort Study, SES: socioeconomic status, SFA: saturated fatty acid, T#: tertile, wk: week(s), y: year(s)

xi ± indicates values of Mean± SD unless otherwise noted

xii BMI: body mass index, CHO: carbohydrate, d: day, GDM: gestational diabetes mellitus, g: gram, GWG: gestational weight gain, hr: hour, kg: kilogram(s), kJ: kilojoule(s), min: minute(s), MVPA: moderate to vigorous physical activity, PA: physical activity, PRO: protein, SES: socioeconomic status, UPBEAT: U.K. Pregnancies Better Eating and Activity Trial, wk: week(s), y: year(s)

xiii ± indicates values of Mean± SD unless otherwise noted

xiv A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xv Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

xvi Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )