# List of abbreviations

Abbreviation: Full name
AMDR: Acceptable Macronutrient Distribution Range
BMI: Body mass index
DP: Dietary pattern
FFQ: Food frequency questionnaire
GWG: Gestational weight gain
HDI: Human Development Index
HHS: Department of Health and Human Services
MED: Mediterranean
NESR: Nutrition Evidence Systematic Review
PPWL: Postpartum weight loss
RCT: Randomized controlled trial
USDA: United States Department of Agriculture