# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^ix^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between dietary patterns consumed during lactation and postpartum weight loss. For this systematic review, the target population considered was women during lactation who were healthy and/or at risk for chronic disease. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern; different levels of adherence to a dietary pattern. The outcomes considered were 1) change in weight from baseline (postpartum) to a later time point during the postpartum period and 2) postpartum weight retention if gestational weight gain is controlled for. The key confounders were age, race/ethnicity, socioeconomic status, physical activity, anthropometry (pre-pregnancy BMI and gestational weight gain), parity, smoking, human milk feeding practices (duration, exclusivity).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and- after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a; 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] including, at a minimum, a description of the foods and beverages in the pattern | - Studies that; 1a Do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed)
Intervention/exposure | and/or
Intervention/exposure | - 2 Diet based on macronutrient distribution outside of the AMDR and; - Include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; - Include at least one macronutrient outside of the acceptable macronutrient distribution range (AMDR^x^) | 2a Examine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | Dietary patterns described by foods and beverages consumed:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; Diets described by macronutrient distribution:; - Different macronutrient distribution of carbohydrate, fat, and protein | - No comparator; - Macronutrient proportion(s) of interest also outside the AMDR
Outcomes | - Change in weight from baseline (postpartum) to a later time point during the postpartum period; - Postpartum weight retention if gestational weight gain is controlled for | - N/A
Date of publication | - January 2000-November 2019 | - Articles published before January 2000 or after November 2019
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xi^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Women during lactation | - Animal and in vitro models; - Pregnancies conceived ONLY using Assisted Reproductive Technologies; - Studies that ONLY enroll multiple gestation pregnancies; - Studies that ONLY report combined data for singleton and multiple gestation pregnancies; - Studies that enroll lactating and non-lactating mothers and ONLY present combined data for lactating and non-lactating mothers; - Men
Health status of study participants | - Studies that enroll mothers who are healthy and/or at risk for chronic disease; - Studies that enroll some mothers diagnosed with a disease; - Studies that enroll some mothers who were severely undernourished prior to pregnancy; - Studies that enroll some or all mothers classified as underweight or obese prior to pregnancy | - Studies that exclusively enroll mothers who gave birth to preterm (<37 weeks and 0/7 days); - Studies that exclusively enroll mothers diagnosed with a disease, including severe undernutrition or hospitalized with an illness or injury
Temporality | - Studies that assess exposure prior to outcome | - Studies that assess outcome prior to exposure; - Studies that assess exposure and outcome during overlapping time periods (irrespective of time period)

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: June 26, 2019, Update: November 7, 2019
- Date range searched: January 1, 2000 – June 26, 2019; Update: January 1, 2000 – November 7, 2019
- Search terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality[tiab] OR eating habit*[tiab] OR dietary habit* OR diet habit* OR food habit* OR “Feeding Behavior”[Mesh] OR feeding behavior*[tiab] OR beverage consumption[tiab] OR beverage habit*[tiab] OR beverage intake*[tiab] OR dietary profile* OR food profile[tiab] OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake[tiab] OR food intake[tiab] OR food consumption[tiab] OR dietary consumption[tiab] OR eating frequenc* OR food frequenc*[tiab] OR eating style*[tiab] OR dietary change*[tiab] OR dietary choice*[tiab] OR food choice*[tiab] OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Healthy Diet”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR high-fat diet* [tiab] OR low fat diet*[tiab] OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR (“Guideline Adherence”[Mesh] AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage[tiab])) OR (diet score* OR diet quality score* OR diet quality index* OR dietary habits score* OR kidmed OR diet index* OR dietary index* OR Food-based Index* OR diet quality index* OR food index* OR food score* OR Mediterranean diet score* OR MedDietScore OR healthy eating index[tiab] OR food frequency questionnaire* OR food frequency survey* OR “Nutrition Surveys”[Mesh] OR nutrition survey*[tiab] OR diet survey*[tiab] OR food survey* OR dietary questionnaire[tiab]) OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - (“Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother[tiab] OR mothers[tiab] OR “Mothers”[Mesh] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpartum[tiab] OR post-partum[tiab] OR perinatal OR peri-natal OR puerperium[tiab] OR postpartal OR post-partal OR postnatal OR post delivery[tiab] OR after birth[tiab] OR “Lactation”[Mesh] OR lactation[tiab] OR lactating[tiab] OR “Breast Feeding”[Mesh] OR breastfeeding[tiab] OR breast-feeding[tiab] OR breast feed* OR breast-feed*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed* OR “Milk, Human”[Mesh] OR human milk[tiab] OR nursing women[tiab]))
  - #3 - (“Gestational Weight Gain”[Mesh] OR gestational weight gain[tiab] OR “Weight Gain”[Mesh:NoExp] OR weight gain[tiab] OR “Obesity”[Mesh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR “body size”[tiab] OR “Body Size”[Mesh] OR overnutrition[tiab] OR “Overnutrition”[Mesh:NoExp] OR adipos*[tiab] OR anthropometry[tiab] OR anthropometric*[tiab] OR “Adiposity”[Mesh] OR adipose[tiab] OR body weight[tiab] OR “Body Weight”[Mesh] OR “Body Composition”[Mesh] OR body fat[tiab] OR weight[ti] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR weight status[tiab] OR “Adipose Tissue”[Mesh] OR healthy weight[tiab] OR body fat mass[tiab] OR weight change[tiab] OR weight changes[tiab] OR “Weight Loss”[Mesh] OR weight loss*[tiab] OR weight reduc*[tiab] OR body weight[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR weight maint* OR “Diet, Reducing”[Mesh] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR (weight[tiab] AND (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain*[tiab] OR decreas*[tiab] OR watch OR control*[tiab] OR change*[tiab] OR gain[tiab]))
  - #4 - #1 AND #2 AND #3
  - #5 - NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/06/26; English, Update: Filters: Publication date from 2000/01/01 to 2019/11/07; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: June 26, 2019; Update: November 7, 2019
- Date range searched: January 1, 2000 – June 26, 2019; Update: January 1, 2000 – November 7, 2019
- Search terms:
  - #1 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR [mh “Feeding Behavior”] OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake” OR “food intake” OR “food consumption” OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR “food choice*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Healthy Diet”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”OR (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR (diet OR diets OR consumption OR intake OR supplement*)) OR (“guideline adherence”) NEAR (diet OR dietary OR food OR beverage)) OR (“diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “dietary habits score” OR kidmed OR “diet index” OR “dietary index” OR “Food-based Index” OR “diet quality index” OR “food index” OR “food score” OR “food scores” OR “Mediterranean diet score” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire” OR “food frequency questionnaires” OR “food frequency survey” OR “food frequency surveys” OR [mh “Nutrition Surveys”] OR “nutrition survey” OR “nutrition surveys” OR “diet survey” OR “diet surveys” OR “food survey” OR “food surveys” OR “dietary questionnaire”):ti,ab,kw OR ((pattern OR patterns OR consumption OR habit*) NEAR ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages)):ti,ab,kw
  - #2 - [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR (pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”):ti,ab,kw
  - #3 - ((weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain)):ti,ab,kw OR (“gestational weight gain” OR “weight gain” OR obesity OR obese OR overweight OR “body size” OR overnutrition OR adipos* OR anthropometry OR anthropometric* OR adipose OR “body weight” OR “body fat” OR weight OR “body mass index” OR BMI OR “weight status” OR “healthy weight” OR “body fat mass” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduct*” OR “body weight” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention”):ti,ab,kw OR [mh “Gestational Weight Gain”] OR [mh ^“Weight Gain”] OR [mh Obesity] OR [mh “Body Size”] OR [mh ^Overnutrition] OR [mh Adiposity] OR [mh “body weight”] OR [mh “Body Composition”] OR [mh “Body Mass Index”] OR [mh “Adipose Tissue”] OR [mh “Weight Loss”] OR [mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Diet, Reducing”]
  - #4 - #1 AND #2 AND #3
    Filters: pubication year from 2000 to 2019, Trials

#### Embase

- Provider: Elsevier
- Date(s) searched: June 26, 2019, Update: November 7, 2019
- Date range searched: January 1, 2000 – June 26, 2019; Update: January 1, 2000 – November 7, 2019
- Search terms:
  - #1 - ‘feeding behavior’/exp OR ‘mediterranean diet’/de OR ‘dash diet’/de OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘beverage consumption’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘beverage intake*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake’:ab,ti OR ‘food intake’:ab,ti OR ‘food consumption’:ab,ti OR ‘dietary consumption’:ab,ti OR ‘eating frequenc*’:ab,ti OR ‘food frequenc*’:ab,ti OR ‘eating style*’:ab,ti OR ‘dietary change*’:ab,ti OR ‘dietary choice*’:ab,ti OR ‘food choice*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR ‘hypo caloric’) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*)):ab,ti)* OR ((‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage)):ab,ti) OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘dietary habits score*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food-based index*’:ab,ti OR ‘diet quality index*’:ab,ti OR ‘food index*’:ab,ti OR ‘food score*’:ab,ti OR ‘mediterranean diet score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti OR ‘food frequency questionnaire*’:ab,ti OR ‘food frequency survey*’:ab,ti OR ‘nutrition survey*’:ab,ti OR ‘diet survey*’:ab,ti OR ‘food survey*’:ab,ti OR ‘dietary questionnaire’:ab,ti OR ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti)
  - #2 - pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR lactation:ab,ti OR lactating:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti OR ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/exp/mj OR ‘maternal nutrition’/mj OR ‘lactation’/mj OR ‘breast feeding’/exp/mj OR ‘breast milk’/exp/mj
  - #3 - ((weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain)):ab,ti) OR ‘gestational weight gain’:ab,ti OR ‘weight gain’:ab,ti OR obesity:ab,ti OR obese:ab,ti OR overweight:ab,ti OR ‘body size’:ab,ti OR overnutrition:ab,ti OR adipos*:ab,ti OR anthropometry:ab,ti OR anthropometric*:ab,ti OR adipose:ab,ti OR ‘body fat’:ab,ti OR weight:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR ‘weight status’:ab,ti OR ‘healthy weight’:ab,ti OR ‘body fat mass’:ab,ti OR ‘weight change’:ab,ti OR ‘weight changes’:ab,ti OR ‘weight loss*’:ab,ti OR ‘weight reduct*’:ab,ti OR ‘body weight’:ab,ti OR ‘weight maint*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight decreas*’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR ‘gestational weight gain’/mj OR ‘body weight gain’/de OR ‘obesity’/exp/mj OR ‘body size’/mj OR ‘overnutrition’/mj OR ‘body weight’/exp/mj OR ‘body composition’/exp/mj OR ‘body mass’/de OR ‘adipose tissue’/exp/mj OR ‘body weight loss’/exp/mj OR ‘weight loss program’/mj OR ‘weight trajectory (body weight)’/mj OR ‘low calorie diet’/exp/mj
  - #4 - #1 AND #2 AND #3
  - #5 - #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) searched: June 26, 2019; Update: November 7, 2019
- Date range searched: January 1, 2000 – June 26, 2019; Update: January 1, 2000 – November 7, 2019
- Search terms:
  - #1 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR MH “Eating Behavior+” OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “food intake*” OR “food consumption” OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR food choice*” OR MH “Diet, Mediterranean” OR “Mediterranean Diet*” OR MH “Dietary Approaches To Stop Hypertension” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR MH “Diet, Gluten-Free” OR “Gluten Free diet*” OR “prudent diet*” OR MH “Diet, Paleolithic” OR “Paleolithic Diet*” OR MH “Diet, Vegetarian” OR “vegetarian diet*” OR “vegan diet*” OR MH “Healthy Diet” OR “plant based diet*” OR MH “Diet, Western” OR “western diet*” OR MH “Diet, Carbohydrate-Restricted” OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR MH “Diet, Fat-Restricted” OR MH “Diet, High-Fat” OR MH “Diet, High-Protein” OR “high protein diet*” OR “high-fat diet*” OR “low fat diet*” OR MH “Diet, Protein-Restricted” OR “low protein diet*” OR MH “Diet, Sodium-Restricted” OR “low-sodium diet*” OR “low salt diet*” OR ((MH “Dietary Proteins” OR “dietary protein*” OR MH “Dietary Carbohydrates” OR “dietary carbohydrate*” OR MH “Dietary Fats” OR “dietary fat*” OR hypocaloric OR hypo-caloric) AND (diet OR diets OR consumption OR intake OR supplementation)) OR (MH “Guideline Adherence” AND (diet OR dietary OR food OR beverage)) OR (“diet score*” OR “diet quality score*” OR “diet quality index*” OR “dietary habits score*” OR kidmed OR “diet index*” OR “dietary index*” OR “Food-based Index*” OR “diet quality index*” OR “food index*” OR “food score*” OR “Mediterranean diet score*” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire*” OR “food frequency survey*” OR MH “Nutrition Surveys” OR “nutrition survey*” OR “diet survey*” OR “food survey*” OR “dietary questionnaire*”) OR ((pattern OR patterns OR consumption OR habit*) AND (MH “Diet” OR diet OR diets OR dietary OR MH “Food” OR food OR foods OR MH “Beverages” OR beverage OR beverages))
  - #2 - postpartum OR post-partum OR MH “Postpartum Period” OR postpartal OR post-partal OR postnatal OR post-natal OR “post deliver*” OR “after birth” OR MH pregnancy OR MH “pregnancy complications” OR MH “Prenatal Exposure Delayed Effects” OR MH “Maternal Exposure” OR MH “pregnant women” OR pregnan* OR pre-pregnancy OR prepregnancy OR prenatal OR antenatal OR maternal OR mother OR mothers OR perinatal OR peri-natal OR peri-conception OR periconception OR MH “Peripartum Period” OR peripartum OR peri-partum OR gestation* OR natal OR puerperium OR MH “Maternal Nutritional Physiological Phenomena” OR MH “Breast Feeding” OR breastfeeding OR breast-feeding OR MH “Milk, Human” OR “human milk” OR MH Lactation OR lactation OR lactating OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed* OR “nursing women” OR “nursing mother*”
  - #3 - MH “Gestational Weight Gain” OR MH “Weight Gain” OR MH Obesity OR MH “Body Size” OR MH Overnutrition OR MH Adiposity OR MH “Body Weight” OR MH “Body Composition” OR MH “Body Mass Index” OR MH “Adipose Tissue” OR MH “Weight Loss” OR MH “Weight Reduction Programs” OR MH “Body-Weight Trajectory” OR MH “Diet, Reducing” OR gestational weight gain OR weight gain OR obesity OR obese OR overweight OR “body size” OR overnutrition OR adipos* OR anthropometry OR anthropometric* OR adipose OR “body weight” OR “body fat” OR weight OR “body mass index” OR BMI OR “weight status” OR “healthy weight” OR “body fat mass” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduc*” OR “body weight” OR MH “Body-Weight Trajectory” OR “weight change*” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention” OR (weight N4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain))
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication)
    Filters: Published Date: 20000101 - 20190626; Update: Published Date: 20000101 - 20191107

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review questions on dietary patterns and PPWL, as well as dietary patterns and gestational weight gain (GWG). Articles on dietary patterns and PPWL and dietary patterns and GWG were searched for and screened together. This was done to leverage the overlap in topical areas and to improve efficiency. After the initial electronic database search (January 2000-June 2019), an updated search was conducted to also capture macronutrient distribution articles (January 2000-November 2019). The results of both electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria for each systematic review question depicted in the flow chart. Refer to Table 4 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns during lactation and postpartum weight loss, as well as between dietary patterns during pregnancy and gestational weight gain. The literature search yielded 17,661 articles. During title screening, 8,654 articles were screened out. During abstract screening, 1,933 articles were screened out. During full-text screening, 631 articles were screened out. During the hand search, 1 additional article was identified to include in the gestational weight gain systematic review. A total of 1 article was included in the postpartum weight loss systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening for the systematic review questions on dietary patterns during lactation and PPWL and dietary patterns during pregnancy and GWG, and includes columns for the categories of inclusion and exclusion criteria (see Table 3) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 4 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1. | Aaltonen, J, Ojala, T, Laitinen, K, Poussa, T, Ozanne, S, Isolauri, E. Impact of maternal diet during pregnancy and breastfeeding on infant metabolic programming: a prospective randomized controlled study. Eur J Clin Nutr. 2011. 65:10–9. doi:10.1038/ejcn.2010.225.20948557 20948557 | Intervention/Exposure; Outcome
2. | Abdel-Aziz, SB, Hegazy, IS, Mohamed, DA, Abu El Kasem, MMA, Hagag, SS. Effect of dietary counseling on preventing excessive weight gain during pregnancy. Public Health. 2018. 154:172–181. doi:10.1016/j.puhe.2017.10.014.29248827 | Intervention/Exposure
3. | Abreu, S, Santos, PC, Montenegro, N, Mota, J. Relationship between dairy product intake during pregnancy and neonatal and maternal outcomes among Portuguese women. Obes Res Clin Pract. 2017. 11:276–286. doi:10.1016/j.orcp.2016.07.001.27473300 | Intervention/Exposure
4. | Adair, LS, Kuzawa, CW, Borja, J. Maternal energy stores and diet composition during pregnancy program adolescent blood pressure. Circulation. 2001. 104:1034–9. doi:10.1161/hc3401.095037.11524398 | Outcome
5. | Adherence to Canada’s Food Guide Recommendations during Pregnancy: Nutritional Epidemiology and Public Health. Curr Dev Nutr. 2017. 1:e000356. doi:10.3945/cdn.116.000356.29955709 | Outcome
6. | Ainscough, K, Kennelly, MA, O’Sullivan, EJ, Lindsay, KL, Gibney, ER, McCarthy, M, McAuliffe, FM. Impact of a smartphone app supporting a lifestyle intervention in overweight and obese pregnancy on on maternal health and lifestyle outcomes. American journal of obstetrics and gynecology. 2018. 218:S598–S599. | Abstract
7. | Akbari, Z, Mansourian, M, Kelishadi, R. Relationship of the intake of different food groups by pregnant mothers with the birth weight and gestational age: Need for public and individual educational programs. J Educ Health Promot. 2015. 4:23. doi:10.4103/2277-9531.154109.25883993 | Intervention/Exposure; Outcome
8. | Allman, BR, Diaz Fuentes, E, Williams, DK, Turner, DE, Andres, A, Borsheim, E. Obesity Status Affects the Relationship Between Protein Intake and Insulin Sensitivity in Late Pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11092190. | Intervention/Exposure; Outcome
9. | Althuizen, E, van Poppel, MN, Seidell, JC, van Mechelen, W. Correlates of absolute and excessive weight gain during pregnancy. J Womens Health (Larchmt). 2009. 18:1559–66. doi:10.1089/jwh.2008.1275.19788365 | Intervention/Exposure
10. | Alves-Santos, NH, Cocate, PG, Benaim, C, Farias, DR, Emmett, PM, Kac, G. Prepregnancy Dietary Patterns and Their Association with Perinatal Outcomes: A Prospective Cohort Study. J Acad Nutr Diet. 2019. doi:10.1016/j.jand.2019.02.016. | Outcome
11. | Alves-Santos, NH, Cocate, PG, Eshriqui, I, Benaim, C, Barros, EG, Emmett, PM, Kac, G. Dietary patterns and their association with adiponectin and leptin concentrations throughout pregnancy: a prospective cohort. Br J Nutr. 2018. 119:320–329. doi:10.1017/s0007114517003580.29345609 | Population
12. | Alves-Santos, NH, Eshriqui, I, Franco-Sena, AB, Cocate, PG, Freitas-Vilela, AA, Benaim, C, Vaz Jdos, S, Castro, MB, Kac, G. Dietary intake variations from pre-conception to gestational period according to the degree of industrial processing: A Brazilian cohort. Appetite. 2016. 105:164–71. doi:10.1016/j.appet.2016.05.027.27233369 | Intervention/Exposure; Outcome
13. | Amezcua-Prieto, C, Martínez-Galiano, JM, Cano-Ibáñez, N, Olmedo-Requena, R, Bueno-Cavanillas, A, Delgado-Rodríguez, M. Types of carbohydrates intake during pregnancy and frequency of a small for gestational age newborn: A case-control study. Nutrients. 2019. 11. doi:10.3390/nu11030523. | Study Design
14. | Anand, SS, Gupta, M, Teo, KK, Schulze, KM, Desai, D, Abdalla, N, Zulyniak, M, de Souza, R, Wahi, G, Shaikh, M, Beyene, J, de Villa, E, Morrison, K, McDonald, SD, Gerstein, H. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. CMAJ Open. 2017. 5:E604–e611. doi:10.9778/cmajo.20170027. | Intervention/Exposure; Outcome
15. | Anleu, E, Reyes, M, Araya, BM, Flores, M, Uauy, R, Garmendia, ML. Effectiveness of an Intervention of Dietary Counseling for Overweight and Obese Pregnant Women in the Consumption of Sugars and Energy. Nutrients. 2019. 11. doi:10.3390/nu11020385. | Intervention/Exposure
16. | Antal, M. Nutritional status of Hungarian pregnant women. Forum Nutr. 2003. 56:229–31.15806876 | Intervention/Exposure; Outcome
17. | Antonakou, A, Papoutsis, D, Panou, I, Chiou, A, Matalas, AL. Role of exclusive breastfeeding in energy balance and weight loss during the first six months postpartum. Clin Exp Obstet Gynecol. 2013. 40:485–8.24597239 | Intervention/Exposure
18. | Apolzan, JW, Myers, CA, Cowley, AD, Brady, H, Hsia, DS, Stewart, TM, Redman, LM, Martin, CK. Examination of the reliability and validity of the Mindful Eating Questionnaire in pregnant women. Appetite. 2016. 100:142–51. doi:10.1016/j.appet.2016.02.025.26879222 | Intervention/Exposure
19. | Arredondo, A, Torres, C, Orozco, E, Pacheco, S, Huang, F, Zambrano, E, Bolanos-Jimenez, F. Socio-economic indicators, dietary patterns, and physical activity as determinants of maternal obesity in middle-income countries: Evidences from a cohort study in Mexico. Int J Health Plann Manage. 2019. 34:e713–e725. doi:10.1002/hpm.2684.30350426 | Outcome
20. | Artal, R, Catanzaro, RB, Gavard, JA, Mostello, DJ, Friganza, JC. A lifestyle intervention of weight-gain restriction: diet and exercise in obese women with gestational diabetes mellitus. Appl Physiol Nutr Metab. 2007. 32:596–601. doi:10.1139/h07-024.17510701 | Intervention/Exposure
21. | Arvizu, M, Afeiche, MC, Hansen, S, Halldorsson, TF, Olsen, SF, Chavarro, JE. Fat intake during pregnancy and risk of preeclampsia: a prospective cohort study in Denmark. European Journal of Clinical Nutrition. 2019. 73:1040–1048. doi:10.1038/s41430-018-0290-z.30194370 | Outcome
22. | Arvizu, M, Stuart, J, Rich-Edwards, J, Gaskins, A, Rosner, B, Chavarro, J. Adherence to Pre-pregnancy DASH Dietary Pattern and Diet Recommendations from the American Heart Association and the Risk of Preeclampsia (OR35-06-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR35-06-19. | Abstract
23. | Asbjornsdottir, B, Ronneby, H, Vestgaard, M, Ringholm, L, Nichum, VL, Jensen, DM, Raben, A, Damm, P, Mathiesen, ER. Lower daily carbohydrate consumption than recommended by the Institute of Medicine is common among women with type 2 diabetes in early pregnancy in Denmark. Diabetes Res Clin Pract. 2019. 152:88–95. doi:10.1016/j.diabres.2019.05.012.31121274 | Intervention/Exposure; Health Status
24. | Asci, O, Rathfisch, G. Effect of lifestyle interventions of pregnant women on their dietary habits, lifestyle behaviors, and weight gain: a randomized controlled trial. J Health Popul Nutr. 2016. 35:7. doi:10.1186/s41043-016-0044-2.26911204 | Intervention/Exposure
25. | Asemi, Z, Samimi, M, Tabassi, Z, Esmaillzadeh, A. The effect of DASH diet on pregnancy outcomes in gestational diabetes: a randomized controlled clinical trial. Eur J Clin Nutr. 2014. 68:490–5. doi:10.1038/ejcn.2013.296.24424076 | Health Status
26. | Asemi, Z, Samimi, M, Tabassi, Z, Sabihi, S, Esmaillzadeh, A. A randomized controlled clinical trial investigating the effect of DASH diet on insulin resistance, inflammation, and oxidative stress in gestational diabetes. Nutrition. 2013. 29:619–624. doi:10.1016/j.nut.2012.11.020.23466048 | Health Status
27. | Ashman, AM, Collins, CE, Hure, AJ, Jensen, M, Oldmeadow, C. Maternal diet during early childhood, but not pregnancy, predicts diet quality and fruit and vegetable acceptance in offspring. Matern Child Nutr. 2016. 12:579–90. doi:10.1111/mcn.12151.25294406 | Outcome
28. | Ashman, AM, Collins, CE, Weatherall, L, Brown, LJ, Rollo, ME, Clausen, D, Blackwell, CC, Pringle, KG, Attia, J, Smith, R, Lumbers, ER, Rae, KM. A cohort of Indigenous Australian women and their children through pregnancy and beyond: the Gomeroi gaaynggal study. J Dev Orig Health Dis. 2016. 7:357–68. doi:10.1017/s204017441600009x.27080434 | Intervention/Exposure
29. | Assaf-Balut, C, de la Torre, NG, Fuentes, M, Durán, A, Bordiú, E, Del Valle, L, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejón, MJ, de Miguel, MP, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of materno-foetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Nutrients. 2019. 11. doi:10.3390/nu11010066. | Study Design; Temporality
30. | Assaf-Balut, C, Garcia de la Torre, N, Duran, A, Fuentes, M, Bordiu, E, Del Valle, L, Valerio, J, Familiar, C, Jimenez, I, Herraiz, MA, Izquierdo, N, Torrejon, MJ, Runkle, I, de Miguel, MP, Moraga, I, Montanez, MC, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. Medical nutrition therapy for gestational diabetes mellitus based on Mediterranean Diet principles: a subanalysis of the St Carlos GDM Prevention Study. BMJ Open Diabetes Res Care. 2018. 6:e000550. doi:10.1136/bmjdrc-2018-000550. | Intervention/Exposure; Outcome
31. | Aydin, EK, Ozturk, S. Assessment of the Diets and Weights of Primiparous and Multiparous Pregnant Women in the Last Trimester. International Journal of Caring Sciences. 2016. 9:1033–1039. | Study Design; Intervention/Exposure
32. | Babaei, M, Banaem, LM. Nutritional status of pregnant women and urine calcium-to-creatinine ratio during 24th-28th weeks of pregnancy and their relationship with the incidence of hypertensive disorders during pregnancy. Journal of Kermanshah University of Medical Sciences. 2018. 22. doi:10.5812/jkums.69638. | Outcome
33. | Badon, SE, Miller, RS, Qiu, C, Sorensen, TK, Williams, MA, Enquobahrie, DA. Maternal healthy lifestyle during early pregnancy and offspring birthweight: differences by offspring sex. J Matern Fetal Neonatal Med. 2018. 31:1111–1117. doi:10.1080/14767058.2017.1309383.28320231 | Outcome; Comparator
34. | Bao, W, Bowers, K, Tobias, DK, Olsen, SF, Chavarro, J, Vaag, A, Kiely, M, Zhang, C. Prepregnancy low-carbohydrate dietary pattern and risk of gestational diabetes mellitus: a prospective cohort study. Am J Clin Nutr. 2014. 99:1378–84. doi:10.3945/ajcn.113.082966.24717341 | Outcome
35. | Bao, W. Comment on Koivusalo et al. Gestational diabetes mellitus can be prevented by lifestyle intervention: the finnish gestational diabetes prevention study (RADIEL): a randomized controlled Trial. Diabetes Care 2016; 39: 24-30. Diabetes Care. 39 (8) (pp e125), 2016. doi:10.2337/dc16-0665.27457641 | Study Design
36. | Bao, W, Tobias, DK, Hu, FB, Chavarro, J, Zhang, C. Pre-pregnancy potato consumption and risk of gestational diabetes mellitus. BMJ: British Medical Journal. 2016. 352:h6898–h6898.26759275 | Outcome
37. | Barbieri, MA, Portella, AK, Silveira, PP, Bettiol, H, Agranonik, M, Silva, AA, Goldani, MZ. Severe intrauterine growth restriction is associated with higher spontaneous carbohydrate intake in young women. Pediatr Res. 2009. 65:215–20. doi:10.1203/PDR.0b013e31818d6850.19047956 | Study Design; Outcome
38. | Barebring, L, Brembeck, P, Lof, M, Brekke, HK, Winkvist, A, Augustin, H. Food intake and gestational weight gain in Swedish women. Springerplus. 2016. 5:377. doi:10.1186/s40064-016-2015-x.27066384 | Study Design; Intervention/Exposure
39. | Barnes, RA, Edghill, N, Mackenzie, J, Holters, G, Ross, GP, Jalaludin, BB, Flack, JR. Predictors of large and small for gestational age birthweight in offspring of women with gestational diabetes mellitus. Diabetic Medicine. 2013. 30:1040–1046. doi:10.1111/dme.12207.23551273 | Intervention/Exposure; Outcome
40. | Bawadi, HA, Al-Kuran, O, Al-Bastoni, LA, Tayyem, RF, Jaradat, A, Tuuri, G, Al-Beitawi, SN, Al-Mehaisen, LM. Gestational nutrition improves outcomes of vaginal deliveries in Jordan: an epidemiologic screening. Nutr Res. 2010. 30:110–7. doi:10.1016/j.nutres.2010.01.005.20226996 | Intervention/Exposure; Comparator
41. | Baykan, A, Yalcin, SS, Yurdakok, K. Does maternal iron supplementation during the lactation period affect iron status of exclusively breast-fed infants? Turk J Pediatr. 2006. 48:301–7.17290563 | Outcome
42. | Beardsall, A, Perreault, M, Farncombe, T, Vanniyasingam, T, Thabane, L, Teo, KK, Atkinson, SA. Maternal and child factors associated with bone length traits in children at 3years of age. Bone. 2019. 127:1–8. doi:10.1016/j.bone.2019.05.025.31132508 | Intervention/Exposure; Outcome
43. | Bechtel-Blackwell, DA. Computer-assisted self-interview and nutrition education in pregnant teens. Clin Nurs Res. 2002. 11:450–62. doi:10.1177/105477302237456.12413116 | Intervention/Exposure
44. | Belan, M, Carranza-Mamane, B, AinMelk, Y, Pesant, MH, Duval, K, Jean-Denis, F, Langlois, MF, Lavoie, H, Waddell, G, Baillargeon, JP. A lifestyle intervention targeting women with obesity and infertility improves their fertility outcomes, especially in women with PCOS: a randomized controlled trial. Fertility and sterility. 2019. 112:e40-. doi:10.1016/j.fertnstert.2019.07.234. | Conference abstract
45. | Ben Naftali, Y, Chermesh, I, Solt, I, Friedrich, Y, Lowenstein, L. Achieving the Recommended Gestational Weight Gain in High-Risk Versus Low-Risk Pregnancies. Isr Med Assoc J. 2018. 20:411–414.30109788 | Intervention/Exposure
46. | Benaim, C, Freitas-Vilela, AA, Pinto, TJP, Lepsch, J, Farias, DR, Dos Santos Vaz, J, El-Bacha, T, Kac, G. Early pregnancy body mass index modifies the association of pre-pregnancy dietary patterns with serum polyunsaturated fatty acid concentrations throughout pregnancy in Brazilian women. Matern Child Nutr. 2018. 14. doi:10.1111/mcn.12480. | Intervention/Exposure; Outcome
47. | Bennett, WL, Liu, SH, Yeh, HC, Nicholson, WK, Gunderson, EP, Lewis, CE, Clark, JM. Changes in weight and health behaviors after pregnancies complicated by gestational diabetes mellitus: the CARDIA study. Obesity (Silver Spring). 2013. 21:1269–75. doi:10.1002/oby.20133.23666593 | Intervention/Exposure; Diet measured (well) before pregnancy
48. | Berkey, CS, Tamimi, RM, Willett, WC, Rosner, B, Hickey, M, Toriola, AT, Lindsay Frazier, A, Colditz, GA. Dietary intake from birth through adolescence in relation to risk of benign breast disease in young women. Breast Cancer Res Treat. 2019. doi:10.1007/s10549-019-05323-8. | Population; Outcome
49. | Bertolotto, A, Volpe, L, Calianno, A, Pugliese, MC, Lencioni, C, Resi, V, Ghio, A, Corfini, M, Benzi, L, Del Prato, S, Di Cianni, G. Physical activity and dietary habits during pregnancy: effects on glucose tolerance. J Matern Fetal Neonatal Med. 2010. 23:1310–4. doi:10.3109/14767051003678150.20334531 | Intervention/Exposure; No association between diet and GWG examined
50. | Bertz, F, Winkvist, A, Brekke, HK. Sustainable weight loss among overweight and obese lactating women is achieved with an energy-reduced diet in line with dietary recommendations: results from the LEVA randomized controlled trial. J Acad Nutr Diet. 2015. 115:78–86. doi:10.1016/j.jand.2014.05.017.25088520 | Outcome
51. | Black, MM, Papas, MA, Bentley, ME, Cureton, P, Saunders, A, Le, K, Anliker, J, Robinson, N. Overweight adolescent African-American mothers gain weight in spite of intentions to lose weight. J Am Diet Assoc. 2006. 106:80–7. doi:10.1016/j.jada.2005.09.049.16390669 | Population
52. | Blumfield, ML, Hure, AJ, MacDonald-Wicks, LK, Smith, R, Simpson, SJ, Giles, WB, Raubenheimer, D, Collins, CE. Dietary balance during pregnancy is associated with fetal adiposity and fat distribution. Am J Clin Nutr. 2012. 96:1032–41. doi:10.3945/ajcn.111.033241.23034964 | Outcome; Comparator
53. | Blumfield, ML, Schreurs, M, Rollo, ME, MacDonald-Wicks, LK, Kokavec, A, Collins, CE. The association between portion size, nutrient intake and gestational weight gain: a secondary analysis in the WATCH study 2006/7. J Hum Nutr Diet. 2016. 29:271–80. doi:10.1111/jhn.12330.26249316 | Intervention/Exposure; Outcome
54. | Bo, S, Menato, G, Lezo, A, Signorile, A, Bardelli, C, De Michieli, F, Massobrio, M, Pagano, G. Dietary fat and gestational hyperglycaemia. Diabetologia. 2001. 44:972–8. doi:10.1007/s001250100590.11484073 | Intervention/Exposure; Outcome
55. | Bobinski, R, Mikulska, M, Mojska, H, Ulman-Wodarz, I, Sodowska, P. Assessment of the diet components of pregnant women as predictors of risk of preterm birth and born baby with low birth weight. Ginekol Pol. 2015. 86:292–9.26117989 | Intervention/Exposure; Outcome
56. | Boghossian, NS, Yeung, EH, Lipsky, LM, Poon, AK, Albert, PS. Dietary patterns in association with postpartum weight retention. Am J Clin Nutr. 2013. 97:1338–45. doi:10.3945/ajcn.112.048702.23576044 | Population
57. | Bonakdar, SA, Dorosty Motlagh, AR, Bagherniya, M, Ranjbar, G, Daryabeygi-Khotbehsara, R, Mohajeri, SAR, Safarian, M. Pre-pregnancy Body Mass Index and Maternal Nutrition in Relation to Infant Birth Size. Clin Nutr Res. 2019. 8:129–137. doi:10.7762/cnr.2019.8.2.129.31089466 | Study Design; Outcome
58. | Bouwland-Both, MI, Steegers-Theunissen, RP, Vujkovic, M, Lesaffre, EM, Mook-Kanamori, DO, Hofman, A, Lindemans, J, Russcher, H, Jaddoe, VW, Steegers, EA. A periconceptional energy-rich dietary pattern is associated with early fetal growth: the Generation R study. Bjog. 2013. 120:435–45. doi:10.1111/1471-0528.12086.23194298 | Outcome
59. | Brandhagen, M, Lissner, L, Brantsaeter, AL, Meltzer, HM, Haggkvist, AP, Haugen, M, Winkvist, A. Breast-feeding in relation to weight retention up to 36 months postpartum in the Norwegian Mother and Child Cohort Study: modification by socio-economic status? Public Health Nutr. 2014. 17:1514–23. doi:10.1017/s1368980013001869.23915637 | Intervention/Exposure
60. | Brantsæter, AL, Haugen, M, Myhre, R, Sengpiel, V, Englund-Ögge, L, Nilsen, RM, Borgen, I, Duarte-Salles, T, Papadopoulou, E, Vejrup, K, Von Ruesten, A, Hillesund, ER, Birgisdottir, BE, Magnus, P, Trogstad, L, Jacobsson, B, Bacelis, J, Myking, S, Knutsen, HK, Kvalem, HE, Alexander, J, Mendez, M, Meltzer, HM. Diet matters, particularly in pregnancy – Results from MoBa studies of maternal diet and pregnancy outcomes. Norsk Epidemiologi. 2014. 24:63–77. | Study Design
61. | Brekke, HK, Bertz, F, Rasmussen, KM, Bosaeus, I, Ellegård, L, Winkvist, A. Diet and exercise interventions among overweight and obese lactating women: Randomized trial of effects on cardiovascular risk factors. PLoS ONE. 2014. 9. doi:10.1371/journal.pone.0088250. | Outcome
62. | Briley, C, Flanagan, NL, Lewis, NM. In-home prenatal nutrition intervention increased dietary iron intakes and reduced low birthweight in low-income African-American women. Journal of the American Dietetic Association. 2002. 102:984–987.12146565 | Intervention/Exposure
63. | Broekhuizen, K, Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JGM, Bosmans, JE, van Poppel, MNM, van Dongen, JM. Cost-effectiveness of healthy eating and/or physical activity promotion in pregnant women at increased risk of gestational diabetes mellitus: economic evaluation alongside the DALI study, a European multicenter randomized controlled trial. Int J Behav Nutr Phys Act. 2018. 15:23. doi:10.1186/s12966-018-0643-y.29540227 | Intervention/Exposure; Outcome
64. | Brustman, LE, Langer, O, Bimson, B, Scarpelli, S, El Daouk, M. Weight gain in gestational diabetes: the effect of treatment modality. J Matern Fetal Neonatal Med. 2016. 29:1025–9. doi:10.3109/14767058.2015.1034101.25902398 | Intervention/Exposure; Comparator
65. | Buckingham-Schutt, LM, Ellingson, LD, Vazou, S, Campbell, CG. The Behavioral Wellness in Pregnancy study: a randomized controlled trial of a multi-component intervention to promote appropriate weight gain. The American journal of clinical nutrition. 2019. 109:1071–1079. doi:10.1093/ajcn/nqy359.30949691 | Intervention/Exposure; Outcome
66. | Buhling, KJ, Elsner, E, Wolf, C, Harder, T, Engel, B, Wascher, C, Siebert, G, Dudenhausen, JW. No influence of high- and low-carbohydrate diet on the oral glucose tolerance test in pregnancy. Clin Biochem. 2004. 37:323–7. doi:10.1016/j.clinbiochem.2003.11.008.15003736 | Outcome
67. | Bzikowska-Jura, A, Czerwonogrodzka-Senczyna, A, Oledzka, G, Szostak-Wegierek, D, Weker, H, Wesolowska, A. Maternal Nutrition and Body Composition During Breastfeeding: Association with Human Milk Composition. Nutrients. 2018. 10. doi:10.3390/nu10101379. | Intervention/Exposure
68. | Cahill, JM, Freeland-Graves, JH, Shah, BS, Lu, H, Pepper, MR. Determinants of weight loss after an intervention in low-income women in early postpartum. J Am Coll Nutr. 2012. 31:133–43.22855919 | Population
69. | Caire-Juvera, G, Casanueva, E, Bolanos-Villar, AV, de Regil, LM, Calderon de la Barca, AM. No changes in weight and body fat in lactating adolescent and adult women from Mexico. Am J Hum Biol. 2012. 24:425–31. doi:10.1002/ajhb.22234.22344621 | Intervention/Exposure
70. | Cano Ibanez, N, Martinez Galiano, JM, Amezcua Prieto, C, Olmedo Requena, R, Bueno Cavanillas, A, Delgado Rodriguez, M. Meat and meat products intake in pregnancy and risk of small for gestational age infants. A case-control study. Nutr Hosp. 2019. 36:405–411. doi:10.20960/nh.2366.30864457 | Study Design
71. | Cao, LL, Yan, CH, Yu, XD, Tian, Y, Zhao, L, Liu, JX, Shen, XM. Relationship between serum concentrations of polychlorinated biphenyls and organochlorine pesticides and dietary habits of pregnant women in Shanghai. Sci Total Environ. 2011. 409:2997–3002. doi:10.1016/j.scitotenv.2011.04.040.21665017 | Outcome
72. | Carmichael, SL, Ma, C, Feldkamp, ML, Shaw, GM. Comparing Usual Dietary Intakes Among Subgroups of Mothers in the Year Before Pregnancy. Public Health Rep. 2019. 134:155–163. doi:10.1177/0033354918821078.30593261 | Study Design; Outcome
73. | Carmichael, SL, Yang, W, Gilboa, S, Ailes, E, Correa, A, Botto, LD, Feldkamp, ML, Shaw, GM. Elevated body mass index and decreased diet quality among women and risk of birth defects in their offspring. Birth Defects Res A Clin Mol Teratol. 2016. 106:164–71. doi:10.1002/bdra.23471.26663631 | Study Design; Outcome
74. | Castro, MB, Kac, G, Sichieri, R. Assessment of protein intake during pregnancy using a food frequency questionnaire and the effect on postpartum body weight variation. Cad Saude Publica. 2010. 26:2112–20.21180984 | Intervention/Exposure; Country
75. | Castro, MBT, Cunha, DB, Araujo, MC, Bezerra, IN, Adegboye, ARA, Kac, G, Sichieri, R. High protein diet promotes body weight loss among Brazilian postpartum women. Matern Child Nutr. 2018. :e12746. doi:10.1111/mcn.12746.30381901 | Population
76. | Castro, PS, de Castro, MBT, Kac, G. Adherence to dietary recommendations by the Institute of Medicine and the effect on body weight during pregnancy. Cadernos de Saude Publica. 2013. 29:1311–1321. doi:10.1590/S0102-311X2013000700006.23842999 | Not English
77. | Centofanti, SF, Francisco, RPV, Phillippi, ST, Galletta, MAK, Sousa, AMS, Rodrigues, AS, Curi, R, Brizot, ML. Maternal nutrient intake and fetal gastroschisis: A case-control study. Am J Med Genet A. 2019. doi:10.1002/ajmg.a.61265. | Study Design
78. | Chan, GM, McElligott, K, McNaught, T, Gill, G. Effects of dietary calcium intervention on adolescent mothers and newborns: a randomized controlled trial. Obstetrics and gynecology. 2006. 108:565–571. doi:10.1097/01.AOG.0000231721.42823.9e.16946216 | Intervention/Exposure; Association btw macronutrient proportion and GWG not analyzed
79. | Chan, KK, Ho, LF, Lao, TT. Nutritional intake and placental size in gestational diabetic pregnancies--a preliminary observation. Placenta. 2003. 24:985–8.14580382 | Outcome
80. | Chandler-Laney, PC, Schneider, CR, Gower, BA, Granger, WM, Mancuso, MS, Biggio, JR. Association of late-night carbohydrate intake with glucose tolerance among pregnant African American women. Matern Child Nutr. 2016. 12:688–98. doi:10.1111/mcn.12181.25786515 | Outcome; Comparator
81. | Chang, MW, Brown, R, Nitzke, S. Fast Food Intake in Relation to Employment Status, Stress, Depression, and Dietary Behaviors in Low-Income Overweight and Obese Pregnant Women. Matern Child Health J. 2016. 20:1506–17. doi:10.1007/s10995-016-1949-5.26973147 | Intervention/Exposure
82. | Chang, MW, Nitzke, S, Brown, R. Design and outcomes of a Mothers In Motion behavioral intervention pilot study. J Nutr Educ Behav. 2010. 42:S11–21. doi:10.1016/j.jneb.2010.01.010.20399404 | Intervention/Exposure; Population
83. | Chang, MW, Schaffir, J, Brown, R, Wegener, DT. Mediation by self-efficacy in the relation between social support and dietary intake in low-income postpartum women who were overweight or obese. Appetite. 2019. 140:248–254. doi:10.1016/j.appet.2019.05.031.31141706 | Intervention/Exposure
84. | Chang, MW, Tan, A, Schaffir, J. Relationships between stress, demographics and dietary intake behaviours among low-income pregnant women with overweight or obesity. Public Health Nutr. 2019. 22:1066–1074. doi:10.1017/s1368980018003385.30621807 | Study Design; Outcome
85. | Charo, L, Lacoursiere, DY. Introduction: obesity and lifestyle issues in women. Obstet Gynecol. 2014. 57:433–45. doi:10.1097/grf.0000000000000040. | Clin Study Design; Diet assessed at same time as final weight
86. | Chatzi, Leda, Garcia, Raquel, Roumeliotaki, Theano, Basterrechea, Mikel, Begiristain, Haizea, Iñiguez, Carmen, Vioque, Jesus, Kogevinas, Manolis, Sunyer, Jordi. Mediterranean diet adherence during pregnancy and risk of wheeze and eczema in the first year of life: INMA (Spain) and RHEA (Greece) mother–child cohort studies. British Journal of Nutrition. 2013. 110:2058–2068. doi:10.1017/S0007114513001426. | Outcome
87. | Chen, GW, Ding, WH, Ku, HY, Chao, HR, Chen, HY, Huang, MC, Wang, SL. Alkylphenols in human milk and their relations to dietary habits in central Taiwan. Food Chem Toxicol. 2010. 48:1939–44. doi:10.1016/j.fct.2010.04.038.20435081 | Outcome
88. | Chen, H, Wang, P, Han, Y, Ma, J, Troy, FA, 2nd, Wang, B. Evaluation of dietary intake of lactating women in China and its potential impact on the health of mothers and infants. BMC Womens Health. 2012. 12:18. doi:10.1186/1472-6874-12-18.22800437 | Outcome; Comparator
89. | Chen, LW, Aris, IM, Bernard, JY, Tint, MT, Chia, A, Colega, M, Gluckman, PD, Shek, LP, Saw, SM, Chong, YS, Yap, F, Godfrey, KM, van Dam, RM, Chong, MF, Lee, YS. Associations of Maternal Dietary Patterns during Pregnancy with Offspring Adiposity from Birth Until 54 Months of Age. Nutrients. 2016. 9. doi:10.3390/nu9010002. | Study Design
90. | Chen, LW, Murrin, CM, Mehegan, J, Kelleher, CC, Phillips, CM. Maternal, but not paternal or grandparental, caffeine intake is associated with childhood obesity and adiposity: The Lifeways Cross-Generation Cohort Study. Am J Clin Nutr. 2019. 109:1648–1655. doi:10.1093/ajcn/nqz019.31136661 | Intervention/Exposure
91. | Chen, LW, Navarro, P, Murrin, CM, Mehegan, J, Kelleher, CC, Phillips, CM. Maternal Dietary Glycemic and Insulinemic Indexes Are Not Associated with Birth Outcomes or Childhood Adiposity at 5 Years of Age in an Irish Cohort Study. J Nutr. 2019. 149:1037–1046. doi:10.1093/jn/nxz025.31049568 | Outcome
92. | Chen, LW, Tint, MT, Fortier, MV, Aris, IM, Bernard, JY, Colega, M, Gluckman, PD, Saw, SM, Chong, YS, Yap, F, Godfrey, KM, Kramer, MS, van Dam, RM, Chong, MFF, Lee, YS. Maternal macronutrient intake during pregnancy is associated with neonatal abdominal adiposity: The growing up in singapore towards healthy outcomes (GUSTO) study. Journal of Nutrition. 2016. 146:1571–1579. doi:10.3945/jn.116.230730. | Study Design; Outcome
93. | Chen, Q, Feng, Y, Yang, H, Wu, W, Zhang, P, Wang, K, Wang, Y, Ko, J, Shen, J, Guo, L, Zhao, F, Du, W, Ru, S, Wang, S, Zhang, Y. A Vitamin Pattern Diet Is Associated with Decreased Risk of Gestational Diabetes Mellitus in Chinese Women: Results from a Case Control Study in Taiyuan, China. J Diabetes Res. 2019. 2019:5232308. doi:10.1155/2019/5232308.31089473 | Study Design; Intervention/Exposure
94. | Chen, X, Scholl, TO, Leskiw, M, Savaille, J, Stein, TP. Differences in maternal circulating fatty acid composition and dietary fat intake in women with gestational diabetes mellitus or mild gestational hyperglycemia. Diabetes Care. 2010. 33:2049–54. doi:10.2337/dc10-0693.20805277 | Outcome; Comparator
95. | Cheng, YW, Chung, JH, Kurbisch-Block, I, Inturrisi, M, Shafer, S, Caughey, AB. Gestational weight gain and gestational diabetes mellitus: perinatal outcomes. Obstetrics & Gynecology. 2008. 112:1015–1022.18978100 | Intervention/Exposure
96. | Chia, AR, de Seymour, JV, Colega, M, Chen, LW, Chan, YH, Aris, IM, Tint, MT, Quah, PL, Godfrey, KM, Yap, F, Saw, SM, Baker, PN, Chong, YS, van Dam, RM, Lee, YS, Chong, MF. A vegetable, fruit, and white rice dietary pattern during pregnancy is associated with a lower risk of preterm birth and larger birth size in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. Am J Clin Nutr. 2016. 104:1416–1423. doi:10.3945/ajcn.116.133892.27733407 | Study Design
97. | Chia, AR, Tint, MT, Han, CY, Chen, LW, Colega, M, Aris, IM, Chua, MC, Tan, KH, Yap, F, Shek, LP, Chong, YS, Godfrey, KM, Fortier, MV, Lee, YS, Chong, MF. Adherence to a healthy eating index for pregnant women is associated with lower neonatal adiposity in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) Study. Am J Clin Nutr. 2018. 107:71–79. doi:10.1093/ajcn/nqx003.29381790 | Outcome; Temporality
98. | Chiu, YH, Williams, PL, Gillman, MW, Hauser, R, Rifas-Shiman, SL, Bellavia, A, Fleisch, AF, Oken, E, Chavarro, JE. Maternal intake of pesticide residues from fruits and vegetables in relation to fetal growth. Environ Int. 2018. 119:421–428. doi:10.1016/j.envint.2018.07.014.30029096 | Intervention/Exposure; Outcome
99. | Chong, MF, Chia, AR, Colega, M, Tint, MT, Aris, IM, Chong, YS, Gluckman, P, Godfrey, KM, Kwek, K, Saw, SM, Yap, F, van Dam, RM, Lee, YS. Maternal Protein Intake during Pregnancy Is Not Associated with Offspring Birth Weight in a Multiethnic Asian Population. J Nutr. 2015. 145:1303–10. doi:10.3945/jn.114.205948.25948786 | Intervention/Exposure; Outcome
100. | Chortatos, A, Haugen, M, Iversen, PO, Vikanes, A, Magnus, P, Veierod, MB. Nausea and vomiting in pregnancy: associations with maternal gestational diet and lifestyle factors in the Norwegian Mother and Child Cohort Study. Bjog. 2013. 120:1642–53. doi:10.1111/1471-0528.12406.23962347 | Intervention/Exposure; Outcome
101. | Clerget-Froidevaux, MS, Sachs, LM. High-fat diet and pregnancy: Are you ready to take risks for your offspring? Endocrinology. 2017. 158:2716–2718. doi:10.1210/en.2017-00611.28911181 | Study Design
102. | Coathup, V, Northstone, K, Izadi, H, Wheeler, S, Smith, L. Do Maternal Dietary Antioxidants Modify the Relationship Between Binge Drinking and Small for Gestational Age? Findings from a Longitudinal Cohort Study. Alcoholism: Clinical and Experimental Research. 2018. 42:2196–2204. doi:10.1111/acer.13864. | Outcome
103. | Coelho Nde, L, Cunha, DB, Esteves, AP, Lacerda, EM, Theme Filha, MM. Dietary patterns in pregnancy and birth weight. Rev Saude Publica. 2015. 49:62. doi:10.1590/s0034-8910.2015049005403.26398873 | No association with GWG as dependent variable
104. | Cohen, TR, Koski, KG. Limiting excess weight gain in healthy pregnant women: importance of energy intakes, physical activity, and adherence to gestational weight gain guidelines. J Pregnancy. 2013. 2013:787032. doi:10.1155/2013/787032.23533762 | Intervention/Exposure
105. | Cohen, TR, Plourde, H, Koski, KG. Are Canadian women achieving a fit pregnancy? A pilot study. Can J Public Health. 2010. 101:87–91.20364546 | Intervention/Exposure
106. | Colatrella, A, Framarino, M, Toscano, V, Bongiovanni, M, Festa, C, Mattei, L, Merola, G, Bitterman, O, Maravalle, M, Napoli, A. Continuous glucose monitoring during breastfeeding in women with recent gestational diabetes mellitus. Diabetes Technol Ther. 2012. 14:576–82. doi:10.1089/dia.2011.0266.22512263 | Intervention/Exposure; Outcome
107. | Colleran, HL, Lovelady, CA. Use of MyPyramid Menu Planner for Moms in a weight-loss intervention during lactation. J Acad Nutr Diet. 2012. 112:553–8. doi:10.1016/j.jand.2011.12.004.22709705 | Intervention/Exposure; Outcome
108. | Collins, CT, Chua, MC, Rajadurai, VS, McPhee, AJ, Miller, LN, Gibson, RA, Makrides, M. Higher protein and energy intake is associated with increased weight gain in pre-term infants. J Paediatr Child Health. 2010. 46:96–102. doi:10.1111/j.1440-1754.2009.01645.x.20105257 | Population; Outcome
109. | Colon-Ramos, U, Racette, SB, Ganiban, J, Nguyen, TG, Kocak, M, Carroll, KN, Volgyi, E, Tylavsky, FA. Association between dietary patterns during pregnancy and birth size measures in a diverse population in Southern US. Nutrients. 2015. 7:1318–32. doi:10.3390/nu7021318.25690420 | Outcome; Association btw DP and GWG not analyzed
110. | Conway, MC, Mulhern, MS, McSorley, EM, van Wijngaarden, E, Strain, JJ, Myers, GJ, Davidson, PW, Shamlaye, CF, Yeates, AJ. Dietary determinants of polyunsaturated fatty acid (PUFA) status in a high fish-eating cohort during pregnancy. Nutrients. 2018. 10. doi:10.3390/nu10070927. | Outcome
111. | Cormick, G, Betran, AP, Harbron, J, Dannemann Purnat, T, Parker, C, Hall, D, Seuc, AH, Roberts, JM, Belizan, JM, Hofmeyr, GJ. Are women with history of pre-eclampsia starting a new pregnancy in good nutritional status in South Africa and Zimbabwe? BMC Pregnancy Childbirth. 2018. 18:236. doi:10.1186/s12884-018-1885-z.29907146 | Intervention/Exposure; Comparator
112. | Courtney, A, O’Brien, E, McAuliffe, F. The DASH (Dietary Approaches to Stop Hypertension) dietary pattern and blood pressure in pregnancy. BJOG. 2019. 126:42-. doi:10.1111/1471-0528.15633. | Abstract
113. | Courville, AB, Harel, O, Lammi-Keefe, CJ. Consumption of a DHA-containing functional food during pregnancy is associated with lower infant ponderal index and cord plasma insulin concentration. Br J Nutr. 2011. 106:208–12. doi:10.1017/s0007114511000961.21521543 | Outcome
114. | Crume, TL, Brinton, JT, Shapiro, A, Kaar, J, Glueck, DH, Siega-Riz, AM, Dabelea, D. Maternal dietary intake during pregnancy and offspring body composition: The Healthy Start Study. Am J Obstet Gynecol. 2016. 215:609.e1–609.e8. doi:10.1016/j.ajog.2016.06.035.27371352 | Intervention/Exposure; Outcome
115. | Cuco, G, Arija, V, Iranzo, R, Vila, J, Prieto, MT, Fernandez-Ballart, J. Association of maternal protein intake before conception and throughout pregnancy with birth weight. Acta Obstet Gynecol Scand. 2006. 85:413–21. doi:10.1080/00016340600572228.16612702 | Outcome
116. | Cuco, G, Fernandez-Ballart, J, Sala, J, Viladrich, C, Iranzo, R, Vila, J, Arija, V. Dietary patterns and associated lifestyles in preconception, pregnancy and postpartum. Eur J Clin Nutr. 2006. 60:364–71. doi:10.1038/sj.ejcn.1602324.16340954 | Outcome; Comparator
117. | Cunha, MPL, Marques, RC, Dorea, JG. Influence of Maternal Fish Intake on the Anthropometric Indices of Children in the Western Amazon. Nutrients. 2018. 10. doi:10.3390/nu10091146. | Intervention/Exposure; Outcome
118. | D. Association of food choices during pregnancy with gestational diabetes mellitus. Clinical Diabetology. 2017. 6:131–135. doi:10.5603/DK.2017.0022. | Study Design; Intervention/Exposure
119. | Dammann, KW, Smith, C. Factors affecting low-income women’s food choices and the perceived impact of dietary intake and socioeconomic status on their health and weight. Journal of Nutrition Education & Behavior. 2009. 41:242–253. doi:10.1016/j.jneb.2008.07.003.19508929 | Intervention/Exposure; Population
120. | Daundasekara, SS, Beasley, AD, O’Connor, DP, Sampson, M, Hernandez, D, Ledoux, T. Validation of the intuitive Eating Scale for pregnant women. Appetite. 2017. 112:201–209. doi:10.1016/j.appet.2017.02.001.28167151 | Intervention/Exposure
121. | Davis, JN, Shearrer, GE, Tao, W, Hurston, SR, Gunderson, EP. Dietary variables associated with substantial postpartum weight retention at 1-year among women with GDM pregnancy. BMC Obes. 2017. 4:31. doi:10.1186/s40608-017-0166-0.28794888 | Intervention/Exposure
122. | de Castro, MB, Freitas Vilela, AA, de Oliveira, AS, Cabral, M, de Souza, RA, Kac, G, Sichieri, R. Sociodemographic characteristics determine dietary pattern adherence during pregnancy. Public Health Nutr. 2016. 19:1245–51. doi:10.1017/s1368980015002700.26400675 | Study Design
123. | de Castro, MB, Kac, G, de Leon, AP, Sichieri, R. High-protein diet promotes a moderate postpartum weight loss in a prospective cohort of Brazilian women. Nutrition. 2009. 25:1120–8. doi:10.1016/j.nut.2009.02.006.19818279 | Intervention/Exposure; Population
124. | de Castro, MB, Sichieri, R, Barbosa Brito Fdos, S, Nascimento, S, Kac, G. Mixed dietary pattern is associated with a slower decline of body weight change during postpartum in a cohort of Brazilian women. Nutr Hosp. 2014. 29:519–25. doi:10.3305/nh.2014.29.3.7155.24558993 | Population; Country
125. | De Jersey, SusanJ, Ross, LyndaJ, Himstedt, Kellie, McIntyre, David H, Callaway, LeonieK. Weight gain and nutritional intake in obese pregnant women: Some clues for intervention. Nutrition & Dietetics. 2011. 68:53–59. doi:10.1111/j.1747-0080.2010.01470.x. | Comparator
126. | de la Torre, NG, Assaf-Balut, C, Jimenez Varas, I, Del Valle, L, Duran, A, Fuentes, M, Del Prado, N, Bordiu, E, Valerio, JJ, Herraiz, MA, Izquierdo, N, Torrejon, MJ, Cuadrado, MA, de Miguel, P, Familiar, C, Runkle, I, Barabash, A, Rubio, MA, Calle-Pascual, AL. Effectiveness of Following Mediterranean Diet Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Foetal Outcomes: A Prospective, Universal, Interventional Study with a Single Group. The St Carlos Study. Nutrients. 2019. 11. doi:10.3390/nu11061210. | Study Design; Intervention/Exposure
127. | Deierlein, AL, Siega-Riz, AM, Herring, A. Dietary energy density but not glycemic load is associated with gestational weight gain. Am J Clin Nutr. 2008. 88:693–9. doi:10.1093/ajcn/88.3.693.18779285 | Intervention/Exposure
128. | Del Prado, M, Villalpando, S, Lance, A, Alfonso, E, Demmelmair, H, Koletzko, B. Contribution of dietary and newly formed arachidonic acid to milk secretion in women on low fat diets. Adv Exp Med Biol. 2000. 478:407–8. doi:10.1007/0-306-46830-1_50.11065105 | Book chapter
129. | Della Libera, B, Ribeiro Baiao, M, de Souza Santos, MM, Padilha, P, Dutra Alves, P, Saunders, C. Adherence of pregnant women to dietary counseling and adequacy of total gestational weight gain. Nutr Hosp. 2011. 26:79–85.21519732 | Study Design; Intervention/Exposure
130. | Denguezli, W, Faleh, R, Fessi, A, Yassine, A, Hajjaji, A, Laajili, H, Sakouhi, M. Risk factors of fetal macrosomia: role of maternal nutrition. Tunis Med. 2009. 87:564–8.20180374 | Outcome; Country
131. | Deniz Ç, D, Özler, S, Sayın, FK, Eryılmaz, MA. Associations between night eating syndrome and metabolic parameters in pregnant women. Turk Jinekoloji ve Obstetrik Dernegi Dergisi. 2019. 16:107–111. doi:10.4274/tjod.galenos.2019.77864. | Study Design; Outcome
132. | Derbyshire, E, Davies, J, Costarelli, V, Dettmar, P. Prepregnancy body mass index and dietary intake in the first trimester of pregnancy. J Hum Nutr Diet. 2006. 19:267–73. doi:10.1111/j.1365-277X.2006.00705.x.16911239 | Study Design; Outcome
133. | deRosset, L, Berry, DC, Sanchez-Lugo, L, Ritter, K, Purdum, C, Santolim, V, Gilliland, R, Pender, L. Mama Sana .. Usted Sana: Lessons Learned From a Postpartum Weight Loss Intervention for Hispanic Women With Infants Six Months or Less. Hispanic Health Care International. 2013. 11:78–86. doi:10.1891/1540-4153.11.2.78.24830730 | Intervention/Exposure; Population
134. | DeSantiago, S, Alonso, L, Ramírez, I, Ortíz, N, Tovar, AR, Torres, N, Bourges, H. Metabolizable energy from a predominantly vegetable diet consumed by Mexican rural lactating women. Nutrition Research. 2000. 20:215–224. doi:10.1016/S0271-5317(99)00154-2. | Intervention/Exposure; Outcome
135. | Dhana, K, Haines, J, Liu, G, Zhang, C, Wang, X, Field, AE, Chavarro, JE, Sun, Q. Association between maternal adherence to healthy lifestyle practices and risk of obesity in offspring: results from two prospective cohort studies of mother-child pairs in the United States. Bmj. 2018. 362:k2486. doi:10.1136/bmj.k2486.29973352 | Outcome
136. | Dharod, JM, Croom, JE, Sady, CG. Food Insecurity: Its Relationship to Dietary Intake and Body Weight among Somali Refugee Women in the United States. Journal of Nutrition Education & Behavior. 2013. 45:47–53. doi:10.1016/j.jneb.2012.03.006.23084983 | Study Design; Outcome
137. | Di Carlo, C, Iannotti, G, Sparice, S, Chiacchio, MP, Greco, E, Tommaselli, GA, Nappi, C. The role of a personalized dietary intervention in managing gestational weight gain: a prospective, controlled study in a low-risk antenatal population. Archives of gynecology and obstetrics. 2014. 289:765–770. doi:10.1007/s00404-013-3054-y.24129610 | Intervention/Exposure; Comparator
138. | Diemert, A, Lezius, S, Pagenkemper, M, Hansen, G, Drozdowska, A, Hecher, K, Arck, P, Zyriax, BC. Maternal nutrition, inadequate gestational weight gain and birth weight: results from a prospective birth cohort. BMC Pregnancy Childbirth. 2016. 16:224. doi:10.1186/s12884-016-1012-y.27528213 | Intervention/Exposure; Comparator
139. | Dieting okay for breastfeeding mothers. J Natl Med Assoc. 2000. 92:A14. | Study Design; Commentary
140. | Dikensoy, E, Balat, O, Cebesoy, B, Ozkur, A, Cicek, H, Can, G. Effect of fasting during Ramadan on fetal development and maternal health. J Obstet Gynaecol Res. 2008. 34:494–8. doi:10.1111/j.1447-0756.2008.00814.x.18937702 | Intervention/Exposure
141. | Dodd, JM, Cramp, C, Sui, Z, Yelland, LN, Deussen, AR, Grivell, RM, Moran, LJ, Crowther, CA, Turnbull, D, McPhee, AJ, Wittert, G, Owens, JA, Robinson, JS. The effects of antenatal dietary and lifestyle advice for women who are overweight or obese on maternal diet and physical activity: the LIMIT randomised trial. BMC Med. 2014. 12:161. doi:10.1186/s12916-014-0161-y.25315237 | Outcome
142. | Dodd, JM, Deussen, AR, Mohamad, I, Rifas-Shiman, SL, Yelland, LN, Louise, J, McPhee, AJ, Grivell, RM, Owens, JA, Gillman, MW, Robinson, JS. The effect of antenatal lifestyle advice for women who are overweight or obese on secondary measures of neonatal body composition: the LIMIT randomised trial. Bjog. 2016. 123:244–53. doi:10.1111/1471-0528.13796.26841217 | Intervention/Exposure; Outcome
143. | Dodd, JM, Grivell, RM, Owens, JA. Antenatal Dietary and Lifestyle Interventions for Women Who are Overweight or Obese: outcomes from the LIMIT Randomized Trial. Current nutrition reports. 2014. 3:392–399. doi:10.1007/s13668-014-0101-7. | Intervention/Exposure
144. | Dodd, JM, Kannieappan, LM, Grivell, RM, Deussen, AR, Moran, LJ, Yelland, LN, Owens, JA. Effects of an antenatal dietary intervention on maternal anthropometric measures in pregnant women with obesity. Obesity (Silver Spring). 2015. 23:1555–62. doi:10.1002/oby.21145.26175260 | Intervention/Exposure
145. | Dodd, JM, Newman, A, Moran, LJ, Deussen, AR, Grivell, RM, Yelland, LN, Crowther, CA, McPhee, AJ, Wittert, G, Owens, JA, Turnbull, D, Robinson, JS. The effect of antenatal dietary and lifestyle advice for women who are overweight or obese on emotional well-being: the LIMIT randomized trial. Acta Obstet Gynecol Scand. 2016. 95:309–18. doi:10.1111/aogs.12832.26618547 | Intervention/Exposure; Outcome
146. | Dodd, JM. Dietary and lifestyle advice for pregnant women who are overweight or obese: the LIMIT randomized trial. Annals of nutrition & metabolism. 2014. 64:197–202. doi:10.1159/000365018.25300260 | Study Design; Intervention/Exposure
147. | Dominguez, LJ, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, Gea, A, Barbagallo, M, Bes-Rastrollo, M. Fast food consumption and gestational diabetes incidence in the SUN project. PLoS One. 2014. 9:e106627. doi:10.1371/journal.pone.0106627.25215961 | Intervention/Exposure; Outcome
148. | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Pre-pregnancy adherences to empirically derived dietary patterns and gestational diabetes risk in a Mediterranean cohort: the Seguimiento Universidad de Navarra (SUN) project. Br J Nutr. 2017. 118:715–721. doi:10.1017/s0007114517002537.28974271 | Outcome
149. | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Soft drink consumption and gestational diabetes risk in the SUN project. Clin Nutr. 2018. 37:638–645. doi:10.1016/j.clnu.2017.02.005.28262323 | Intervention/Exposure; Outcome
150. | Donnelly, JM, Walsh, JM, Byrne, J, Molloy, EJ, McAuliffe, FM. Impact of maternal diet on neonatal anthropometry: a randomized controlled trial. Pediatr Obes. 2015. 10:52–6. doi:10.1111/j.2047-6310.2013.00216.x.24443392 | Intervention/Exposure
151. | Dos Santos, K, Tavares Patricio, P, Santana Vieira Lima, T, Cavalcante de Barros, D, Saunders, C. A pilot intervention to reduce postpartum weight retention at primary health care in Brazil. Nutr Hosp. 2019. doi:10.20960/nh.02508. | Comparator
152. | Drehmer, M, Camey, SA, Nunes, MA, Duncan, BB, Lacerda, M, Pinheiro, AP, Schmidt, MI. Fibre intake and evolution of BMI: from pre-pregnancy to postpartum. Public Health Nutr. 2013. 16:1403–13. doi:10.1017/s1368980012003849.22916703 | Study Design; Intervention/Exposure
153. | Drouillet, P, Forhan, A, De Lauzon-Guillain, B, Thiébaugeorges, O, Goua, V, Magnin, G, Schweitzer, M, Kaminski, M, Ducimetière, P, Charles, M. Maternal fatty acid intake and fetal growth: evidence for an association in overweight women. The ‘EDEN mother-child’ cohort (study of pre- and early postnatal determinants of the child’s development and health). British Journal of Nutrition. 2009. 101:583–591. doi:10.1017/S0007114508025038. | Outcome; Comparator
154. | Drouillet, P, Kaminski, M, De Lauzon-Guillain, B, Forhan, A, Ducimetiere, P, Schweitzer, M, Magnin, G, Goua, V, Thiebaugeorges, O, Charles, MA. Association between maternal seafood consumption before pregnancy and fetal growth: evidence for an association in overweight women. The EDEN mother-child cohort. Paediatr Perinat Epidemiol. 2009. 23:76–86. doi:10.1111/j.1365-3016.2008.00982.x.19228317 | Outcome
155. | Dubois, L, Diasparra, M, Bédard, B, Colapinto, CK, Fontaine-Bisson, B, Tremblay, RE, Fraser, WD. Adequacy of nutritional intake during pregnancy in relation to prepregnancy BMI: results from the 3D Cohort Study. British Journal of Nutrition. 2018. 120:335–344. doi:10.1017/S0007114518001393. | Intervention/Exposure
156. | Dujmovic, M, Kresic, G, Mandic, ML, Kenjeric, D, Cvijanovic, O. Changes in dietary intake and body weight in lactating and non-lactating women: prospective study in northern coastal Croatia. Coll Antropol. 2014. 38:179–87.24851615 | Comparator; Not all lactating
157. | Durham, HA, Lovelady, CA, Brouwer, RJ, Krause, KM, Ostbye, T. Comparison of dietary intake of overweight postpartum mothers practicing breastfeeding or formula feeding. J Am Diet Assoc. 2011. 111:67–74. doi:10.1016/j.jada.2010.10.001.21185967 | Study Design; Outcome
158. | Easter, A, Naumann, U, Northstone, K, Schmidt, U, Treasure, J, Micali, N. A longitudinal investigation of nutrition and dietary patterns in children of mothers with eating disorders. J Pediatr. 2013. 163:173–8.e1. doi:10.1016/j.jpeds.2012.11.092.23333130 | Intervention/Exposure; Population
159. | Ebrahimi, F, Shariff, ZM, Tabatabaei, SZ, Fathollahi, MS, Mun, CY, Nazari, M. Relationship between sociodemographics, dietary intake, and physical activity with gestational weight gain among pregnant women in Rafsanjan City, Iran. J Health Popul Nutr. 2015. 33:168–76.25995733 | Study Design; Intervention/Exposure
160. | Eichler, J, Schmidt, R, Hiemisch, A, Kiess, W, Hilbert, A. Gestational weight gain, physical activity, sleep problems, substance use, and food intake as proximal risk factors of stress and depressive symptoms during pregnancy. BMC Pregnancy Childbirth. 2019. 19:175. doi:10.1186/s12884-019-2328-1.31101019 | Intervention/Exposure
161. | Ellery, THP, Sampaio, HAC, Carioca, AAF, Silva, Bydc, Alves, JAG, Da Silva Costa, F, Araujo Junior, E, Melo, MLP. Association between Dietary Glycemic Index and Excess Weight in Pregnant Women in the First Trimester of Pregnancy. Rev Bras Ginecol Obstet. 2019. 41:4–10. doi:10.1055/s-0038-1676096.30541181 | Study Design
162. | Elliott, SA, Pereira, LCR, McCargar, LJ, Prado, CM, Bell, RC. Trajectory and determinants of change in lean soft tissue over the postpartum period. Br J Nutr. 2019. 121:1137–1145. doi:10.1017/s0007114518002015.30178726 | Intervention/Exposure; Population
163. | Elvebakk, T, Mostad, IL, Morkved, S, Salvesen, KA, Stafne, SN. Dietary Intakes and Dietary Quality during Pregnancy in Women with and without Gestational Diabetes Mellitus-A Norwegian Longitudinal Study. Nutrients. 2018. 10. doi:10.3390/nu10111811. | Intervention/Exposure; Outcome
164. | Englund-Ogge, L, Brantsaeter, AL, Juodakis, J, Haugen, M, Meltzer, HM, Jacobsson, B, Sengpiel, V. Associations between maternal dietary patterns and infant birth weight, small and large for gestational age in the Norwegian Mother and Child Cohort Study. Eur J Clin Nutr. 2018. doi:10.1038/s41430-018-0356-y. | Outcome
165. | Eshriqui, I, Vilela, AA, Rebelo, F, Farias, DR, Castro, MB, Kac, G. Gestational dietary patterns are not associated with blood pressure changes during pregnancy and early postpartum in a Brazilian prospective cohort. Eur J Nutr. 2016. 55:21–32. doi:10.1007/s00394-014-0819-4.25526968 | Outcome
166. | Estimated dietary vitamin D intake during pregnancy. Proceedings of the nutrition society. 2017. Conference: Nutrition Society Irish Section Conference 2017: What Governs What We Eat? United Kingdom. 76:E62. doi:10.1017/S0029665117001355. | Abstract
167. | Facchinetti, F, Gambigliani Zoccoli, S, Petrella, E, Bertarini, V, Di Cerbo, L, Neri, I. 160: counseling lifestyle changes in overweight/obese pregnant women: a randomized controlled trial. American journal of obstetrics and gynecology. 2019. 220:S120–S121. doi:10.1016/j.ajog.2018.11.181. | Abstract
168. | Facchinetti, F, Vijay, V, Petrella, E, Gambigliani Zoccoli, S, Bertarini, V, Di Cerbo, L, Neri, I. 78: impact of glycemic-index(GI) reduction on birthweight in overweight/obese pregnant women enrolled in a lifestyle program. American journal of obstetrics and gynecology. 2019. 220:S62-. doi:10.1016/j.ajog.2018.11.086. | Abstract
169. | Fadakar, SK, Ghavi, A, Niknami, M, Kazemnejad, LE. Relationship between mothers’ gt<GT> nutritional status and weight gain during pregnancy with low birth weight. Journal of Guilan University of Medical Sciences. 2012. 21:27–35. | Not English
170. | Fadzil, F, Shamsuddin, K, Sharifa, EWP, Tamil, AM, Ahmad, S, Hayi, NSA, Samad, AA, Ismail, R, Shauki, NIA. Predictors of postpartum weight retention among urban Malaysian mothers: A prospective cohort study. Obesity Research & Clinical Practice. 2018. 12:493–499. doi:10.1016/j.orcp.2018.06.003.29960869 | Intervention/Exposure
171. | Fahey, CA, Chevrier, J, Crause, M, Obida, M, Bornman, R, Eskenazi, B. Seasonality of antenatal care attendance, maternal dietary intake, and fetal growth in the VHEMBE birth cohort, South Africa. PLoS ONE. 2019. 14. doi:10.1371/journal.pone.0222888. | Outcome; Country
172. | Fahey, MC, Wayne Talcott, G, Cox Bauer, CM, Bursac, Z, Gladney, L, Hare, ME, Harvey, J, Little, M, McCullough, D, Hryshko-Mullen, AS, Klesges, RC, Kocak, M, Waters, TM, Krukowski, RA. Moms fit 2 fight: Rationale, design, and analysis plan of a behavioral weight management intervention for pregnant and postpartum women in the U.S. military. Contemporary Clinical Trials. 2018. 74:46–54. doi:10.1016/j.cct.2018.09.012.30291998 | Intervention/Exposure; Outcome
173. | Fereidooni, B, Jenabi, E. The use of omega 3 on pregnancy outcomes: a single-center study. J Pak Med Assoc. 2014. 64:1363–5.25842578 | Intervention/Exposure; Outcome
174. | Ferland, S, O’Brien, HT. Maternal dietary intake and pregnancy outcome. J Reprod Med. 2003. 48:86–94.12621791 | Intervention/Exposure; Outcome
175. | Ferranti, EP, Hartman, TJ, Elliott, AJ, Mitchell, DC, Angal, J, Nickleach, D, Bellissimo, M, Breslow, R. Diet Quality of Pregnant American Indian Women in the Northern Plains. Prev Chronic Dis. 2019. 16:E53. doi:10.5888/pcd16.180536.31022368 | Outcome
176. | Ferrara, P, Sandullo, F, Di Ruscio, F, Franceschini, G, Peronti, B, Blasi, V, Bietolini, S, Ruggiero, A. The impact of lacto-ovo-/lacto-vegetarian and vegan diets during pregnancy on the birth anthropometric parameters of the newborn. J Matern Fetal Neonatal Med. 2019. :1–7. doi:10.1080/14767058.2019.1590330. | Outcome
177. | Fiese, BH, Musaad, S, Bost, KK, McBride, BA, Lee, SY, Teran-Garcia, M, Donovan, SM. The STRONG Kids 2 Birth Cohort Study: A Cell-to-Society Approach to Dietary Habits and Weight Trajectories across the First 5 Years of Life. Curr Dev Nutr. 2019. 3:nzz007. doi:10.1093/cdn/nzz007.30882062 | Intervention/Exposure; Outcome
178. | Florencio, TM, Bueno, NB, Clemente, AP, Albuquerque, FC, Britto, RP, Ferriolli, E, Sawaya, AL. Weight gain and reduced energy expenditure in low-income Brazilian women living in slums: a 4-year follow-up study. Br J Nutr. 2015. 114:462–71. doi:10.1017/s0007114515001816.26123236 | Intervention/Exposure; Population
179. | Flynn, A, Poston, L, Goff, L. The UK pregnancies better eating and activity trial (UPBEAT) intervention in women with obesity; nutritional responses according to ethnic and BMI sub-groups. BJOG: an international journal of obstetrics and gynaecology. Conference: 19th annual conference of the british maternal and fetal medicine society, BMFMS 2017. Netherlands. 2017. 124:98. doi:10.1111/1471-0528.14588. | Conference abstract
180. | Flynn, AC, Schneeberger, C, Seed, PT, Barr, S, Poston, L, Goff, LM. The Effects of the UK Pregnancies Better Eating and Activity Trial Intervention on Dietary Patterns in Obese Pregnant Women Participating in a Pilot Randomized Controlled Trial. Nutr Metab Insights. 2015. 8:79–86. doi:10.4137/nmi.S29529.27385914 | Outcome
181. | Flynn, AC, Seed, PT, Patel, N, Barr, S, Bell, R, Briley, AL, Godfrey, KM, Nelson, SM, Oteng-Ntim, E, Robinson, SM, Sanders, TA, Sattar, N, Wardle, J, Poston, L, Goff, LM. Dietary patterns in obese pregnant women; influence of a behavioral intervention of diet and physical activity in the UPBEAT randomized controlled trial. Int J Behav Nutr Phys Act. 2016. 13:124. doi:10.1186/s12966-016-0450-2.27894316 | Outcome
182. | Forbes, LE, Graham, JE, Berglund, C, Bell, RC. Dietary change during pregnancy and women’s reasons for change. Nutrients. 2018. 10. doi:10.3390/nu10081032. | Study Design; Outcome
183. | Fowler, JK, Evers, SE, Campbell, MK. Inadequate dietary intakes among pregnant women. Can J Diet Pract Res. 2012. 73:72–7. doi:10.3148/73.2.2012.72.22668840 | Study Design; Outcome
184. | Fowles, ER, Gabrielson, M. First trimester predictors of diet and birth outcomes in low-income pregnant women. J Community Health Nurs. 2005. 22:117–30. doi:10.1207/s15327655jchn2202_5.15877540 | Outcome
185. | Fowles, ER, Timmerman, GM, Bryant, M, Kim, S. Eating at fast-food restaurants and dietary quality in low-income pregnant women. West J Nurs Res. 2011. 33:630–51. doi:10.1177/0193945910389083.21131508 | Outcome
186. | Fowles, ER, Walker, LO. Correlates of dietary quality and weight retention in postpartum women. J Community Health Nurs. 2006. 23:183–97. doi:10.1207/s15327655jchn2303_5.16863403 | Population
187. | Fukuda, Y, Yamamoto, S, Nishida, K, Takaoka, Y, Kameda, M. A study on the effect of nutrient intake on the body mass index of mothers of children with food allergies. Asian Pac J Allergy Immunol. 2019. doi:10.12932/ap-260718-0377. | Population; Outcome
188. | Gallagher, D, Rosenn, B, Toro-Ramos, T, Paley, C, Gidwani, S, Horowitz, M, Crane, J, Lin, S, Thornton, JC, Pi-Sunyer, X, Toro-Ramos, T, Pi-Sunyer, X. Greater Neonatal Fat-Free Mass and Similar Fat Mass Following a Randomized Trial to Control Excess Gestational Weight Gain. Obesity (19307381). 2018. 26:578–587. doi:10.1002/oby.22079. | Intervention/Exposure; Outcome
189. | Garay, SM, Savory, KA, Sumption, L, Penketh, R, Janssen, AB, John, RM. The Grown in Wales Study: Examining dietary patterns, custom birthweight centiles and the risk of delivering a small-for-gestational age (SGA) infant. PLoS One. 2019. 14:e0213412. doi:10.1371/journal.pone.0213412.30861017 | Study Design
190. | Garg, A, Kashyap, S. Effect of counseling on nutritional status during pregnancy. Indian J Pediatr. 2006. 73:687–92.16936363 | Country
191. | Gazquez, A, Uhl, O, Ruiz-Palacios, M, Gill, C, Patel, N, Koletzko, B, Poston, L, Larque, E. Placental lipid droplet composition: Effect of a lifestyle intervention (UPBEAT) in obese pregnant women. Biochim Biophys Acta Mol Cell Biol Lipids. 2018. 1863:998–1005. doi:10.1016/j.bbalip.2018.04.020.29702246 | Intervention/Exposure
192. | Gennaro, S, Fehder, W. Health behaviors in postpartum women. Family & Community Health. 2000. 22:16–26. | Intervention/Exposure; Comparator
193. | George, GC, Hanss-Nuss, H, Milani, TJ, Freeland-Graves, JH. Food choices of low-income women during pregnancy and postpartum. J Am Diet Assoc. 2005. 105:899–907. doi:10.1016/j.jada.2005.03.028.15942539 | Outcome
194. | George, GC, Milani, TJ, Hanss-Nuss, H, Freeland-Graves, JH. Compliance with dietary guidelines and relationship to psychosocial factors in low-income women in late postpartum. J Am Diet Assoc. 2005. 105:916–26. doi:10.1016/j.jada.2005.03.009.15942541 | Outcome
195. | Geraghty, AA, O’Brien, EC, Alberdi, G, Horan, MK, Donnelly, J, Larkin, E, Segurado, R, Mehegan, J, Molloy, EJ, McAuliffe, FM. Maternal protein intake during pregnancy is associated with child growth up to 5 years of age, but not through insulin-like growth factor-1: findings from the ROLO study. Br J Nutr. 2018. 120:1252–1261. doi:10.1017/s0007114518002611.30484757 | Intervention/Exposure; Comparator
196. | Gesteiro, E, Bastida, S, Sanchez Muniz, FJ. Effects of maternal glucose tolerance, pregnancy diet quality and neonatal insulinemia upon insulin resistance/sensitivity biomarkers in normoweight neonates. Nutr Hosp. 2011. 26:1447–55. doi:10.1590/s0212-16112011000600036.22411395 | Outcome
197. | Ghani, RA, Shyam, S, Arshad, F, Wahab, NA, Chinna, K, Safii, NS, Nisak, MY, Kamaruddin, NA. The influence of fasting insulin level in post-gestational diabetes mellitus women receiving low-glycaemic-index diets. Nutr Diabetes. 2014. 4:e107. doi:10.1038/nutd.2014.5.24535618 | Population; Outcome
198. | Gicevic, S, Gaskins, AJ, Fung, TT, Rosner, B, Tobias, DK, Isanaka, S, Willett, WC. Evaluating pre-pregnancy dietary diversity vs. dietary quality scores as predictors of gestational diabetes and hypertensive disorders of pregnancy. PLoS ONE. 2018. 13. doi:10.1371/journal.pone.0195103. | Outcome
199. | Giesta, JM, Zoche, E, Correa, RDS, Bosa, VL. Associated factors with early introduction of ultra-processed foods in feeding of children under two years old. Cien Saude Colet. 2019. 24:2387–2397. doi:10.1590/1413-81232018247.24162017.31340258 | Study Design
200. | Gignac, F, Romaguera, D, Fernandez-Barres, S, Phillipat, C, Garcia Esteban, R, Lopez-Vicente, M, Vioque, J, Fernandez-Somoano, A, Tardon, A, Iniguez, C, Lopez-Espinosa, MJ, Garcia de la Hera, M, Amiano, P, Ibarluzea, J, Guxens, M, Sunyer, J, Julvez, J. Maternal nut intake in pregnancy and child neuropsychological development up to 8 years old: a population-based cohort study in Spain. Eur J Epidemiol. 2019. 34:661–673. doi:10.1007/s10654-019-00521-6.31062119 | Intervention/Exposure
201. | Gingras, V, Paradis, AM, Tchernof, A, Weisnagel, SJ, Robitaille, J. Relationship between the adoption of preventive practices and the metabolic profile of women with prior gestational diabetes mellitus. Appl Physiol Nutr Metab. 2012. 37:1232–8. doi:10.1139/h2012-114.23176529 | Population; Outcome
202. | Giroux, I, Inglis, SD, Lander, S, Gerrie, S, Mottola, MF. Dietary intake, weight gain, and birth outcomes of physically active pregnant women: a pilot study. Appl Physiol Nutr Metab. 2006. 31:483–9. doi:10.1139/h06-024.17111001 | Intervention/Exposure
203. | Goletzke, J, Buyken, AE, Louie, JC, Moses, RG, Brand-Miller, JC. Dietary micronutrient intake during pregnancy is a function of carbohydrate quality. Am J Clin Nutr. 2015. 102:626–32. doi:10.3945/ajcn.114.104836.26178724 | Intervention/Exposure; Outcome
204. | Gonzalez, HF, Malpeli, A, Mansur, JL, De Santiago, S, Etchegoyen, GS. Changes in body composition in lactating adolescent mothers. Arch Latinoam Nutr. 2005. 55:252–6.16454051 | Intervention/Exposure
205. | Gonzalez-Clemente, JM, Carro, O, Gallach, I, Vioque, J, Humanes, A, Sauret, C, Abella, M, Gimenez-Perez, G, Mauricio, D. Increased cholesterol intake in women with gestational diabetes mellitus. Diabetes Metab. 2007. 33:25–9. doi:10.1016/j.diabet.2006.07.002.17258930 | Intervention/Exposure; Outcome
206. | Gonzalez-Nahm, S, Mendez, M, Robinson, W, Murphy, SK, Hoyo, C, Hogan, V, Rowley, D. Low maternal adherence to a Mediterranean diet is associated with increase in methylation at the MEG3-IG differentially methylated region in female infants. Environ Epigenet. 2017. 3:dvx007. doi:10.1093/eep/dvx007.29492309 | Population
207. | Goodarzi-Khoigani, M, Mahmoodabad, SSM, Moghadam, MHB, Nadjarzadeh, A, Mardanian, F, Fallahzadeh, H, Dadkhah-Tirani, A. Prevention of insulin resistance by dietary intervention among pregnant mothers: A randomized controlled trial. International Journal of Preventive Medicine. 2017. 8. doi:10.4103/ijpvm.IJPVM_405_16. | Intervention/Exposure
208. | Goodman, M, Thomson, J, Landry, A. Nutrition Environment Scores of Local Food Retailers and Proximity to Study Participants’ Residence in Rural South (P04-157-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz051.P04-157-19. | Abstract
209. | Grandy, M, Snowden, JM, Boone-Heinonen, J, Purnell, JQ, Thornburg, KL, Marshall, NE. Poorer maternal diet quality and increased birth weight(). J Matern Fetal Neonatal Med. 2018. 31:1613–1619. doi:10.1080/14767058.2017.1322949.28514885 | Study Design
210. | Gray-Donald, K, Robinson, E, Collier, A, David, K, Renaud, L, Rodrigues, S. Intervening to reduce weight gain in pregnancy and gestational diabetes mellitus in Cree communities: an evaluation. Cmaj. 2000. 163:1247–51.11107459 | Intervention/Exposure
211. | Gresham, E, Collins, CE, Mishra, GD, Byles, JE, Hure, AJ. Diet quality before or during pregnancy and the relationship with pregnancy and birth outcomes: the Australian Longitudinal Study on Women’s Health. Public health nutrition. 2016. 19:2975–2983.27238757 | Outcome
212. | Guelinckx, I, Devlieger, R, Mullie, P, Vansant, G. Effect of lifestyle intervention on dietary habits, physical activity, and gestational weight gain in obese pregnant women: a randomized controlled trial. Am J Clin Nutr. 2010. 91:373–80. doi:10.3945/ajcn.2009.28166.19955397 | Intervention/Exposure; Outcome
213. | Guilloty, NI, Soto, R, Anzalota, L, Rosario, Z, Cordero, JF, Palacios, C. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J. 2015. 19:2453–61. doi:10.1007/s10995-015-1764-4.26100133 | Intervention/Exposure
214. | Gunther, J, Hoffmann, J, Kunath, J, Spies, M, Meyer, D, Stecher, L, Rosenfeld, E, Kick, L, Rauh, K, Hauner, H. Effects of a Lifestyle Intervention in Routine Care on Prenatal Dietary Behavior-Findings from the Cluster-Randomized GeliS Trial. J Clin Med. 2019. 8. doi:10.3390/jcm8070960. | Comparator
215. | Gunther, J, Hoffmann, J, Rauh, K, Kunath, J, Rosenfeld, E, Kick, L, Stecher, L, Hauner, H. The effect of lifestyle counselling on dietary behavior of pregnant women - Secondary results of the randomised controlled GeliS trial. Obesity facts. 2019. 12:171-. doi:10.1159/000489691. | Abstract
216. | Gunther, J, Hoffmann, J, Spies, M, Meyer, D, Kunath, J, Stecher, L, Rosenfeld, E, Kick, L, Rauh, K, Hauner, H. Associations between the Prenatal Diet and Neonatal Outcomes-A Secondary Analysis of the Cluster-Randomised GeliS Trial. Nutrients. 2019. 11. doi:10.3390/nu11081889. | Outcome
217. | Gur, EB, Turan, GA, Ince, O, Karadeniz, M, Tatar, S, Kasap, E, Sahin, N, Guclu, S. Effect of Ramadan fasting on metabolic markers, dietary intake and abdominal fat distribution in pregnancy. Hippokratia. 2015. 19:298–303.27688692 | Intervention/Exposure
218. | Guzel, AI, Cinar, M, Erkilinc, S, Aksoy, RT, Yumusak, OH, Celik, F, Celik, Y. Association between adverse perinatal outcomes and amino acid levels measured with nutrient questionnaire in adolescent pregnancies. J Chin Med Assoc. 2016. 79:335–9. doi:10.1016/j.jcma.2015.12.008.27071985 | Intervention/Exposure; Outcome
219. | Haakstad, LAH, Voldner, N, Bø, K. Pregnancy and advanced maternal age—The associations between regular exercise and maternal and newborn health variables. Acta Obstetricia et Gynecologica Scandinavica. 2019. doi:10.1111/aogs.13738. | Intervention/Exposure
220. | Hagberg, LA, Brekke, HK, Bertz, F, Winkvist, A. Cost-utility analysis of a randomized controlled weight loss trial among lactating overweight/obese women. BMC Public Health. 2014. 14:38. doi:10.1186/1471-2458-14-38.24428802 | Outcome
221. | Haire-Joshu, DL, Schwarz, CD, Peskoe, SB, Budd, EL, Brownson, RC, Joshu, CE. A group randomized controlled trial integrating obesity prevention and control for postpartum adolescents in a home visiting program. Int J Behav Nutr Phys Act. 2015. 12:88. doi:10.1186/s12966-015-0247-8.26112041 | Intervention/Exposure; Population
222. | Hajianfar, H, Esmaillzadeh, A, Feizi, A, Shahshahan, Z, Azadbakht, L. Major Maternal Dietary Patterns during Early Pregnancy and Their Association with Neonatal Anthropometric Measurement. Biomed Res Int. 2018. 2018:4692193. doi:10.1155/2018/4692193.29955602 | Outcome
223. | Hajianfar, H, Esmaillzadeh, A, Feizi, A, Shahshahan, Z, Azadbakht, L. The association between major dietary patterns and pregnancy-related complications. Archives of Iranian Medicine. 2018. 21:443–451.30415552 | Outcome
224. | Halldorsson, TI, Meltzer, HM, Thorsdottir, I, Knudsen, V, Olsen, SF. Is high consumption of fatty fish during pregnancy a risk factor for fetal growth retardation? A study of 44,824 Danish pregnant women. Am J Epidemiol. 2007. 166:687–96. doi:10.1093/aje/kwm133.17631607 | Outcome
225. | Halldorsson, TI, Thorsdottir, I, Meltzer, HM, Strom, M, Olsen, SF. Dioxin-like activity in plasma among Danish pregnant women: dietary predictors, birth weight and infant development. Environ Res. 2009. 109:22–8. doi:10.1016/j.envres.2008.08.011.18945425 | Outcome
226. | Hamad, R, Collin, DF, Baer, RJ, Jelliffe-Pawlowski, LL. Association of Revised WIC Food Package With Perinatal and Birth Outcomes: A Quasi-Experimental Study. JAMA Pediatrics. 2019. 173:845–852. doi:10.1001/jamapediatrics.2019.1706.31260072 | Intervention/Exposure
227. | Han, SY, Brewis, AA. Influence of weight concerns on breastfeeding: Evidence from the Norwegian mother and child cohort study. Am J Hum Biol. 2018. 30:23–28. doi:10.1002/ajhb.23086. | Intervention/Exposure; Outcome
228. | Harley, K, Eskenazi, B, Block, G. The association of time in the US and diet during pregnancy in low-income women of Mexican descent. Paediatr Perinat Epidemiol. 2005. 19:125–34. doi:10.1111/j.1365-3016.2005.00640.x.15787887 | Comparator; Association btw DP and GWG not analyzed
229. | Harmon, KA, Gerard, L, Jensen, DR, Kealey, EH, Hernandez, TL, Reece, MS, Barbour, LA, Bessesen, DH. Continuous glucose profiles in obese and normal-weight pregnant women on a controlled diet: metabolic determinants of fetal growth. Diabetes Care. 2011. 34:2198–204. doi:10.2337/dc11-0723.21775754 | Intervention/Exposure
230. | Harreiter, J, Simmons, D, Desoye, G, Corcoy, R, Adelantado, JM, Devlieger, R, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Dunne, F, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Mantaj, U, Hill, D, Jelsma, JGM, Snoek, FJ, Leutner, M, Lackinger, C, Worda, C, Bancher-Todesca, D, Scharnagl, H, van Poppel, MNM, Kautzky-Willer, A. Nutritional Lifestyle Intervention in Obese Pregnant Women, Including Lower Carbohydrate Intake, Is Associated With Increased Maternal Free Fatty Acids, 3-beta-Hydroxybutyrate, and Fasting Glucose Concentrations: A Secondary Factorial Analysis of the European Multicenter, Randomized Controlled DALI Lifestyle Intervention Trial. Diabetes Care. 2019. doi:10.2337/dc19-0418. | Intervention/Exposure
231. | Haruna, M, Shiraishi, M, Matsuzaki, M, Yatsuki, Y, Yeo, S. Effect of tailored dietary guidance for pregnant women on nutritional status: A double-cohort study. Matern Child Nutr. 2017. 13. doi:10.1111/mcn.12391. | Intervention/Exposure
232. | Hassiotou, F, Geddes, DT. Programming of appetite control during breastfeeding as a preventative strategy against the obesity epidemic. J Hum Lact. 2014. 30:136–42. doi:10.1177/0890334414526950.24646683 | Outcome
233. | Hauner, H, Much, D, Vollhardt, C, Brunner, S, Schmid, D, Sedlmeier, EM, Heimberg, E, Schuster, T, Zimmermann, A, Schneider, KT, Bader, BL, Amann-Gassner, U. Effect of reducing the n-6:n-3 long-chain PUFA ratio during pregnancy and lactation on infant adipose tissue growth within the first year of life: an open-label randomized controlled trial. Am J Clin Nutr. 2012. 95:383–94. doi:10.3945/ajcn.111.022590.22205307 | Intervention/Exposure
234. | Hauner, H, Vollhardt, C, Schneider, KT, Zimmermann, A, Schuster, T, Amann-Gassner, U. The impact of nutritional fatty acids during pregnancy and lactation on early human adipose tissue development. Rationale and design of the INFAT study. Ann Nutr Metab. 2009. 54:97–103. doi:10.1159/000209267.19295192 | Outcome; No Results
235. | Hawkins, M, Hosker, M, Marcus, BH, Rosal, MC, Braun, B, Stanek, EJ, 3rd, Markenson, G, Chasan-Taber, L. A pregnancy lifestyle intervention to prevent gestational diabetes risk factors in overweight Hispanic women: a feasibility randomized controlled trial. Diabet Med. 2015. 32:108–15. doi:10.1111/dme.12601.25306925 | Intervention/Exposure
236. | Heery, E, Kelleher, CC, Wall, PG, McAuliffe, FM. Prediction of gestational weight gain - a biopsychosocial model. Public Health Nutr. 2015. 18:1488–98. doi:10.1017/s1368980014001815.25171690 | Intervention/Exposure
237. | Heery, E, Wall, PG, Kelleher, CC, McAuliffe, FM. Effects of dietary restraint and weight gain attitudes on gestational weight gain. Appetite. 2016. 107:501–510. doi:10.1016/j.appet.2016.08.103.27545671 | Intervention/Exposure
238. | Hernandez, TL, Van Pelt, RE, Anderson, MA, Reece, MS, Reynolds, RM, de la Houssaye, BA, Heerwagen, M, Donahoo, WT, Daniels, LJ, Chartier-Logan, C, Janssen, RC, Friedman, JE, Barbour, LA. Women With Gestational Diabetes Mellitus Randomized to a Higher-Complex Carbohydrate/Low-Fat Diet Manifest Lower Adipose Tissue Insulin Resistance, Inflammation, Glucose, and Free Fatty Acids: A Pilot Study. Diabetes Care. 2016. 39:39–42. doi:10.2337/dc15-0515.26223240 | Health Status
239. | Herrick, K, Phillips, DI, Haselden, S, Shiell, AW, Campbell-Brown, M, Godfrey, KM. Maternal consumption of a high-meat, low-carbohydrate diet in late pregnancy: relation to adult cortisol concentrations in the offspring. J Clin Endocrinol Metab. 2003. 88:3554–60. doi:10.1210/jc.2003-030287.12915635 | Intervention/Exposure; Outcome
240. | Hill, AJ, Cairnduff, V, McCance, DR. Nutritional and clinical associations of food cravings in pregnancy. J Hum Nutr Diet. 2016. 29:281–9. doi:10.1111/jhn.12333.26400798 | Intervention/Exposure; Outcome
241. | Hill, AJ, McCance, DR. Anthropometric and nutritional associations of food cravings in pregnancy. Pregnancy Hypertens. 2014. 4:235. doi:10.1016/j.preghy.2014.03.018. | Study Design
242. | Hinkle, S, Li, M, Grewal, J, Yisahak, S, Grantz, K, Ajjarapu, A, Zhang, C. Beverage Intake in U.S. Women Across Pregnancy and Gestational Diabetes Risk (P11-010-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.P11-010-19. | Abstract
243. | Hinkle, SN, Rawal, S, Bjerregaard, AA, Halldorsson, TI, Li, M, Ley, SH, Wu, J, Zhu, Y, Chen, L, Liu, A, Grunnet, LG, Rahman, ML, Kampmann, FB, Mills, JL, Olsen, SF, Zhang, C. A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019. doi:10.1093/ajcn/nqz094. | Intervention/Exposure
244. | Hinton, PS, Olson, CM. Postpartum exercise and food intake: the importance of behavior-specific self-efficacy. J Am Diet Assoc. 2001. 101:1430–7. doi:10.1016/s0002-8223(01)00345-5.11762738 | Intervention/Exposure
245. | Horan, M, Donnelly, J, McGowan, C, Gibney, E, McAuliffe, F. The association between maternal nutrition and lifestyle during pregnancy and 2-year-old offspring adiposity: analysis from the ROLO study. Journal of Public Health (09431853). 2016. 24:427–436. doi:10.1007/s10389-016-0740-9. | Intervention/Exposure; Population
246. | Horan, MK, McGowan, CA, Gibney, ER, Donnelly, JM, McAuliffe, FM. Maternal low glycaemic index diet, fat intake and postprandial glucose influences neonatal adiposity--secondary analysis from the ROLO study. Nutr J. 2014. 13:78. doi:10.1186/1475-2891-13-78.25084967 | Intervention/Exposure; Comparator
247. | Horan, MK, McGowan, CA, Gibney, ER, Donnelly, JM, McAuliffe, FM. Maternal diet and weight at 3 months postpartum following a pregnancy intervention with a low glycaemic index diet: results from the ROLO randomised control trial. Nutrients. 2014. 6:2946–55. doi:10.3390/nu6072946.25057103 | Intervention/Exposure
248. | Hronek, M, Doubkova, P, Hrnciarikova, D, Zadak, Z. Dietary intake of energy and nutrients in relation to resting energy expenditure and anthropometric parameters of Czech pregnant women. Eur J Nutr. 2013. 52:117–25. doi:10.1007/s00394-011-0293-1.22198818 | Intervention/Exposure; Comparator
249. | Hronek, M, Doubkova, P, Tosner, J, Zadak, Z. Prediction of nutritive intake energy and substrates of Czech pregnant women. Nutrition. 2011. 27:1118–24. doi:10.1016/j.nut.2010.12.008.21514115 | Intervention/Exposure
250. | Hsu, WY, Wu, CH, Hsieh, CT, Lo, HC, Lin, JS, Kao, MD. Low body weight gain, low white blood cell count and high serum ferritin as markers of poor nutrition and increased risk for preterm delivery. Asia Pac J Clin Nutr. 2013. 22:90–9. doi:10.6133/apjcn.2013.22.1.05.23353616 | Intervention/Exposure
251. | Hu, G, Tian, H, Zhang, F, Liu, H, Zhang, C, Zhang, S, Wang, L, Liu, G, Yu, Z, Yang, X, Qi, L, Zhang, C, Wang, H, Li, M, Leng, J, Li, Y, Dong, L, Tuomilehto, J. Tianjin Gestational Diabetes Mellitus Prevention Program: study design, methods, and 1-year interim report on the feasibility of lifestyle intervention program. Diabetes Res Clin Pract. 2012. 98:508–17. doi:10.1016/j.diabres.2012.09.015.23010556 | Intervention/Exposure
252. | Huang, RC, Silva, D, Beilin, L, Neppe, C, Mackie, KE, Roffey, E, Gibson, LY, D’Vaz, N, Christian, H, Reid, CM, Prescott, SL. Feasibility of conducting an early pregnancy diet and lifestyle e-health intervention: the Pregnancy Lifestyle Activity Nutrition (PLAN) project. J Dev Orig Health Dis. 2019. :1–13. doi:10.1017/s2040174419000400.30919803 | Comparator; Exercise co-intervention
253. | Huang, Z, Li, N, Hu, YM. Dietary patterns and their effects on postpartum weight retention of lactating women in south central China. Nutrition. 2019. 67–68:110555. doi:10.1016/j.nut.2019.110555. | Study Design
254. | Huddy, RL, Torres, SJ, Milte, CM, McNaughton, SA, Teychenne, M, Campbell, KJ. Higher Adherence to the Australian Dietary Guidelines Is Associated with Better Mental Health Status among Australian Adult First-Time Mothers. J Acad Nutr Diet. 2016. 116:1406–1412. doi:10.1016/j.jand.2016.01.010.26947337 | Study Design; Outcome
255. | Huh, SY, Rifas-Shiman, SL, Kleinman, KP, Rich-Edwards, JW, Lipshultz, SE, Gillman, MW. Maternal protein intake is not associated with infant blood pressure. Int J Epidemiol. 2005. 34:378–84. doi:10.1093/ije/dyh373.15576466 | Intervention/Exposure; Outcome
256. | Hui, A, Back, L, Ludwig, S, Gardiner, P, Sevenhuysen, G, Dean, H, Sellers, E, McGavock, J, Morris, M, Bruce, S, Murray, R, Shen, GX. Lifestyle intervention on diet and exercise reduced excessive gestational weight gain in pregnant women under a randomised controlled trial. Bjog. 2012. 119:70–7. doi:10.1111/j.1471-0528.2011.03184.x.22017967 | Intervention/Exposure; Comparator
257. | Hui, A, Back, L, Ludwig, S, Gardiner, P, Sevenhuysen, G, Dean, H, Sellers, E, McGavock, J, Morris, M, Bruce, S, , . Exercise and dietary intervention increases physical activity, promotes healthy diet and reduces excessive gestational weight gain in pregnant women: a randomized controlled trial in Urban community. Diabetes. 2011. 60:A351-. doi:10.2337/db11-868-1281. | Abstract
258. | Hui, A, Back, L, Ludwig, S, Gardiner, P, Sevenhuysen, G, Dean, H, Sellers, E, McGavock, J, Morris, M, Bruce, S, , . Lifestyle intervention on diet and exercise reduced excessive gestational weight gain in pregnant women under a randomized controlled trial. Obstetrical & gynecological survey. 2012. 67:263–264. doi:10.1097/OGX.0b013e3182561861. | Editorial comment
259. | Hui, AL, Back, L, Ludwig, S, Gardiner, P, Sevenhuysen, G, Dean, HJ, Sellers, E, McGavock, J, Morris, M, Jiang, D, Shen, GX. Effects of lifestyle intervention on dietary intake, physical activity level, and gestational weight gain in pregnant women with different pre-pregnancy Body Mass Index in a randomized control trial. BMC Pregnancy Childbirth. 2014. 14:331. doi:10.1186/1471-2393-14-331.25248797 | Intervention/Exposure; Exercise co-intervention
260. | Hui, AL, Back, L, Reid, A, Sevenhuysen, G, Ludwig, S, Dean, H, Sellers, E, McGavock, J, Morris, M, Shen, G. Effects of physical activity and dietary intakes on weight gain of pregnant women with normal and above normal prepregnancy weight. Canadian journal of diabetes. 2012. 36:S8-. | Abstract
261. | Huseinovic, E, Bertz, F, Brekke, HK, Winkvist, A. Two-year follow-up of a postpartum weight loss intervention: Results from a randomized controlled trial. Maternal and Child Nutrition. 2018. 14. doi:10.1111/mcn.12539. | Intervention/Exposure; Population
262. | Huseinovic, E, Bertz, F, Leu Agelii, M, Hellebo Johansson, E, Winkvist, A, Brekke, HK. Effectiveness of a weight loss intervention in postpartum women: results from a randomized controlled trial in primary health care. Am J Clin Nutr. 2016. 104:362–70. doi:10.3945/ajcn.116.135673.27413127 | Intervention/Exposure
263. | Huseinovic, E, Ohlin, M, Winkvist, A, Bertz, F, Sonesson, U, Brekke, HK. Does diet intervention in line with nutrition recommendations affect dietary carbon footprint? Results from a weight loss trial among lactating women. Eur J Clin Nutr. 2017. 71:1241–1245. doi:10.1038/ejcn.2017.63.28488687 | Intervention/Exposure; Population
264. | Huseinovic, E, Winkvist, A, Bertz, F, Berteus Forslund, H, Brekke, HK. Eating frequency, energy intake and body weight during a successful weight loss trial in overweight and obese postpartum women. Eur J Clin Nutr. 2014. 68:71–6. doi:10.1038/ejcn.2013.200.24193227 | Intervention/Exposure
265. | Huseinovic, E, Winkvist, A, Bertz, F, Brekke, HK. Changes in food choice during a successful weight loss trial in overweight and obese postpartum women. Obesity (Silver Spring). 2014. 22:2517–23. doi:10.1002/oby.20895.25234605 | Outcome
266. | Huseinovic, E, Winkvist, A, Bertz, F, Hellebo Johansson, E, Brekke, HK. Dietary assessment among women with overweight and obesity in early postpartum. J Hum Nutr Diet. 2016. 29:411–7. doi:10.1111/jhn.12350.26696534 | Study Design; Outcome
267. | Hutchison, SM, Masse, LC, Glier, MB, Brain, U, Devlin, AM, Oberlander, TF. Impact of Prenatal Selective Serotonin Reuptake Inhibitor Antidepressant Exposure and Maternal Mood on Physical Activity, Dietary Intake, and Markers of Adiposity at Age 6 Years. J Dev Behav Pediatr. 2019. 40:266–274. doi:10.1097/dbp.0000000000000658.30950906 | Intervention/Exposure
268. | Huvinen, E, Koivusalo, SB, Meinila, J, Valkama, A, Tiitinen, A, Rono, K, Stach-Lempinen, B, Eriksson, JG. Effects of a Lifestyle Intervention During Pregnancy and First Postpartum Year: Findings From the RADIEL Study. J Clin Endocrinol Metab. 2018. 103:1669–1677. doi:10.1210/jc.2017-02477.29409025 | Outcome; Comparator
269. | Ilmonen, J, Isolauri, E, Poussa, T, Laitinen, K. Impact of dietary counselling and probiotic intervention on maternal anthropometric measurements during and after pregnancy: a randomized placebo-controlled trial. Clin Nutr. 2011. 30:156–64. doi:10.1016/j.clnu.2010.09.009.20970896 | Population; Outcome
270. | Jaakkola, J, Hakala, P, Isolauri, E, Poussa, T, Laitinen, K. Eating behavior influences diet, weight, and central obesity in women after pregnancy. Nutrition. 2013. 29:1209–13. doi:10.1016/j.nut.2013.03.008.23800568 | Intervention/Exposure; Outcome
271. | Jaakkola, J, Isolauri, E, Poussa, T, Laitinen, K. Benefits of repeated individual dietary counselling in long-term weight control in women after delivery. Matern Child Nutr. 2015. 11:1041–8. doi:10.1111/mcn.12115.24521459 | Intervention/Exposure; Population
272. | Jackson, RA, Stotland, NE, Caughey, AB, Gerbert, B. Improving diet and exercise in pregnancy with Video Doctor counseling: a randomized trial. Patient Educ Couns. 2011. 83:203–9. doi:10.1016/j.pec.2010.05.019.21459255 | Intervention/Exposure; Comparator
273. | Janmohamed, R, Montgomery-Fajic, E, Sia, W, Germaine, D, Wilkie, J, Khurana, R, Nerenberg, KA. Cardiovascular risk reduction and weight management at a hospital-based postpartum preeclampsia clinic. J Obstet Gynaecol Can. 2015. 37:330–337. doi:10.1016/s1701-2163(15)30283-8.26001686 | Intervention/Exposure
274. | Jansson, N, Nilsfelt, A, Gellerstedt, M, Wennergren, M, Rossander-Hulthen, L, Powell, TL, Jansson, T. Maternal hormones linking maternal body mass index and dietary intake to birth weight. Am J Clin Nutr. 2008. 87:1743–9. doi:10.1093/ajcn/87.6.1743.18541564 | Outcome; Comparator
275. | Jardí, C, Aparicio, E, Bedmar, C, Aranda, N, Abajo, S, March, G, Basora, J, Arija, V. Food consumption during pregnancy and post-partum. ECLIPSES study. Nutrients. 2019. 11. doi:10.3390/nu11102447. | Outcome
276. | Jaruratanasirikul, S, Sangsupawanich, P, Koranantakul, O, Chanvitan, P, Sriplung, H, Patanasin, T. Influence of maternal nutrient intake and weight gain on neonatal birth weight: a prospective cohort study in southern Thailand. J Matern Fetal Neonatal Med. 2009. 22:1045–50. doi:10.3109/14767050903019668.19900042 | Intervention/Exposure; Outcome
277. | Jedrychowski, W, Perera, FP, Tang, D, Stigter, L, Mroz, E, Flak, E, Spengler, J, Budzyn-Mrozek, D, Kaim, I, Jacek, R. Impact of barbecued meat consumed in pregnancy on birth outcomes accounting for personal prenatal exposure to airborne polycyclic aromatic hydrocarbons: Birth cohort study in Poland. Nutrition. 2012. 28:372–7. doi:10.1016/j.nut.2011.07.020.22079395 | Intervention/Exposure; Outcome
278. | Jiang, F, Li, Y, Xu, P, Li, J, Chen, X, Yu, H, Gao, B, Xu, B, Li, X, Chen, W. The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. 2019. doi:10.1111/jhn.12654. | Outcome
279. | Jing, W, Huang, Y, Liu, X, Luo, B, Yang, Y, Liao, S. The effect of a personalized intervention on weight gain and physical activity among pregnant women in China. Int J Gynaecol Obstet. 2015. 129:138–41. doi:10.1016/j.ijgo.2014.11.014.25697965 | Comparator; Exercise co-intervention
280. | Juhl, M, Madsen, M, Andersen, AMN, Andersen, PK, Olsen, J. Distribution and predictors of exercise habits among pregnant women in the Danish National Birth Cohort. Scandinavian Journal of Medicine & Science in Sports. 2012. 22:128–138. doi:10.1111/j.1600-0838.2010.01125.x.20500556 | Outcome
281. | Jung, YM, Choi, MJ. Nutrient Intake according to Weight Gain during Pregnancy, Job Status, and Household Income. Clin Nutr Res. 2017. 6:27–37. doi:10.7762/cnr.2017.6.1.27.28168179 | Study Design; Intervention/Exposure
282. | Kac, G, Benicio, MH, Velasquez-Melendez, G, Valente, JG, Struchiner, CJ. Breastfeeding and postpartum weight retention in a cohort of Brazilian women. Am J Clin Nutr. 2004. 79:487–93. doi:10.1093/ajcn/79.3.487.14985226 | Intervention/Exposure
283. | Karamanos, B, Thanopoulou, A, Anastasiou, E, Assaad-Khalil, S, Albache, N, Bachaoui, M, Slama, CB, El Ghomari, H, Jotic, A, Lalic, N, Lapolla, A, Saab, C, Marre, M, Vassallo, J, Savona-Ventura, C. Relation of the Mediterranean diet with the incidence of gestational diabetes. Eur J Clin Nutr. 2014. 68:8–13. doi:10.1038/ejcn.2013.177.24084515 | Comparator; Country
284. | Karayiannis, D, Kontogianni, MD, Mendorou, C, Mastrominas, M, Yiannakouris, N. Adherence to the Mediterranean diet and IVF success rate among non-obese women attempting fertility. Hum Reprod. 2018. 33:494–502. doi:10.1093/humrep/dey003.29390148 | Population; Outcome
285. | Kay, MC, Wasser, H, Adair, LS, Thompson, AL, Siega-Riz, AM, Suchindran, CM, Bentley, ME. Consumption of key food groups during the postpartum period in low-income, non-Hispanic black mothers. Appetite. 2017. 117:161–167. doi:10.1016/j.appet.2017.06.023.28651972 | Intervention/Exposure; Outcome
286. | Keller, C, Todd, M, Ainsworth, B, Records, K, Vega-Lopez, S, Permana, P, Coonrod, D, Williams, AN. Overweight, Obesity, and Neighborhood Characteristics among Postpartum Latinas. Journal of Obesity. 2013. 2013:1–8. doi:10.1155/2013/916468. | Intervention/Exposure; Outcome
287. | Kennedy, RAK, Turner, MJ. Development of a novel Periconceptual Nutrition Score (PENS) to examine the relationship between maternal dietary quality and fetal growth. Early Human Development. 2019. 132:6–12. doi:10.1016/j.earlhumdev.2019.03.004.30908989 | Outcome
288. | Khoury, J, Henriksen, T, Christophersen, B, Tonstad, S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. American journal of obstetrics and gynecology. 2005. 193:1292–1301. doi:10.1016/j.ajog.2005.05.016.16202717 | Intervention/Exposure
289. | Kim, JH, Lee, SJ, Kim, SY, Choi, G, Lee, JJ, Kim, HJ, Kim, S, Park, J, Moon, HB, Choi, K, Kim, S, Choi, SR. Association of food consumption during pregnancy with mercury and lead levels in cord blood. Sci Total Environ. 2016. 563–564:118–24. doi:10.1016/j.scitotenv.2016.04.082. | Intervention/Exposure; Outcome
290. | Kim, MJ, Kim, TH, Park, Y, Lee, HH, Kim, JM, Lim, H, Hwang, SY. A study of the dietary intakes by the pre-pregnancy body mass index in pregnant women. Clin Exp Obstet Gynecol. 2017. 44:27–29.29714861 | Outcome; Comparator
291. | Kim, O, Ahn, Y, Lee, HY, Jang, HJ, Kim, S, Lee, JE, Jung, H, Cho, E, Lim, JY, Kim, MJ, Willett, WC, Chavarro, JE, Park, HY. The Korea Nurses’ Health Study: A Prospective Cohort Study. J Womens Health (Larchmt). 2017. 26:892–899. doi:10.1089/jwh.2016.6048.28771383 | Intervention/Exposure; Population
292. | Kim, SH, Kim, MY, Yang, JH, Park, SY, Yim, CH, Han, KO, Yoon, HK, Park, S. Nutritional risk factors of early development of postpartum prediabetes and diabetes in women with gestational diabetes mellitus. Nutrition. 2011. 27:782–8. doi:10.1016/j.nut.2010.08.019.21106349 | Intervention/Exposure
293. | Kinnunen, T, Puhkala, J, Raitanen, J, Ahonen, S, Aittasalo, M, Virtanen, SM, Luoto, R. Effects of dietary counselling on food habits and dietary intake of Finnish pregnant women at increased risk for gestational diabetes - a secondary analysis of a cluster-randomized controlled trial. Maternal & Child Nutrition. 2014. 10:184–197. doi:10.1111/j.1740-8709.2012.00426.x.22735030 | Outcome
294. | Kinnunen, TI, Pasanen, M, Aittasalo, M, Fogelholm, M, Weiderpass, E, Luoto, R. Reducing postpartum weight retention--a pilot trial in primary health care. Nutr J. 2007. 6:21. doi:10.1186/1475-2891-6-21.17825113 | Intervention/Exposure
295. | Kiyak Caglayan, E, Engin-Ustun, Y, Sari, N, Gocmen, AY, Polat, MF. The effects of prolonged fasting on the levels of adiponectin, leptin, apelin, and omentin in pregnant women. J Obstet Gynaecol. 2016. 36:555–8. doi:10.3109/01443615.2015.1103716.26759187 | Intervention/Exposure
296. | Kiziltan, G, Karabudak, E, Tuncay, G, Avsar, F, Tuncay, P, Mungan, O, Meral, P. Dietary intake and nutritional status of Turkish pregnant women during Ramadan. Saudi Med J. 2005. 26:1782–7.16311666 | Country
297. | Kizirian, N, Garnett, S, Markovic, T, Ross, G, Muirhead, R, Brodie, S, Petocz, P, Brand-Miller, J. Maternal diet and infant body composition in women at risk of gestational diabetes mellitus. Obesity research & clinical practice. 2014. 8:55-. doi:10.1016/j.orcp.2014.10.102. | Abstract
298. | Kizirian, NV, Markovic, TP, Muirhead, R, Brodie, S, Garnett, SP, Louie, JC, Petocz, P, Ross, GP, Brand-Miller, JC. Macronutrient Balance and Dietary Glycemic Index in Pregnancy Predict Neonatal Body Composition. Nutrients. 2016. 8. doi:10.3390/nu8050270. | Intervention/Exposure; Outcome
299. | Knudsen, VK, Heitmann, BL, Halldorsson, TI, Sorensen, TI, Olsen, SF. Maternal dietary glycaemic load during pregnancy and gestational weight gain, birth weight and postpartum weight retention: a study within the Danish National Birth Cohort. Br J Nutr. 2013. 109:1471–8. doi:10.1017/s0007114512003443.22906835 | Population
300. | Kombol, P. ILCA’s Inside Track: a resource for breastfeeding mothers. Breastfeeding after weight loss surgery. J Hum Lact. 2008. 24:341–2. doi:10.1177/08903344080240031801.18689722 | Study Design
301. | Kominiarek, MA. A Survey of Health Behaviors in Minority Women in Pregnancy: The Influence of Body Mass Index. Women’s Health Issues. 2014. 24:e291–5. doi:10.1016/j.whi.2014.02.007.24794542 | Study Design; Intervention/Exposure
302. | Kong, A, Odoms-Young, AM, Schiffer, LA, Berbaum, ML, Porter, SJ, Blumstein, L, Fitzgibbon, ML. Racial/Ethnic Differences in Dietary Intake among WIC Families Prior to Food Package Revisions. Journal of Nutrition Education & Behavior. 2013. 45:39–46. doi:10.1016/j.jneb.2012.04.014.23073175 | Study Design; Outcome
303. | Korpi-Hyovalti, E, Schwab, U, Laaksonen, DE, Linjama, H, Heinonen, S, Niskanen, L. Effect of intensive counselling on the quality of dietary fats in pregnant women at high risk of gestational diabetes mellitus. Br J Nutr. 2012. 108:910–7. doi:10.1017/s0007114511006118.22093485 | Intervention/Exposure
304. | Koutelidakis, AE, Alexatou, O, Kousaiti, S, Gkretsi, E, Vasios, G, Sampani, A, Tolia, M, Kiortsis, DN, Giaginis, C. Higher adherence to Mediterranean diet prior to pregnancy is associated with decreased risk for deviation from the maternal recommended gestational weight gain. Int J Food Sci Nutr. 2018. 69:84–92. doi:10.1080/09637486.2017.1330403.28614986 | Study Design
305. | Krawczyk, P, Sioma-Markowska, U, Nowak-Brzezińska, A, Skrzypulec-Plinta, V, Kubiak, E. Relationship of eating habits of pregnant women and daily delivery of nutrients as well as their influence on the course of pregnancy and condition of the neonate. Ginekologia i Poloznictwo. 2016. 42:33–42. | Outcome
306. | Kubota, K, Itoh, H, Tasaka, M, Naito, H, Fukuoka, Y, Muramatsu Kato, K, Kohmura, YK, Sugihara, K, Kanayama, N. Changes of maternal dietary intake, bodyweight and fetal growth throughout pregnancy in pregnant Japanese women. J Obstet Gynaecol Res. 2013. 39:1383–90. doi:10.1111/jog.12070.23815608 | Intervention/Exposure
307. | Kunath, J, Günther, J, Rauh, K, Hoffmann, J, Stecher, L, Rosenfeld, E, Kick, L, Ulm, K, Hauner, H. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. BMC Medicine. 2019. 17. doi:10.1186/s12916-018-1235-z. | Intervention/Exposure
308. | Lagiou, P, Lagiou, A, Samoli, E, Hsieh, CC, Adami, HO, Trichopoulos, D. Diet during pregnancy and levels of maternal pregnancy hormones in relation to the risk of breast cancer in the offspring. Eur J Cancer Prev. 2006. 15:20–6.16374225 | Outcome; Comparator
309. | Lagiou, P, Samoli, E, Lipworth, L, Lagiou, A, Fang, F, Rossi, M, Xu, B, Yu, GP, Adami, HO, Hsieh, CC, Trichopoulos, D. Energy intake during pregnancy in relation to offspring gender by maternal height. Eur J Epidemiol. 2011. 26:39–44. doi:10.1007/s10654-010-9528-3.21116838 | Study Design; Intervention/Exposure
310. | Lagiou, P, Tamimi, RM, Mucci, LA, Adami, HO, Hsieh, CC, Trichopoulos, D. Diet during pregnancy in relation to maternal weight gain and birth size. Eur J Clin Nutr. 2004. 58:231–7. doi:10.1038/sj.ejcn.1601771.14749741 | Intervention/Exposure; Comparator
311. | Lai, JS, Soh, SE, Loy, SL, Colega, M, Kramer, MS, Chan, JKY, Tan, TC, Shek, LPC, Yap, FKP, Tan, KH, Godfrey, KM, Chong, YS, Chong, MFF. Macronutrient composition and food groups associated with gestational weight gain: the GUSTO study. Eur J Nutr. 2019. 58:1081–1094. doi:10.1007/s00394-018-1623-3.29441408 | Intervention/Exposure
312. | Lamichhane, DK, Leem, JH, Kim, HC, Lee, JY, Park, MS, Jung, DY, Ko, JK, Ha, M, Kim, Y, Hong, YC, Ha, EH. Impact of prenatal exposure to polycyclic aromatic hydrocarbons from maternal diet on birth outcomes: a birth cohort study in Korea. Public Health Nutr. 2016. 19:2562–71. doi:10.1017/s1368980016000550.27056033 | Intervention/Exposure
313. | Lamyian, M, Hosseinpour-Niazi, S, Mirmiran, P, Moghaddam Banaem, L, Goshtasebi, A, Azizi, F. Pre-Pregnancy Fast Food Consumption Is Associated with Gestational Diabetes Mellitus among Tehranian Women. Nutrients. 2017. 9. doi:10.3390/nu9030216. | Intervention/Exposure
314. | Laraia, B, Vinikoor-Imler, LC, Siega-Riz, AM. Food insecurity during pregnancy leads to stress, disordered eating, and greater postpartum weight among overweight women. Obesity. 2015. 23:1303–11. doi:10.1002/oby.21075.25959858 | Intervention/Exposure
315. | Laraia, BA, Adler, NE, Coleman-Phox, K, Vieten, C, Mellin, L, Kristeller, JL, Thomas, M, Stotland, NE, Lustig, RH, Dallman, MF, Hecht, FM, Bush, NR, de Groat, CL, Epel, E. Novel Interventions to Reduce Stress and Overeating in Overweight Pregnant Women: A Feasibility Study. Matern Child Health J. 2018. 22:670–678. doi:10.1007/s10995-018-2435-z.29455384 | Intervention/Exposure
316. | Laraia, BA, Bodnar, LM, Siega-Riz, AM. Pregravid body mass index is negatively associated with diet quality during pregnancy. Public Health Nutr. 2007. 10:920–6. doi:10.1017/s1368980007657991.17381955 | Outcome
317. | Laraia, BA, Siega-Riz, AM, Dole, N, London, E. Pregravid weight is associated with prior dietary restraint and psychosocial factors during pregnancy. Obesity (Silver Spring). 2009. 17:550–8. doi:10.1038/oby.2008.585.19131943 | Intervention/Exposure; Outcome
318. | Larranaga, I, Santa-Marina, L, Begiristain, H, Machon, M, Vrijheid, M, Casas, M, Tardon, A, Fernandez-Somoano, A, Llop, S, Rodriguez-Bernal, CL, Fernandez, MF. Socio-economic inequalities in health, habits and self-care during pregnancy in Spain. Matern Child Health J. 2013. 17:1315–24. doi:10.1007/s10995-012-1134-4.22983810 | Intervention/Exposure; Outcome
319. | Larsen, SC, Angquist, L, Laurin, C, Morgen, CS, Jakobsen, MU, Paternoster, L, Smith, GD, Olsen, SF, Sorensen, TI, Nohr, EA. Association between Maternal Fish Consumption and Gestational Weight Gain: Influence of Molecular Genetic Predisposition to Obesity. PLoS One. 2016. 11:e0150105. doi:10.1371/journal.pone.0150105.26930408 | Intervention/Exposure
320. | Latva-Pukkila, U, Isolauri, E, Laitinen, K. Dietary and clinical impacts of nausea and vomiting during pregnancy. J Hum Nutr Diet. 2010. 23:69–77. doi:10.1111/j.1365-277X.2009.01019.x.19943842 | Intervention/Exposure; Comparator
321. | Lavie, M, Lavie, I, Maslovitz, S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7–11. doi:10.1016/j.ejogrb.2019.08.013.31522093 | Study Design
322. | Leahy, K, Berlin, KS, Banks, GG, Bachman, J. The Relationship Between Intuitive Eating and Postpartum Weight Loss. Matern Child Health J. 2017. 21:1591–1597. doi:10.1007/s10995-017-2281-4.28176035 | Study Design; Intervention/Exposure
323. | Ledoux, T, Robinson, J, Sampson, M, Beasley, A. Effect of Intuitive Eating on Gestational Weight Gain. Journal of the Academy of Nutrition & Dietetics. 2016. 116:A16–A16. doi:10.1016/j.jand.2016.06.041. | Conference abstract
324. | Lee, JI, Lee, JA, Lim, HS. Morning sickness reduces dietary diversity, nutrient intakes, and infant outcome of pregnant women. Nutrition Research. 2004. 24:531–540. doi:10.1016/j.nutres.2003.10.011. | Intervention/Exposure
325. | Leslie, DA, Hesketh, KD, Campbell, KJ. Breastfeeding mothers consume more vegetables and a greater variety of fruits and vegetables than non-breastfeeding peers: The influence of socioeconomic position. Nutrition & Dietetics. 2012. 69:84–90. doi:10.1111/j.1747-0080.2012.01584.x. | Study Design; Outcome
326. | Lesser, MNR, Mauldin, K, Sawrey-Kubicek, L, Gildengorin, V, King, JC. The Type of Dietary Fat in an Isocaloric Breakfast Meal Does Not Modify Postprandial Metabolism in Overweight/Obese Pregnant Women. Nutrients. 2019. 11. doi:10.3390/nu11030490. | Intervention/Exposure; Outcome
327. | Li, S, Zhu, Y, Chavarro, JE, Bao, W, Tobias, DK, Ley, SH, Forman, JP, Liu, A, Mills, J, Bowers, K, Strom, M, Hansen, S, Hu, FB, Zhang, C. Healthful Dietary Patterns and the Risk of Hypertension Among Women With a History of Gestational Diabetes Mellitus: A Prospective Cohort Study. Hypertension. 2016. 67:1157–65. doi:10.1161/hypertensionaha.115.06747.27091899 | Population; Outcome
328. | Li, YM, Shen, YD, Li, YJ, Xun, GL, Liu, H, Wu, RR, Xia, K, Zhao, JP, Ou, JJ. Maternal dietary patterns, supplements intake and autism spectrum disorders: A preliminary case-control study. Medicine (Baltimore). 2018. 97:e13902. doi:10.1097/md.0000000000013902.30593205 | Study Design; Outcome
329. | Lignell, S, Winkvist, A, Bertz, F, Rasmussen, KM, Glynn, A, Aune, M, Brekke, HK. Environmental organic pollutants in human milk before and after weight loss. Chemosphere. 2016. 159:96–102. doi:10.1016/j.chemosphere.2016.05.077.27281542 | Intervention/Exposure; Outcome
330. | Lindsay, K, Buss, C, Entringer, S, Wadhwa, P. The Interplay Between Diet Quality and Pre-pregnancy Body Mass Index on Glycemic Parameters in Pregnancy: A Comparison of Various Diet Quality Scores (OR35-02-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR35-02-19. | Abstract
331. | Lindsay, KL, Heneghan, C, McNulty, B, Brennan, L, McAuliffe, FM. Lifestyle and dietary habits of an obese pregnant cohort. Matern Child Health J. 2015. 19:25–32. doi:10.1007/s10995-014-1491-2.24740724 | Population
332. | Linné, Y, Rössner, S. Interrelationships between weight development and weight retention in subsequent pregnancies: The SPAWN study. Acta Obstetricia et Gynecologica Scandinavica. 2003. 82:318–325. doi:10.1034/j.1600-0412.2003.00150.x.12716315 | Intervention/Exposure
333. | Lioret, S, Cameron, AJ, McNaughton, SA, Crawford, D, Spence, AC, Hesketh, K, Campbell, KJ. Association between maternal education and diet of children at 9 months is partially explained by mothers’ diet. Matern Child Nutr. 2015. 11:936–47. doi:10.1111/mcn.12031.23560743 | Outcome
334. | Lipsmeyer, M, Diaz, E, Sims, C, Cleves, M, Shankar, K, Andres, A. Antenatal and Postnatal Factors Associated with Offspring Adiposity During the First Two Years of Life (FS18-08-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz041.FS18-08-19. | Abstract
335. | Liu, K, Ye, K, Han, Y, Sheng, J, Jin, Z, Bo, Q, Hu, C, Hu, C, Li, L. Maternal and cord blood fatty acid patterns with excessive gestational weight gain and neonatal macrosomia. Asia Pac J Clin Nutr. 2017. 26:291–297. doi:10.6133/apjcn.012016.11.28244708 | Study Design; Intervention/Exposure
336. | Liu, MJ, Li, HT, Yu, LX, Xu, GS, Ge, H, Wang, LL, Zhang, YL, Zhou, YB, Li, Y, Bai, MX, Liu, JM. A correlation study of DHA dietary intake and plasma, erythrocyte and breast milk DHA concentrations in lactatingwomen from Coastland, Lakeland, and Inland areas of China. Nutrients. 2016. 8. doi:10.3390/nu8050312. | Intervention/Exposure; Outcome
337. | Lof, M, Hilakivi-Clarke, L, Sandin, SS, de Assis, S, Yu, W, Weiderpass, E. Dietary fat intake and gestational weight gain in relation to estradiol and progesterone plasma levels during pregnancy: a longitudinal study in Swedish women. BMC Womens Health. 2009. 9:10. doi:10.1186/1472-6874-9-10.19402915 | Intervention/Exposure; Comparator
338. | Lombard, CB, Deeks, AA, Ball, K, Jolley, D, Teede, HJ. Weight, physical activity and dietary behavior change in young mothers: short term results of the HeLP-her cluster randomized controlled trial. Nutr J. 2009. 8:17. doi:10.1186/1475-2891-8-17.19409085 | Population
339. | Long, VA, Martin, T, Janson-Sand, C. The Great Beginnings program: impact of a nutrition curriculum on nutrition knowledge, diet quality, and birth outcomes in pregnant and parenting teens. Journal of the American Dietetic Association. 2002. 102:S86–9.11902397 | Intervention/Exposure; Population
340. | Lopez-Cepero, A, Nobel, L, Moore-Simas, T, Rosal, M. Maternal Diet Quality and Infant Growth Trajectories During the First Year of Life (OR35-07-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR35-07-19. | Abstract
341. | Lopez-Olmedo, N, Hernandez-Cordero, S, Neufeld, LM, Garcia-Guerra, A, Mejia-Rodriguez, F, Mendez Gomez-Humaran, I. The Associations of Maternal Weight Change with Breastfeeding, Diet and Physical Activity During the Postpartum Period. Matern Child Health J. 2016. 20:270–80. doi:10.1007/s10995-015-1826-7.26525558 | Intervention/Exposure
342. | Lotfi, MH, Fallahzadeh, H, Rahmanian, M, Hosseinzadeh, M, Lashkardoost, H, Doaei, S, Gholamalizadeh, M, Hamedi, A. Association of food groups intake and physical activity with gestational diabetes mellitus in Iranian women. J Matern Fetal Neonatal Med. 2019. :1–6. doi:10.1080/14767058.2019.1579189. | Study Design; Intervention/Exposure
343. | Louie, JC, Markovic, TP, Perera, N, Foote, D, Petocz, P, Ross, GP, Brand-Miller, JC. A randomized controlled trial investigating the effects of a low-glycemic index diet on pregnancy outcomes in gestational diabetes mellitus. Diabetes Care. 2011. 34:2341–6. doi:10.2337/dc11-0985.21900148 | Health Status
344. | Louie, JCY, Markovic, TP, Ross, GP, Foote, D, Brand-Miller, JC. Effect of a low glycaemic index diet in gestational diabetes mellitus on post-natal outcomes after 3 months of birth: a pilot follow-up study. Maternal & Child Nutrition. 2015. 11:409–414. doi:10.1111/mcn.12039.23638904 | Intervention/Exposure; Population
345. | Lovelady, CA, Stephenson, KG, Kuppler, KM, Williams, JP. The effects of dieting on food and nutrient intake of lactating women. J Am Diet Assoc. 2006. 106:908–12. doi:10.1016/j.jada.2006.03.007.16720131 | Intervention/Exposure; Outcome
346. | Lu, MS, Chen, QZ, He, JR, Wei, XL, Lu, JH, Li, SH, Wen, XX, Chan, FF, Chen, NN, Qiu, L, Mai, WB, Zhang, RF, Hu, CY, Xia, HM, Qiu, X. Maternal Dietary Patterns and Fetal Growth: A Large Prospective Cohort Study in China. Nutrients. 2016. 8. doi:10.3390/nu8050257. | Outcome
347. | Lundeen, E, Park, S, Baidal, JAW, Sharma, A, Blanck, HM. Prevalence of and Factors Associated with Sugar-sweetened Beverage Intake Among Women of Reproductive Age-12 States and District of Columbia, 2017 (P16-022-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz050.P16-022-19. | Abstract
348. | Luoto, R, Kharazmi, E, Saarinen, NM, Smeds, AI, Mäkelä, S, Fallah, M, Raitanen, J, Hilakivi-Clarke, L. Effect of dietary intervention on serum lignan levels in pregnant women - a controlled trial. Reproductive Health. 2010. 7:6p–6p. doi:10.1186/1742-4755-7-26.20462413 | Intervention/Exposure; Outcome
349. | Luoto, RM, Kinnunen, TI, Aittasalo, M, Ojala, K, Mansikkamaki, K, Toropainen, E, Kolu, P, Vasankari, T. Prevention of gestational diabetes: design of a cluster-randomized controlled trial and one-year follow-up. BMC Pregnancy Childbirth. 2010. 10:39. doi:10.1186/1471-2393-10-39.20682023 | Study Design; Intervention/Exposure
350. | Lyu, LC, Lo, CC, Chen, HF, Wang, CY, Liu, DM. A prospective study of dietary intakes and influential factors from pregnancy to postpartum on maternal weight retention in Taipei, Taiwan. Br J Nutr. 2009. 102:1828–37. doi:10.1017/s0007114509991243.19678967 | Intervention/Exposure; Population
351. | Ma, C, Shaw, GM, Scheuerle, AE, Canfield, MA, Carmichael, SL. Association of microtia with maternal nutrition. Birth Defects Res A Clin Mol Teratol. 2012. 94:1026–32. doi:10.1002/bdra.23053.22821770 | Outcome
352. | Ma, L, Lu, Q, Ouyang, J, Huang, J, Huang, S, Jiao, C, Zhang, Z, Mao, L. How are maternal dietary patterns and maternal/fetal cytokines associated with birth weight? A path analysis. Br J Nutr. 2019. 121:1178–1187. doi:10.1017/s0007114519000382.31140960 | Outcome
353. | Ma, WJ, Huang, ZH, Huang, BX, Qi, BH, Zhang, YJ, Xiao, BX, Li, YH, Chen, L, Zhu, HL. Intensive low-glycaemic-load dietary intervention for the management of glycaemia and serum lipids among women with gestational diabetes: a randomized control trial. Public Health Nutr. 2015. 18:1506–13. doi:10.1017/s1368980014001992.25222105 | Intervention/Exposure
354. | Mak, JKL, Pham, NM, Lee, AH, Tang, L, Pan, XF, Binns, CW, Sun, X. Dietary patterns during pregnancy and risk of gestational diabetes: a prospective cohort study in Western China. Nutr J. 2018. 17:107. doi:10.1186/s12937-018-0413-3.30454043 | Outcome
355. | Makela, J, Lagstrom, H, Kaljonen, A, Simell, O, Niinikoski, H. Hyperglycemia and lower diet quality in pregnant overweight women and increased infant size at birth and at 13 months of age--STEPS study. Early Hum Dev. 2013. 89:439–44. doi:10.1016/j.earlhumdev.2013.01.007.23375946 | Intervention/Exposure
356. | Malek, L, Makrides, M. 2.8 Nutrition in pregnancy and lactation. World Rev Nutr Diet. 2015. 113:127–33. doi:10.1159/000367872.25906871 | Study Design; Book chapter
357. | Man, YB, Chow, KL, Xing, GH, Chan, JKY, Wu, SC, Wong, MH. A pilot study on health risk assessment based on body loadings of PCBs of lactating mothers at Taizhou, China, the world’s major site for recycling transformers. Environ Pollut. 2017. 227:364–371. doi:10.1016/j.envpol.2017.04.069.28482316 | Intervention/Exposure
358. | Mannion, CA, Gray-Donald, K, Johnson-Down, L, Koski, KG. Lactating women restricting milk are low on select nutrients. J Am Coll Nutr. 2007. 26:149–55.17536126 | Intervention/Exposure
359. | Markhus, MW, Graff, IE, Dahl, L, Seldal, CF, Skotheim, S, Braarud, HC, Stormark, KM, Malde, MK. Establishment of a seafood index to assess the seafood consumption in pregnant women. Food & Nutrition Research. 2013. 57:1–11. doi:10.3402/fnr.v57i0.19272. | Outcome
360. | Markovic, TP, Muirhead, R, Overs, S, Kizirian, N, Louie, J, Sweeting, A, Petocz, P, Denyer, G, Hyett, J, Ross, GP, . Predictors of birthweight in women at high risk of gestational diabetes mellitus. Obesity research and clinical practice. 2013. 7:e3–e4. doi:10.1016/j.orcp.2013.12.505. | Abstract
361. | Markovic, TP, Muirhead, R, Overs, S, Ross, GP, Louie, JC, Kizirian, N, Denyer, G, Petocz, P, Hyett, J, Brand-Miller, JC. Randomized Controlled Trial Investigating the Effects of a Low-Glycemic Index Diet on Pregnancy Outcomes in Women at High Risk of Gestational Diabetes Mellitus: The GI Baby 3 Study. Diabetes Care. 2016. 39:31–8. doi:10.2337/dc15-0572.26185283 | Comparator
362. | Marshburn, MK. Helping Obese Pregnant Women Achieve Healthy Weight Gain: Is Provider Intervention Feasible? Helping Obese Pregnant Women Achieve Healthy Weight Gain: Is Provider Intervention Feasible? 2017. :1–1. | Dissertation
363. | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, Robinson, WR, Daniels, JL, Perrin, EM, Stuebe, AM. Maternal Dietary Patterns during Pregnancy Are Associated with Child Growth in the First 3 Years of Life. J Nutr. 2016. 146:2281–2288. doi:10.3945/jn.116.234336.27683873 | Intervention/Exposure; Outcome
364. | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, Robinson, WR, Daniels, JL, Perrin, EM, Stuebe, AM. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol. 2016. 30:246–55. doi:10.1111/ppe.12279.26848932 | Outcome
365. | Martin, J, MacDonald-Wicks, L, Hure, A, Smith, R, Collins, CE. Reducing postpartum weight retention and improving breastfeeding outcomes in overweight women: a pilot randomised controlled trial. Nutrients. 2015. 7:1464–79. doi:10.3390/nu7031464.25723973 | Intervention/Exposure
366. | Martinez-Galiano, JM, Olmedo-Requena, R, Barrios-Rodriguez, R, Amezcua-Prieto, C, Bueno-Cavanillas, A, Salcedo-Bellido, I, Jimenez-Moleon, JJ, Delgado-Rodriguez, M. Effect of Adherence to a Mediterranean Diet and Olive Oil Intake during Pregnancy on Risk of Small for Gestational Age Infants. Nutrients. 2018. 10. doi:10.3390/nu10091234. | Study Design; Outcome
367. | Martins, AP, Benicio, MH. Influence of dietary intake during gestation on postpartum weight retention. Rev Saude Publica. 2011. 45:870–7. doi:10.1590/s0034-89102011005000056.21829976 | Population
368. | Martins, MC, Trujillo, J, Freitas-Vilela, AA, Farias, DR, Rosado, EL, Struchiner, CJ, Kac, G. Associations between obesity candidate gene polymorphisms (fat mass and obesity-associated (FTO), melanocortin-4 receptor (MC4R), leptin (LEP) and leptin receptor (LEPR)) and dietary intake in pregnant women. Br J Nutr. 2018. 120:454–463. doi:10.1017/s0007114518001423.29893663 | Outcome
369. | Maslova, E, Halldorsson, TI, Astrup, A, Olsen, SF. Dietary protein-to-carbohydrate ratio and added sugar as determinants of excessive gestational weight gain: a prospective cohort study. BMJ Open. 2015. 5:e005839. doi:10.1136/bmjopen-2014-005839. | Intervention/Exposure
370. | Maslova, E, Rytter, D, Bech, BH, Henriksen, TB, Olsen, SF, Halldorsson, TI. Maternal intake of fat in pregnancy and offspring metabolic health - A prospective study with 20 years of follow-up. Clin Nutr. 2016. 35:475–483. doi:10.1016/j.clnu.2015.03.018.25933442 | Intervention/Exposure; Outcome
371. | Maugeri, A, Barchitta, M, Agrifoglio, O, Favara, G, La Mastra, C, La Rosa, MC, Magnano San Lio, R, Panella, M, Cianci, A, Agodi, A. The impact of social determinants and lifestyles on dietary patterns during pregnancy: evidence from the “Mamma & Bambino” study. Ann Ig. 2019. 31:81–89. doi:10.7416/ai.2019.2280.30994167 | Study Design; Outcome
372. | McGiveron, A, Foster, S, Pearce, J, Taylor, MA, McMullen, S, Langley-Evans, SC. Limiting antenatal weight gain improves maternal health outcomes in severely obese pregnant women: findings of a pragmatic evaluation of a midwife-led intervention. J Hum Nutr Diet. 2015. 28 Suppl 1:29–37. doi:10.1111/jhn.12240.24809211 | Intervention/Exposure
373. | McGowan, CA, Curran, S, McAuliffe, FM. Relative validity of a food frequency questionnaire to assess nutrient intake in pregnant women. Journal of Human Nutrition & Dietetics. 2014. :167–174. doi:10.1111/jhn.12120.23627971 | Outcome
374. | McGowan, CA, McAuliffe, FM. Maternal dietary patterns and associated nutrient intakes during each trimester of pregnancy. Public Health Nutr. 2013. 16:97–107. doi:10.1017/s1368980012000997.22494917 | Outcome
375. | McGowan, CA, Walsh, JM, Byrne, J, Curran, S, McAuliffe, FM. The influence of a low glycemic index dietary intervention on maternal dietary intake, glycemic index and gestational weight gain during pregnancy: a randomized controlled trial. Nutr J. 2013. 12:140. doi:10.1186/1475-2891-12-140.24175958 | Intervention/Exposure
376. | McGuire, E. Breastfeeding and high maternal body mass index. Breastfeed Rev. 2013. 21:7–14. | Study Design
377. | McGurk, P, Hill, AJ, McCance, DR. An investigation of dietary intake of pregnant women in the third trimester in Northern Ireland. Journal of Human Nutrition & Dietetics. 2011. 24:293–294. doi:10.1111/j.1365-277X.2011.01175_22.x. | Conference abstract
378. | McIlvride, S, Nikolova, V, Fan, HM, McDonald, JAK, Wahlstrom, A, Bellafante, E, Jansen, E, Adorini, L, Shapiro, D, Jones, P, Marchesi, JR, Marschall, HU, Williamson, C. Obeticholic acid ameliorates dyslipidemia but not glucose tolerance in mouse model of gestational diabetes. Am J Physiol Endocrinol Metab. 2019. 317:E399–e410. doi:10.1152/ajpendo.00407.2018.31237448 | Intervention/Exposure; Human
379. | McKenzie, KM, Dissanayake, HU, McMullan, R, Caterson, ID, Celermajer, DS, Gordon, A, Hyett, J, Meroni, A, Phang, M, Raynes-Greenow, C, Polson, JW, Skilton, MR. Quantity and Quality of Carbohydrate Intake during Pregnancy, Newborn Body Fatness and Cardiac Autonomic Control: Conferred Cardiovascular Risk? Nutrients. 2017. 9. doi:10.3390/nu9121375. | Intervention/Exposure; Outcome
380. | Meinila, J, Koivusalo, SB, Valkama, A, Rono, K, Erkkola, M, Kautiainen, H, Stach-Lempinen, B, Eriksson, JG. Nutrient intake of pregnant women at high risk of gestational diabetes. Food & nutrition research. 2015. 59. doi:10.3402/fnr.v59.26676. | Outcome
381. | Meinila, J, Valkama, A, Koivusalo, SB, Stach-Lempinen, B, Lindstrom, J, Kautiainen, H, Eriksson, JG, Erkkola, M. Healthy Food Intake Index (HFII) - Validity and reproducibility in a gestational-diabetes-risk population. BMC Public Health. 2016. 16:680. doi:10.1186/s12889-016-3303-7.27475905 | Outcome
382. | Meinila, J, Valkama, A, Koivusalo, SB, Stach-Lempinen, B, Rono, K, Lindstrom, J, Kautiainen, H, Eriksson, JG, Erkkola, M. Is improvement in the Healthy Food Intake Index (HFII) related to a lower risk for gestational diabetes? Br J Nutr. 2017. 117:1103–1109. doi:10.1017/s0007114517001015.28535829 | Population; Outcome
383. | Meltzer, HM, Brantsaeter, AL, Nilsen, RM, Magnus, P, Alexander, J, Haugen, M. Effect of dietary factors in pregnancy on risk of pregnancy complications: results from the Norwegian Mother and Child Cohort Study. Am J Clin Nutr. 2011. 94:1970s–1974s. doi:10.3945/ajcn.110.001248.21543541 | Study Design; Outcome
384. | Meng, Y, Groth, SW, Li, D. The Association between Obesity-Risk Genes and Gestational Weight Gain Is Modified by Dietary Intake in African American Women. J Nutr Metab. 2018. 2018:5080492. doi:10.1155/2018/5080492.29686896 | Intervention/Exposure
385. | Meng, Y, Groth, SW, Stewart, P, Smith, JA. An Exploration of the Determinants of Gestational Weight Gain in African American Women: Genetic Factors and Energy Expenditure. Biol Res Nurs. 2018. 20:118–125. doi:10.1177/1099800417743326.29161908 | Intervention/Exposure
386. | Merkx, A, Ausems, M, Bude, L, de Vries, R, Nieuwenhuijze, MJ. Weight gain in healthy pregnant women in relation to pre-pregnancy BMI, diet and physical activity. Midwifery. 2015. 31:693–701. doi:10.1016/j.midw.2015.04.008.25981808 | Study Design; Intervention/Exposure
387. | Micali, N, Al Essimii, H, Field, AE, Treasure, J. Pregnancy loss of control over eating: A longitudinal study of maternal and child outcomes. American Journal of Clinical Nutrition. 2018. 108:101–107. doi:10.1093/ajcn/nqy040. | Intervention/Exposure; Outcome
388. | Mielke, RT. Determinants of excessive gestational weight gain in Mexican American women in Los Angeles. 2010. :174 p–174 p. | Dissertation
389. | Mikkelsen, TB, Osler, M, Orozova-Bekkevold, I, Knudsen, VK, Olsen, SF. Association between fruit and vegetable consumption and birth weight: a prospective study among 43,585 Danish women. Scand J Public Health. 2006. 34:616–22. doi:10.1080/14034940600717688.17132595 | Outcome
390. | Milajerdi, A, Tehrani, H, Haghighatdoost, F, Larijani, B, Surkan, PJ, Azadbakht, L. Associations between higher egg consumption during pregnancy with lowered risks of high blood pressure and gestational diabetes mellitus. Int J Vitam Nutr Res. 2018. 88:166–175. doi:10.1024/0300-9831/a000505.30932793 | Study Design; Intervention/Exposure
391. | Min, Y, Djahanbakhch, O, Hutchinson, J, Bhullar, AS, Raveendran, M, Hallot, A, Eram, S, Namugere, I, Nateghian, S, Ghebremeskel, K. Effect of docosahexaenoic acid-enriched fish oil supplementation in pregnant women with Type 2 diabetes on membrane fatty acids and fetal body composition--double-blinded randomized placebo-controlled trial. Diabet Med. 2014. 31:1331–40. doi:10.1111/dme.12524.24925713 | Study Design; Intervention/Exposure
392. | Mirmiran, P, Hosseinpour-Niazi, S, Moghaddam-Banaem, L, Lamyian, M, Goshtasebi, A, Azizi, F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. Int J Vitam Nutr Res. 2019. :1–8. doi:10.1024/0300-9831/a000475. | Intervention/Exposure
393. | Mise, N, Ohtsu, M, Ikegami, A, Mizuno, A, Cui, X, Kobayashi, Y, Nakagi, Y, Nohara, K, Yoshida, T, Kayama, F. Hijiki seaweed consumption elevates levels of inorganic arsenic intake in Japanese children and pregnant women. Food Addit Contam Part A Chem Anal Control Expo Risk Assess. 2019. 36:84–95. doi:10.1080/19440049.2018.1562228.30632947 | Intervention/Exposure; Outcome
394. | Mitchell, EA, Robinson, E, Clark, PM, Becroft, DM, Glavish, N, Pattison, NS, Pryor, JE, Thompson, JM, Wild, CJ. Maternal nutritional risk factors for small for gestational age babies in a developed country: a case-control study. Arch Dis Child Fetal Neonatal Ed. 2004. 89:F431–5. doi:10.1136/adc.2003.036970.15321964 | Outcome
395. | Miyake, Y, Okubo, H, Sasaki, S, Tanaka, K, Hirota, Y. Maternal dietary patterns during pregnancy and risk of wheeze and eczema in Japanese infants aged 16-24 months: the Osaka Maternal and Child Health Study. Pediatr Allergy Immunol. 2011. 22:734–41. doi:10.1111/j.1399-3038.2011.01176.x.21539616 | Outcome
396. | Moller, UK, Streym, S, Heickendorff, L, Mosekilde, L, Rejnmark, L. Effects of 25OHD concentrations on chances of pregnancy and pregnancy outcomes: a cohort study in healthy Danish women. Eur J Clin Nutr. 2012. 66:862–8. doi:10.1038/ejcn.2012.18.22378226 | Intervention/Exposure; Outcome
397. | Molyneaux, E, Poston, L, Khondoker, M, Howard, LM. Obesity, antenatal depression, diet and gestational weight gain in a population cohort study. Arch Womens Ment Health. 2016. 19:899–907. doi:10.1007/s00737-016-0635-3.27178124 | Intervention/Exposure; Outcome
398. | Monteagudo, C, Mariscal-Arcas, M, Heras-Gonzalez, L, Ibanez-Peinado, D, Rivas, A, Olea-Serrano, F. Effects of maternal diet and environmental exposure to organochlorine pesticides on newborn weight in Southern Spain. Chemosphere. 2016. 156:135–142. doi:10.1016/j.chemosphere.2016.04.103.27174826 | Intervention/Exposure; Outcome
399. | Moore, VM, Davies, MJ, Willson, KJ, Worsley, A, Robinson, JS. Dietary composition of pregnant women is related to size of the baby at birth. J Nutr. 2004. 134:1820–6. doi:10.1093/jn/134.7.1820.15226475 | Intervention/Exposure
400. | Moradi, M, Maracy, MR, Esmaillzadeh, A, Surkan, PJ, Azadbakht, L. Associations Between Dietary Energy Density in Mothers and Growth of Breast-feeding Infants During the First 4 Months of Life. J Am Coll Nutr. 2018. :1–7. doi:10.1080/07315724.2018.1465486. | Intervention/Exposure
401. | Moran, LJ, Flynn, AC, Louise, J, Deussen, AR, Dodd, JM. The effect of a lifestyle intervention on pregnancy and postpartum dietary patterns determined by factor analysis. Obesity (Silver Spring). 2017. 25:1022–1032. doi:10.1002/oby.21848.28452404 | Study Design; Outcome
402. | Moran, LJ, McNaughton, SA, Sui, Z, Cramp, C, Deussen, AR, Grivell, RM, Dodd, JM. The characterisation of overweight and obese women who are under reporting energy intake during pregnancy. BMC Pregnancy Childbirth. 2018. 18:204. doi:10.1186/s12884-018-1826-x.29859056 | Intervention/Exposure; Outcome
403. | Moran, LJ, Sui, Z, Cramp, CS, Dodd, JM. A decrease in diet quality occurs during pregnancy in overweight and obese women which is maintained post-partum. Int J Obes (Lond). 2013. 37:704–11. doi:10.1038/ijo.2012.129.22868828 | Outcome; Comparator
404. | Moreno, MA. Advice for patients. Breastfeeding as obesity prevention. Arch Pediatr Adolesc Med. 2011. 165:772. doi:10.1001/archpediatrics.2011.140.21810641 | Study Design
405. | Moreno-Castilla, C, Hernandez, M, Bergua, M, Alvarez, MC, Arce, MA, Rodriguez, K, Martinez-Alonso, M, Iglesias, M, Mateu, M, Santos, MD, Pacheco, LR, Blasco, Y, Martin, E, Balsells, N, Aranda, N, Mauricio, D. Low-Carbohydrate diet for the treatment of gestational diabetes mellitus: A randomized controlled trial. Diabetes Care. 2013. 36:2233–2238. doi:10.2337/dc12-2714.23564917 | Health Status
406. | Morisset, AS, Cote, JA, Michaud, A, Robitaille, J, Tchernof, A, Dube, MC, Veillette, J, Weisnagel, SJ. Dietary intakes in the nutritional management of gestational diabetes mellitus. Can J Diet Pract Res. 2014. 75:64–71. doi:10.3148/75.2.2014.64.24897011 | Comparator
407. | Moses, RG, Casey, SA, Quinn, EG, Cleary, JM, Tapsell, LC, Milosavljevic, M, Petocz, P, Brand-Miller, JC. Pregnancy and Glycemic Index Outcomes study: Effects of low glycemic index compared with conventional dietary advice on selected pregnancy outcomes. American Journal of Clinical Nutrition. 2014. 99:517–523. doi:10.3945/ajcn.113.074138. | Intervention/Exposure
408. | Moses, RG, Luebcke, M, Davis, WS, Coleman, KJ, Tapsell, LC, Petocz, P, Brand-Miller, JC. Effect of a low-glycemic-index diet during pregnancy on obstetric outcomes. Am J Clin Nutr. 2006. 84:807–12. doi:10.1093/ajcn/84.4.807.17023707 | Intervention/Exposure
409. | Most, J, Amant, MS, Hsia, DS, Altazan, AD, Thomas, DM, Gilmore, LA, Vallo, PM, Beyl, RA, Ravussin, E, Redman, LM. Evidence-based recommendations for energy intake in pregnant women with obesity. J Clin Invest. 2019. 130:4682–4690. doi:10.1172/jci130341. | Intervention/Exposure
410. | Most, J, Rebello, CJ, Altazan, AD, Martin, CK, Amant, MS, Redman, LM. Behavioral Determinants of Objectively Assessed Diet Quality in Obese Pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11071446. | Outcome
411. | Mujsindi, W, Habash, D, Childs, G. Impact of nutrition education on gestational weight gain in obese pregnant women. American journal of obstetrics and gynecology. 2014. 210:S188. doi:10.1016/j.ajog.2013.10.402. | Abstract
412. | Muliyil, DE, Rose, A, Senthamizh, SV, Chatterjee, T, Helan, J, Kang, G, Muliyil, J. Prevalence and Risk Factors of Vitamin A Deficiency in Children and Women of Childbearing Age in a Southern Indian Tribal Population: A Cross-Sectional Study. Indian J Community Med. 2019. 44:162–165. doi:10.4103/ijcm.IJCM_213_18.31333297 | Study Design; Population
413. | Mullaney, L, O’Higgins, AC, Cawley, S, Kennedy, R, McCartney, D, Turner, MJ. Breastfeeding and postpartum maternal weight trajectories. Public Health Nutr. 2016. 19:1397–404. doi:10.1017/s1368980015002967.26466770 | Population
414. | Munda, A, Starcic Erjavec, M, Molan, K, Ambrozic Avgustin, J, Zgur-Bertok, D, Pongrac Barlovic, D. Association between pre-pregnancy body weight and dietary pattern with large-for-gestational-age infants in gestational diabetes. Diabetol Metab Syndr. 2019. 11:68. doi:10.1186/s13098-019-0463-5.31462931 | Intervention/Exposure; Outcome
415. | Murrin, CM, Heinen, MM, Kelleher, CC. Are Dietary Patterns of Mothers during Pregnancy Related to Children’s Weight Status? Evidence from the Lifeways Cross-Generational Cohort Study. AIMS Public Health. 2015. 2:274–296. doi:10.3934/publichealth.2015.3.274.29546111 | Outcome
416. | Navarro, P, Mehegan, J, Murrin, CM, Kelleher, CC, Phillips, CM. Adherence to the Healthy Eating Index-2015 across Generations Is Associated with Birth Outcomes and Weight Status at Age 5 in the Lifeways Cross-Generation Cohort Study. Nutrients. 2019. 11. doi:10.3390/nu11040928. | Outcome
417. | Ng, SK, Cameron, CM, Hills, AP, McClure, RJ, Scuffham, PA. Socioeconomic disparities in prepregnancy BMI and impact on maternal and neonatal outcomes and postpartum weight retention: the EFHL longitudinal birth cohort study. BMC Pregnancy Childbirth. 2014. 14:314. doi:10.1186/1471-2393-14-314.25201481 | Study Design; Intervention/Exposure
418. | Nicklas, JM, Zera, CA, Seely, EW. Predictors of very early postpartum weight loss in women with recent gestational diabetes mellitus. J Matern Fetal Neonatal Med. 2018. :1–7. doi:10.1080/14767058.2018.1487937. | Intervention/Exposure
419. | Nikniaz, L, Jr, Mahdavi, R, Arefhoesseini, SR, Sowti Khiabani, M. Association between fat content of breast milk and maternal nutritional status and infants’ weight in tabriz, iran. Malays J Nutr. 2009. 15:37–44.22691803 | Intervention/Exposure; Outcome
420. | Nikniaz, L, Mahavi, R, Ostadrahimi, A, Nikniaz, Z, Taghipour, S. Synbiotic supplementation is not effective on breast milk selenium concentrations and growth of exclusively breast fed infants: a pilot study. Int J Vitam Nutr Res. 2019. 1–7. doi:10.1024/0300-9831/a000549. | Intervention/Exposure; Outcome
421. | Nikniaz, L, Mahdavi, R, Gargari, BP, Gayem Magami, SJ, Nikniaz, Z. Maternal body mass index, dietary intake and socioeconomic status: differential effects on breast milk zinc, copper and iron content. Health Promot Perspect. 2011. 1:140–6. doi:10.5681/hpp.2011.015.24688910 | Study Design; Intervention/Exposure
422. | Normia, J, Niinivirta-Joutsa, K, Isolauri, E, Jääskeläinen, SK, Laitinen, K. Perinatal nutrition impacts on the functional development of the visual tract in infants. Pediatric Research. 2019. 85:72–78. doi:10.1038/s41390-018-0161-2.30237571 | Intervention/Exposure; Comparator
423. | Northstone, K, Emmett, P, Rogers, I. Dietary patterns in pregnancy and associations with socio-demographic and lifestyle factors. Eur J Clin Nutr. 2008. 62:471–9. doi:10.1038/sj.ejcn.1602741.17375108 | Outcome
424. | Nunes, MA, Ferri, CP, Manzolli, P, Soares, RM, Drehmer, M, Buss, C, Giacomello, A, Hoffmann, JF, Ozcariz, S, Melere, C, Manenti, CN, Camey, S, Duncan, BB, Schmidt, MI. Nutrition, mental health and violence: from pregnancy to postpartum Cohort of women attending primary care units in Southern Brazil--ECCAGE study. BMC Psychiatry. 2010. 10:66. doi:10.1186/1471-244x-10-66.20807429 | Intervention/Exposure; No Results
425. | Nunes, MA, Pinheiro, AP, Camey, SA, Schmidt, MI. Binge eating during pregnancy and birth outcomes: a cohort study in a disadvantaged population in Brazil. Int J Eat Disord. 2012. 45:827–31. doi:10.1002/eat.22024.22531873 | Intervention/Exposure
426. | Nykjaer, C, Higgs, C, Greenwood, DC, Simpson, NAB, Cade, JE, Alwan, NA. Maternal Fatty Fish Intake Prior to and during Pregnancy and Risks of Adverse Birth Outcomes: Findings from a British Cohort. Nutrients. 2019. 11. doi:10.3390/nu11030643. | Intervention/Exposure
427. | O’Brien, CM, Louise, J, Deussen, A, Dodd, JM. In Overweight or Obese Pregnant Women, Maternal Dietary Factors are not Associated with Fetal Growth and Adiposity. Nutrients. 2018. 10. doi:10.3390/nu10070870. | Outcome
428. | O’Brien, EC, Alberdi, G, Geraghty, AA, McAuliffe, FM. Lower education predicts poor response to dietary intervention in pregnancy, regardless of neighbourhood affluence: secondary analysis from the ROLO randomised control trial. Public Health Nutr. 2017. 20:2959–2969. doi:10.1017/s1368980017001951.28807059 | Intervention/Exposure
429. | O’Brien, EC, Geraghty, AA, O’Sullivan, EJ, Riordan, JA, Horan, MK, Larkin, E, Donnelly, J, Mehegan, J, Twomey, PJ, McAuliffe, FM. Five-year follow up of a low glycaemic index dietary randomised controlled trial in pregnancy-no long-term maternal effects of a dietary intervention. Bjog. 2019. 126:514–524. doi:10.1111/1471-0528.15500.30303614 | Intervention/Exposure; Outcome
430. | Oken, E, Ning, Y, Rifas-Shiman, SL, Rich-Edwards, JW, Olsen, SF, Gillman, MW. Diet during pregnancy and risk of preeclampsia or gestational hypertension. Ann Epidemiol. 2007. 17:663–8. doi:10.1016/j.annepidem.2007.03.003.17521921 | Intervention/Exposure; Outcome
431. | Olafsdottir, AS, Magnusardottir, AR, Thorgeirsdottir, H, Hauksson, A, Skuladottir, GV, Steingrimsdottir, L. Relationship between dietary intake of cod liver oil in early pregnancy and birthweight. Bjog. 2005. 112:424–9. doi:10.1111/j.1471-0528.2005.00477.x.15777439 | Intervention/Exposure
432. | Olafsdottir, AS, Skuladottir, GV, Thorsdottir, I, Hauksson, A, Steingrimsdottir, L. Combined effects of maternal smoking status and dietary intake related to weight gain and birth size parameters. Bjog. 2006. 113:1296–302. doi:10.1111/j.1471-0528.2006.01077.x.17004979 | Intervention/Exposure; Comparator
433. | Olafsdottir, AS, Skuladottir, GV, Thorsdottir, I, Hauksson, A, Steingrimsdottir, L. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). 2006. 30:492–9. doi:10.1038/sj.ijo.0803184.16331301 | Intervention/Exposure
434. | Olmedo-Requena, R, Gomez-Fernandez, J, Amezcua-Prieto, C, Mozas-Moreno, J, Khan, KS, Jimenez-Moleon, JJ. Pre-Pregnancy Adherence to the Mediterranean Diet and Gestational Diabetes Mellitus: A Case-Control Study. Nutrients. 2019. 11. doi:10.3390/nu11051003. | Study Design
435. | Olson, CM, Strawderman, MS, Hinton, PS, Pearson, TA. Gestational weight gain and postpartum behaviors associated with weight change from early pregnancy to 1 y postpartum. Int J Obes Relat Metab Disord. 2003. 27:117–27. doi:10.1038/sj.ijo.0802156.12532163 | Intervention/Exposure
436. | Olson, CM, Strawderman, MS. Modifiable behavioral factors in a biopsychosocial model predict inadequate and excessive gestational weight gain. J Am Diet Assoc. 2003. 103:48–54. doi:10.1053/jada.2003.50001.12525793 | Intervention/Exposure
437. | Opie, RS, Neff, M, Tierney, AC. A behavioural nutrition intervention for obese pregnant women: Effects on diet quality, weight gain and the incidence of gestational diabetes. Aust N Z J Obstet Gynaecol. 2016. 56:364–73. doi:10.1111/ajo.12474.27170563 | Intervention/Exposure
438. | Orloff, NC, Flammer, A, Hartnett, J, Liquorman, S, Samelson, R, Hormes, JM. Food cravings in pregnancy: Preliminary evidence for a role in excess gestational weight gain. Appetite. 2016. 105:259–65. doi:10.1016/j.appet.2016.04.040.27215835 | Study Design; Intervention/Exposure
439. | Ostadrahimi, A, Nikniaz, L, Mahdavi, R, Hejazi, MA, Nikniaz, Z. Effects of synbiotic supplementation on lactating mothers’ energy intake and BMI, and infants’ growth. Int J Food Sci Nutr. 2013. 64:711–4. doi:10.3109/09637486.2013.775229.23480276 | Intervention/Exposure; Comparator
440. | Ostbye, T, Peterson, BL, Krause, KM, Swamy, GK, Lovelady, CA. Predictors of postpartum weight change among overweight and obese women: results from the Active Mothers Postpartum study. J Womens Health (Larchmt). 2012. 21:215–22. doi:10.1089/jwh.2011.2947.22092110 | Intervention/Exposure; Population
441. | Overby, NC, Hillesund, ER, Sagedal, LR, Vistad, I, Bere, E. The Fit for Delivery study: rationale for the recommendations and test-retest reliability of a dietary score measuring adherence to 10 specific recommendations for prevention of excessive weight gain during pregnancy. Matern Child Nutr. 2015. 11:20–32. doi:10.1111/mcn.12026.23241065 | Intervention/Exposure; Outcome
442. | Padilha, P, Felizardo, C, Saunders, C, Cunha, L, Pinheiro, A, Belfort, G, Santos, K, Ferreira, N. Consumption of Ultraprocessed Foods by Pregnant Women with Diabetes Mellitus (P11-021-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.P11-021-19. | Abstract
443. | Pajaujiene, S, Dabasinskiene, L, Santos-Rocha, R. Health promotion program for improving women’s body composition and active lifestyle in postpartum: A pilot study. Acta Medica Mediterranea. 2018. 34:1365–1375. doi:10.19193/0393-6384_2018_5_209. | Intervention/Exposure
444. | Paknahad, Z, Fallah, A, Moravejolahkami, AR. Maternal Dietary Patterns and Their Association with Pregnancy Outcomes. Clin Nutr Res. 2019. 8:64–73. doi:10.7762/cnr.2019.8.1.64.30746349 | Outcome
445. | Palmer, JR, Kipping-Ruane, K, Wise, LA, Yu, J, Rosenberg, L. Lactation in Relation to Long-Term Maternal Weight Gain in African-American Women. Am J Epidemiol. 2015. 181:932–9. doi:10.1093/aje/kwv027.25944887 | Intervention/Exposure; Outcome
446. | Papadopoulou, E, Kogevinas, M, Botsivali, M, Pedersen, M, Besselink, H, Mendez, MA, Fleming, S, Hardie, LJ, Knudsen, LE, Wright, J, Agramunt, S, Sunyer, J, Granum, B, Gutzkow, KB, Brunborg, G, Alexander, J, Meltzer, HM, Brantsaeter, AL, Sarri, K, Chatzi, L, Merlo, DF, Kleinjans, JC, Haugen, M. Maternal diet, prenatal exposure to dioxin-like compounds and birth outcomes in a European prospective mother-child study (NewGeneris). Sci Total Environ. 2014. 484:121–8. doi:10.1016/j.scitotenv.2014.03.047.24691212 | Outcome
447. | Parisi, F, Rousian, M, Huijgen, NA, Koning, AHJ, Willemsen, SP, de Vries, JHM, Cetin, I, Steegers, EAP, Steegers-Theunissen, RPM. Periconceptional maternal ‘high fish and olive oil, low meat’ dietary pattern is associated with increased embryonic growth: The Rotterdam Periconceptional Cohort (Predict) Study. Ultrasound Obstet Gynecol. 2017. 50:709–716. doi:10.1002/uog.17408.28078758 | Outcome
448. | Park, HJ, Lee, J, Kim, JM, Lee, HA, Kim, SH, Kim, Y. A study of snack consumption, night-eating habits, and nutrient intake in gestational diabetes mellitus. Clin Nutr Res. 2013. 2:42–51. doi:10.7762/cnr.2013.2.1.42.23431085 | Intervention/Exposure
449. | Parker, H, McCurdy, K, Tovar, A, Vadiveloo, M. The Relationship Between Gestational Weight Gain, Pre-pregnancy BMI, and Prenatal Diet Quality (P18-039-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz039.P18-039-19. | Study Design
450. | Parker, HW, Tovar, A, McCurdy, K, Vadiveloo, M. Associations between pre-pregnancy BMI, gestational weight gain, and prenatal diet quality in a national sample. PLoS One. 2019. 14:e0224034. doi:10.1371/journal.pone.0224034.31626677 | Only presented DP score by GWG, not GWG by DP score
451. | Parlapani, E, Agakidis, C, Karagiozoglou-Lampoudi, T, Sarafidis, K, Agakidou, E, Athanasiadis, A, Diamanti, E. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. J Matern Fetal Neonatal Med. 2017. :1–8. doi:10.1080/14767058.2017.1399120. | Study Design; Diet assessed at same time as weight gain
452. | Pathirathna, ML, Sekijima, K, Sadakata, M, Fujiwara, N, Muramatsu, Y, Wimalasiri, KMS. Impact of Second Trimester Maternal Dietary Intake on Gestational Weight Gain and Neonatal Birth Weight. Nutrients. 2017. 9. doi:10.3390/nu9060627. | Intervention/Exposure
453. | Patwardhan, G, Soni, A, Rachwani, N, Kadam, S, Patole, S, Pandit, A. Factors Associated with Time to Full Feeds in Preterm Very Low Birth Weight Infants. J Trop Pediatr. 2018. 64:495–500. doi:10.1093/tropej/fmx102.29300996 | Outcome; Country
454. | Paul, IM, Williams, JS, Anzman-Frasca, S, Beiler, JS, Makova, KD, Marini, ME, Hess, LB, Rzucidlo, SE, Verdiglione, N, Mindell, JA, Birch, LL. The Intervention Nurses Start Infants Growing on Healthy Trajectories (INSIGHT) study. BMC Pediatr. 2014. 14:184. doi:10.1186/1471-2431-14-184.25037579 | Intervention/Exposure; Outcome
455. | Pauley, AM, Hohman, E, Savage, JS, Rivera, DE, Guo, P, Leonard, KS, Symons Downs, D. Gestational Weight Gain Intervention Impacts Determinants of Healthy Eating and Exercise in Overweight/Obese Pregnant Women. Journal of Obesity. 2018. 2018. doi:10.1155/2018/6469170. | Intervention/Exposure; Comparator
456. | Peccei, A, Blake-Lamb, T, Rahilly, D, Hatoum, I, Bryant, A. Intensive Prenatal Nutrition Counseling in a Community Health Setting. Obstetrics and Gynecology. 2017. 130:423–432. doi:10.1097/AOG.0000000000002134.28697099 | Intervention/Exposure
457. | Pellonpera, O, Koivuniemi, E, Vahlberg, T, Mokkala, K, Tertti, K, Ronnemaa, T, Laitinen, K. Dietary quality influences body composition in overweight and obese pregnant women. Clin Nutr. 2019. 38:1613–1619. doi:10.1016/j.clnu.2018.08.029.30224302 | Outcome; Outcome not reported by DP adherence
458. | Peraita-Costa, I, Llopis-Gonzalez, A, Perales-Marin, A, Sanz, F, Llopis-Morales, A, Morales-Suarez-Varela, M. A Retrospective Cross-Sectional Population-Based Study on Prenatal Levels of Adherence to the Mediterranean Diet: Maternal Profile and Effects on the Newborn. Int J Environ Res Public Health. 2018. 15. doi:10.3390/ijerph15071530. | Study Design
459. | Perez-Ferre, N, Del Valle, L, Torrejon, MJ, Barca, I, Calvo, MI, Matia, P, Rubio, MA, Calle-Pascual, AL. Diabetes mellitus and abnormal glucose tolerance development after gestational diabetes: A three-year, prospective, randomized, clinical-based, Mediterranean lifestyle interventional study with parallel groups. Clin Nutr. 2015. 34:579–85. doi:10.1016/j.clnu.2014.09.005.25262459 | Population; Outcome
460. | Petersen, SB, Rasmussen, MA, Olsen, SF, Vestergaard, P, Mølgaard, C, Halldorsson, T, Strøm, M. Maternal Dietary Patterns during Pregnancy in Relation to Offspring Forearm Fractures: Prospective Study from the Danish National Birth Cohort. Nutrients. 2015. 7:2382–2400. doi:10.3390/nu7042382.25849947 | Outcome
461. | Petrella, E, Bruno, R, Pedrielli, G, Bertarini, V, Neri, I, Facchinetti, F. A customized low glycaemic-index (GI) diet prevents both the gestational diabetes mellitus (GDM) and the large for gestational age (LGA) babies in overweight/obese pregnant women. American journal of obstetrics and gynecology. 2016. 214:S159-. | Abstract
462. | Petrella, E, Facchinetti, F, Bertarini, V, Pignatti, L, Neri, I, Battistini, NC. Occurrence of pregnancy complications in women with BMI >25 submitted to a healthy lifestyle and eating habits program. American journal of obstetrics and gynecology. 2013. 208:S33–S34. doi:10.1016/j.ajog.2012.10.229. | Abstract
463. | Petrella, E, Malavolti, M, Bertarini, V, Pignatti, L, Neri, I, Battistini, NC, Facchinetti, F. Gestational weight gain in overweight and obese women enrolled in a healthy lifestyle and eating habits program. J Matern Fetal Neonatal Med. 2014. 27:1348–52. doi:10.3109/14767058.2013.858318.24175912 | Intervention/Exposure
464. | Phang, M, Dissanayake, HU, McMullan, RL, Hyett, J, Gordon, A, Garg, ML, Skilton, MR. Increased alpha-Linolenic Acid Intake during Pregnancy is Associated with Higher Offspring Birth Weight. Curr Dev Nutr. 2019. 3:nzy081. doi:10.1093/cdn/nzy081.30820488 | Intervention/Exposure; Outcome
465. | Phelan, S, Phipps, MG, Abrams, B, Darroch, F, Grantham, K, Schaffner, A, Wing, RR. Does behavioral intervention in pregnancy reduce postpartum weight retention? Twelve-month outcomes of the Fit for Delivery randomized trial. Am J Clin Nutr. 2014. 99:302–11. doi:10.3945/ajcn.113.070151.24284438 | Intervention/Exposure; Population
466. | Phelan, S, Phipps, MG, Abrams, B, Darroch, F, Schaffner, A, Wing, RR. Randomized trial of a behavioral intervention to prevent excessive gestational weight gain: the fit for delivery study. Obstetrical & gynecological survey. 2011. 66:471–472. doi:10.1097/OGX.0b013e31823520b3. | Editorial comment
467. | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, TA, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, Yin, E, Phipps, MG, Keadle, S, Abrams, B. Randomized controlled clinical trial of behavioral lifestyle intervention with partial meal replacement to reduce excessive gestational weight gain. American Journal of Clinical Nutrition. 2018. 107:183–194. doi:10.1093/ajcn/nqx043. | Intervention/Exposure
468. | Pinto, TJ, Farias, DR, Rebelo, F, Lepsch, J, Vaz, JS, Moreira, JD, Cunha, GM, Kac, G. Lower inter-partum interval and unhealthy life-style factors are inversely associated with n-3 essential fatty acids changes during pregnancy: a prospective cohort with Brazilian women. PLoS One. 2015. 10:e0121151. doi:10.1371/journal.pone.0121151.25822204 | Intervention/Exposure; Outcome
469. | Plante, AS, Savard, C, Lemieux, S, Carbonneau, E, Robitaille, J, Provencher, V, Morisset, AS. Trimester-Specific Intuitive Eating in Association With Gestational Weight Gain and Diet Quality. J Nutr Educ Behav. 2019. 51:677–683. doi:10.1016/j.jneb.2019.01.011.30765299 | Intervention/Exposure; Outcome
470. | Pollak, KI, Alexander, SC, Bennett, G, Lyna, P, Coffman, CJ, Bilheimer, A, Farrell, D, Bodner, ME, Swamy, GK, Ostbye, T. Weight-related SMS texts promoting appropriate pregnancy weight gain: a pilot study. Patient education and counseling. 2014. 97:256–260. doi:10.1016/j.pec.2014.07.030.25153313 | Intervention/Exposure
471. | Pomerleau, CS, Brouwer, RJ, Jones, LT. Weight concerns in women smokers during pregnancy and postpartum. Addict Behav. 2000. 25:759–67.11023016 | Intervention/Exposure
472. | Poston, L, Bell, R, Croker, H, Flynn, AC, Godfrey, KM, Goff, L, Hayes, L, Khazaezadeh, N, Nelson, SM, Oteng-Ntim, E, Pasupathy, D, Patel, N, Robson, SC, Sandall, J, Sanders, TA, Sattar, N, Seed, PT, Wardle, J, Whitworth, MK, Briley, AL. Effect of a behavioural intervention in obese pregnant women (the UPBEAT study): a multicentre, randomised controlled trial. Lancet Diabetes Endocrinol. 2015. 3:767–77. doi:10.1016/s2213-8587(15)00227-2.26165396 | Intervention/Exposure
473. | Pullmer, R, Zaitsoff, S, Cobb, R. Body Satisfaction During Pregnancy: The Role of Health-Related Habit Strength. Matern Child Health J. 2018. 22:391–400. doi:10.1007/s10995-017-2406-9.29190007 | Intervention/Exposure; Outcome
474. | Quick, V, Martin-Biggers, J, Byrd-Bredbenner, C. Moms’ Eating, Sleeping, and Physical Activity Behaviors Differ By Weight Status: Implications for Nutrition Education Interventions. Journal of the Academy of Nutrition & Dietetics. 2016. 116:A24–A24. doi:10.1016/j.jand.2016.06.077. | Conference abstract
475. | Quinlivan, JA, Lam, LT, Fisher, J. A randomised trial of a four-step multidisciplinary approach to the antenatal care of obese pregnant women. Aust N Z J Obstet Gynaecol. 2011. 51:141–6. doi:10.1111/j.1479-828X.2010.01268.x.21466516 | Intervention/Exposure
476. | Quinn, EA, Kuzawa, CW. A dose-response relationship between fish consumption and human milk DHA content among Filipino women in Cebu City, Philippines. Acta Paediatr. 2012. 101:e439–45. doi:10.1111/j.1651-2227.2012.02777.x.22759234 | Outcome
477. | Quinn, EA, Largado, F, Power, M, Kuzawa, CW. Predictors of breast milk macronutrient composition in Filipino mothers. Am J Hum Biol. 2012. 24:533–40. doi:10.1002/ajhb.22266.22434662 | Study Design; Outcome
478. | Radesky, JS, Oken, E, Rifas-Shiman, SL, Kleinman, KP, Rich-Edwards, JW, Gillman, MW. Diet during early pregnancy and development of gestational diabetes. Paediatr Perinat Epidemiol. 2008. 22:47–59. doi:10.1111/j.1365-3016.2007.00899.x.18173784 | Outcome
479. | Radwan, H, Hashim, M, Shaker Obaid, R, Hasan, H, Naja, F, Al Ghazal, H, Jan Jan Mohamed, H, Rizk, R, Al Hilali, M, Rayess, R, Izzaldin, G. The Mother-Infant Study Cohort (MISC): Methodology, challenges, and baseline characteristics. PLoS One. 2018. 13:e0198278. doi:10.1371/journal.pone.0198278.29851999 | Study Design; Intervention/Exposure
480. | Ramage, SM, McCargar, LJ, Berglund, C, Harber, V, Bell, RC. Assessment of Pre-Pregnancy Dietary Intake with a Food Frequency Questionnaire in Alberta Women. Nutrients. 2015. 7:6155–6166. doi:10.3390/nu7085277.26225996 | Outcome
481. | Ramon, R, Ballester, F, Iniguez, C, Rebagliato, M, Murcia, M, Esplugues, A, Marco, A, Garcia de la Hera, M, Vioque, J. Vegetable but not fruit intake during pregnancy is associated with newborn anthropometric measures. J Nutr. 2009. 139:561–7. doi:10.3945/jn.108.095596.19158218 | Intervention/Exposure; Outcome
482. | Rauh, K, Gunther, J, Kunath, J, Stecher, L, Hauner, H. Lifestyle intervention to prevent excessive maternal weight gain: mother and infant follow-up at 12 months postpartum. BMC pregnancy and childbirth. 2015. 15. doi:10.1186/s12884-015-0701-2. | Intervention/Exposure
483. | Redman, LM, Gilmore, LA, Breaux, J, Thomas, DM, Elkind-Hirsch, K, Stewart, T, Hsia, DS, Burton, J, Apolzan, JW, Cain, LE, Altazan, AD, Ragusa, S, Brady, H, Davis, A, Tilford, JM, Sutton, EF, Martin, CK. Effectiveness of SmartMoms, a Novel eHealth Intervention for Management of Gestational Weight Gain: Randomized Controlled Pilot Trial. JMIR Mhealth Uhealth. 2017. 5:e133. doi:10.2196/mhealth.8228.28903892 | Intervention/Exposure
484. | Renault, KM, Carlsen, EM, Norgaard, K, Nilas, L, Pryds, O, Secher, NJ, Cortes, D, Jensen, JE, Olsen, SF, Halldorsson, TI. Intake of carbohydrates during pregnancy in obese women is associated with fat mass in the newborn offspring. Am J Clin Nutr. 2015. 102:1475–81. doi:10.3945/ajcn.115.110551.26561621 | Intervention/Exposure; Outcome
485. | Renault, KM, Carlsen, EM, Norgaard, K, Nilas, L, Pryds, O, Secher, NJ, Olsen, SF, Halldorsson, TI. Intake of Sweets, Snacks and Soft Drinks Predicts Weight Gain in Obese Pregnant Women: Detailed Analysis of the Results of a Randomised Controlled Trial. PLoS One. 2015. 10:e0133041. doi:10.1371/journal.pone.0133041.26192183 | Intervention/Exposure
486. | Renault, KM, Norgaard, K, Nilas, L, Carlsen, EM, Cortes, D, Pryds, O, Secher, NJ. The Treatment of Obese Pregnant Women (TOP) study: a randomized controlled trial of the effect of physical activity intervention assessed by pedometer with or without dietary intervention in obese pregnant women. Am J Obstet Gynecol. 2014. 210:134.e1–9. doi:10.1016/j.ajog.2013.09.029.24060449 | Intervention/Exposure
487. | Renzaho, AM, Skouteris, H, Oldroyd, J. Preventing gestational diabetes mellitus among migrant women and reducing obesity and type 2 diabetes in their offspring: a call for culturally competent lifestyle interventions in pregnancy. J Am Diet Assoc. 2010. 110:1814–7. doi:10.1016/j.jada.2010.09.017.21111090 | Study Design
488. | Rerkasem, K, Wongthanee, A, Rerkasem, A, Chiowanich, P, Sritara, P, Pruenglampoo, S, Mangklabruks, A. Intrauterine nutrition and carotid intimal media thickness in young Thai adults. Asia Pac J Clin Nutr. 2012. 21:247–52.22507612 | Outcome
489. | Reyes, L, Garcia, R, Ruiz, S, Dehghan, M, Lopez-Jaramillo, P. Nutritional status among women with pre-eclampsia and healthy pregnant and non-pregnant women in a Latin American country. J Obstet Gynaecol Res. 2012. 38:498–504. doi:10.1111/j.1447-0756.2011.01763.x.22353171 | Study Design; Outcome
490. | Rhodes, ET, Pawlak, DB, Takoudes, TC, Ebbeling, CB, Feldman, HA, Lovesky, MM, Cooke, EA, Leidig, MM, Ludwig, DS. Effects of a low-glycemic load diet in overweight and obese pregnant women: a pilot randomized controlled trial. Am J Clin Nutr. 2010. 92:1306–15. doi:10.3945/ajcn.2010.30130.20962162 | Intervention/Exposure
491. | Rich-Edwards, JW, Stuart, JJ, Skurnik, G, Roche, AT, Tsigas, E, Fitzmaurice, GM, Wilkins-Haug, LE, Levkoff, SE, Seely, EW. Randomized Trial to Reduce Cardiovascular Risk in Women with Recent Preeclampsia. J Womens Health (Larchmt). 2019. doi:10.1089/jwh.2018.7523. | Population; Outcome
492. | Rodriguez-Bernal, CL, Rebagliato, M, Iniguez, C, Vioque, J, Navarrete-Munoz, EM, Murcia, M, Bolumar, F, Marco, A, Ballester, F. Diet quality in early pregnancy and its effects on fetal growth outcomes: the Infancia y Medio Ambiente (Childhood and Environment) Mother and Child Cohort Study in Spain. Am J Clin Nutr. 2010. 91:1659–66. doi:10.3945/ajcn.2009.28866.20410088 | Outcome
493. | Rogers, I, Emmett, P, Ness, A, Golding, J. Maternal fish intake in late pregnancy and the frequency of low birth weight and intrauterine growth retardation in a cohort of British infants. J Epidemiol Community Health. 2004. 58:486–92. doi:10.1136/jech.2003.013565.15143117 | Intervention/Exposure; Outcome
494. | Rohatgi, KW, Tinius, RA, Cade, WT, Steele, EM, Cahill, AG, Parra, DC. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017. 5:e4091. doi:10.7717/peerj.4091.29230355 | Study Design
495. | Romon, M, Nuttens, MC, Vambergue, A, Verier-Mine, O, Biausque, S, Lemaire, C, Fontaine, P, Salomez, JL, Beuscart, R. Higher carbohydrate intake is associated with decreased incidence of newborn macrosomia in women with gestational diabetes. J Am Diet Assoc. 2001. 101:897–902. doi:10.1016/s0002-8223(01)00220-6.11501863 | Outcome
496. | Ruiz-Gracia, T, Duran, A, Fuentes, M, Rubio, MA, Runkle, I, Carrera, EF, Torrejon, MJ, Bordiu, E, Valle, LD, Garcia de la Torre, N, Bedia, AR, Montanez, C, Familiar, C, Calle-Pascual, AL. Lifestyle patterns in early pregnancy linked to gestational diabetes mellitus diagnoses when using IADPSG criteria. The St Carlos gestational study. Clin Nutr. 2016. 35:699–705. doi:10.1016/j.clnu.2015.04.017.25998584 | Intervention/Exposure
497. | Sally, EOF, Anjos, LAD, Ramos, EG, Fonseca, VM, Silva, Bamd, Wahrlich, V. Dietary intake of pregnant adolescents cared for in primary health care units of a Brazilian urban municipality. Nutr Hosp. 2018. 35:596–605. doi:10.20960/nh.1412.29974768 | Intervention/Exposure; Outcome
498. | Salmenhaara, M, Uusitalo, L, Uusitalo, U, Kronberg-Kippila, C, Sinkko, H, Ahonen, S, Veijola, R, Knip, M, Kaila, M, Virtanen, SM. Diet and weight gain characteristics of pregnant women with gestational diabetes. Eur J Clin Nutr. 2010. 64:1433–40. doi:10.1038/ejcn.2010.167.20808329 | Intervention/Exposure; Outcome
499. | Salunkhe, AH, Pratinidhi, A, Salunkhe, JA, Kakade, SV, Mohite, VR, Hiremath, P. Frequency and nutrient content of meals of the mothers and the birth weight and gestational age of the baby. Journal of Krishna Institute of Medical Sciences University. 2018. 7:33–41. | Outcome
500. | Samur, G, Akkus, Ö Ö, Ede, G, Ayaz, A, Akyol, A, Akkus, M, Danisman, N. Nutritional status among women with preeclampsia and healthy pregnant women. Progress in Nutrition. 2016. 18:360–368. | Study Design; Intervention/Exposure
501. | Santos, KD, Moreira, TM, Belfort, GP, Silva, Cfmd, Padilha, PC, Barros, DC, Saunders, C. Adaptation of DASH diet (Dietary Approach to Stop Hypertension) for postpartum nutritional care at primary healthcare. Rev Bras Epidemiol. 2019. 22:e190035. doi:10.1590/1980-549720190035.31038616 | Outcome
502. | Sartorelli, DS, Barbieri, P, Perdona, GC. Fried food intake estimated by the multiple source method is associated with gestational weight gain. Nutr Res. 2014. 34:667–73. doi:10.1016/j.nutres.2014.07.008.25176040 | Intervention/Exposure
503. | Sauder, KA, Starling, AP, Shapiro, AL, Kaar, JL, Ringham, BM, Glueck, DH, Leiferman, JA, Siega-Riz, AM, Dabelea, D. Diet, physical activity and mental health status are associated with dysglycaemia in pregnancy: the Healthy Start Study. Diabet Med. 2016. 33:663–7. doi:10.1111/dme.13093.26872289 | Intervention/Exposure; Outcome
504. | Saunders, L, Guldner, L, Costet, N, Kadhel, P, Rouget, F, Monfort, C, Thome, JP, Multigner, L, Cordier, S. Effect of a Mediterranean diet during pregnancy on fetal growth and preterm delivery: results from a French Caribbean Mother-Child Cohort Study (TIMOUN). Paediatr Perinat Epidemiol. 2014. 28:235–44. doi:10.1111/ppe.12113.24754337 | Study Design; Diet assessed after delivery
505. | Savard, C, Lemieux, S, Carbonneau, E, Provencher, V, Gagnon, C, Robitaille, J, Morisset, AS. Trimester-Specific Assessment of Diet Quality in a Sample of Canadian Pregnant Women. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16030311. | Outcome
506. | Schoenaker, DA, Soedamah-Muthu, SS, Callaway, LK, Mishra, GD. Pre-pregnancy dietary patterns and risk of gestational diabetes mellitus: results from an Australian population-based prospective cohort study. Diabetologia. 2015. 58:2726–35. doi:10.1007/s00125-015-3742-1.26358582 | Population; Outcome
507. | Schoenaker, DA, Soedamah-Muthu, SS, Mishra, GD. Quantifying the mediating effect of body mass index on the relation between a Mediterranean diet and development of maternal pregnancy complications: the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr. 2016. 104:638–45. doi:10.3945/ajcn.116.133884.27465377 | Outcome
508. | Sedaghat, F, Akhoondan, M, Ehteshami, M, Aghamohammadi, V, Ghanei, N, Mirmiran, P, Rashidkhani, B. Maternal Dietary Patterns and Gestational Diabetes Risk: A Case-Control Study. Journal of Diabetes Research. 2017. 2017. doi:10.1155/2017/5173926. | Outcome
509. | Senol Eren, N, Sencan, I, Aksoy, H, Koc, EM, Kasim, I, Kahveci, R, Samur, G, Ozkara, A. Evaluation of dietary habits during pregnancy. Turk J Obstet Gynecol. 2015. 12:89–95. doi:10.4274/tjod.79923.28913050 | Study Design; Intervention/Exposure
510. | Shah, BS, Freeland-Graves, JH, Cahill, JM, Lu, H, Graves, GR. Diet quality as measured by the healthy eating index and the association with lipid profile in low-income women in early postpartum. J Am Diet Assoc. 2010. 110:274–9. doi:10.1016/j.jada.2009.10.038.20102856 | Population
511. | Shankar, K, Zhong, Y, Kang, P, Chintapalli, S, Thakali, K, Piccolo, B, Andres, A. Maternal BMI Modulates Placental Expression of Lipid Transport, Metabolism and Innate Immune Response Genes at Term (OR35-01-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR35-01-19. | Abstract
512. | Shapiro, AL, Kaar, JL, Crume, TL, Starling, AP, Siega-Riz, AM, Ringham, BM, Glueck, DH, Norris, JM, Barbour, LA, Friedman, JE, Dabelea, D. Maternal diet quality in pregnancy and neonatal adiposity: the Healthy Start Study. Int J Obes (Lond). 2016. 40:1056–62. doi:10.1038/ijo.2016.79.27133623 | Outcome
513. | Sharma, SS, Greenwood, DC, Simpson, NAB, Cade, JE. Is dietary macronutrient composition during pregnancy associated with offspring birth weight? An observational study. Br J Nutr. 2018. 119:330–339. doi:10.1017/s0007114517003609.29316991 | Intervention/Exposure; Outcome
514. | Sharma, SV, Chuang, RJ, Byrd-Williams, C, Danho, M, Upadhyaya, M, Berens, P, Hoelscher, DM. Pilot evaluation of HEAL - A natural experiment to promote obesity prevention behaviors among low-income pregnant women. Prev Med Rep. 2018. 10:254–262. doi:10.1016/j.pmedr.2018.04.005.29868377 | Intervention/Exposure; Outcome
515. | Shieh, C, Yang, Z, Haas, DM, Carpenter, JS. Feasibility and Potential Benefits of a Self-Monitoring Enhanced Lifestyle Intervention to Prevent Excessive Gestational Weight Gain in Women Who Are Overweight or Obese. J Obstet Gynecol Neonatal Nurs. 2017. 46:182–196. doi:10.1016/j.jogn.2016.09.006. | Intervention/Exposure
516. | Shiell, AW, Campbell-Brown, M, Haselden, S, Robinson, S, Godfrey, KM, Barker, DJ. High-meat, low-carbohydrate diet in pregnancy: relation to adult blood pressure in the offspring. Hypertension. 2001. 38:1282–8.11751704 | Outcome; Comparator
517. | Shyam, S, Fatimah, A, Rohana, AG, Norasyikin, AW, Nik Shanita, S, Chinna, K, Mohd. Yusof, BN, Nor Azmi, K. Effect of Including Glycaemic Index (GI) Nutrition Education, within the Conventional Healthy Dietary Recommendation Framework, on Body Weight and Composition of Women with Prior Gestational Diabetes Mellitus: Results from a One-Year Randomised Controlled Trial. Malaysian Journal of Nutrition. 2015. 21:269–283. | Intervention/Exposure; Population
518. | Siegmund, T, Rad, NT, Ritterath, C, Siebert, G, Henrich, W, Buhling, KJ. Longitudinal changes in the continuous glucose profile measured by the CGMS in healthy pregnant women and determination of cut-off values. Eur J Obstet Gynecol Reprod Biol. 2008. 139:46–52. doi:10.1016/j.ejogrb.2007.12.006.18262325 | Outcome; Comparator
519. | Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, L, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JG, van Poppel, MN. Effect of Physical Activity and/or Healthy Eating on GDM Risk: The DALI Lifestyle Study. J Clin Endocrinol Metab. 2017. 102:903–913. doi:10.1210/jc.2016-3455.27935767 | Intervention/Exposure
520. | Simmons, D, Jelsma, JG, Galjaard, S, Devlieger, R, van Assche, A, Jans, G, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Lapolla, A, Dalfra, M, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Rebollo, P, Snoek, FJ, van Poppel, MN. Results From a European Multicenter Randomized Trial of Physical Activity and/or Healthy Eating to Reduce the Risk of Gestational Diabetes Mellitus: The DALI Lifestyle Pilot. Diabetes Care. 2015. 38:1650–6. doi:10.2337/dc15-0360.26112044 | Intervention/Exposure
521. | Simmons, D, Devlieger, R, van Assche, A, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ. Association between Gestational Weight Gain, Gestational Diabetes Risk, and Obstetric Outcomes: A Randomized Controlled Trial Post Hoc Analysis. Nutrients. 2018. 10:1568. doi:10.3390/nu10111568. | Intervention/Exposure
522. | Simoes-Wust, AP, Molto-Puigmarti, C, Jansen, EH, van Dongen, MC, Dagnelie, PC, Thijs, C. Organic food consumption during pregnancy and its association with health-related characteristics: the KOALA Birth Cohort Study. Public Health Nutr. 2017. 20:2145–2156. doi:10.1017/s1368980017001215.28625206 | Intervention/Exposure
523. | Singh, SB, Madan, J, Coker, M, Hoen, A, Baker, ER, Karagas, MR, Mueller, NT. Does birth mode modify associations of maternal pre-pregnancy BMI and gestational weight gain with the infant gut microbiome? Int J Obes (Lond). 2019. doi:10.1038/s41366-018-0273-0. | Intervention/Exposure
524. | Singhal, A, Kennedy, K, Lanigan, J, Fewtrell, M, Cole, TJ, Stephenson, T, Elias-Jones, A, Weaver, LT, Ibhanesebhor, S, MacDonald, PD, Bindels, J, Lucas, A. Nutrition in infancy and long-term risk of obesity: evidence from 2 randomized controlled trials. Am J Clin Nutr. 2010. 92:1133–44. doi:10.3945/ajcn.2010.29302.20881062 | Intervention/Exposure; Outcome
525. | Skaug, MA, Helland, I, Solvoll, K, Saugstad, OD. Presence of ochratoxin A in human milk in relation to dietary intake. Food Addit Contam. 2001. 18:321–7. doi:10.1080/02652030117740.11339267 | Outcome
526. | Skreden, M, Bere, E, Sagedal, LR, Vistad, I, Overby, NC. Changes in fruit and vegetable consumption habits from pre-pregnancy to early pregnancy among Norwegian women. BMC Pregnancy Childbirth. 2017. 17:107. doi:10.1186/s12884-017-1291-y.28376732 | Intervention/Exposure
527. | Skreden, M, Hillesund, ER, Wills, AK, Brantsaeter, AL, Bere, E, Overby, NC. Adherence to the New Nordic Diet during pregnancy and subsequent maternal weight development: a study conducted in the Norwegian Mother and Child Cohort Study (MoBa). Br J Nutr. 2018. 119:1286–1294. doi:10.1017/s0007114518000776.29770760 | Intervention/Exposure; Population
528. | Slane, JD, Levine, MD. Association of Restraint and Disinhibition to Gestational Weight Gain among Pregnant Former Smokers. Womens Health Issues. 2015. 25:390–5. doi:10.1016/j.whi.2015.03.005.26048757 | Intervention/Exposure
529. | Sloan, NL, Lederman, SA, Leighton, J, Himes, JH, Rush, D. The effect of prenatal dietary protein intake on birth weight. Nutrition Research. 2001. 21:129–139. doi:10.1016/S0271-5317(00)00258-X. | Intervention/Exposure; Data collected in 1983
530. | Sommer, C, Sletner, L, Jenum, AK, Mrkrid, K, Andersen, LF, Birkeland, K, Mosdl, A. Ethnic differences in maternal dietary patterns are largely explained by socioeconomic score and integration score: a population-based study. Food & Nutrition Research. 2013. 57:1–12. doi:10.3402/fnr.v57i0.21164. | Study Design; Outcome
531. | Sotres-Alvarez, D, Herring, AH, Siega-Riz, AM. Latent transition models to study women’s changing of dietary patterns from pregnancy to 1 year postpartum. Am J Epidemiol. 2013. 177:852–61. doi:10.1093/aje/kws303.23538942 | Outcome
532. | Spencer, L, Rollo, M, Hutchesson, M, Collins, C. Perceived healthy eating and physical activity factors influencing weight management in postpartum women: A mixed methods analysis. Obesity Research & Clinical Practice. 2014. 8:96–96. doi:10.1016/j.orcp.2014.10.176. | Conference abstract
533. | Sridhar, SB, Darbinian, J, Ehrlich, SF, Markman, MA, Gunderson, EP, Ferrara, A, Hedderson, MM. Maternal gestational weight gain and offspring risk for childhood overweight or obesity. Am J Obstet Gynecol. 2014. 211:259.e1–8. doi:10.1016/j.ajog.2014.02.030.24735804 | Intervention/Exposure; Outcome
534. | Stendell-Hollis, NR, Laudermilk, MJ, West, JL, Thompson, PA, Thomson, CA. Recruitment of lactating women into a randomized dietary intervention: successful strategies and factors promoting enrollment and retention. Contemp Clin Trials. 2011. 32:505–11. doi:10.1016/j.cct.2011.03.007.21382511 | Study Design; Outcome
535. | Stephens, TV, Woo, H, Innis, SM, Elango, R. Healthy pregnant women in Canada are consuming more dietary protein at 16- and 36-week gestation than currently recommended by the Dietary Reference Intakes, primarily from dairy food sources. Nutr Res. 2014. 34:569–76. doi:10.1016/j.nutres.2014.07.001.25150115 | Study Design; Intervention/Exposure
536. | Stuebe, AM, Oken, E, Gillman, MW. Associations of diet and physical activity during pregnancy with risk for excessive gestational weight gain. Am J Obstet Gynecol. 2009. 201:58.e1–8. doi:10.1016/j.ajog.2009.02.025.19467640 | Intervention/Exposure
537. | Su, T, Lu, J, Ma, H. Lifestyle intervention prevents pregnant woman from gestational diabetes mellitus: a Chinese randomized controlled trial. International journal of clinical and experimental medicine. 2016. 9:23584–23590. | Intervention/Exposure
538. | Suliga, E, Adamczyk-Gruszka, OK. Health behaviours of pregnant women and gestational weight gains -A pilot study. Medical Studies/Studia Medyczne. 2015. 31:161–167. doi:10.5114/ms.2015.54753. | Diet assessed at same time as final weight
539. | Suliga, E, Rokita, W, Adamczyk-Gruszka, O, Pazera, G, Ciesla, E, Gluszek, S. Factors associated with gestational weight gain: a cross-sectional survey. BMC Pregnancy Childbirth. 2018. 18:465. doi:10.1186/s12884-018-2112-7.30509248 | Study Design
540. | Surendran, S, Aji, AS, Ariyasra, U, Sari, SR, Malik, SG, Tasrif, N, Yani, FF, Lovegrove, JA, Sudji, IR, Lipoeto, NI, Vimaleswaran, KS. A nutrigenetic approach for investigating the relationship between vitamin B12 status and metabolic traits in Indonesian women. J Diabetes Metab Disord. 2019. 18(2):389–399. doi:10.1007/s40200-019-00424-z.31890664 | Study Design
541. | Swendeman, D, Comulada, WS, Koussa, M, Worthman, CM, Estrin, D, Rotheram-Borus, MJ, Ramanathan, N. Longitudinal Validity and Reliability of Brief Smartphone Self-Monitoring of Diet, Stress, and Physical Activity in a Diverse Sample of Mothers. JMIR Mhealth Uhealth. 2018. 6:e176. doi:10.2196/mhealth.9378.30249576 | Intervention/Exposure; Population
542. | Swensen, AR, Harnack, LJ, Ross, JA. Nutritional assessment of pregnant women enrolled in the Special Supplemental Program for Women, Infants, and Children (WIC). J Am Diet Assoc. 2001. 101:903–8. doi:10.1016/s0002-8223(01)00221-8.11501864 | Study Design; Outcome
543. | Switkowski, KM, Jacques, PF, Must, A, Hivert, MF, Fleisch, A, Gillman, MW, Rifas-Shiman, S, Oken, E. Higher Maternal Protein Intake during Pregnancy Is Associated with Lower Cord Blood Concentrations of Insulin-like Growth Factor (IGF)-II, IGF Binding Protein 3, and Insulin, but Not IGF-I, in a Cohort of Women with High Protein Intake. J Nutr. 2017. 147:1392–1400. doi:10.3945/jn.117.250589.28592512 | Intervention/Exposure; Outcome
544. | Szmeja, MA, Cramp, C, Grivell, RM, Deussen, AR, Yelland, LN, Dodd, JM. Use of a DVD to provide dietary and lifestyle information to pregnant women who are overweight or obese: a nested randomised trial. BMC Pregnancy Childbirth. 2014. 14:409. doi:10.1186/s12884-014-0409-8.25495459 | Intervention/Exposure; Outcome
545. | Tadayon, M, Khavayet, F, Abedi, P, Malehi, AS. The relationship between maternal lifestyle and children’s body mass index: A cross-sectional study in Abadan, Iran. Journal of Midwifery & Reproductive Health. 2019. 7:1824–1833. doi:10.22038/jmrh.2019.24445.1263. | Study Design; Intervention/Exposure
546. | Tahir, MJ, Haapala, JL, Foster, LP, Duncan, KM, Teague, AM, Kharbanda, EO, McGovern, PM, Whitaker, KM, Rasmussen, KM, Fields, DA, Jacobs, DR, Jr, Harnack, LJ, Demerath, EW. Higher Maternal Diet Quality during Pregnancy and Lactation Is Associated with Lower Infant Weight-For-Length, Body Fat Percent, and Fat Mass in Early Postnatal Life. Nutrients. 2019. 11. doi:10.3390/nu11030632. | Study Design
547. | Talai Rad, N, Ritterath, C, Siegmund, T, Wascher, C, Siebert, G, Henrich, W, Buhling, KJ. Longitudinal analysis of changes in energy intake and macronutrient composition during pregnancy and 6 weeks post-partum. Arch Gynecol Obstet. 2011. 283:185–90. doi:10.1007/s00404-009-1328-1.20024570 | Outcome; Comparator
548. | Tavares, MP, Devincenzi, MU, Sachs, A, de Vilhena Abrão, ACF. Nutritional status and diet quality of nursing mothers on exclusive breastfeeding. Acta Paulista de Enfermagem. 2013. 26:294–298. | Study Design; Outcome
549. | Taveras, E, Blackburn, K, Gillman, M, Haines, J, McDonald, J, Price, S, Oken, E. First Steps for Mommy and Me: A Pilot Intervention to Improve Nutrition and Physical Activity Behaviors of Postpartum Mothers and Their Infants. Maternal & Child Health Journal. 2011. 15:1217–1227. doi:10.1007/s10995-010-0696-2.20957514 | Intervention/Exposure; Outcome
550. | Teixeira, VH, Moreira, P. Maternal food intake and socioeconomic status to tackle childhood malnutrition. Jornal de Pediatria. 2016. 92:546–548. doi:10.1016/j.jped.2016.08.002.27542915 | Editorial
551. | Thomas Berube, L, Messito, MJ, Woolf, K, Deierlein, A, Gross, R. Correlates of Prenatal Diet Quality in Low-Income Hispanic Women. J Acad Nutr Diet. 2019. doi:10.1016/j.jand.2019.02.004. | Study Design; Outcome
552. | Thomson, JL, Tussing-Humphreys, LM, Goodman, MH, Olender, S. Baseline Demographic, Anthropometric, Psychosocial, and Behavioral Characteristics of Rural, Southern Women in Early Pregnancy. Matern Child Health J. 2016. 20:1980–8. doi:10.1007/s10995-016-2016-y.27146396 | Study Design
553. | Thomson, JL, Tussing-Humphreys, LM, Goodman, MH, Olender, SE. Gestational Weight Gain: Results from the Delta Healthy Sprouts Comparative Impact Trial. J Pregnancy. 2016. 2016:5703607. doi:10.1155/2016/5703607.27595023 | Intervention/Exposure
554. | Thomson, JL, Tussing-Humphreys, LM, Goodman, MH. Delta Healthy Sprouts: a randomized comparative effectiveness trial to promote maternal weight control and reduce childhood obesity in the Mississippi Delta. Contemp Clin Trials. 2014. 38:82–91. doi:10.1016/j.cct.2014.03.004.24685997 | Study Design; No Results
555. | Tian, HM, Wu, YX, Lin, YQ, Chen, XY, Yu, M, Lu, T, Xie, L. Dietary patterns affect maternal macronutrient intake levels and the fatty acid profile of breast milk in lactating Chinese mothers. Nutrition. 2019. 58:83–88. doi:10.1016/j.nut.2018.06.009.30391695 | Study Design
556. | Tielemans, MJ, Erler, NS, Franco, OH, Jaddoe, VWV, Steegers, EAP, Kiefte-de jong, JC. Dietary acid load and blood pressure development in pregnancy: The Generation R Study. Clinical Nutrition. 2018. 37:597–603. doi:10.1016/j.clnu.2017.01.013.28189385 | Outcome; Association btw DP and GWG not analyzed
557. | Timmermans, S, Steegers-Theunissen, RP, Vujkovic, M, den Breeijen, H, Russcher, H, Lindemans, J, Mackenbach, J, Hofman, A, Lesaffre, EE, Jaddoe, VV, Steegers, EA. The Mediterranean diet and fetal size parameters: the Generation R Study. Br J Nutr. 2012. 108:1399–409. doi:10.1017/s000711451100691x.22348517 | Outcome
558. | Tobias, DK, Hu, FB, Chavarro, J, Rosner, B, Mozaffarian, D, Zhang, C. Healthful dietary patterns and type 2 diabetes mellitus risk among women with a history of gestational diabetes mellitus. Arch Intern Med. 2012. 172:1566–72. doi:10.1001/archinternmed.2012.3747.22987062 | Population; Outcome
559. | Torjusen, H, Brantsaeter, AL, Haugen, M, Lieblein, G, Stigum, H, Roos, G, Holmboe-Ottesen, G, Meltzer, HM. Characteristics associated with organic food consumption during pregnancy; data from a large cohort of pregnant women in Norway. BMC Public Health. 2010. 10:775. doi:10.1186/1471-2458-10-775.21172040 | Outcome
560. | Tovar, A, Guthrie, LB, Platek, D, Stuebe, A, Herring, SJ, Oken, E. Modifiable predictors associated with having a gestational weight gain goal. Matern Child Health J. 2011. 15:1119–26. doi:10.1007/s10995-010-0659-7.20711804 | Intervention/Exposure; Outcome
561. | Tovar, A, Kaar, JL, McCurdy, K, Field, AE, Dabelea, D, Vadiveloo, M. Maternal vegetable intake during and after pregnancy. BMC Pregnancy Childbirth. 2019. 19:267. doi:10.1186/s12884-019-2353-0.31349808 | Intervention/Exposure; Outcome
562. | Tovar, A, Must, A, Bermudez, OI, Hyatt, RR, Chasan-Taber, L. The impact of gestational weight gain and diet on abnormal glucose tolerance during pregnancy in Hispanic women. Matern Child Health J. 2009. 13:520–30. doi:10.1007/s10995-008-0381-x.18597166 | Intervention/Exposure
563. | Trak-Fellermeier, MA, Campos, M, Melendez, M, Pomeroy, J, Palacios, C, Rivera-Vinas, J, Mendez, K, Febo, I, Willett, W, Gillman, MW, Franks, PW, Joshipura, K. PEARLS randomized lifestyle trial in pregnant Hispanic women with overweight/obesity: gestational weight gain and offspring birthweight. Diabetes Metab Syndr Obes. 2019. 12:225–238. doi:10.2147/dmso.S179009.30858715 | Intervention/Exposure
564. | Trude, A, Black, M, Hurley, K, Ojeda, LC, Wang, Y. Maternal Anxiety Symptoms and Mother-toddler Diet Quality Among WIC Participants (OR03-08-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR03-08-19. | Abstract
565. | Tryggvadottir, EA, Medek, H, Birgisdottir, BE, Geirsson, RT, Gunnarsdottir, I. Association between healthy maternal dietary pattern and risk for gestational diabetes mellitus. Eur J Clin Nutr. 2016. 70:237–42. doi:10.1038/ejcn.2015.145.26350393 | Outcome
566. | Turner, RE, Langkamp-Henken, B, Littell, RC, Lukowski, MJ, Suarez, MF. Comparing nutrient intake from food to the estimated average requirements shows middle- to upper-income pregnant women lack iron and possibly magnesium. Journal of the American Dietetic Association. 2003. 103:461–466.12669009 | Intervention/Exposure
567. | Tussing-Humphreys, LM, Thomson, JL, Goodman, MH, Olender, S. Maternal diet quality and nutrient intake in the gestational period: results from the delta healthy sprouts comparative impact trial. Matern Health Neonatol Perinatol. 2016. 2:8. doi:10.1186/s40748-016-0036-7.27536380 | Outcome
568. | Uusitalo, U, Arkkola, T, Ovaskainen, ML, Kronberg-Kippila, C, Kenward, MG, Veijola, R, Simell, O, Knip, M, Virtanen, SM. Unhealthy dietary patterns are associated with weight gain during pregnancy among Finnish women. Public Health Nutr. 2009. 12:2392–9. doi:10.1017/s136898000900528x.19323867 | Study Design; Diet assessed at same time as GWG
569. | Vahamiko, S, Isolauri, E, Laitinen, K. Weight status and dietary intake determine serum leptin concentrations in pregnant and lactating women and their infants. Br J Nutr. 2013. 110:1098–106. doi:10.1017/s0007114513000214.23432806 | Intervention/Exposure
570. | Vahamiko, S, Isolauri, E, Pesonen, U, Koskinen, P, Ekblad, U, Laitinen, K. Dietary sucrose intake is related to serum leptin concentration in overweight pregnant women. Eur J Nutr. 2010. 49:83–90. doi:10.1007/s00394-009-0052-8.19727896 | Intervention/Exposure
571. | Valkama, A, Koivusalo, S, Lindstrom, J, Meinila, J, Kautiainen, H, Stach-Lempinen, B, Rono, K, Klemetti, M, Poyhonen-Alho, M, Tiitinen, A, Huvinen, E, Laivuori, H, Andersson, S, Roine, R, Eriksson, JG. The effect of dietary counselling on food intakes in pregnant women at risk for gestational diabetes: a secondary analysis of a randomised controlled trial RADIEL. Eur J Clin Nutr. 2016. 70:912–7. doi:10.1038/ejcn.2015.205.26669570 | Intervention/Exposure; Outcome
572. | Valkama, AJ, Meinila, JM, Koivusalo, SB, Lindstrom, J, Rono, K, Stach-Lempinen, B, Eriksson, JG. Diet quality as assessed by the Healthy Food Intake Index and relationship with serum lipoprotein particles and serum fatty acids in pregnant women at increased risk for gestational diabetes. Br J Nutr. 2018. 120:914–924. doi:10.1017/s0007114518002404.30223910 | Outcome
573. | van der Wijden, CL, Steinbach, S, van der Ploeg, HP, van Mechelen, W, van Poppel, MN. A longitudinal study on the relationship between eating style and gestational weight gain. Appetite. 2014. 83:304–8. doi:10.1016/j.appet.2014.09.001.25218880 | Intervention/Exposure
574. | van Elten, TM, Karsten, MDA, Geelen, A, Gemke, Rjbj, Groen, H, Hoek, A, van Poppel, MNM, Roseboom, TJ. Preconception lifestyle intervention reduces long term energy intake in women with obesity and infertility: a randomised controlled trial. Int J Behav Nutr Phys Act. 2019. 16:3. doi:10.1186/s12966-018-0761-6.30621789 | Intervention/Exposure; Population
575. | van Poppel, MNM, Jelsma, JGM, Simmons, D, Devlieger, R, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Tanvig, M, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Desoye, G, Snoek F J. Mediators of lifestyle behaviour changes in obese pregnant women. Secondary analyses from the DALI lifestyle randomised controlled trial. Nutrients. 2019. 11. doi:10.3390/nu11020311. | Outcome
576. | Vander Wyst, KB, Vercelli, ME, O’Brien, KO, Cooper, EM, Pressman, EK, Whisner, CM. A social media intervention to improve nutrition knowledge and behaviors of low income, pregnant adolescents and adult women. PLoS One. 2019. 14:e0223120. doi:10.1371/journal.pone.0223120.31647852 | Comparator
577. | Vandyousefi, S, Whaley, S, Asigbee, F, Landry, M, Ghaddar, R, Davis, J. Association of Breastfeeding and Sugar-Sweetened Beverage Consumption with Obesity Prevalence in Offspring Born to Mothers with and Without Gestational Diabetes Mellitus (P11-098-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.P11-098-19. | Abstract
578. | Vega-Lopez, S, Pignotti, GA, Todd, M, Keller, C. Egg Intake and Dietary Quality among Overweight and Obese Mexican-American Postpartum Women. Nutrients. 2015. 7:8402–12. doi:10.3390/nu7105402.26445060 | Outcome
579. | Ventegodt, S, Flensborg-Madsen, T, Andersen, NJ, Merrick, J. Which factors determine our quality of life, health and ability? Results from a Danish population sample and the Copenhagen Perinatal Cohort. Journal of the College of Physicians and Surgeons Pakistan. 2008. 18:445–450. doi:10.1017/BJN20061929.18760073 | Study Design; Outcome
580. | Vesco, K, Leo, M, Gillman, M, King, J, McEvoy, C, Karanjaa, N, Perrin, N, Eckhardt, C, Smith, KS, Stevens, V. Impact of a weight management intervention on pregnancy outcomes among obese women: the Healthy Moms Trial. American journal of obstetrics and gynecology. 2013. 208:S352. doi:10.1016/j.ajog.2012.12.009. | Abstract
581. | Vesco, KK, Karanja, N, King, JC, Gillman, MW, Leo, MC, Perrin, N, McEvoy, CT, Eckhardt, CL, Smith, KS, Stevens, VJ. Efficacy of a group-based dietary intervention for limiting gestational weight gain among obese women: a randomized trial. Obesity (Silver Spring). 2014. 22:1989–96. doi:10.1002/oby.20831.25164259 | Intervention/Exposure
582. | Vieten, C, Laraia, BA, Kristeller, J, Adler, N, Coleman-Phox, K, Bush, NR, Wahbeh, H, Duncan, LG, Epel, E. The mindful moms training: development of a mindfulness-based intervention to reduce stress and overeating during pregnancy. BMC Pregnancy Childbirth. 2018. 18:201. doi:10.1186/s12884-018-1757-6.29859038 | Intervention/Exposure; Outcome
583. | Vilela, AA, Pinto Tde, J, Rebelo, F, Benaim, C, Lepsch, J, Dias-Silva, CH, Castro, MB, Kac, G. Association of Prepregnancy Dietary Patterns and Anxiety Symptoms from Midpregnancy to Early Postpartum in a Prospective Cohort of Brazilian Women. J Acad Nutr Diet. 2015. 115:1626–35. doi:10.1016/j.jand.2015.01.007.25769749 | Outcome
584. | Villar-Vidal, M, Amiano, P, Rodriguez-Bernal, C, Santa Marina, L, Mozo, I, Vioque, J, Navarrete-Munoz, EM, Romaguera, D, Valvi, D, Fernandez Samoano, A, Tardon, A, Ibarluzea, J. Compliance of nutritional recommendations of Spanish pregnant women according to sociodemographic and lifestyle characteristics: a cohort study. Nutr Hosp. 2015. 31:1803–12. doi:10.3305/nh.2015.31.4.8293.25795974 | Study Design
585. | Vinter, CA, Jensen, DM, Ovesen, P, Beck-Nielsen, H, Tanvig, M, Lamont, RF, Jorgensen, JS. Postpartum weight retention and breastfeeding among obese women from the randomized controlled Lifestyle in Pregnancy (LiP) trial. Acta Obstet Gynecol Scand. 2014. 93:794–801. doi:10.1111/aogs.12429.24834792 | Intervention/Exposure
586. | Vinter, CA, Jørgensen, JS, Ovesen, P, Beck-Nielsen, H, Skytthe, A, Jensen, DM. Metabolic effects of lifestyle intervention in obese pregnant women. Results from the randomized controlled trial ‘Lifestyle in Pregnancy’ (LiP). Diabetic Medicine. 2014. 31:1323–1330. doi:10.1111/dme.12548.24989831 | Intervention/Exposure
587. | Vlaardingerbroek, H, Roelants, JA, Rook, D, Dorst, K, Schierbeek, H, Vermes, A, Vermeulen, MJ, van Goudoever, JB, van den Akker, CH. Adaptive regulation of amino acid metabolism on early parenteral lipid and high-dose amino acid administration in VLBW infants - a randomized, controlled trial. Clin Nutr. 2014. 33:982–90. doi:10.1016/j.clnu.2014.01.002.24461877 | Intervention/Exposure
588. | von Ruesten, A, Brantsaeter, AL, Haugen, M, Meltzer, HM, Mehlig, K, Winkvist, A, Lissner, L. Adherence of pregnant women to Nordic dietary guidelines in relation to postpartum weight retention: results from the Norwegian Mother and Child Cohort Study. BMC Public Health. 2014. 14:75. doi:10.1186/1471-2458-14-75.24456804 | Population
589. | Wadhwa, EL, Ma, C, Shaw, GM, Carmichael, SL. Gastroschisis and maternal intake of phytoestrogens. Am J Med Genet A. 2016. 170:2078–82. doi:10.1002/ajmg.a.37659.27232448 | Study Design; Intervention/Exposure
590. | Walker, LO, Kang, S, Sterling B S. Weight-Loss Resilience Among Low-Income Postpartum Women: Association With Health Habits. West J Nurs Res. 2019. :193945918824598. doi:10.1177/0193945918824598. | Intervention/Exposure
591. | Wall, CR, Gammon, CS, Bandara, DK, Grant, CC, Atatoa Carr, PE, Morton, SM. Dietary Patterns in Pregnancy in New Zealand-Influence of Maternal Socio-Demographic, Health and Lifestyle Factors. Nutrients. 2016. 8. doi:10.3390/nu8050300. | Outcome
592. | Walsh, J, Mahony, R, Foley, M, Mc Auliffe, F. A randomised control trial of low glycaemic index carbohydrate diet versus no dietary intervention in the prevention of recurrence of macrosomia. BMC Pregnancy Childbirth. 2010. 10:16. doi:10.1186/1471-2393-10-16.20416041 | Study Design; Study protocol
593. | Walsh, J, McGowan, C, Byrne, J, Foley, M, Mahony, R, McAuliffe, F. The influence of a low glycaemic index dietary intervention on maternal glycaemic index, dietary intake and gestational weight gain. American journal of obstetrics and gynecology. 2013. 208:S33. doi:10.1016/j.ajog.2012.10.228. | Abstract
594. | Walsh, JM, Mahony, RM, Canty, G, Foley, ME, McAuliffe, FM. Identification of those most likely to benefit from a low-glycaemic index dietary intervention in pregnancy. Br J Nutr. 2014. 112:583–9. doi:10.1017/s000711451400110x.24896237 | Intervention/Exposure
595. | Walsh, JM, Mahony, RM, Culliton, M, Foley, ME, McAuliffe, FM. Impact of a low glycemic index diet in pregnancy on markers of maternal and fetal metabolism and inflammation. Reprod Sci. 2014. 21:1378–81. doi:10.1177/1933719114525275.24642719 | Outcome
596. | Walsh, JM, McGowan, CA, Mahony, R, Foley, ME, McAuliffe, FM. Low glycaemic index diet in pregnancy to prevent macrosomia (ROLO study): randomised control trial. Bmj. 2012. 345:e5605. doi:10.1136/bmj.e5605.22936795 | Intervention/Exposure
597. | Wand, H, Ramjee, G. High prevalence of obesity among women who enrolled in HIV prevention trials in KwaZulu-Natal, South Africa: healthy diet and life style messages should be integrated into HIV prevention programs. BMC Public Health. 2013. 13:159–159. doi:10.1186/1471-2458-13-159.23432964 | Population; Country
598. | Wang, C, Gao, J, Liu, N, Yu, S, Qiu, L, Wang, D. Maternal factors associated with neonatal vitamin D deficiency. J Pediatr Endocrinol Metab. 2019. 32:167–172. doi:10.1515/jpem-2018-0422.30730843 | Outcome
599. | Wang, L, Liu, H, Zhang, S, Leng, J, Liu, G, Zhang, C, Li, WQ, Li, N, Li, W, Li, Y, Sun, S, Yu, Z, Yang, X, Hu, G. Obesity index and the risk of diabetes among Chinese women with prior gestational diabetes. Diabetic Medicine. 2014. 31:1368–1377. doi:10.1111/dme.12532.24961948 | Study Design; Population
600. | Wang, L, Dalton, WT, 3rd, Schetzina, KE, Fulton-Robinson, H, Holt, N, Ho, A, Tudiver, F, Wu, T. Home food environment, dietary intake, and weight among overweight and obese children in Southern Appalachia. Southern Medical Journal. 2013. 106:550–557. doi:10.1097/SMJ.0000000000000008.24096948 | Population; Outcome
601. | Wansink, B. Project M.O.M.: Mothers & Others & MyPyramid. J Am Diet Assoc. 2008. 108:1302–4. doi:10.1016/j.jada.2008.06.444.18656569 | Study Design; Commentary
602. | Watson, PE, McDonald, BW. Major influences on nutrient intake in pregnant New Zealand women. Maternal & Child Health Journal. 2009. 13:695–706. doi:10.1007/s10995-008-0405-6.18766432 | Intervention/Exposure; Outcome
603. | Watson, PE, McDonald, BW. Seasonal variation of nutrient intake in pregnancy: effects on infant measures and possible influence on diseases related to season of birth. Eur J Clin Nutr. 2007. 61:1271–80. doi:10.1038/sj.ejcn.1602644.17299488 | Outcome
604. | Watson, PE, McDonald, BW. The association of maternal diet and dietary supplement intake in pregnant New Zealand women with infant birthweight. Eur J Clin Nutr. 2010. 64:184–93. doi:10.1038/ejcn.2009.134.19920847 | Intervention/Exposure; Comparator
605. | Wen, LM, Flood, VM, Simpson, JM, Rissel, C, Baur, LA. Dietary behaviours during pregnancy: findings from first-time mothers in southwest Sydney, Australia. International Journal of Behavioral Nutrition & Physical Activity. 2010. 7:7p–7p. doi:10.1186/1479-5868-7-13. | Study Design; Outcome
606. | Wen, LM, Simpson, JM, Rissel, C, Baur, LA. Maternal “junk food” diet during pregnancy as a predictor of high birthweight: findings from the healthy beginnings trial. Birth. 2013. 40:46–51. doi:10.1111/birt.12028.24635424 | Outcome
607. | Whisner, CM, Young, BE, Pressman, EK, Queenan, RA, Cooper, EM, O’Brien, KO. Maternal diet but not gestational weight gain predicts central adiposity accretion in utero among pregnant adolescents. Int J Obes (Lond). 2015. 39:565–70. doi:10.1038/ijo.2014.202.25468827 | Outcome; Comparator
608. | White, SL, Flynn, AC, Poston, L. Impact of a positive or negative diagnosis of gestational diabetes and treatment, on weight change and dietary behaviour in an obese cohort: secondary analysis of the UK pregnancies better eating and activity trial (UPBEAT) randomised controlled trial (RCT). Diabetic medicine. 2019. 36:65-. doi:10.1111/dme.13883. | Abstract
609. | Wilkinson, SA, McIntyre, HD. Evaluation of the ‘healthy start to pregnancy’ early antenatal health promotion workshop: a randomized controlled trial. BMC Pregnancy Childbirth. 2012. 12:131. doi:10.1186/1471-2393-12-131.23157894 | Outcome
610. | Wilkinson, SA, van der Pligt, P, Gibbons, KS, McIntyre, HD. Trial for Reducing Weight Retention in New Mums: a randomised controlled trial evaluating a low intensity, postpartum weight management programme. J Hum Nutr Diet. 2015. 28 Suppl 1:15–28. doi:10.1111/jhn.12193.24267102 | Intervention/Exposure; Comparator
611. | Willcox, JC, Wilkinson, SA, Lappas, M, Ball, K, Crawford, D, McCarthy, EA, Fjeldsoe, B, Whittaker, R, Maddison, R, Campbell, KJ. A mobile health intervention promoting healthy gestational weight gain for women entering pregnancy at a high body mass index: the txt4two pilot randomised controlled trial. Bjog. 2017. 124:1718–1728. doi:10.1111/1471-0528.14552.28220604 | Intervention/Exposure
612. | Williams, JE, Carrothers, JM, Lackey, KA, Beatty, NF, York, MA, Brooker, SL, Shafii, B, Price, WJ, Settles, ML, McGuire, MA, McGuire, MK. Human Milk Microbial Community Structure Is Relatively Stable and Related to Variations in Macronutrient and Micronutrient Intakes in Healthy Lactating Women. J Nutr. 2017. 147:1739–1748. doi:10.3945/jn.117.248864.28724659 | Intervention/Exposure; Outcome
613. | Wiltheiss, GA, Lovelady, CA, West, DG, Brouwer, RJ, Krause, KM, Ostbye, T. Diet quality and weight change among overweight and obese postpartum women enrolled in a behavioral intervention program. J Acad Nutr Diet. 2013. 113:54–62. doi:10.1016/j.jand.2012.08.012.23146549 | Population
614. | Winkvist, A, Bertz, F, Ellegard, L, Bosaeus, I, Brekke, HK. Metabolic risk profile among overweight and obese lactating women in Sweden. PLoS One. 2013. 8:e63629. doi:10.1371/journal.pone.0063629.23667649 | Intervention/Exposure; Outcome
615. | Worawong, C. A nutrition intervention focused on goals of Thai pregnant women. 2008. :221 p–221 p. | Dissertation
616. | Wyst, KV, Buman, M, Shaibi, G, Petrov, M, Reifsnider, E, Whisner, C. Evaluation of Variability in Resting Energy Expenditure and Its Relationship with Macronutrients and Gestational Weight Gain During the Second Trimester of Pregnancy (P11-136-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.P11-136-19. | Abstract
617. | Xu, Q, Gao, ZY, Li, LM, Wang, L, Zhang, Q, Teng, Y, Zhao, X, Ge, S, Jing, HJ, Yang, YT, Liu, XJ, Lyu, CJ, Mao, L, Yu, XM, Liu, YH, Kong, AJ, Yang, XY, Liu, Z, Zhang, Y, Wang, J, Zhang, XS, Xue, CY, Lu, YP. The Association of Maternal Body Composition and Dietary Intake with the Risk of Gestational Diabetes Mellitus during the Second Trimester in a Cohort of Chinese Pregnant Women. Biomed Environ Sci. 2016. 29:1–11. doi:10.3967/bes2016.001.26822508 | Intervention/Exposure; Outcome
618. | Xuto, Piyanut, Sinsuksai, Nittaya, Piaseu, Noppawan, Nityasuddhi, Dechavush, Phupong, Vorapong. A Causal Model of Postpartum Weight Retention among Thais. Pacific Rim International Journal of Nursing Research. 2012. 16:48–63. | Intervention/Exposure
619. | Yao, J, Cong, L, Zhu, B, Wang, T. Effect of dietary approaches to stop hypertension diet plan on pregnancy outcome patients with gestational diabetes mellitus. Bangladesh Journal of Pharmacology. 2015. 10:732–738. doi:10.3329/bjp.v10i4.23813. | Health Status
620. | Yin, J, Quinn, S, Dwyer, T, Ponsonby, AL, Jones, G. Maternal diet, breastfeeding and adolescent body composition: a 16-year prospective study. Eur J Clin Nutr. 2012. 66:1329–34. doi:10.1038/ejcn.2012.122.23047715 | Outcome
621. | Yisahak, S, Hinkle, S, Mumford, S, Li, M, Andriessen, V, Grantz, K, Zhang, C, Grewal, J. Association of Maternal Vegetarian Diets with Neonatal Anthropometry in the NICHD Fetal Growth Study (OR35-08-19). Curr Dev Nutr. 2019. 3. doi:10.1093/cdn/nzz048.OR35-08-19. | Abstract
622. | Yong, HY, Shariff, ZM, Mohd Yusof, BN, Rejali, Z, Bindels, J, Tee, YYS, van der Beek, EM. Associations between the dietary patterns of pregnant Malaysian women and ethnicity, education, and early pregnancy waist circumference: A prospective cohort study. Nutr Res Pract. 2019. 13:230–239. doi:10.4162/nrp.2019.13.3.230.31214291 | Outcome
623. | Yusuf, H, Subih, HS, Obeidat, BS, Sharkas, G. Associations of macro and micronutrients and antioxidants intakes with preeclampsia: A case-control study in Jordanian pregnant women. Nutr Metab Cardiovasc Dis. 2019. 29:458–466. doi:10.1016/j.numecd.2019.01.008.30952573 | Study Design
624. | Zambrano, E, Nathanielsz, PW. Relative contributions of maternal Western-type high fat, high sugar diets and maternal obesity to altered metabolic function in pregnancy. Journal of Physiology. 2017. 595:4573–4574. doi:10.1113/JP274392. | Study Design
625. | Zareei, S, Homayounfar, R, Naghizadeh, MM, Ehrampoush, E, Rahimi, M. Dietary pattern in pregnancy and risk of gestational diabetes mellitus (GDM). Diabetes Metab Syndr. 2018. 12:399–404. doi:10.1016/j.dsx.2018.03.004.29576522 | Study Design; Outcome
626. | Zeng, L, Yan, H, Cheng, Y, Dibley, MJ. Modifying effects of wealth on the response to nutrient supplementation in pregnancy on birth weight, duration of gestation, and perinatal mortality in rural western china: double-blind cluster randomized controlled trial. Obstetrical & gynecological survey. 2011. 66:477–478. doi:10.1097/OGX.0b013e31823520d5. | Editorial comment
627. | Zhang, C, Liu, S, Solomon, CG, Hu, FB. Dietary fiber intake, dietary glycemic load, and the risk for gestational diabetes mellitus. Diabetes Care. 2006. 29:2223–2230.17003297 | Intervention/Exposure; Outcome
628. | Zhang, C, Schulze, MB, Solomon, CG, Hu, FB. A prospective study of dietary patterns, meat intake and the risk of gestational diabetes mellitus. Diabetologia. 2006. 49:2604–13. doi:10.1007/s00125-006-0422-1.16957814 | Outcome
629. | Zhang, C, Tobias, DK, Chavarro, JE, Bao, W, Wang, D, Ley, SH, Hu, FB. Adherence to healthy lifestyle and risk of gestational diabetes mellitus: prospective cohort study. Bmj. 2014. 349:g5450. doi:10.1136/bmj.g5450.25269649 | Outcome
630. | Zielinska, MA, Hamulka, J, Wesolowska, A. Carotenoid Content in Breastmilk in the 3rd and 6th Month of Lactation and Its Associations with Maternal Dietary Intake and Anthropometric Characteristics. Nutrients. 2019. 11. doi:10.3390/nu11010193. | Intervention/Exposure; Population
631. | Zulyniak, MA, de Souza, RJ, Shaikh, M, Desai, D, Lefebvre, DL, Gupta, M, Wilson, J, Wahi, G, Subbarao, P, Becker, AB, Mandhane, P, Turvey, SE, Beyene, J, Atkinson, S, Morrison, KM, McDonald, S, Teo, KK, Sears, MR, Anand, SS. Does the impact of a plant-based diet during pregnancy on birth weight differ by ethnicity? A dietary pattern analysis from a prospective Canadian birth cohort alliance. BMJ Open. 2017. 7:e017753. doi:10.1136/bmjopen-2017-017753. | Outcome

ix Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: < 45 or > 65 percent of energy;
- Protein (age 19 years and older): < 10 or > 35 percent of energy;
- Fat (age 19 years and older): < 20 or > 35 percent of energy.

Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press; 2002.

xi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).