# List of abbreviations

Abbreviation: Full name
ADD: Attention deficit disorder
ADHD: Attention-deficit/hyperactivity disorder
ARA: Arachidonic acid
ASD: Autism spectrum disorder
CNPP: Center for Nutrition Policy and Promotion
DHA: Docosahexaenoic acid
EPA: Eicosapentaenoic acid
FNS: Food and Nutrition Service
HHS: Department of Health and Human Services
MTHF: Methyl tetrahydrofolate
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
RCT: Randomized controlled trial
PCS: Prospective cohort study
USDA: United States Department of Agriculture
WASI: Wechsler Abbreviated Scale of Intelligence
WISC: Wechsler Intelligence Scale for Children
WPPSI: Wechsler Primary and Preschool Scale of Intelligence