# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xx^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 2. Food, Beverage, and Nutrient Consumption During Pregnancy and Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between omega-3 fatty acids from supplements consumed before and during pregnancy and lactation on developmental milestones, including neurocognitive development, in the child. For this systematic review, the target population considered was women up to 6 months before and during pregnancy and/or lactation who were healthy and/or at risk for chronic disease. The interventions or exposures considered were omega-3 fatty acids from dietary supplements (including multiple-nutrient supplements) and their comparators were different levels of exposure to omega-3 fatty acids from dietary supplements (including multiple-nutrient supplements). The outcomes considered were Developmental domains, examined via milestone achievement and/or scales/indices, including: Cognitive, Language/communication, Movement/physical, Social-emotional; Academic performance, Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD), Anxiety, Depression, and Autism spectrum disorder (ASD) in Infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years). The key confounders were age, race/ethnicity, socioeconomic status, fish and other seafood consumption, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy and lactation)), smoking, parity, child sex, gestational age, and human milk feeding practices (intensity, duration). Other factors to be considered include maternal substance use (alcohol, drug use), family history/diagnosis of neurocognitive disorders, and complementary feeding.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 10 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Uncontrolled before-and-after studies; - Cross-sectional studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Exposure to, including intake of, Omega-3 fatty acids from:; ○ Dietary supplements (including multiple-nutrient supplements) | - Exposure to multiple-micronutrient supplements in which nutrients other than the nutrient of interest vary
Comparator | - Different levels of exposure to, including intake of, Omega-3 fatty acids from:; ○ Dietary supplements (including multiple-nutrient supplements) | - No comparator; - Exposure to multiple-micronutrient supplements in which nutrients other than the nutrient of interest vary
Outcome:; Developmental milestones, including neurocognitive health | - Developmental domains, examined via milestone achievement and/or scales/indices, including:; ○ Cognitive,; ○ Language/communication,; ○ Movement/physical,; ○ Social-emotional; - Academic performance; - Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD); - Anxiety; - Depression; - Autism spectrum disorder (ASD) | - N/A
Date of publication | - January 1980 – February 2020 | - Articles published prior to January 1980
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xxi^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants | - Non-human participants (e.g., animal or in-vitro models); - Studies that exclusively enroll women who became pregnant using Assisted Reproductive Technologies; - Studies that exclusively enroll women with multiple gestation pregnancies; - Studies that enroll both singleton and multiple pregnancies and do not account for singleton and multiple gestation in the design or analyses and only present aggregate findings
Life stage of study participants - intervention or exposure | - Women up to 6 months before pregnancy; - Women during pregnancy; - Women during lactation | - N/A
Life stage of study participants - outcomes | - Infants and toddlers (birth – 24 months); - Children and adolescents (2 – 18 years) | - Adults (19 – 64 years); - Older adults (65 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or with the health outcome of interest:; ○ Neurocognitive disorders (ADD, ADHD, anxiety, depression, or ASD); ○ Studies that enroll some participants who are deficient in omega-3 fatty acids; - Studies that enroll some mothers with infants who are born preterm (<37 weeks and 0/7 days gestational age); - Studies that exclusively enroll or enroll some mothers diagnosed with the outcome of interest that is to be examined in the infant/child (developmental milestones, including neurocognitive development) | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll participants with obesity will not be excluded.); - Studies that exclusively enroll participants with the outcome of interest (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest); - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: February 5, 2020
- Date range searched: January 1, 1980 – February 5, 2020
- Search Terms:
  - #1 - “Fatty Acids, Omega-3”[Mesh] OR omega-3[tiab] OR N-3 fat*[tiab] OR N-3 polyunsat*[tiab] OR PUFA*[tiab] OR linolenic [tiab] OR eicosapentaenoic [tiab] OR EPA[tiab] OR docosahexaenoic acid*[tiab] OR DHA[tiab] OR ((fat [tiab] OR fats[tiab] OR fatty[tiab]) AND (unsatur*[tiab] OR monounsatur*[tiab] OR mono-unsatur*[tiab] OR polyunsatur*[tiab] OR poly-unsatur*[tiab] )) OR fish oils[mh] OR fish oil*[tiab] OR plant oils[mh] OR plant oil*[tiab] OR vegetable oil*[tiab] OR n-3 oil*[tiab] OR n3 oil*[tiab] OR n3 fat*[tiab]
  - #2 - “Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother*[tiab] OR “Mothers”[Mesh] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestat*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpart*[tiab] OR post-part*[tiab] OR postnatal[tiab] OR post-natal[tiab] OR post-delivery[tiab] OR postdelivery[tiab] OR after birth[tiab] OR Lactation[Mesh] OR lactat*[tiab] OR breast feeding[Mesh] OR breastfe*[tiab] OR breast fe*[tiab] OR Milk, Human [Mesh] OR breastmilk[tiab] OR “breast milk”[tiab] OR “human milk”[tiab] OR “maternal milk”[tiab] OR “nursing women”[tiab]
  - #3 - “Mental Disorders”[Mesh] OR mental disorder*[tiab] OR “Cognition”[Mesh] OR Neuropsychological Tests[MeSH] OR cogniti*[tiab] OR metacogniti*[tiab] OR neurocogniti*[tiab] OR neurodevelop*[tiab] OR neurolog*[tiab] OR “Depression”[Mesh] OR depress*[tiab] OR anxi*[tiab] OR “Psychomotor Performance”[Mesh] OR psychomotor[tiab] OR motor skill*[tiab] OR “Executive Function”[Mesh] OR executive function*[tiab] OR attention deficit disorder*[tiab] OR attention deficit hyperactivity disorder*[tiab] OR ADHD[tiab] OR behavior disorder*[tiab] OR behaviour disorder*[tiab] OR behavioral disorder*[tiab] OR behavioural disorder*[tiab] OR developmental disorder*[tiab] OR Autis*[tiab] OR Asperger*[tiab] OR language processing[tiab] OR language delay*[tiab] OR “Child Development”[Mesh] OR child develop*[tiab] OR developmental delay[tiab] OR developmental disabilit*[tiab] OR “Problem Solving”[Mesh] OR problem solv*[tiab] OR developmental domain* OR academic[tiab] OR “Academic Performance”[Mesh]
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])

Filters: Publication date from 1980/01/01 to 2020/02/05; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: February 5, 2020
- Date range searched: January 1, 1980 – February 5, 2020
- Search Terms:
  - #1 - “linolenic acid*” OR “omega 3” OR “omega-3” OR “N3 fatty acid*” OR “n-3 fat*” OR pufa* OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR [mh “Fatty Acids, Unsaturated”] OR ((fat OR fatty OR fats) NEAR/5 (unsatur* OR monounsatur* OR mono-unsatur* OR polyunsatur* OR poly-unsatur* OR “linolenic acid*”)) OR [mh “fish oils”] OR fish oil* OR [mh “plant oils”] OR “plant oil*” OR “vegetable oil*” OR “n-3 oil*” OR “n3 oil*” OR “n3 fat*”
  - #2 - [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother* OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestat* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR lact* OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”
  - #3 - [mh “Mental Disorders”] OR [mh “Cognition”] OR [mh “Cognitive Dysfunction”] OR [mh “Depressive Disorder”] OR [mh “Depression”] OR [mh “Psychomotor Performance”] OR [mh “Executive Function”] OR [mh “Attention Deficit and Disruptive Behavior Disorders”] OR [mh “Child Behavior Disorders”] OR “behavior disorder*” OR “behaviour disorder*” OR “behavioral disorder*” OR “behavioural disorder*” OR “developmental disorder*” OR [mh “Child Development”] OR [mh “Autism Spectrum Disorder”] OR [mh “Developmental Disabilities”] OR [mh “Motor Skills Disorders”] OR [mh “Problem Solving”] OR “mental disorder*” OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR depression OR anxiety OR “motor skill*” OR “executive function*” OR “attention deficit disorder*” OR ADHD OR “developmental disorder*” OR autism OR autistic OR Asperger* OR “language processing” OR “language delay” OR “child develop*” OR “developmental delay” OR “developmental disabilit*” OR “motor skill*” OR “developmental domain*” OR “academic performance” OR [mh “academic performance”] OR “academic achievement” OR “academic failure” OR “academic success*”
  - #4 - #1 AND #2 AND #3

Filters – Date limited from 1980 to 2020, Trials

#### Embase

- Provider: Elsevier
- Date(s) Searched: February 5, 2020
- Date range searched: January 1, 1980 – February 5, 2020
- Search Terms:
  - #1 - ‘Omega 3 fatty acid’/exp OR ‘linolenic acid*’:ab,ti OR ‘omega-3’:ab,ti OR ‘n-3 fatty acid*’:ab,ti OR pufa*:ab,ti OR ‘alpha-linolenic acid*’:ab,ti OR ‘eicosapentaenoic acid*’:ab,ti OR ‘docosahexaenoic acid*’:ab,ti OR monounsatur*:ti,ab OR mono-unsat*:ti,ab OR polyunsat*:ti,ab OR ‘fish oils’/exp OR fish oil*:ti,ab OR ‘plant oils’/exp OR ‘plant oil*’:ti,ab OR ‘vegetable oil*’:ti,ab OR ‘n-3 oil*’:ti,ab OR ‘n3 oil*’:ti,ab OR ‘n3 fat*’:ti,ab
  - #2 - pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR ‘pregnancy’/exp OR ‘pregnancy complication’/exp OR ‘prenatal exposure’/exp OR ‘maternal exposure’/exp OR ‘pregnant woman’/exp OR ‘mother’/mj OR ‘puerperium’/exp OR ‘maternal nutrition’/exp OR Lact*:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti OR ‘lactation’/exp OR ‘breast feeding’/exp OR ‘breast milk’/exp
  - #3 - ‘mental disease’/exp OR ‘cognition’/exp OR ‘cognitive defect’/exp OR ‘depression’/exp OR ‘psychomotor performance’/de OR ‘executive function’/de OR ‘attention deficit disorder’/de OR ‘autism’/exp OR ‘child development’/de OR ‘developmental disorder’/exp OR ‘psychomotor disorder’/de OR ‘problem solving’/de OR ‘academic performance’/exp OR ‘mental disorder*’:ab,ti OR cognition:ab,ti OR cognitive:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR neurodevelop*:ab,ti OR neurological:ab,ti OR depression:ab,ti OR anxiety:ab,ti OR ‘executive function*’:ab,ti OR ‘attention deficit disorder*’:ab,ti OR adhd:ab,ti OR ‘developmental disorder*’:ab,ti OR autism:ab,ti OR asperger:ab,ti OR ‘language processing’:ab,ti OR ‘language delay’:ab,ti OR ‘developmental delay’:ab,ti OR ‘developmental disabilit*’:ab,ti OR ‘motor skill*’:ab,ti OR ‘developmental domain*’:ab,ti OR ‘academic performance’:ab,ti OR ‘academic achievement’:ab,ti OR ‘academic failure’:ab,ti OR ‘academic success*’:ab,ti
  - #4 - #1 AND #2 AND #3
  - #5 - #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: February 5, 2020
- Date range searched: January 1, 1980 – February 5, 2020
- Search Terms:
  - #1 - “omega-3” OR “omega 3” OR “N-3 fat*” OR PUFA* OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linolenic acid*”OR (MH “fish oils) OR fish oil* OR (MH “plant oils”) OR “plant oil*” OR “vegetable oil*” OR “n-3 oil*” OR “n3 oil*” OR “n3 fat*” OR (MH “Docosahexaenoic Acids”) OR (MH “Eicosapentaenoic Acid”)
  - #2 - postpartum OR post-partum OR MH “Postpartum Period” OR postpartal OR post-partal OR postnatal OR post-natal OR “post deliver*” OR “after birth” OR MH “pregnancy” OR MH “pregnancy complications” OR MH “Prenatal Exposure Delayed Effects” OR MH “Maternal Exposure” OR MH “pregnant women” OR pregnan* OR pre-pregnancy OR prepregnancy OR prenatal OR antenatal OR maternal OR mother OR mothers OR perinatal OR peri-natal OR peri-conception OR periconception OR MH “Peripartum Period” OR peripartum OR peri-partum OR gestation* OR natal OR puerperium OR MH “Maternal Nutritional Physiological Phenomena” OR MH “Breast Feeding”OR breastfeeding OR breast-feeding OR MH “Milk, Human” OR “human milk” OR MH Lactation OR lactation OR lactating OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed* OR “nursing women” OR “nursing mother*”
  - #3 - (MH “Mental Disorders+”) OR “mental disorder*” OR (MH “Cognition+”) OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR “cognitive dysfunction” OR “depressive disorders OR (MH “Depression”) OR depression OR (MH “Anxiety”) OR anxiety OR (MH “Psychomotor Performance”) OR motor skill* OR (MH “Executive Function”) OR executive function* OR (MH “Attention Deficit Hyperactivity Disorder”) OR attention deficit disorder* OR ADHD OR (MH “Child Behavior Disorders”) OR (MH “Child Development”) OR “child develop*” OR developmental disorder* OR (MH “Autistic Disorder”) OR autism OR Asperger OR “language processing” OR language delay* OR (MH “Developmental Disabilities”) OR developmental delay* OR developmental disabilit* OR (MH “Motor Skills Disorders”) OR motor skill* OR (MH “Problem Solving”) OR “problem solv*” OR developmental domain* OR (MH “academic performance”) OR “academic performance” OR “academic achievement” OR “academic failure” OR academic success*
  - #4 - #1 AND #2 AND #3
  - #5 - NOT (MH “Literature Review” OR MH “Meta-Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication) Filters - Published Date: 1980-2020, English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 11 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the combined literature search and screening results for articles examining the relationship between omega-3 fatty acids from supplements consumed before and during pregnancy and lactation on developmental milestones, including neurocognitive development. The literature search yielded 1750 articles, and 1393 articles after duplicates were removed. During title screening, 1218 articles were screened out. During abstract screening, 128 articles were screened out. During full-text screening, 17 articles were screened out. During the hand search, 3 additional articles were identified to include. A total of 33 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes the categories of inclusion and exclusion criteria (see Table 10) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 11 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1. | Bernard, JY, De Agostini, M, Forhan, A, de Lauzon-Guillain, B, Charles, MA, Heude, B. The dietary n6:n3 fatty acid ratio during pregnancy is inversely associated with child neurodevelopment in the EDEN mother-child cohort. J Nutr. 2013. 143:1481–8. doi:10.3945/jn.113.178640 .23902952 23902952 | Intervention/Exposure
2. | Campoy, C, Escolano-Margarit, MV, Ramos, R, Parrilla-Roure, M, Csábi, G, Beyer, J, Ramirez-Tortosa, MC, Molloy, AM, Decsi, T, Koletzko, BV. Effects of prenatal fish-oil and 5methyltetrahydrofolate supplementation on cognitive development of children at 6.5 y of age1-5. American Journal of Clinical Nutrition. 2011. 94:1880S–1888S. doi:10.3945/ajcn.110.001107 . | Duplicate
3. | Cheatham, CL, Nerhammer, AS, Asserhoj, M, Michaelsen, KF, Lauritzen, L. Fish oil supplementation during lactation: effects on cognition and behavior at 7 years of age. Lipids. 2011. 46:637–45. doi:10.1007/s11745-011-3557-x .21512889 | Intervention/Exposure
4. | Gould, JF, Treyvaud, K, Yelland, LN, Anderson, PJ, Smithers, LG, Gibson, RA, McPhee, AJ, Makrides, M. Does n-3 LCPUFA supplementation during pregnancy increase the IQ of children at school age? Follow-up of a randomised controlled trial. BMJ Open. 2016. 6:e011465. doi:10.1136/bmjopen-2016-011465 . | Protocol
5. | Hurtado, JA, Iznaola, C, Pena, M, Ruiz, J, Pena-Quintana, L, Kajarabille, N, Rodriguez-Santana, Y, Sanjurjo, P, Aldamiz-Echevarria, L, Ochoa, J, Lara-Villoslada, F. Effects of Maternal Omega-3 Supplementation on Fatty Acids and on Visual and Cognitive Development. J Pediatr Gastroenterol Nutr. 2015. 61:472–80. doi:10.1097/mpg.0000000000000864 .25988553 | Intervention/Exposure; Fortified food
6. | Jensen, CL, Voigt, RG, Prager, TC, Zou, YL, Fraley, JK, Rozelle, J, Turcich, M, Llorente, AM, Heird, WC. Effects of maternal docosahexaenoic acid (DHA) supplementation on visual function and neurodevelopment of breast-fed infants. Pediatric research. 2001. 49:448A. | Abstract
7. | Kim, Y, Ha, EH, Park, H, Ha, M, Kim, Y, Hong, YC, Lee, EJ, Kim, H, Chang, N, Kim, BN. Prenatal mercury exposure, fish intake and neurocognitive development during first three years of life: Prospective cohort mothers and Children’s environmental health (MOCEH) study. Sci Total Environ. 2018. 615:1192–1198. doi:10.1016/j.scitotenv.2017.10.014 .29751424 | Intervention/Exposure
8. | Lauritzen, L, Jørgensen, MH, Mikkelsen, TB, Skovgaard, IM, Straarup, EM, Olsen, SF, Høy, CE, Michaelsen, KF. Maternal fish oil supplementation in lactation: Effect on visual acuity and n-3 fatty acid content of infant erythrocytes. Lipids. 2004. 39:195–206. doi:10.1007/s11745-004-1220-8 .15233397 | Intervention/Exposure; Fortified food
9. | Lauritzen, L, Jorgensen, MH, Olsen, SF, Straarup, EM, Michaelsen, KF. Maternal fish oil supplementation in lactation: effect on developmental outcome in breast-fed infants. Reprod Nutr Dev. 2005. 45:535–47. doi:10.1051/rnd:2005044 .16188206 | Intervention/Exposure; Fortified food
10. | Malin, AJ, Busgang, SA, Cantoral, AJ, Svensson, K, Orjuela, MA, Pantic, I, Schnaas, L, Oken, E, Baccarelli, AA, Tellez-Rojo, MM, Wright, RO, Gennings, C. Quality of Prenatal and Childhood Diet Predicts Neurodevelopmental Outcomes among Children in Mexico City. Nutrients. 2018. 10. doi:10.3390/nu10081093 . | Intervention/Exposure
11. | Miyake, Y, Tanaka, K, Okubo, H, Sasaki, S, Arakawa, M. Maternal fat intake during pregnancy and behavioral problems in 5-y-old Japanese children. Nutrition. 2018. 50:91–96. doi:10.1016/j.nut.2017.12.001 .29549849 | Intervention/Exposure
12. | Ogaz-Gonzalez, R, Merida-Ortega, A, Torres-Sanchez, L, Schnaas, L, Hernandez-Alcaraz, C, Cebrian, ME, Rothenberg, SJ, Garcia-Hernandez, RM, Lopez-Carrillo, L. Maternal dietary intake of polyunsaturated fatty acids modifies association between prenatal DDT exposure and child neurodevelopment: A cohort study. Environ Pollut. 2018. 238:698–705. doi:10.1016/j.envpol.2018.03.100 .29621729 | Intervention/Exposure
13. | Rees, A, Sirois, S, Wearden, A. Maternal docosahexaenoic acid intake levels during pregnancy and infant performance on a novel object search task at 22 months. Child Dev. 2014. 85:2131–9. doi:10.1111/cdev.12280 .25109611 | Intervention/Exposure
14. | Tofail, F, Kabir, I, Hamadani, JD, Chowdhury, F, Yesmin, S, Mehreen, F, Huda, SN. Supplementation of fish-oil and soy-oil during pregnancy and psychomotor development of infants. J Health Popul Nutr. 2006. 24:48–56.16796150 | Country
15. | Vollet, K, Ghassabian, A, Sundaram, R, Chahal, N, Yeung, EH. Prenatal fish oil supplementation and early childhood development in the Upstate KIDS Study. J Dev Orig Health Dis. 2017. 8:465–473. doi:10.1017/s2040174417000253 .28434427 | Supplementation during pregnancy assessed postpartum
16. | Waylen, A, Ford, T, Goodman, R, Samara, M, Wolke, D. Can early intake of dietary omega-3 predict childhood externalizing behaviour?. Acta Paediatr. 2009. 98:1805–8. doi:10.1111/j.1651-2227.2009.01434.x .19627260 | Intervention/Exposure
17. | Zeng, J, Yu, W, Dong, X, Zhao, S, Wang, Z, Liu, Y, Wong, MS, Wang, Y. A nanoencapsulation suspension biomimetic of milk structure for enhanced maternal and fetal absorptions of DHA to improve early brain development. Nanomedicine. 2019. 15:119–128. doi:10.1016/j.nano.2018.09.006 .30296487 | Human

xx Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xxi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).