# WHAT IS THE RELATIONSHIP BETWEEN OMEGA-3 FATTY ACID SUPPLEMENTS CONSUMED BEFORE AND DURING PREGNANCY AND LACTATION AND DEVELOPMENTAL MILESTONES, INCLUDING NEUROCOGNITIVE DEVELOPMENT, IN THE CHILD?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between omega-3 fatty acid supplements consumed before and during pregnancy and lactation and developmental milestones, including neurocognitive development, in the child?

### What is the answer to the question?

Pregnancy

- Limited evidence suggests that omega-3 fatty acid supplementation during pregnancy may result in favorable cognitive development in the child.
- Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation, or during pregnancy only, and language and social emotional development in the child.
- Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during pregnancy and motor and visual development, academic performance, and the risk of attention-deficit disorder, attention-deficit/hyperactivity disorder, and autism spectrum disorder in the child.
- No evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation, or during pregnancy only, and anxiety or depression in the child.
- Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and cognitive development in the child.
- No evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and visual development, academic performance, or the risk of attention-deficit disorder, attention-deficit/hyperactivity disorder, or autism spectrum disorder in the child.

Lactation

- Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during both pregnancy and lactation or during lactation alone, and cognitive, language, motor, and visual development in the child.
- No evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during both pregnancy and lactation or during lactation alone and academic performance, anxiety, depression, or the risk of attention-deficit disorder, attention-deficit/hyperactivity disorder, or autism spectrum disorder in the child.
- No evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during lactation and social-emotional development in the child.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Pregnancy and Lactation Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- For the intervention/exposure, generally healthy women before and/or during pregnancy and lactation.
- For the outcome, infants and toddlers (birth to 24 months) and children and adolescents (ages 2-18 years).

### What evidence was found?

- This systematic review includes 33 articles that present evidence about omega-3 fatty acid supplementation during pregnancy alone (25 articles), during both pregnancy and lactation (6 articles), or during lactation alone (2 articles).
- Most of the evidence is about cognitive development in children. Generally, omega-3 fatty acid supplementation during pregnancy alone had either no effect or a beneficial effect on child cognitive development. Although the evidence is based on studies with a strong design (randomized controlled trials), the results were somewhat inconsistent across the different measures of child cognitive development.
- Due to inconsistent results, a conclusion could not be drawn on the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation or during lactation alone and cognitive development in children.
- Due to inconsistent results or an insufficient number of studies, a conclusion could not be drawn on the relationship between omega-3 fatty acid supplementation and language, motor, visual, and social-emotional development; academic performance, anxiety, and depression; and the risk of attention-deficit disorder (ADD), attention-deficit/hyperactivity disorder (ADHD), and autism spectrum disorder (ASD).

### How up-to-date is this systematic review?

- This review searched for studies from January 1980 to February 2020.

## FULL REVIEW

### Systematic review question

What is the relationship between omega-3 fatty acids from supplements consumed before and during pregnancy and lactation and developmental milestones, including neurocognitive development, in the child?

### Conclusion statements and grades

#### Pregnancy

Limited evidence suggests that omega-3 fatty acid supplementation during pregnancy may result in favorable cognitive development in the child. (Grade: Limited)

Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation, or during pregnancy only, and language and social emotional development in the child. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during pregnancy and motor and visual development, academic performance, and the risk of attention-deficit disorder, attention-deficit/hyperactivity disorder, and autism spectrum disorder in the child. (Grade: Grade not assignable)

No evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation, or during pregnancy only, and anxiety or depression in the child. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and cognitive development in the child. (Grade: Grade not assignable)

No evidence is available to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and visual development, academic performance, or the risk of attention-deficit disorder, attentiondeficit/hyperactivity disorder, or autism spectrum disorder in the child. (Grade: Grade not assignable)

#### Lactation

Insufficient evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during both pregnancy and lactation or during lactation alone, and cognitive, language, motor, and visual development in the child. (Grade: Grade not assignable)

No evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during both pregnancy and lactation or during lactation alone and academic performance, anxiety, depression, or the risk of attention-deficit disorder, attention-deficit/hyperactivity disorder, or autism spectrum disorder in the child. (Grade: Grade not assignable)

No evidence is available to determine the relationship between omega-3 fatty acid supplementation consumed during lactation and social-emotional development in the child. (Grade: Grade not assignable)

### Summary of the evidence

#### Pregnancy only, and both pregnancy and lactation

- This systematic review included 31 articles from 14 RCTs and 1 PCS published between 1980 and 2020.^1–31^
- Studies included in this review assessed interventions/exposures during:
  ○ Pregnancy only: 11 RCTs (24 articles); 1 PCS (1 article)
  ○ Both pregnancy and lactation: 3 RCTs (6 articles)
- 11 of the 14 RCTs assessed cognitive development
  ○ Eight RCTs delivered omega-3 fatty acid supplements during pregnancy alone. Of those 8 RCTs, 5 studies (11 articles) reported at least one statistically significant finding that supplementation resulted in favorable cognitive development in the child. One study reported at least one statistically significant finding that supplementation resulted in unfavorable measures of cognitive development in the child. All 8 studies reported at least one statistically non-significant result. Overall, results were inconsistent across different measures both within and between studies.
  ○ Three RCTs delivered omega-3 fatty acid supplements during both pregnancy and lactation. Of those 3 RCTs, 1 study reported at least one statistically significant finding that supplementation resulted in favorable cognitive development in the child. All 3 studies reported at least one statistically non-significant result.
- For language, motor, visual, and social-emotional development, findings were inconsistent and therefore a conclusion statement could not be drawn. Although all studies reported at least one statistically non-significant result, the number and direction of statistically significant findings varied across the body of evidence.
- Only 1 study examined academic performance; therefore, a conclusion could not be drawn.
- No evidence was available on omega-3 fatty acid supplementation and anxiety or depression.
- Only 1 study (2 articles) assessed the risk of attention-deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD); therefore a conclusion could not be drawn.
- Only 1 RCT and 1 PCS study assessed risk of autism spectrum disorder (ASD), and both had methodological limitations; therefore, the evidence was deemed insufficient to draw a conclusion.
- The ability to draw strong conclusions was limited by the following issues:
  ○ Wide variation in the developmental domains assessed, as well as in the measures used to evaluate child performance in each of those domains, which limited the ability to compare results across studies.
  ○ Potential risk of bias due to missing outcome data. Further, a lack of pre-registered data analysis plans potentially increased the risk of bias due to selectivity in results presented.
  ○ Findings were mixed both within and between studies, and these inconsistencies could not be explained by methodological differences.
  ○ Although some studies published results from multiple follow-up assessments, an insufficient number of studies were available to investigate the relationship between omega-3 fatty acid supplementation and developmental milestones in the child for many exposure-outcome pairs. Additionally, several studies did not provide evidence of sufficient sample size to detect effects, either because the study did not achieve the required sample size estimated by power calculations or because the study did not report a power calculation. This is particularly true for the long-term outcome assessments.
  ○ People with lower socioeconomic status, adolescents, and racially and ethnically diverse populations were underrepresented in the body of evidence.

#### Lactation only, and both pregnancy and lactation

- This systematic review included 8 articles from 4 RCTs published between 1980 and 2020.^1,13–15,30–33^
- Studies included in this review assessed interventions and exposures during:
  ○ Both pregnancy and lactation: 3 RCTs (6 articles)
  ○ Lactation alone: 1 RCT (2 articles)
- All 4 RCTs assessed cognitive development:
  ○ Three RCTs provided omega-3 fatty acid supplements during both pregnancy and lactation. Of those 3 RCTs, 1 study reported at least one statistically significant finding that supplementation resulted in favorable cognitive development in the child. All 3 studies reported at least one statistically non-significant result.
  ○ One RCT provided omega-3 fatty acid supplements during lactation alone and showed a benefit of supplementation on one measure of cognitive development in the child. The study also reported statistically non-significant results on other measures of cognitive development.
- For language, motor, and social-emotional development, findings were inconsistent and therefore a conclusion statement could not be drawn. Although all studies reported at least one statistically non-significant result, the number and direction of statistically significant findings varied across the body of evidence.
- No evidence was available on omega-3 fatty acid supplementation and visual development, academic performance, anxiety, depression or the risk of ADD, ADHD, or ASD.
- The ability to draw strong conclusions was limited by the following issues:
  ○ Wide variation in the developmental domains assessed, as well as in the measures used to evaluate child performance in each of those domains, limited the ability to compare results across studies.
  ○ Missing outcome data raised concerns about risk of bias. Further, a lack of preregistered data analysis plans potentially increased the risk of bias due to selectivity in results presented.
  ○ Findings were mixed both within and between studies, and these inconsistencies could not be explained by methodological differences.
  ○ Although some studies published results from multiple follow-up assessments, an insufficient number of studies were available to investigate the relationship between omega-3 fatty acid supplementation and developmental milestones in the child for many exposure-outcome pairs. Additionally, multiple studies did not provide evidence of sufficient sample size to detect effects, either because the study did not achieve the required sample size estimated by power calculations or because the study did not report a power calculation. This is particularly true for the long-term outcome assessments.
  ○ People with lower socioeconomic status, adolescents, and racially and ethnically diverse populations were underrepresented in the body of evidence.

### Description of the evidence

This systematic review included articles that address the relationship between omega-3 fatty acid supplements^ii^ consumed before or during pregnancy and/or lactation and developmental milestones, including neurocognitive development, in the child. The search included articles from very high and high Human Development Index^iii^ countries and the search timeframe spanned from January 1980 to February 2020. Studies included generally healthy women before and/or during pregnancy and lactation. The following study designs were included: RCTs, non-randomized controlled trials, prospective and retrospective cohort studies and nested case-control studies.

This body of evidence includes 33 articles from 16 studies, including 15 RCTs^1–15,17–33^ and 1 PCS.^16^ References are included for each study in Table 1 with trial/cohort names or locations when names were unavailable.

Five of the 16 studies were conducted in the United States.^5,6,12,16,18,32,33^ In addition, 2 studies each were conducted in Australia,^7,9–11,19,20,22,28^ Canada,^17,23,24^ and Germany,^1–4,8^ and 1 each in Hungary,^2,3,8^ Iran,^25^ Mexico,^26,27,29^ the Netherlands,^30,31^ Norway,^13–15^ Spain,^2–4,8^ and the United Kingdom.^21^

Table 1 Included trials and cohorts

Trial/Cohort name | Reference numbers for included article
Randomized controlled trials
DOMInO trial ^iv^ | ^9^ ^–^ ^11^ ^,^ ^19^ ^,^ ^20^ ^,^ ^28^
KUDOS ^iv^ | ^5^ ^,^ ^6^
NUHEAL ^iv^ | ^2^ ^–^ ^4^ ^,^ ^8^
POSGRAD | ^26^ ^,^ ^27^ ^,^ ^29^
Oslo (Norway) | ^13^ ^–^ ^15^
Gronigen (Netherlands) | ^30^ ^,^ ^31^
Houston (USA) | ^32^ ^,^ ^33^
Perth (Australia) | ^7^ ^,^ ^22^
Vancouver (Canada) Mulder et al | ^23^ ^,^ ^24^
Pittsburgh (USA) | ^18^
Tabriz (Iran) | ^25^
INFAT | ^1^
Vancouver (Canada) Innis and Friesen | ^17^
Glasgow (UK) | ^21^
Kansas City (USA) | ^12^
Prospective Cohort Studies
MARBLES ^iv^ | ^16^

#### Participant characteristics

- Sample size of the RCTs ranged from 44^12^ to 900 participants,^29^ and the PCS included 258 participants.^16^
- All of the studies were conducted predominantly in adult women (mean age ~26-34 years) who had singleton pregnancies.
- Race/ethnicity: Six of the 16 studies noted that the participants were predominantly or exclusively White.^7,10,11,16,17,19,22–24,32,33^ Catena et al^3^ reported that 100 percent of the children in the follow-up were White. One study exclusively included mothers from Mexico,^26,27,29^ and another exclusively included Black women.^18^ Ostadrahimi et al^25^ exclusively recruited Iranian women. Six percent and 31 percent of participants identified as Hispanic or Black, respectively, in the Colombo et al study.^5,6^ The Gustafson et al study^12^ reported the following on race/ethnicity: 37.3 percent Black, 46.3 percent White, 13.4 percent Hispanic, and 3 percent Asian. Five studies did not report race/ethnicity.^1,9–11,13–15,19–21,30,31^
- Socio-economic status
  ○ Maternal education:
    ■ A majority of the studies reported that the participants had at least some college education, on average.^1,5–7,9–17,19,20,22–24,26–33^
    ■ Four studies did not report maternal education.^18,21^
  ○ Income: Two studies included predominantly^5,6^ or exclusively^18^ women with low or middle incomes and 2 studies^3,17^ reported that >75 percent of participants had middle or high incomes. In 1 study nearly 20 percent of participants reported insufficient income.^25^ The remaining studies did not report income.

#### Intervention/Exposures

##### Supplement dose and composition

- Seven RCTs provided docosahexaenoic acid (DHA),^5,6,12,17,21,23,24,26,27,29,32,33^ 4 RCTs provided both DHA and eicosapentaenoic acid (EPA),^1–4,7–11,19,20,22,25,28,30,31^ and 1 RCT was a 2x2 trial of DHA and arachidonic acid (ARA).^30,31^ In addition to DHA and EPA, Keenan et al^18^ also provided 40 mg/d docosapentaenoic and 90 mg/d eicosatetraenoic acids. Helland et al^13–15^ provided 10 mL/d cod liver oil.
  ○ DHA dose ranged from 120 mg/d to 2.2 g/d and EPA dose ranged from 100 mg/d to 1.1 g/d.
- Most of the RCTs included a placebo composed of corn oil,^13–15^ soybean oil,^30,31^ or both.^5,6,12,17,23,24,26,27,29,32,33^ Keenan et al18 included a placebo of soybean oil combined with vitamin E and small amounts of DHA and EPA. Placebos in other studies contained sunflower oil alone^21^ or in combination with rapeseed and palm oils,^9–11,19,28^ olive oil,^7,22^ or liquid paraffin.^25^ One study included only the vitamins and minerals also included in the intervention supplement, minus DHA, EPA, and 5-MTHF.^2–4^ Brei et al^1^ did not include a placebo, but the control group received general information about a healthy diet.
- The PCS by Huang et al^16^ examined omega-3 fatty acid supplementation dose as a continuous variable, but did not specify supplement composition.

##### Timing of exposure

- Studies included in this review assessed interventions/exposures during:
  ○ [underlined: Pregnancy alone]: 11 RCTs^2–12,17–31^ provided supplements from some point during the second trimester through delivery with one exception: Keenan et al^18^ provided supplements from week 16-20 of gestation and continued for 6 weeks (i.e., provided omega-3 fatty acid supplements only during second trimester). One PCS assessed omega-3 fatty acid supplement intake throughout pregnancy.^16^
  ○ [underlined: Both pregnancy and lactation]: Three RCTs provided supplements from the second trimester of pregnancy through 3 months^13–15,30,31^ or 4 months postpartum.^1^
  ○ [underlined: Lactation alone]: One RCT provided supplements from 5 days after birth through 4 months postpartum.^32,33^

#### Outcome

##### Cognitive development

- 12 RCTs assessed cognitive development, using measures of intelligence, attention, executive function, and information processing speed, as well as more general or comprehensive measures (see Table 2 for details). Of those 12 studies, 8 provided omega-3 fatty acid supplements during pregnancy alone,^2,4–7,9–12,19,22–27,29^ 3 during both pregnancy and lactation,^1,13–15,31^ and 1 during lactation alone.^32,33^
- The timing of cognitive development assessment in the children ranged from the neonatal period to 10 years, with the following distribution:
  ○ Birth to 12 months: 8 RCTs^5,12,13,22,24,25,29,33^
  ○ >12 months to 2 years: 5 RCTs^6,9,10,19,24,27,31^
  ○ >2 years to 5 years: 7 RCTs^1,6,7,9,10,15,26,32,33^
  ○ >5 years: 5 RCTs^2,4,6,11,14,23^

##### Language development

- Nine RCTs assessed language development (see Table 3). Of those 9, 7 provided omega-3 fatty acid supplements during pregnancy alone,^6,7,9–11,18,19,22,23,25,26^ 1 during both pregnancy and lactation,^1^ and 1 during lactation alone.^33^
- The timing of language development assessment in the children ranged from 3 months to 12 years postpartum, with the following distributions:
  ○ Birth to 12 months: 4 RCTs^18,23,25,33^
  ○ >12 months to 2 years: 3 RCTs^6,9,19,23^
  ○ >2 years to 5 years: 6 RCTs^1,6,7,10,26,33^
  ○ >5 years: 3 RCTs^11,22,23^

##### Motor development

- Ten RCTs assessed motor development, including measures of gross and fine motor function (detailed in Table 4). Of those 10, 7 provided omega-3 fatty acid supplements during pregnancy alone,^2,12,18,19,24–27^ 2 during both pregnancy and lactation,^1,30,31^ and 1 during lactation alone.^32,33^
- The timing of motor development assessment in the children ranged from 1 week to 5.5 years postpartum, with the following distributions:
  ○ Birth to 12 months: 5 RCTs^12,18,25,30,33^
  ○ >12 months to 18 months: 5 RCTs^19,24,27,31,33^
  ○ >18 to <2.5 years: 0 RCTs
  ○ 2.5 years to 7 years: 4 RCTs^1,2,26,32,33^

##### Visual development

- Six RCTs assessed visual development, including visual acuity (see Table 5). Of those 6, 5 provided omega-3 fatty acid supplements during pregnancy alone,^17,21,24,28,29^ and 1 during lactation alone.^32,33^
- The timing of visual development assessment in the children ranged from the neonatal period to 5 years postpartum, with the following distributions:
  ○ Birth to 6 months: 6 RCTs^17,21,24,28,29,33^
  ○ >6 months to 12 months: 2 RCTs^24,33^
  ○ >12 months to <5 years: 0 RCTs
  ○ 5 years: 1 RCTs^32^

##### Social-emotional development

- Eight RCTs assessed social-emotional development (Table 6). Of those 8, 7 provided omega-3 fatty acid supplements during pregnancy alone^6,7,10–12,18,19,22,25–27^ and 1 during both pregnancy and lactation.^1^
- The timing of social-emotional development assessment in the children ranged from 1 week to 12 years postpartum, with the following distributions:
  ○ Birth to 12 months: 3 RCTs^12,18,25^
  ○ >12 months to 2 years: 2 RCTs^19,27^
  ○ >2 years to 5 years: 5 RCTs^1,6,7,10,26^
  ○ >5 years: 3 RCTs^5,11,22^

##### Academic performance

- One RCT assessed academic performance, including reading, spelling, and math computation at age 7 years among children of mothers who participated in an intervention during pregnancy alone (Table 7).^11^

##### Anxiety and Depression

- No studies meeting the inclusion criteria assessed anxiety or depression in children.

##### ADD/ADHD

- One RCT assessed hyperactivity disorders at 4 years^10^ and ADHD at age 7 years^11^ among children of mothers who participated in an intervention during pregnancy alone (Table 7).

##### Autism spectrum disorder

- Two studies assessed the risk of autism spectrum disorder in children (Table 7). One study was an RCT that supplemented mothers during pregnancy alone and assessed children at 4 years.^10^ The other study was a PCS that assessed children at 36 months.^16^

### Evidence synthesis

The 33 articles from 16 studies, including 15 RCTs and 1 PCS, provided a substantial body of evidence to examine the relationship between omega-3 fatty acid supplementation during pregnancy and/or lactation and developmental milestones in the child. Among these studies, however, the time period of both the intervention/exposure and the outcome assessment varied widely. Furthermore, heterogeneity in the developmental domains assessed, as well as in the measures used to evaluate child performance in each of those domains, limited the ability to compare results across studies. Many of the assessment tools administered in the included studies are widely used and have been validated for use in similar populations, including the Bayley Scales of Infant Development, the Wechsler scales of intelligence (WISC, WPPSI, and WASI), the Kaufman Assessment Battery for Children, and the Fagan Test of Infant Intelligence. However, the validity and reliability of any measure of neurobehavioral development depend on multiple factors, such as the appropriate administration of the assessment, the training of study personnel who administer the assessment, and the quality of data processing and statistical analysis; this detailed information was not provided in all studies. Further, whether an assessment is able to detect the effects of a nutrition intervention depends on its sensitivity to the functions, brain areas that are affected by the nutrient of interest and timing of assessment. This may be particularly relevant in populations without overt nutrient deficiencies, as the effects of interventions are smaller and thus require greater sensitivity of neurobehavioral assessments. Therefore, assessments targeting multiple cognitive functions, even within a single population may not produce consistent results.

Due to concerns about sample size, multiple testing without adjustment for multiple comparisons, and interpretability of interactions, only main effects were considered in this review. Key confounders were considered in this body of evidence. However, it was less of a concern because most of the studies included in this body of evidence were RCTs. Publication bias is always a consideration, however, it is not a serious concern for this body of evidence because 3 studies reported only non-significant findings^1–4,16^ while the remaining studies report a mix of significant and non-significant results.

#### Cognitive development

##### Supplementation during pregnancy alone

###### Summary

Five of 8 studies found a statistically significant, favorable effect of supplementation on at least one measure of child cognitive development (detailed in Table 2).^5–7,10–12,19,26^ One study found a statistically significant, unfavorable effect of supplementation on a single measure of child cognitive development. Specifically, Makrides et al^10^ and Gould et al^11^ found that children of mothers who consumed omega-3 fatty acid supplements during pregnancy scored less favorably on a parent-reported measure of executive function at age 4 years and 7 years. All 8 RCTs also found no effect of treatment on at least one measure of cognitive development in children ages 1 week to 8.5 years.^2–7,10–12,19,22–27,29^

When examining the totality of the evidence a general pattern emerged of more favorable, as opposed to unfavorable, outcomes of cognitive development among children of women who consumed omega-3 fatty acid supplements during pregnancy. However, a number of measures across all studies showed no statistically significant treatment effect of omega-3 fatty acid supplementation on cognitive development in the child. No notable differences in the timing of the intervention/exposure, the dose or composition of omega-3 fatty acid supplements, nor in the timing or method of outcome assessment, could explain the mixed results.

#### Assessment of the evidence^v^

The following conclusion statement was based on 8 RCTs and was graded “limited.”

“Limited evidence suggests that omega-3 fatty acid supplementation during pregnancy may result in favorable cognitive development in the child.”

As outlined and described below, the body of evidence examining omega-3 fatty acid supplementation during pregnancy and cognitive development in the child was assessed for the following elements used when grading the strength of the evidence (see also Table 8).

- Risk of bias was graded as strong for the RCTs included in this body of evidence. Overall, the RCTs included in this body of evidence had strong designs, were well conducted, and had few major flaws, resulting in overall low risk of bias based on randomization, deviations from intended interventions, and outcome measurement for all studies. The few concerns noted were unlikely to alter the results, and are described below:
  - Two studies had probable differences in reasons for attrition between intervention and control groups, resulting in increased risk of bias due to missing outcome data.^5,7,22^
  - Generally, the included studies had some risk of bias due to selection of the reported results. Few studies published pre-registered analysis plans, and thus it was unclear whether the reported analyses were selected based on the outcome. However, given that the reported domains were generally consistent with pre-registered protocols and that all of the studies reported at least one non-statistically significant result, the risk was judged to be moderate.
  - One article reported analyses that were consistent with the published protocol,^11^ but another study reported only some of the analyses outlined in the pre-published analysis plan.^24^ Further, Catena et al^4^ excluded children with >50 percent error on the Attention Network Task, but did not report the comparison of analyses with and without those data.
- Consistency was graded limited. Findings were mixed both within and between studies. These inconsistencies could not be explained by methodological differences, as there were no obvious differences in the specific timing or duration of the intervention, the composition or dose of the omega-3 fatty acid supplements or placebos, or in the timing or measurement tool for the outcome assessment that could explain the heterogeneity of the results. However, the wide variety in the timing of outcome assessments made it difficult to compare results across studies.
- Directness was graded as strong for the RCTs in this body of evidence. All studies were designed to examine an intervention of omega-3 fatty acid supplementation during pregnancy and with one exception,^7,22^ the primary or pre-registered secondary outcome was cognitive development in the child.
- Precision was graded as moderate for the studies. There were an adequate number of studies to investigate the relationship between omega-3 supplementation during pregnancy and cognitive development in children. Two studies had substantial sample sizes that, based on estimated effect sizes in similar studies, were likely sufficient to examine this relationship, especially at earlier outcome assessments.^10,11,19,26,27^ Two studies reported power calculations suggesting that the studies were sufficiently powered.^5,6,25^ Four studies generally did not report power calculations and it is unclear whether the final sample size was sufficiently powered.^7,12,22–24^ In addition to power, number of studies that were included in the body of evidence and variability within and across studies were considered while grading precision. Overall, none of the studies unduly influenced the findings of this systematic review and removing a single study from this body of evidence would not likely change the conclusions.
- Generalizability was graded as moderate for this body of evidence. Two studies were conducted in the United States and both were from the same research group.^5,6,12^ Minority women were generally underrepresented in this body of evidence. Two studies did not provide any information regarding race/ethnicity,^24,10,11,19^ and 2 studies recruited primarily White participants.^7,22–24^ However, the remaining 4 studies recruited primarily non-White participants, including the U.S.-based studies.^5,6,12,25–27^ Regarding socioeconomic status, the studies mostly included women with post-secondary education. Participants were primarily adult women and none of the studies focused on adolescent mothers. For these reasons, the findings from this systematic review are somewhat applicable to the general U.S. population.

##### Supplementation during pregnancy and lactation

###### Summary

Three RCTs examined the effects of omega-3 fatty acid supplementation during both pregnancy and lactation on cognitive development in the child (ages 6 months to 7 years) (Table 2).^1,13–15,31^ One study found a statistically significant, favorable effect of supplementation on one measure of intelligence in the child at age 4 years.^15^ All 3 RCTs found no treatment effect on at least one measure of cognitive development from ages 6 months to 7 years.

###### Assessment of the evidence

Given the mixed results and the small number of studies, risk of bias due to deviations from intended interventions because of large attrition rates (Table 8), and limited information on the generalizability of results to the general U.S. population, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and cognitive development in the child. Therefore, the body of evidence was rated ‘grade not assignable.’

##### Supplementation during lactation alone

###### Summary

One RCT examined the effects of omega-3 fatty acid supplementation during lactation alone on cognitive development in the child (ages 2.5 years to 5 years) (Table 2).^32,33^ Jensen et al^32,33^ reported a statistically significant, favorable effect of supplementation on one measure of sustained attention in the child at age 5 years, as well as no association with multiple measures of cognitive development at ages 12 months, 2.5 years, and 5 years.

###### Assessment of the evidence

The entire body of evidence consisted of a single study with concerns regarding statistical power to detect effects in these secondary outcomes, risk of bias due to outcome measurement and deviations from the intended intervention (Table 8), and a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during lactation alone and cognitive development in the child, and the body of evidence was rated ‘grade not assignable.’

Table 2 Description of evidence on relationship between omega-3 fatty acid supplementation and cognitive development^vi^

Study and Participant Characteristics | Intervention (All RCTs) | Outcome(s) | Results | Limitations
Pregnancy only
Campoy, 2011 ^2^; Germany, Hungary, Spain \| NUHEAL; N=154; Mothers were age ~31y and ~47% eligible for university entrance or degree. Race/ethnicity NR. | Placebo vs; FO: 500mg/d DHA + 150 mg/d EPA vs; 5-MTHF: 400 ug/d vs; FO + 5-MTHF; 20wk through delivery | Intelligence: K-ABC; at 6.5y | Non-significant:; All main effects; - Mental Processing Composite; - Sequential Processing Scale; - Simultaneous Processing Scale | - Outcome assessor blinding NR, but standard methods used; - Pre-registered analysis plan NR
Catena, 2016 ^4^; Germany, Hungary, Spain \| NUHEAL; N=136; Mothers were age ~32y and ~43% eligible for university entrance or degree. Race/ethnicity NR. | Placebo vs; FO: 500mg/d DHA + 150 mg/d EPA vs; 5-MTHF: 400 ug/d vs; FO + 5-MTHF; 20wk through delivery | Attention/Executive function: Attention Network Task at 8.5y | Non-significant:; All main effects; - Total errors (%); - Interference errors (%); - Orienting errors (%); - Alerting errors (%) | - Excluded children with >50% conflict errors; comparison of results with and without those children NR; - Pre-registered analysis plan NR
Catena, 2019 ^3^; Spain \| NUHEAL; N=74; Mothers were age ~31y at delivery, 76% medium to high SES, and ~32% completed secondary education or higher. Race/Ethnicity: 100% White children. | Placebo vs; FO: 500mg/d DHA + 150 mg/d EPA vs; 5-MTHF: 400 ug/d vs; FO + 5-MTHF; 20wk through delivery | Intelligence: K-ABC-II; at 6.6y | Non-significant:; All main effects; - Mental Processing Index | - Outcome assessor blinding NR, but standard methods used; - Pre-registered analysis plan NR
Colombo, 2016 ^5^; USA \| KUDOS; N=156; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Visual learning: Visual habituation task with simultaneous heart rate; at 4mo, 6mo, 9mo | Significant:; Favors Intervention; Attrition due to fussiness; Overall, P<0.01; Control: N=64, Intervention: N=47; at 6 mo, P<0.001; Control: N=23, Intervention: N=6; at 9 mo, P<0.05; Control: N=22, Intervention: N=14; Non-significant:; All other main effects; - Peak look duration; - Looks to habituation, P=0.056; ○ Faster habituation in DHA vs placebo | - Proportions and reasons for missingness differ, seemingly more dropout in placebo group; - Major differences in those followed up and not followed up; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | BSID-II; at 18mo | Non-significant:; All main effects; - Mental Development Index; - Psychomotor Development Index; - Behavior Rating Scale total | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | WPPSI-III; at 36, 48, 72mo | Non-significant:; All main effects; - Verbal IQ; - Performance IQ; - Processing Speed; - Full Scale IQ | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Executive function: Willatts problem-solving task; at 10mo | Non-significant:; All main effects; - Total score | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Executive function: Delayed Response spatial memory task; at 24 and 30mo | Significant:; Favors intervention; at 24 mo; Initial trials, P<0.05; Effect size (d): 0.063; Reversal trials, P<0.05; Effect size (d): 0.278; at 30 mo; Initial trials, P<0.05; Effect size (d): 0.128; Reversal trials, P<0.05; Effect size (d): 0.340 | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Executive function: Dimensional Change Card Sort task and Stroop task; at 36, 42, 48, 60mo | Non-significant:; All main effects; Dimensional Change Card; - Prestwich total; - Postswitch total; - Percent passing; Stroop task; - Total score | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Executive function: Tower of Hanoi; at 60 and 72mo | Non-significant:; All main effects; - Max steps; - Efficiency | - (See Colombo, 2016); - More outcomes reported in the paper than on the clinical trials registry.; - Pre-registered data analysis plan NR
Dunstan, 2008 ^7^; Australia; N=72; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | GMDS; at 2.5y | Significant:; Favors Intervention; Eye and hand coordination subscale quotient; P=0.021; Control (Mean± SD): 108.0± 11.3; Intervention: 114.0± 10.2; Non-significant:; All other main effects; - Locomotor; - Personal social; - Speech and hearing; - Performance; - Practical reasoning; - General quotient score | - Probable differences in reasons for attrition; - No power calculation for neurobehavioral results; - Pre-registered data analysis plan NR
Gould, 2014 ^10^; Australia \| DOMInO; N=158; Mothers were age ~30y at enrollment and ~65% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Attention: Sustained attention (Single Object task); at 27 ± 2mo | Non-significant:; All main effects; - Total duration of time spent looking at the toy; - Percentage of time spent looking at the toy; - Average length of look at the toy; - No. of looks at the toy; - No. of times looked away from the toy | - Power calculation NR; - Pre-registered analysis plan NR
Gould, 2014 ^10^; Australia \| DOMInO; N=158; Mothers were age ~30y at enrollment and ~65% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Attention: Sustained attention (Multiple Object task); at 27 ± 2mo | Significant:; Favors intervention; No. of times looked away from toys; Adj P=0.03; Ref: Control; Mean Difference: −2.0, 95% CI: (−3.9, −0.2); Non-significant:; All other main effects; - No. of times shifted looks between toys; - Total duration of time looking at toys; - Percentage of time spent looking at toys; - Average length of a look at a toy | - Power calculation NR; - Pre-registered analysis plan NR
Gould, 2014 ^10^; Australia \| DOMInO; N=158; Mothers were age ~30y at enrollment and ~65% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Attention: Distractibility (Multiple Object with distractor task); at 27 ± 2mo | Non-significant:; All main effects; - Average latency to turn to the distractor when attention was focused; - Percentage of times distracted when focused; - Average latency to look to the distractor when attention was casual; - Percentage of times distracted when attention was casual; - Total duration of time spent looking at the distractor when the distractor was on; - Total duration of time spent looking at the distractor when the distractor was off | - Power calculation NR; - Pre-registered analysis plan NR
Gould, 2014 ^10^; Australia \| DOMInO; N=158; Mothers were age ~30y at enrollment and ~65% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | WMIC: A-not-B task:; at 27 ± 2mo | Significant:; Favors intervention; Average accuracy during training trials; Adj P=0.05; Ref: Control; Adj Mean Difference (mm): 14.4, 95% CI: (20.2, 29.1); Non-significant:; All other main effects; - Average accuracy during test trials | - Power calculation NR; - Pre-registered analysis plan NR
Gould, 2017 ^11^; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Executive function: TEACh Sky Search; RAVLT Trial 1 correct words; Rey Complex Figure Copy; Fruit Stroop Test; CELF-4; at 7y | Non-significant:; All main effects; TEACh Sky Search; - Total; - Score; - Creature Counting; - Sky Search Dual Task; RAVLT; - Trial 1 correct words; - Total (trials 1-5) correct words; - Delayed recall correct words; Rey Complex Figure Copy; - Raw score; - Organizational raw score; Fruit Stroop Test; - Interference score; CELF-4; - Recall of digits total | - No major limitations
Gould, 2017 ^11^; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Parent-reported executive function: BRIEF; at 7y | Significant:; Favors control; Global executive composite; Adj P=0.01; Ref: Contol; Adj Mean Difference: 2.38, 95% CI: (0.67, 4.08); Behavioral regulation index; Adj P=0.02; Ref: Contol; Adj Mean Difference: 2.09, 95% CI: (0.40, 3.79); Metacognitiion index; Adj P=0.01; Ref: Contol; Adj Mean Difference: 2.25, 95% CI: (0.57, 3.92) | - No major limitations
Gould, 2017 ^11^; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Intelligence: WASI-II full scale IQ; at 7y | Significant:; Favors intervention; Perceptual reasoning; Adj P=0.03; Ref: Control; Adj Mean Difference: 2.01, 95% CI: (0.23, 3.79); Non-significant:; All other main effects; - Verbal comprehension; - Full-scale IQ <85 | - No major limitations
Gustafson, 2013 ^12^; USA; N=44; Mothers were age ~26y at enrollment and completed ~14y education. Race/Ethnicity: 37.3% Black, 46.3% White, 13.4% Hispanic, 3% Asian. | 600 mg/d DHA vs placebo (corn and soybean oils); 12-20wk through delivery | NBAS: Habituation, Orienting, Autonomic, and Reflexes scales; at 1wk | Significant:; Favors intervention; Autonomic, P=0.029; Control (Mean± SD): 14.83± 16.90; Intervention: 18.13± 14.48; Non-significant:; All other main effects; - Habituation; - Orienting; - Reflexes | - No power calculation; - Pre-registered analysis plan NR
Makrides, 2010 ^19^; Australia \| DOMInO; N=694; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | BSID-III: Cognitive Scale, continuous, accelerated, and delayed; at 18mo | Significant:; Favors intervention; Cognitive Standardized Score, Continuous <85, Adj P=0.007; Ref: Control; Adj RR: 0.41, 95% CI: (0.22, 0.78); Non-significant:; All other main effects; - Cognitive Standardized Score, Delayed; - Cognitive Standardized Score, Accelerated | - Pre-registered analysis plan NR
Makrides, 2014 ^20^; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | DAS-II: General Conceptual Ability, Non-verbal Reasoning, Verbal Reasoning, and Spatial Scales; at 4y | Non-significant:; All main effects; - General Conceptual Ability Scale; - Non-verbal Reasoning Scale; - Verbal Reasoning Scale; - Spatial Scale | - Pre-registered analysis plan NR
Makrides, 2014 ^20^; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Executive function: DAS II: Day-night Stroop; at 4y | Non-significant:; All main effects; DAS II; - Recall of Digits Forwards; - Recognition of Pictures; Day-night Stroop | - Pre-registered analysis plan NR
Makrides, 2014 ^20^; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Parent-reported executive function: BRIEF; at 4y | Significant:; Favors control; Emergent Meta-Cognition Index; Adj P=0.03; Ref: Contol; Adj Mean Difference: 1.52, 95% CI: (0.11, 2.92); Plan/Organize Scale; Adj P=0.02; Ref: Contol; Adj Mean Difference: 1.54, 95% CI: (0.21, 2.87); Non-significant:; All other main effects; - Global Executive Composite; - Inhibitory Self-Control index; - Flexibility Index; - Inhibition Scale; - Shift Scale; - Emotional Control Scale; - Working Memory Scale | - Pre-registered analysis plan NR
Meldrum, 2015 ^22^; Australia; N=48; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | WISC-IV; Beery-Buktenica Developmental Test of Visual-Motor Integration; at 12y | Non-significant:; All main effects; WISC-IV; - Full Scale IQ; - Verbal Comprehension; - Perceptual Reasoning; - Working Memory; - Processing Speed; Beery-Buktenica; - Standard Score; - Percentiles | - Among those followed to 12y, birth weight differed by treatment group; - Possible differences in reasons for attrition; - No power calculation, Likely under-powered
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Executive function: Willatts problem-solving task; at 9mo | Non-significant:; All main effects; - Pass/fail | - No power calculation; - Pre-registered data analysis outlined multiple regression, not reported in the paper
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | BSID-III; at 18mo | Non-significant:; All main effects (Risk that placebo group fails to achieve the outcome); - Highest quartile cognitive score | - No power calculation; - Pre-registered data analysis outlined multiple regression, not reported in the paper
Mulder, 2018 ^23^; Canada; N=89; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | K-ABC; at 5.75y | Non-significant:; All main effects; - Sequential Processing Scale; - Learning Ability Scale; - Simultaneous Processing Scale; - Mental Performance Index | - Unclear whether outcome assessors were blinded to treatment group; - No power calculation; - Pre-registered analysis plan NR
Mulder, 2018 ^23^; Canada; N=89; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Beery-Buktenica Developmental Test of Visual-Motor Integration; at 5.75y | Non-significant:; All main effects; - Score | - Unclear whether outcome assessors were blinded to treatment group; - No power calculation; - Pre-registered analysis plan NR
Mulder, 2018 ^23^; Canada; N=89; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Test of Variables of Attention; at 5.75y | Non-significant:; All main effects; - RT variability; - RT; - Errors of commission; - Errors of omission | - Unclear whether outcome assessors were blinded to treatment group; - No power calculation; - Pre-registered analysis plan NR
Ostadrahimi, 2018 ^25^; Iran; N=146; Mothers were age ~26y at enrollment and ~8% completed >12y education. ~19% had non-adequate family income. Race/ethnicity NR. | 120mg/d DHA + 180mg/d EPA vs placebo (liquid paraffin); 16-20wk through delivery | Parent reported: ASQ-2; at 4mo and 6mo | Non-significant:; All main effects; Total; - Subnormal development; Problem solving subscale; - Mean score; - Subnormal development | - Pre-registered analysis plan NR
Ramakrishnan, 2015 ^27^; Mexico \| POSGRAD; N=730; Mothers were age ~26y at enrollment and ~59% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | BSID-II: Mental Development Index; at 18mo | Non-significant:; All main effects; - Mean score; - Risk of delay | - Pre-registered data analysis NR
Ramakrishnan, 2016 ^26^; Mexico \| POSGRAD; N=797; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | MSCA; at 5y | Non-significant:; All main effects; - Perceptual performance scale; ○ Mean raw score; ○ Scale index score; - Quantitative scale; ○ Mean raw score; ○ Scale index score; - Memory scale; ○ Mean raw score; ○ Scale index score; - General cognitive scale; ○ Mean raw score; ○ Scale index score | - Pre-registered data analysis NR
Ramakrishnan, 2016 ^26^; Mexico \| POSGRAD; N=797; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | Attention: K-CPT; at 5y | Significant:; Favors Intervention; Inattention Corrected P<0.0001; T-score <-1SD for omissions; Control: 14.4%, Intervention: 25.7%; T-score >1SD for omissions; Control: 16.2%, Intervention: 9.7%; Non-significant:; All other main effects; Overall; - Omissions score; - Commissions; ○ Score; ○ Score relative to standard sample; - Hit RT; ○ Score; ○ Score relative to standard sample; - Response style score relative to standard sample; - Overall score relative to standard sample; Inattention scores; - Hit RT, speed consistency; - Variability; - Detectability; - Hit RT ISI change; - Hit speed consistency ISI change; Impulsivity scores; - Perseverations; Vigilance scores; - Hit RT block change; - Hit speed consistency by block change | - Pre-registered data analysis NR
Stein, 2012 ^29^; Mexico \| POSGRAD; N=900; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | ABR; at 1mo and 3mo | Non-significant:; All main effects; - Latency 1; - Latency 3; - Latency 5; - Interpeak latency 1-3; - Interpeak latency 3-5; - Interpeak latency 1-5 | Pre-registered data analysis NR
Pregnancy and Lactation
Brei, 2017 ^1^; Germany \| INFAT; N=130; Mothers were age ~33y at enrollment and 73% completed ≥12y education. Race/Ethnicity: NR. | 1020 mg/d DHA + 180 mg/d EPA + 9 mg/d Vitamin E vs general nutrition advice; 15wk gestation through 4mo postpartum | Parent reported: Child Development Inventory: General development, Numbers; at 4y and 5y | Non-significant:; All main effects; - General development scale classification (Normal, Borderline, Delay); - Numbers scale classification (Normal, Borderline, Delay) | - Reasons for missingness by group NR; - Results were parent-reported; - Pre-registered data analysis NR
Helland, 2001 ^13^; Norway; N=245; Mothers were age ~28y at enrollment and ~72% completed ≥12y education. Race/ethnicity: NR. | 10mL/d cod liver oil vs placebo (corn oil); 17-19wk gestation through 3mo postpartum | Memory: FTII; at 6mo and 9mo | Non-significant:; All main effects; - Novelty preference; ○ 6mo only; ○ 9mo only; ○ 6mo and 9mo combined | - Details of allocation sequence NR; - 38% withdrew before delivery, many due to non-adherence or “discomfort taking the oil”; - Nearly 60% attrition, unclear if reasons for missingness were balanced across groups; - N=130 infants received cod liver oil, per Norwegian recs but NR by groups; - No evidence of performance above chance in either group; - Pre-registered analysis NR
Helland, 2003 ^15^; Norway; N=84; Mothers were age ~28y at enrollment and ~73% completed ≥12y education. Race/ethnicity: NR. | 10mL/d cod liver oil vs placebo (corn oil); 17-19wk gestation through 3mo postpartum | Intelligence: K-ABC; at 4y | Significant:; Favors Intervention; Mental Processing Composite, P=0.049; Control (Mean± SD): 102.3± 11.3; Intervention: 106.4± 7.4; Non-significant:; All other main effects; - Sequential Processing scale; - Simultaneous Processing scale; - Nonverbal scale | - Substantial attrition, unclear if reasons for missingness were balanced across groups
Helland, 2008 ^14^; Norway; N=143; Mothers were age ~29y at delivery, with mean education 14.9y. Race/ethnicity: NR. | 10mL/d cod liver oil vs placebo (corn oil); 17-19wk gestation through 3mo postpartum | Intelligence: K-ABC; at 7y | Non-significant:; All main effects; - Mental Processing Composite; - Sequential Processing scale; - Simultaneous Processing scale; - Nonverbal scale | - See Helland, 2001 and Helland, 2003
van Goor, 2011 ^31^; The Netherlands; N=114; Mothers were age ~33y at enrollment and ~75% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk gestation through 3mo postpartum | BSID-II (Dutch edition); at 18mo | Non-significant:; All main effects; - Mental developmental scale | - Unclear power to find results, but attrition and reasons reasonably balanced; - Unclear whether outcomes would be affected by unblinded assessors
Lactation only
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | BSID-II: Mental development scale; at 2.5y | Non-significant:; All main effects; - Mean score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual-motor problem-solving: Clinical Adaptive Test; at 12mo and 2.5y | Non-significant:; All main effects; - Mean score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | WPPSI-R; at 5y | Non-significant:; All main effects; - Information Subset score; - Block Design Subtest score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Executive function: WPPSI-R; KABC; at 5y | Non-significant:; All main effects; WPPSI-R; - Animal Pegs Subset score; K-ABC; - Hand Movement Subscale score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual-motor integration: Developmental Test of Visual-Motor Integration-III; at 5y | Non-significant:; All main effects; - Visual component score; - Motor component score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Sustained attention: Leiter International Performance Scale-Revised:; at 5y | Significant:; Favors intervention; Sustained attention subtest, P=0.008; Control (Mean± SD): 41.8± 9.3; Intervention: 46.5± 8.9 | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR

#### Language development

##### Supplementation during pregnancy alone

###### Summary

Seven RCTs examined the effects of omega-3 fatty acid supplementation during pregnancy alone on language development in the child (Table 3).^6,7,10,11,18,19,22–26^ All 7 RCTs, which assessed children from ages 3 months to 12 years, found no effect of treatment on at least one measure of language development.

Two studies found statistically significant, favorable effects of supplementation on at least one measure of language development in the child at ages 4 months,^25^ and ages 14 and 18 months.^24^ Notably, Ostadrahimi et al^25^ found a benefit on a continuous measure of language at 4 months, but no effect on this continuous measure at 6 months, nor on the risk of subnormal language development at either age.

###### Assessment of the evidence^vii^

Given the mixed results and some concerns regarding risk of bias due to selection of reported results (Table 8), insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and language development in the child, and therefore the body of evidence was rated ‘grade not assignable.’

##### Supplementation during both pregnancy and lactation

###### Summary

One RCT examined the effects of omega-3 fatty acid supplementation during both pregnancy and lactation on language development in the child,^1^ and reported a statistically significant favorable effect for a single measure of language development at age 5 years, but no association with other measures from the same tool at ages 4 years and 5 years (Table 3).

###### Assessment of the evidence

The entire body of evidence consisted of a single study, with concerns regarding statistical power to detect effects in these secondary outcomes, and limited information on the generalizability of results to the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and language development in the child, and the body of evidence was rated ‘grade not assignable.’

##### Supplementation during lactation alone

###### Summary

One RCT examined the effects of omega-3 fatty acid supplementation during lactation alone on language development in the child (Table 3).^32,33^ Jensen et al^32,33^ reported no association with multiple measures of language development at ages 12 months, 2.5 years, and 5 years.

###### Assessment of the evidence

The entire body of evidence consisted of a single study with concerns regarding statistical power to detect effects in these secondary outcomes, risk of bias due to outcome measurement and deviations from the intended intervention (Table 8), and a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during lactation alone and language development in the child, and the body of evidence was rated ‘grade not assignable.’

Table 3 Description of evidence on relationship between omega-3 fatty acid supplementation and language development^viii^

Study and Participant Characteristics | Intervention (All RCTs) | Outcome(s) | Results | Limitations
Pregnancy only
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | MacArthur-Bates CDI; at 18mo | Non-significant:; All main effects; - Words Produced; - Sentence Length; - Complexity | - More outcomes reported in the paper than on the clinical trials registry; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | TOPEL; at 42mo | Non-significant:; All main effects; - Early Literacy Index | - More outcomes reported in the paper than on the clinical trials registry; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Sentence Repetition tasks; at 36, 42, 48mo | Non-significant:; All main effects; - Score | - More outcomes reported in the paper than on the clinical trials registry; - Pre-registered data analysis plan NR
Colombo, 2019 ^6^; USA \| KUDOS; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | PPVT, Third Edition; at 5y | Non-significant:; All main effects; - Standard Score | - More outcomes reported in the paper than on the clinical trials registry; - Pre-registered data analysis plan NR
Dunstan, 2008 ^7^; Australia; N=72; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | Language Development Survey; Receptive: PPVT-IIIA; at 2.5y | Non-significant:; All main effects; - Standard Score | - Probable differences in reasons for attrition; - No power calculation for neurobehavioral results; - Pre-registered data analysis plan NR
Gould, 2017 ^11^; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | CELF-4: Core language score; at 7y | Non-significant:; All main effects; - Score | - No major limitations
Keenan, 2016 ^18^; USA; N=49; Age 20-30y. 100% Medicaid eligible. Race/Ethnicity: 100% Black. | 450 mg/d DHA + 40 mg/d DPA + 40 mg/d ETA + 90 mg/d EPA + 10 mg/d Vitamin E vs 990 mg/d soybean oil + 16.5 mg/d Vitamin E + 10 mg/d EPA + 10 mg/d DHA; 16-21wk for 6wk | BSID-III: Receptive and Expressive Communication; at 3mo | Non-significant:; All main effects; - Receptive Communication; - Expressive Communication | - Reasons for missingness by group NR; - Pre-registered data analysis plan NR
Makrides, 2010 ^19^; Australia \| DOMInO; N=694; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | BSID-III: Language Scale, continuous, delayed, and accelerated; at 18mo | Non-significant:; All main effects; - Language Standardized Score, Continuous; - Language Standardized Score, Delayed; - Language Standardized Score, Accelerated | - Pre-registered analysis plan NR
Makrides, 2014 ^20^; Autralia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | CELF-P2; at 4y | Non-significant:; All main effects; - Core language score | - Pre-registered analysis plan NR
Meldrum, 2015; Australia; N=48; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | Child Communication Checklist; at 12y | Non-significant:; All main effects; - Percentile rank | - Among those followed to 12y, birth weight differed by treatment group; - Possible differences in reasons for attrition; - No power calculation, Likely under-powered
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Non-native consonant recognition task; at 9mo | Non-significant:; All main effects; - Pass/Fail | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | MacArthur Infant CDI; at 14mo | Significant:; Favors intervention; All main effects (Risk that placebo group fails to achieve the outcome); Highest quartile words understood; Adj P=0.002; Adj OR: 3.22, 95% CI: (1.49-6.94); Highest quartile words produced; Adj P=0.009; Adj OR: 2.61, 95% CI: (1.22-5.58) | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | MacArthur Infant and Toddler CDI; at 18mo | Significant:; Favors intervention; All other main effects (Risk that placebo group fails to achieve the outcome); Infant Highest quartile words understood; Adj P=0.01; Adj OR: 2.77, 95% CI: (1.23-6.28); Toddler Highest quartile words produced; Adj P=0.02; Adj OR: 2.60, 95% CI: (1.15-5.89); Non-significant:; Infant Highest quartile words produced | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | BSID-III: Language composite scale; at 18mo | Significant:; Favors intervention; (Risk that placebo group fails to achieve the outcome); Receptive language; Adj P=0.03; Adj OR: 2.23, 95% CI: (1.08, 4.60); Non-significant:; Expressive language | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Mulder, 2018 ^23^; Canada; N=89; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Receptive: PPVT-4; at 5.75y | Non-significant:; All main effects; - Score | - Unclear whether outcome assessors were blinded to treatment group; - No power calculation; - Pre-registered analysis plan NR
Ostadrahimi, 2018 ^25^; Iran; N=146; Mothers were age ~26y at enrollment and ~8% completed >12y education. ~19% had non-adequate family income. Race/ethnicity NR. | 120mg/d DHA + 180mg/d EPA vs placebo (liquid paraffin); 16-20wk through delivery | Parent reported: ASQ-2 Communciation subscale; at 4mo | Significant:; Favors intervention; 4mo, mean score; Adj P=0.02; Ref: Control; Adj Mean Difference:; 2.63, 95% CI: (0.36, 4.89); Non-significant:; All other main effects; - Mean score; - Subnormal development | - Pre-registered analysis plan NR
Ostadrahimi, 2018 ^25^; Iran; N=146; Mothers were age ~26y at enrollment and ~8% completed >12y education. ~19% had non-adequate family income. Race/ethnicity NR. | 120mg/d DHA + 180mg/d EPA vs placebo (liquid paraffin); 16-20wk through delivery | Communciation subscale; at 6mo | Non-significant:; All other main effects; - Mean score; - Subnormal development | - Pre-registered analysis plan NR
Ramakrishnan, 2016 ^26^; Mexico; N=797; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | MSCA: Verbal scale; at 5y | Non-significant:; All main effects; - Mean raw score; - Mean scale index score | - Pre-registered data analysis NR
Pregnancy and Lactation
Brei, 2017 ^1^; Germany \| INFAT; N=130; Mothers were age ~33y at enrollment and 73% completed ≥12y education. Race/Ethnicity: NR. | 1020 mg/d DHA + 180 mg/d EPA + 9 mg/d Vitamin E vs general nutrition advice; 15wk gestation through 4mo postpartum | Parent reported: Child Development Inventory: Expressive, language comprehension, letters scales; at 4y and 5y | Significant:; Favors intervention; Letter scales at 5y; Borderline/developmentally delayed, P=0.043; Control: N=4 of 60; Intervention: N=0 of 70; Non-significant:; All other main effects; - Expressive language scale classification (Normal, Borderline, Delay); - Language comprehension scale classification (Normal, Borderline, Delay) | - Reasons for missingness by group NR; - Results were parent-reported; - Pre-registered data analysis NR
Lactation only
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | CLAMS; at 12mo and 2.5y | Non-significant:; All main effects; - Mean score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | WPPSI-R; at 5y | Non-significant:; All main effects; - Vocabulary Subtest score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR

#### Motor development

##### Supplementation during pregnancy alone

###### Summary

Seven RCTs examined the effects of omega-3 fatty acid supplementation during pregnancy alone on motor development in the child (ages 1 week to 5.5 years)^2,12,18,19,24–27^ (Table 4). Of those 7 RCTs, 6 found no treatment effect on at least one measure of motor development among children ages 1 week to 5.5 years.^2,18,19,24–27^ Gustafson et al^12^ found statistically significant, favorable effects of supplementation on a single measure of motor function in the neonate.

###### Assessment of the evidence^ix^

Given the mixed results and concerns regarding risk of bias due to missing outcome data, outcome measurement, and selection of reported results, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and motor development in the child, and therefore the body of evidence was rated ‘grade not assignable.’

##### Supplementation during both pregnancy and lactation

###### Summary

Both of the RCTs that examined the effect of omega-3 fatty acid supplementation during both pregnancy and lactation found no statistically significant effect on at least one measure of motor development in the child (ages 2 weeks to 5 years)^1,30,31^ (Table 4). Brei et al^1^ found that a single measure of motor development, namely, the mirror movement ratio in the dominant hand only at 5 years, was more favorable in the intervention group than in the control group, but no other measures were statistically significantly different. At 2 weeks and 12 weeks postpartum, van Goor et al^30^ found that infants whose mothers consumed DHA had a greater risk of mildly abnormal general movements compared to infants whose mothers consumed placebo. There were no differences in quality of general movements among infants whose mothers consumed DHA+ARA versus placebo or whose mothers consumed DHA+ARA versus DHA. Notably, the rates of mildly abnormal movements exceeded rates in other studies of healthy infants, and thus the authors disclosed blinding and discontinued the intervention before reaching recruitment goals.

###### Assessment of the evidence

Given the mixed results, the early discontinuation of one of the trials (due to adverse effects of DHA supplements), concerns regarding risk of bias due to outcome measurement and selection of reported results, and limited information on the generalizability of results to the general U.S. population, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and motor development in the child, and therefore the body of evidence was rated ‘grade not assignable.’

##### Supplementation during lactation alone

###### Summary

A single RCT examined the effect of omega-3 fatty acid supplementation during lactation alone on motor development in the child (ages 12 months to 5 years)^32,33^ (Table 4). Jensen et al^32,33^ reported higher scores on one measure of motor development at age ~2.5 years,^33^ and the authors noted that scores in both the supplemented and placebo groups were higher than in other studies of healthy toddlers. Additional results revealed no association with other measures of motor development at ages 12 months, 2.5 years, and 5 years.

###### Assessment of the evidence

The entire body of evidence consisted of a single study with concerns regarding statistical power to detect effects in these secondary outcomes, risk of bias due to outcome measurement and deviations from the intended intervention (Table 8), and a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during lactation alone and motor development in the child, and the body of evidence was rated ‘grade not assignable.’

Table 4 Description of evidence on relationship between omega-3 fatty acid supplementation and motor development^x^

Study and Participant Characteristics | Intervention (All RCTs) | Outcome(s) | Results | Limitations
Pregnancy Only
Escolano-Margarit, 2011 ^8^; Germany, Hungary, Spain \| NUHEAL; N=167; Mothers were age ~31y at enrollment and ~48% eligible for university entrance or degree. Race/ethnicity NR. | Placebo vs; FO: 500mg/d DHA + 150 mg/d EPA vs; 5-MTHF: 400 ug/d vs; FO + 5-MTHF; 20wk through delivery | Hempel Assessment; at 4y | Non-significant:; All main effects; - Clinical conclusion (normal, simple MND, complex MND); - NOS; - Fluency score | - Outcome assessor binding NR, but standard methods used; - Pre-registered analysis plan NR
Escolano-Margarit, 2011 ^8^; Germany, Hungary, Spain \| NUHEAL; N=167; Mothers were age ~31y at enrollment and ~48% eligible for university entrance or degree. Race/ethnicity NR. | Placebo vs; FO: 500mg/d DHA + 150 mg/d EPA vs; 5-MTHF: 400 ug/d vs; FO + 5-MTHF; 20wk through delivery | Touwen Assessment at 5.5y | Non-significant:; All main effects; - Clinical conclusion (normal, simple MND, complex MND); - NOS | - Outcome assessor binding NR, but standard methods used; - Pre-registered analysis plan NR
Gustafson, 2013 ^12^; USA; N=44; Mothers were age ~26y at enrollment and completed ~14y education. Race/Ethnicity: 37.3% Black, 46.3% White, 13.4% Hispanic, 3% Asian. | 600 mg/d DHA vs placebo (corn and soybean oils); 12-20wk through delivery | NBAS Motor scale; at 1wk | Significant:; Favors intervention; Adj P=0.038; Control (Mean± SD): 23.08± 11.40; Intervention: 26.07± 18.13 | - No power calculation; - Pre-registered analysis plan NR
Keenan, 2016 ^18^; USA; N=49; Age 20-30y. 100% Medicaid eligible. Race/Ethnicity: 100% Black. | 450 mg/d DHA + 40 mg/d DPA + 40 mg/d ETA + 90 mg/d EPA + 10 mg/d Vitamin E; 990 mg/d soybean oil + 16.5 mg/d Vitamin E + 10 mg/d EPA + 10 mg/d DHA; 16-21wk for 6wk | BSID-III: Fine motor and gross motor scales; at 3mo | Non-significant:; All main effects; - Fine motor scale; - Gross motor scale | - Reasons for missingness by group NR; - Pre-registered data analysis plan NR
Makrides, 2010 ^19^; Australia \| DOMInO; N=694; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil placebo; 18-21wk through delivery | BSID-III: Motor scubscale; at 18mo | Non-significant:; All main effects; Motor Standardized Score | - Pre-registered analysis plan NR
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | BSID-III: Fine motor and gross motor scales; at 18mo | Non-significant:; All main effects (Risk the placebo group fails to achieve the outcome); - Highest quartile fine motor score; - Highest quartile gross motor score | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Ostadrahimi, 2018 ^25^; Iran; N=146; Mothers were age ~26y at enrollment and ~8% completed >12y education. ~19% had non-adequate family income. Race/ethnicity NR. | 120mg/d DHA + 180mg/d EPA vs placebo (liquid paraffin); 16-20wk through delivery | Parent reported: ASQ-2 Fine and Gross motor subscales; at 4mo and 6mo | Non-significant:; All main effects; - Mean scores; - Subnormal development | - Pre-registered analysis plan NR
Ramakrishnan, 2015 ^27^; Mexico \| POSGRAD; N=730; Mothers were age ~26y at enrollment and ~59% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | BSID-II: Psychomotor Scale; at 18mo | Non-significant:; All main effects; - Mean score; - Risk of delay | - Pre-registered data analysis NR
Ramakrishnan, 2016 ^26^; Mexico \| POSGRAD; N=797; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | MSCA: Motor score at 5y | Non-significant:; All main effects; - Mean raw score; - Mean scale index score | - Pre-registered data analysis NR
Pregnancy and Lactation
van Goor, 2010 ^30^; The Netherlands; N=119; Mothers were age ~33y at enrollment and ~71% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | Neonatal neurological classification; at 2wk | Non-significant:; All main effects; - Mildly abnormal | - >30% attrition before delivery; - Early trial discontinuation due to high incidence mildly abnormal general movements at 12wk in DHA group; - Participant & assessors unblinded at trial discontinuation; - Pre-registered data analysis NR
van Goor, 2010 ^30^; The Netherlands; N=119; Mothers were age ~33y at enrollment and ~71% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | General movements at 2wk | Significant:; Favors control; Mildly abnormal; Control vs DHA; Adj P=0.021; Adj β: 3.867, 95% CI: (1.228, 12.173)
van Goor, 2010 ^30^; The Netherlands; N=119; Mothers were age ~33y at enrollment and ~71% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | General movements at 12wk | Significant:; Favors control; Mildy abnormal; Control vs DHA; Adj P=0.014; Adj β: 4.121, 95% CI: (1.335, 12.719)
van Goor, 2010 ^30^; The Netherlands; N=119; Mothers were age ~33y at enrollment and ~71% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | Neurological optimality score (NOS); at 12wk | Non-significant:; All main effects; - Score
van Goor, 2011 ^31^; The Netherlands; N=114; Mothers were age ~33y at enrollment and ~75% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | Hempel Assessment; at 18mo | Non-significant:; All main effects; - Neurological optimality score; - Fluency score; - Normal neurological condition; - Simple MND; - Complex MND | - Unclear power to find results, but attrition and reasons reasonably balanced; - Unclear whether outcomes would be affected by unblinded assessors
van Goor, 2011 ^31^; The Netherlands; N=114; Mothers were age ~33y at enrollment and ~75% completed ≥12y education. Race/ethnicity: NR. | 220mg/d DHA + 220mg/d ARA vs; 220mg/d DHA + placebo (soy) vs; 2 placebos (soy); 14-20wk through 3mo postpartum | BSID-II (Dutch edition); at 18mo | Non-significant:; All main effects; - Psychomotor developmental index | - BSID not mentioned in protocol
Brei, 2017 ^1^; Germany \| INFAT; N=130; Mothers were age ~33y at enrollment and 73% completed ≥12y education. Race/Ethnicity: NR. | 1020 mg/d DHA + 180 mg/d EPA + 9 mg/d Vitamin E vs general nutrition advice; 15wk gestation through 4mo postpartum | Mirror movement ratio; at 5y | Significant:; Favors intervention; Dominant hand, slow frequency; Adj Est Difference: −0.39, 95% CI: (−0.76, −0.02); Non-significant:; All other main effects; - Dominant hand, fast frequency; - Non-dominant hand, slow frequency; - Non-dominant hand, fast frequency | - Reasons for missingness by group NR; - Results were parent-reported; - Pre-registered data analysis NR
Brei, 2017 ^1^; Germany \| INFAT; N=130; Mothers were age ~33y at enrollment and 73% completed ≥12y education. Race/Ethnicity: NR. | 1020 mg/d DHA + 180 mg/d EPA + 9 mg/d Vitamin E vs general nutrition advice; 15wk gestation through 4mo postpartum | Parent reported: Child Development Inventory: Gross and fine motor scales; at 5y | Non-significant:; All main effects; - Gross motor scale classification (Normal, Borderline, Delay); - Fine motor scale classification (Normal, Borderline, Delay) | - Reasons for missingness by group NR; - Results were parent-reported; - Pre-registered data analysis NR
Lactation only
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | BSID-II: Psychomotor Scale; at 2.5y | Significant:; Favors intervention; Adj P=0.008; Control (Mean± SD): 108.4± 18.9; Intervention: 116.8± 15.2 | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Gesell Developmental Inventory at; 12mo and 2.5y | Non-significant:; All main effects; - Mean score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Gross motor: MSCA; K-ABC; at 5y | Non-significant:; All main effects; MSCA; - Leg Coordination subscale score; K-ABC; - Hand Movement subscale score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Fine motor: Purdue Pegboard Test; Developmental Test of Visual-Motor Integration-III; at 5y | Non-significant:; All main effects; Purdue Pegboard Test; - Dominant Hand score; - Non-Dominant Hand score; Developmental Test of; Visual-Motor Integration-III; - Motor component score | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR

#### Visual development

##### Supplementation during pregnancy alone

###### Summary

Five RCTs examined the effects of omega-3 fatty acid supplementation during pregnancy alone on visual development in the child (ages 1 day to 12 months)^17,21,24,28,29^ (Table 5). All 5 studies found no effect of treatment on at least one measure of visual development among children assessed from the neonatal period through 12 months. Two RCTs found statistically significant, favorable effects of omega-3 fatty acid supplementation on one measure of visual acuity in the child at approximately age 2 months.^17,24^

###### Assessment of the evidence^xi^

The evidence was characterized by mixed results, samples that may not reflect the diversity of the general U.S. population, and risk of bias due to deviations from the intended intervention and selection of the reported results (Table 8). Given these limitations, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and visual development in the child and the body of evidence was rated ‘grade not assignable.’

##### Supplementation during both pregnancy and lactation

###### Summary

No studies examined the effects of omega-3 fatty acid supplementation during both pregnancy and lactation on visual development in the child, and therefore a grade was not assignable.

##### Supplementation during lactation alone

###### Summary

One RCT examined the effect of omega-3 fatty acid supplementation during lactation alone on visual development in the child^32,33^ (Table 5). Jensen et al reported unfavorable outcomes for a single, electrophysiological measure of visual acuity at ages 4 months and 8 months,^33^ but no association with another electrophysiological measure at the same ages. Additional results revealed no association with other measures of visual development at ages 4 months, 8 months, and 5 years.^32,33^

###### Assessment of the evidence

The entire body of evidence consisted of a single study with concerns regarding statistical power to detect effects in these secondary outcomes, risk of bias due to selection of reported results (Table 8), and a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during lactation alone and visual development in the child, and the body of evidence was rated ‘grade not assignable.’

Table 5 Description of evidence on relationship between omega-3 fatty acid supplementation and visual development^xii^

Study and Participant Characteristics | Intervention (All RCTs) | Outcome(s) | Results | Limitations
Pregnancy only
Innis, 2008 ^17^; Canada; N=135; Mothers were age ~33y at enrollment, with ~77% ≥middle income, and ~76% completed university educated. Race/ethnicity: ~72% White. | 400 mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Visual acuity: Teller Acuity Card at 60d | Significant:; Favors intervention; Lower visual acuity threshold; Adj β: 1.215, Adj SE: 1.64, Adj OR: 3.37; Non-significant:; All other main effects; - Acuity score (cycles/degree) | - Unclear how many women started the study; - Unclear whether missing data proportions/reasons differ by group; - Pre-registered data analysis NR
Malcolm, 2003 ^21^; UK; N=59; Sample characteristics NR. | 200 mg/d DHA fish oil vs placebo (oleic acid-rich sunflower); 15wk through delivery | Visual acuity: Transient flash and pattern-reversal VEPs at 1-5d, 10wk, 6mo | Non-significant:; All main effects; Transient flash VEPs mean peak latency; - N1; - P1; - N2; - P2; - N3; - No. of components (10wk and 6mo only); Pattern-reversal VEPs (10wk and 6mo only); - P100 peak latency; - Threshold check size | - Details of randomization and allocation NR; - Most common reason for attrition during pregnancy: poor adherence; - Pre-registered analysis plan NR
Mulder, 2013 ^24^; Canada; N=154; Mothers were age ~33y at enrollment and 94.4% completed post-secondary eduation. Race/Ethnicity: ~74% White. | 400mg/d DHA vs placebo (corn and soybean oils); 16wk through delivery | Visual acuity: Teller Acuity Card at 2mo and 12mo | Significant:; Favors intervention; Failure to achieve high visual acuity (2mo); Adj P=0.03; Adj OR: 2.50, 95% CI: (1.02, 6.14); Non-significant:; Failure to achieve high visual acuity (12mo) | - No power calculation; - Pre-registered data analysis outlined multiple regression, NR in paper
Smithers, 2011 ^28^; Australia \| DOMInO; N=182; Mothers were age ~29y at enrollment and ~62% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Visual acuity: VEP-acuity; VEP-Latency; at 4mo | Non-significant:; All main effects; - Adjusted VEP acuity; - Unadjusted VEP acuity; - VEP latency; ○ 69 min of arc; ○ 48 min of arc; ○ 20 min of arc | - Pre-registered analysis plan NR
Stein, 2012 ^29^; Mexico \| POSGRAD; N=900; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | Visual acuity: VEP at 3mo and 6mo | Non-significant:; All main effects; - N1 latency; - P1 latency; - P1 amplitude; - N3 latency | - Pre-registered analysis plan NR
Lactation only
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual acuity: Transient VEP; at 4mo and 8mo | Significant:; Favors control; VEP Amplitude, P<0.03; 4mo; Control (Mean± SD): 33.3± 12.42; Intervention: 28.9± 12.1; 8mo, P<0.03; Control: 27.9± 11.02; Intervention: 24.3± 8.9; Non-significant:; All other main effects; - VEP Latency | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual acuity: Teller Acuity Card; at 4mo and 8mo | Non-significant:; All main effects; - Score (cycle/degree) | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2005 ^33^; USA; N=160; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 77% White, ~16% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual acuity: Sweep VEP; at 4mo | Non-significant:; All main effects; - Score (cycle/degree) | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual acuity: VEP; at 5y | Non-significant:; All main effects; - VEP Amplitude, P=0.06; ○ Placebo > DHA; - VEP Latency; - Sweep VEP acuity (cycle/degree) | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR
Jensen, 2010 ^32^; USA; N=118; Mothers were age ~32y at enrollment, with mean education 16y. Race/ethnicity of children: 79% White, ~14% Black, ~6% Hispanic. | 200mg/d DHA vs placebo (corn and soybean oils); 5d through 4mo postpartum | Visual acuity/Stereoacuity: Bailey-Lovie chart; Titmus Fly Stereotest; at 5y | Non-significant:; All main effects; Bailey-Lovie chart; - Right eye no. correct letters; - Left eye no. correct letters; Titmus Fly Stereotest; - Smallest target identified | - Statistical power estimate based on other outcomes; - Pre-registered data analysis NR

#### Social-emotional development

##### Supplementation during pregnancy alone

###### Summary

Seven RCTs examined the effect of omega-3 fatty acid supplementation during pregnancy alone on social-emotional development in the child (ages 1 week to 7 years).^6,7,11,12,18–20,22,25–27^ Two found statistically significant effects (Table 6).^11,18,20^ In 1 study, children of mothers in the omega-3 fatty acid supplemented group were more likely to have higher total difficulties or hyperactivity on a parent-reported measure of child behavior at 4 years, but supplementation had no effect on other parameters measured with the same tool.^20^ At 7 years, using an age-appropriate version of the same tool, the authors reported that the total score indicated unfavorable outcomes for children of mothers in the supplemented group.^11^ Another study revealed that omega-3 fatty acid supplementation resulted in a more attenuated (favorable) stress response at 3 months.^18^ The remaining studies did not report any statistically significant results.^6,7,12,22,25–27^

###### Assessment of the evidence^xiii^

Given the mixed results and concerns regarding the risk of bias due to parent-reported outcomes (Table 8), insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and social-emotional development in the child, and therefore the body of evidence was rated ‘grade not assignable.’

##### Supplementation during both pregnancy and lactation

###### Summary

One RCT reported no effect of omega-3 fatty acid supplementation during both pregnancy and lactation on a parent-reported measure of social-emotional development in the child at age 4 years and 5 years (Table 6).^1^

###### Assessment of the evidence

The entire body of evidence consisted of a single study with concerns regarding statistical power to detect effects in these secondary outcomes, risk of bias concerns due to parent-reported outcomes (Table 8), and limited information on the generalizability of results to the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during both pregnancy and lactation and social-emotional development in the child, and the body of evidence was rated ‘grade not assignable.’

##### Supplementation during lactation alone

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during lactation alone on social-emotional development in the child, and therefore a grade was not assignable.

Table 6 Description of evidence on relationship between omega-3 fatty acid supplementation and social-emotional development^xiv^

Study and Participant Characteristics | Intervention (All RCTs) | Outcome(s) | Results | Limitations
Pregnancy only
Colombo, 2019 ^6^; USA; N=161; Mothers were age ~26y at enrollment, with mean income <$46K and ~14y education. Race/Ethnicity: 6% Hispanic, 31% Black. | 600 mg/d DHA vs placebo (corn and soybean oils); ~14.5wk through delivery | Behavior--Parent reported: BASC; at 36mo, 48mo, 60mo, 72mo | Non-significant:; All main effects; - Externalizing Problems; - Internalizing Problems; - Behavioral Symptoms; - Adaptive Skills | - Results parent-reported; - More outcomes reported in the paper than on the clinical trials registry; - Pre-registered data analysis plan NR
Dunstan, 2008 ^7^; Australia; N=72; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | Behavior--Parent Reported: CBCL: 1.5.5y; at 2.5y | Non-significant:; All main effects; - Internalizing scale; - Externalizing scale; - Total problem behavioral scale | - Results parent-reported; - Probable differences in reasons for attrition, no power calculation for neurobehavioral results; - Pre-registered data analysis plan NR
Gould, 2017 ^11^; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Behavior--Parent reported: SDQ; at 7y | Significant:; Favors control; Total difficulties score; Adj P=0.02; Ref: Control; Adj Mean Difference: 1.09, 95% CI: (0.18, 2.00) | - Results parent-reported
Gustafson, 2013 ^12^; USA; N=44; Mothers were age ~26y at enrollment and completed ~14y education. Race/Ethnicity: 37.3% Black, 46.3% White, 13.4% Hispanic, 3% Asian. | 600 mg/d DHA vs placebo (corn and soybean oils); 12-20wk through delivery | NBAS: State organization, State regulation scales; at 1wk | Non-significant:; All main effects; - State organization; - State regulation scales | - No power calculation; - Pre-registered analysis plan NR
Keenan, 2016 ^18^; USA; N=49; Age 20-30y. 100% Medicaid eligible. Race/Ethnicity: 100% Black. | 450 mg/d DHA + 40 mg/d DPA + 40 mg/d ETA + 90 mg/d EPA + 10 mg/d Vitamin E vs 990 mg/d soybean oil + 16.5 mg/d Vitamin E + 10 mg/d EPA + 10 mg/d DHA; 16-21wk for 6wk | Behavior--Stress reactivity: FFSF cortisol response at 3mo | Significant:; Favors intervention; Adj P=0.018; F=5.36 | - Reasons for missingness by group NR; - Pre-registered data analysis plan NR
Makrides, 2010 ^19^; Australia \| DOMInO; N=694; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil placebo; 18-21wk through delivery | BSID-III: Social-emotional scale; Adaptive Behavioral subscales; at 18mo | Non-significant:; All main effects; - Social-emotional Standardized Score; - Adaptive Behavior Standardized Score | - Pre-registered analysis plan NR
Makrides, 2014 ^20^; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Behavior--Parent Reported: SDQ scales, subscales; at 4y | Significant:; Favors control; Total difficulties; Adj P=0.04; Ref: Control; Adj Mean Difference: 0.63, 95% CI: (0.03, 1.23); Hyperactivity; Adj P=0.04; Ref: Control; Adj Mean Difference: 0.30, 95% CI: (0.01, 0.59); Non-significant:; All other main effects; - Emotional Symptoms; - Conduct Problems; - Peer Problems; - Prosocial Behavior; - Impact | - Results parent-reported; - Pre-registered analysis plan NR
Meldrum, 2015 ^22^; Australia; N=48; Mothers were age ~32y at enrollment and ~73% completed ≥12y education. Race/Ethnicity: 100% White. | 2.2g/d DHA + 1.1 g/d EPA vs placebo (olive oil); 20wk through delivery | Behavior--Parent, Child Reported: CBCL; at 12y | Non-significant:; All main effects; Parent-Report; - Internalizing Behaviors; - Externalizing Behaviors; - Total Behaviors score; - Total Competence score; Child-Self Report; - Internalizing Behaviors; - Externalizing Behaviors; - Total Behaviors score; - Total Competence score | - Results parent-reported; - Among those followed to 12y, birth weight differed by treatment group; - Possible differences in reasons for attrition; - No power calculation, Likely under-powered
Ostadrahimi, 2018 ^25^; Iran; N=146; Mothers were age ~26y at enrollment and ~8% completed >12y education. ~19% had non-adequate family income. Race/ethnicity NR. | 120mg/d DHA + 180mg/d EPA vs placebo (liquid paraffin); 16-20wk through delivery | Behavior--Parent reported: ASQ-2 Personal-social subscale at 4mo and 6mo | Non-significant:; All main effects; - Mean score; - Subnormal development | - Behavioral data parent-reported data; - Pre-registered analysis plan NR
Ramakrishnan, 2015 ^27^; Mexico \| POSGRAD; N=730; Mothers were age ~26y at enrollment and ~59% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | BSID-II: Behavior Rating Scale at 18mo | Non-significant:; All main effects; - Mean score; - Risk of delay | - Results parent-reported; - Pre-registered data analysis NR
Ramakrishnan, 2016 ^26^; Mexico \| POSGRAD; N=797; Mothers were age ~26y at enrollment and ~58% completed ≥12y education. | 400mg/d DHA vs placebo (corn and soybean oils); 18-22wk through delivery | Behavior--Parent Reported: BASC-2 at 5y | Non-significant:; All main effects; - Externalizing problems composite; ○ Hyperactivity; ○ Aggression; - Internalizing problems composite; ○ Anxiety; ○ Depression; ○ Somatization; - Adaptive skills composite; ○ Withdrawal; ○ Adaptability; ○ Activities in daily life; ○ Atypicality; ○ Attention problems; ○ Functional communication; ○ Social skills; - Behavioral Symptoms Index; ○ Anger control; ○ Bullying; ○ Developmental and social disorders; ○ Emotional selfcontrol; ○ Executive functioning; ○ Negative emotionality; ○ Resiliency | - Results parent-reported; - Pre-registered data analysis NR
Pregnancy and Lactation
Brei, 2017 ^1^; Germany \| INFAT; N=130; Mothers were age ~33y at enrollment and 73% completed ≥12y education. Race/Ethnicity: NR. | 1020 mg/d DHA + 180 mg/d EPA + 9 mg/d Vitamin E vs general nutrition advice; 15wk gestation through 4mo postpartum | Behavior--Parent reported: Child Development Inventory: Social, self-help scales; at 4y and 5y | Non-significant:; All main effects; - Social scale classification (Normal, Borderline, Delay); - Self help scale classification (Normal, Borderline, Delay) | - Reasons for missingness by group NR; - Results were parent-reported; - Pre-registered data analysis NR

#### Academic performance

##### Supplementation during pregnancy alone

###### Summary

A single RCT examined the effect of omega-3 fatty acid supplementation during pregnancy alone on academic performance in the child and found no effect on a measure of reading, spelling, and math computation at age 7 years (Table 7).^11^

###### Assessment of the evidence^xv^

The entire body of evidence consisted of a single study in a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and academic performance in the child, and the body of evidence was rated ‘grade not assignable.’

##### Supplementation during both pregnancy and lactation

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during both pregnancy and lactation on academic performance in the child, and therefore a grade was not assignable.

##### Supplementation during lactation alone

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during lactation alone on academic performance in the child, and therefore a grade was not assignable.

#### Anxiety

##### Summary

No studies examined the effect of omega-3 fatty acid supplementation during pregnancy and/or lactation on anxiety in the child, and therefore a grade was not assignable.

#### Depression

##### Summary

No studies examined the effect of omega-3 fatty acid supplementation during pregnancy and/or lactation on depression in the child, and therefore a grade was not assignable.

#### ADD/ADHD

##### Supplementation during pregnancy alone

###### Summary

A single RCT examined the effect of omega-3 fatty acid supplementation during pregnancy alone on risk of ADD/ADHD in the child. The results showed no effect at age 4 years,^10^ and a higher risk of ADHD among children of mothers in the treatment group at 7 years (Table 7).^11^

###### Assessment of the evidence

The entire body of evidence consisted of a single study in a sample that may not reflect the diversity of the general U.S. population. Therefore, insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and ADD/ADHD in the child, and a grade was not assignable.

##### Supplementation during both pregnancy and lactation

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during both pregnancy and lactation on risk of ADD/ADHD in the child, and therefore a grade was not assignable.

##### Supplementation during lactation alone

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during lactation alone on risk of ADD/ADHD in the child, and therefore a grade was not assignable.

#### Autism spectrum disorder

##### Supplementation during pregnancy alone

###### Summary

One RCT^10^ and 1 PCS^16^ examined the effect of omega-3 fatty acid supplementation during pregnancy alone on risk of autism spectrum disorder in the child (ages 36 months to 4 years), and neither study reported a statistically significant relationship (Table 7).

###### Assessment of the evidence

Given the small number of studies in samples that may not reflect the diversity of the general U.S. population, as well as concerns regarding risk of bias due to confounding, classification of exposures, and the selection of reported results (Table 9), insufficient evidence existed to determine the relationship between omega-3 fatty acid supplementation during pregnancy alone and autism spectrum disorder in the child, and therefore a grade was not assignable.

##### Supplementation during both pregnancy and lactation

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during both pregnancy and lactation on risk of autism spectrum disorder in the child, and therefore a grade was not assignable.

##### Supplementation during lactation alone

###### Summary

No studies examined the effect of omega-3 fatty acid supplementation during lactation alone on risk of autism spectrum disorder in the child, and therefore a grade was not assignable.

Table 7 Description of evidence on relationship between omega-3 fatty acid supplementation and academic performance, risk of ADD/ADHD, or risk of Autism spectrum disorder^xvi^

Study and Participant Characteristics | Intervention/Exposure | Outcome(s) | Results | Limitations
Pregnancy Only
Academic Performance
Gould, 2017^11^ \| RCT; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | WRAT-4; at 7y | Non-significant:; All main effects; - Word reading; - Spelling; - Math computation | - No major limitations
ADD/ADHD
Gould, 2017^11^ \| RCT; Australia \| DOMInO; N=543; Mothers were age ~30y at enrollment and ~66% completed secondary education. Race/ethnicity NR. | Average supplemental Omega-3 (100 mg/d); 1mo through delivery | ADHD score; Conners 3 AI-parent; at 7y | Significant:; Favors control; ADHD score; Adj P=0.02; Ref: Control; Adj Mean Difference: 2.84, 95% CI: (0.38, 5.30) | - No major limitations
Makrides, 2014^20^ \| RCT; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | Hyperactivity disorders: No methodological details; at 4y | Non-significant:; - All main effects Diagnosis | - No methodological details for hyperactivity disorders; - Pre-registered analysis plan NR
Autism Spectrum Disporder
Makrides, 2014^20^ \| RCT; Australia \| DOMInO; N=646; Mothers were age ~29y at enrollment and ~68% completed more than secondary education. Race/ethnicity NR. | 800mg/d DHA + 100 mg/d EPA vs Vegetable oil (rapeseed, sunflower, and palm) placebo; 18-21wk through delivery | ASD diagnosis; at 4y | Non-significant:; All main effects; - Diagnosis | - No methodological details for ASD diagnosis; - Pre-registered analysis plan NR
Huang, 2020^16^ \| PCS; USA \| MARBLES; N=258; Mothers were age ~34y at enrollment and ~59% completed ≥Bachelor’s degree. Race/ethnicity: ~55% White. | Omega-3 supplement intake (100 mg/d increments); 1mo-9mo | ASD diagnosis: Mullen Scales of Early Learning, Autism Diagnostic Observation Schedule; at 36mo | Non-significant:; All main effects; - Diagnosis | - Multiple key confounders not accounted for; - Critical co-exposures NR; - No information on missing outcome data, but other missing data appears to be balanced across groups; - Pre-registered data analysis plan NR

Table 8 Risk of bias for randomized controlled trials examining omega-3 fatty acid supplementation and developmental milestones, including neurocognitive development, in the child^xvii^ ^xviii^

| Randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Brei, 2017^1^ | Low | Low | Some concerns | High | Some concerns
Campoy, 2011^2^ | Low | Low | Low | Low | Some concerns
Catena, 2016^4^ | Low | Low | Low | Low | High
Catena, 2019^3^ | Low | Low | Low | Low | Some concerns
Colombo, 2016^5^ | Low | Low | High | Low | Some concerns
Colombo, 2019^6^ | Low | Low | Low | Low | Some concerns
Dunstan, 2008^7^ | Low | Low | Some concerns | Low | Some concerns
Escolano-Margarit, 2011^8^ | Low | Low | Low | Some concerns | Some concerns
Gould, 2014^10^ | Low | Low | Low | Low | Some concerns
Gould, 2016^9^ | Low | Low | Some concerns | Low | Some concerns
Gould, 2017^11^ | Low | Low | Low | Low | Low
Gustafson, 2013^12^ | Low | Low | Low | Low | Some concerns
Helland, 2001^13^ | Some concerns | High | Some concerns | Low | Some concerns
Helland, 2003^15^ | Some concerns | High | Some concerns | Low | Some concerns
Helland, 2008^14^ | Some concerns | High | Some concerns | Low | Some concerns
Innis, 2008^17^ | Low | Low | Some concerns | Low | Some concerns
Jensen, 2005^33^ | Low | Low | Low | Low | Some concerns
Jensen, 2010^32^ | Low | Low | Low | Low | Some concerns
Keenan, 2016^18^ | Low | Low | Some concerns | Low | Some concerns
Makrides, 2010^19^ | Low | Low | Low | Low | Some concerns
Makrides, 2014^20^ | Low | Low | Low | Low | Some concerns
Malcolm, 2003^21^ | Some concerns | High | Low | Low | Some concerns
Meldrum, 2015^22^ | Low | Low | Some concerns | Low | Some concerns
Mulder, 2013^24^ | Low | Low | Low | Low | High
Mulder, 2018^23^ | Low | Low | Low | Low | Some concerns
Ostadrahimi, 2018^25^ | Low | Low | Low | Low | Some concerns
Ramakrishnan, 2015^27^ | Low | Low | Low | Low | Some concerns
Ramakrishnan, 2016^26^ | Low | Low | Low | Low/High | Some concerns
Smithers, 2011^28^ | Low | Low | Low | Low | Some concerns
Stein, 2012^29^ | Low | Low | Low | Low | Some concerns
van Goor, 2010^30^ | Some concerns | Low | Low | Low | Some concerns
van Goor, 2011^31^ | Some concerns | Low | Low | Some concerns | Some concerns

Table 9 Risk of bias for observational studies examining omega-3 fatty acid supplementation and developmental milestones, including neurocognitive development, in the child^xix^

| Confounding | Selection of participant | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Huang, 2020^16^ | Serious | Moderate | Serious | No Information | No Information | Moderate | Serious

### Research recommendations

- Strive to include participants who are reflective of the U.S. population on characteristics such as race/ethnicity, socioeconomic background, age, etc.
- Research is needed to determine whether the magnitude and/or direction of effects differ when omega-3 fatty acids are consumed as an individual nutrient supplement during pregnancy and/or lactation versus as in combination with a multi-vitamin/mineral supplement or in fortified foods, in relation to neurobehavioral development in the child.
- More research is needed to understand the relationship between omega-3 fatty acid supplementation during pregnancy and/or lactation and cognitive, language, motor, visual, and social-emotional development in the child. In particular, research should consider the baseline omega-3 fatty acid status of the mother and usual intakes in the U.S. population.
- More research is needed to understand the relationship between omega-3 fatty acid supplementation during pregnancy and/or lactation and academic performance in the child. In particular, research should consider the maternal baseline omega-3 fatty acid status and usual intakes in the U.S. population.
- More research is needed to understand the relationship between omega-3 fatty acid supplementation during pregnancy and/or lactation and risk of anxiety, depression, ADD/ADHD, and autism spectrum disorder in the child. In particular, research should consider the maternal baseline omega-3 fatty acid status and usual intakes in the U.S. population.
- Research is needed to understand the relationship between omega-3 fatty acid supplementation during pregnancy and/or lactation and risk of maternal anxiety and depression. In particular, research should consider the maternal baseline omega-3 fatty acid status and usual intakes in the U.S. population.
- Additional research is needed to better identify the time period(s) during pregnancy and/or lactation when an effect of omega-3 fatty acid supplementation on child development is more likely to be observed. Specifically, more studies are needed to investigate the effect of supplementation during both pregnancy and lactation, and during lactation alone on child development.
- Further research is needed to determine whether there are differential effects of the various forms of omega-3 fatty acid supplements during pregnancy and/or lactation on child development.

### Included articles

1 Brei C, Stecher L, Brunner S, . Impact of the n-6:n-3 long-chain PUFA ratio during pregnancy and lactation on offspring neurodevelopment: 5-year follow-up of a randomized controlled trial. Eur J Clin Nutr. 2017;71(9):1114–1120.doi: 10.1038/ejcn.2017.79.28537583
2 Campoy C, Escolano-Margarit MV, Ramos R, . Effects of prenatal fish-oil and 5-methyltetrahydrofolate supplementation on cognitive development of children at 6.5 y of age. Am J Clin Nutr. 2011;94(6 Suppl):1880S–1888S.doi: 10.3945/ajcn.110.001107.21849596
3 Catena A, Martinez-Zaldivar C, Diaz-Piedra C, . On the relationship between head circumference, brain size, prenatal long-chain PUFA/5-methyltetrahydrofolate supplementation and cognitive abilities during childhood. Br J Nutr. 2019;122(s1):S40–S48.doi: 10.1017/S0007114516004281.28351446
4 Catena A, Munoz-Machicao JA, Torres-Espinola FJ, . Folate and long-chain polyunsaturated fatty acid supplementation during pregnancy has long-term effects on the attention system of 8.5-y-old offspring: a randomized controlled trial. Am J Clin Nutr. 2016;103(1):115–127.doi: 10.3945/ajcn.115.109108.26561619
5 Colombo J, Gustafson KM, Gajewski BJ, . Prenatal DHA supplementation and infant attention. Pediatr Res. 2016;80(5):656–662.doi: 10.1038/pr.2016.134.27362506
6 Colombo J, Shaddy DJ, Gustafson K, . The Kansas University DHA Outcomes Study (KUDOS) clinical trial: long-term behavioral follow-up of the effects of prenatal DHA supplementation. Am J Clin Nutr. 2019;109(5):1380–1392.doi: 10.1093/ajcn/nqz018.31004139
7 Dunstan JA, Simmer K, Dixon G, Prescott SL. Cognitive assessment of children at age 2(1/2) years after maternal fish oil supplementation in pregnancy: a randomised controlled trial. Arch Dis Child Fetal Neonatal Ed. 2008;93(1):F4550.doi: 10.1136/adc.2006.099085.
8 Escolano-Margarit MV, Ramos R, Beyer J, . Prenatal DHA status and neurological outcome in children at age 5.5 years are positively associated. J Nutr. 2011;141(6):1216–1223.doi: 10.3945/jn.110.129635.21525247
9 Gould JF, Anderson AJ, Yelland LN, Gibson RA, Makrides M. Maternal characteristics influence response to DHA during pregnancy. Prostaglandins Leukot Essent Fatty Acids. 2016;108:5–12.doi: 10.1016/j.plefa.2016.03.011.27154359
10 Gould JF, Makrides M, Colombo J, Smithers LG. Randomized controlled trial of maternal omega-3 long-chain PUFA supplementation during pregnancy and early childhood development of attention, working memory, and inhibitory control. Am J Clin Nutr. 2014;99(4):851–859.doi: 10.3945/ajcn.113.069203.24522442
11 Gould JF, Treyvaud K, Yelland LN, . Seven-Year Follow-up of Children Born to Women in a Randomized Trial of Prenatal DHA Supplementation. JAMA. 2017;317(11):1173–1175.doi: 10.1001/jama.2016.21303.28324081
12 Gustafson KM, Carlson SE, Colombo J, . Effects of docosahexaenoic acid supplementation during pregnancy on fetal heart rate and variability: a randomized clinical trial. Prostaglandins Leukot Essent Fatty Acids. 2013;88(5):331–338.doi: 10.1016/j.plefa.2013.01.009.23433688
13 Helland IB, Saugstad OD, Smith L, . Similar effects on infants of n-3 and n-6 fatty acids supplementation to pregnant and lactating women. Pediatrics. 2001;108(5):E82.doi: 10.1542/peds.108.5.e82.11694666
14 Helland IB, Smith L, Blomen B, Saarem K, Saugstad OD, Drevon CA. Effect of supplementing pregnant and lactating mothers with n-3 very-long-chain fatty acids on children’s IQ and body mass index at 7 years of age. Pediatrics. 2008;122(2):e472–479.doi: 10.1542/peds.2007-2762.18676533
15 Helland IB, Smith L, Saarem K, Saugstad OD, Drevon CA. Maternal supplementation with very-long-chain n-3 fatty acids during pregnancy and lactation augments children’s IQ at 4 years of age. Pediatrics. 2003;111(1):e39–44.doi: 10.1542/peds.111.1.e39.12509593
16 Huang Y, Iosif AM, Hansen RL, Schmidt RJ. Maternal polyunsaturated fatty acids and risk for autism spectrum disorder in the MARBLES high-risk study. Autism. 2020:1362361319877792.doi: 10.1177/1362361319877792.
17 Innis SM, Friesen RW. Essential n-3 fatty acids in pregnant women and early visual acuity maturation in term infants. Am J Clin Nutr. 2008;87(3):548–557.doi: 10.1093/ajcn/87.3.548.18326591
18 Keenan K, Hipwell A, McAloon R, Hoffmann A, Mohanty A, Magee K. The effect of prenatal docosahexaenoic acid supplementation on infant outcomes in African American women living in low-income environments: A randomized, controlled trial. Psychoneuroendocrinology. 2016;71:170–175.doi: 10.1016/j.psyneuen.2016.05.023.27290652
19 Makrides M, Gibson RA, McPhee AJ, . Effect of DHA supplementation during pregnancy on maternal depression and neurodevelopment of young children: a randomized controlled trial. JAMA. 2010;304(15):1675–1683.doi: 10.1001/jama.2010.1507.20959577
20 Makrides M, Gould JF, Gawlik NR, . Four-year follow-up of children born to women in a randomized trial of prenatal DHA supplementation. JAMA. 2014;311(17):1802–1804.doi: 10.1001/jama.2014.2194.24794375
21 Malcolm CA, McCulloch DL, Montgomery C, Shepherd A, Weaver LT. Maternal docosahexaenoic acid supplementation during pregnancy and visual evoked potential development in term infants: a double blind, prospective, randomised trial. Arch Dis Child Fetal Neonatal Ed. 2003;88(5):F383–390.doi: 10.1136/fn.88.5.f383.12937042
22 Meldrum S, Dunstan JA, Foster JK, Simmer K, Prescott SL. Maternal fish oil supplementation in pregnancy: a 12 year follow-up of a randomised controlled trial. Nutrients. 2015;7(3):2061–2067.doi: 10.3390/nu7032061.25803546
23 Mulder KA, Elango R, Innis SM. Fetal DHA inadequacy and the impact on child neurodevelopment: a follow-up of a randomised trial of maternal DHA supplementation in pregnancy. Br J Nutr. 2018;119(3):271–279.doi: 10.1017/S0007114517003531.29316994
24 Mulder KA, King DJ, Innis SM. Omega-3 fatty acid deficiency in infants before birth identified using a randomized trial of maternal DHA supplementation in pregnancy. PLoS One. 2014;9(1):e83764.doi: 10.1371/journal.pone.0083764.24427279
25 Ostadrahimi A, Salehi-Pourmehr H, Mohammad-Alizadeh-Charandabi S, Heidarabady S, Farshbaf-Khalili A. The effect of perinatal fish oil supplementation on neurodevelopment and growth of infants: a randomized controlled trial. Eur J Nutr. 2018;57(7):2387–2397.doi: 10.1007/s00394-017-1512-1.28752418
26 Ramakrishnan U, Gonzalez-Casanova I, Schnaas L, . Prenatal supplementation with DHA improves attention at 5 y of age: a randomized controlled trial. Am J Clin Nutr. 2016;104(4):1075–1082.doi: 10.3945/ajcn.114.101071.27604770
27 Ramakrishnan U, Stinger A, DiGirolamo AM, . Prenatal Docosahexaenoic Acid Supplementation and Offspring Development at 18 Months: Randomized Controlled Trial. PLoS One. 2015;10(8):e0120065.doi: 10.1371/journal.pone.0120065.26262896
28 Smithers LG, Gibson RA, Makrides M. Maternal supplementation with docosahexaenoic acid during pregnancy does not affect early visual development in the infant: a randomized controlled trial. Am J Clin Nutr. 2011;93(6):1293–1299.doi: 10.3945/ajcn.110.009647.21490140
29 Stein AD, Wang M, Rivera JA, Martorell R, Ramakrishnan U. Auditory- and visual-evoked potentials in Mexican infants are not affected by maternal supplementation with 400 mg/d docosahexaenoic acid in the second half of pregnancy. J Nutr. 2012;142(8):1577–1581.doi: 10.3945/jn.112.162461.22739364
30 van Goor SA, Dijck-Brouwer DA, Doornbos B, . Supplementation of DHA but not DHA with arachidonic acid during pregnancy and lactation influences general movement quality in 12-week-old term infants. Br J Nutr. 2010;103(2):235–242.doi: 10.1017/S0007114509991528.19703327
31 van Goor SA, Dijck-Brouwer DA, Erwich JJ, Schaafsma A, Hadders-Algra M. The influence of supplemental docosahexaenoic and arachidonic acids during pregnancy and lactation on neurodevelopment at eighteen months. Prostaglandins Leukot Essent Fatty Acids. 2011;84(5–6):139–146.doi: 10.1016/j.plefa.2011.01.002.21316208
32 Jensen CL, Voigt RG, Llorente AM, . Effects of early maternal docosahexaenoic acid intake on neuropsychological status and visual acuity at five years of age of breast-fed term infants. J Pediatr. 2010;157(6):900–905.doi: 10.1016/j.jpeds.2010.06.006.20655543
33 Jensen CL, Voigt RG, Prager TC, . Effects of maternal docosahexaenoic acid intake on visual function and neurodevelopment in breastfed term infants. Am J Clin Nutr. 2005;82(1):125–132.doi: 10.1093/ajcn.82.1.125.16002810

ii Dietary supplement was defined as a product (other than tobacco) that: is intended to supplement the diet; contains one or more dietary ingredients (including vitamins; minerals; herbs or other botanicals; amino acids; and other substances) or their constituents; is intended to be taken by mouth as a pill, capsule, tablet, or liquid; and is labeled on the front panel as being a dietary supplement (ODS; Dietary Supplement Health and Education Act, 1994). Fortification was defined as the deliberate addition of one or more essential nutrients to a food, whether or not it is normally contained in the food (FDA).

iii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

iv DOMInO: DHA to Optimize Mother Infant Outcome; INFAT: The Impact of the Nutritional Fatty Acids During Pregnancy and Lactation for Early Human Adipose Tissue Development; KUDOS: Kansas University DHA Outcomes Study; MARBLES: Markers of Autism Risk in Babies-Learning Early Signs; NUHEAL: Nutraceuticals for a Healthier Life; POSGRAD: Prenatal Omega 3 Supplementation on child Growth and Development

v A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi ABR: Auditory brainstem response; Adj: adjusted; ARA: arachidonic acid; ASQ: Ages and Stages Questionnaire; BRIEF: Behavior Rating Inventory of Executive Function-Preschool; BSID: Bayley Scales of Infant Development; CELF: Clinical Evaluation of Language Fundamentals; CI: confidence interval; DAS: Differential Ability Scales; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; FO: fish oil; FTII: Fagan Test of Infant Intelligence; GMDS: Griffiths Mental Development Scales; INFAT: The Impact of the Nutritional Fatty Acids During Pregnancy and Lactation for Early Human Adipose Tissue Development; IQ: intellignce quotient; ISI: interstimuli interval; K-ABC: Kaufman Assessment Battery for Children; K-CPT: Kiddie Continuous Performance Test; KUDOS: Kansas University DHA Outcomes Study; MSCA: McCarthy Scales of Children’s Abilities; MTHF: methyl tetrahydrofolate; NBAS: Neonatal Behavioral Assessment Scale; NR: not reported; NUHEAL: Nutraceuticals for a Healthier Life; POSGRAD: Prenatal Omega 3 Supplementation on child Growth and Development; RAVLT: Rey Auditory Verbal Learning Test; RCT: randomized controlled trial; SD: standard deviation; SE: standard error; RT: reaction time; TEACh: Test of Everyday Attention for Children; WASI: Wechsler Abbreviated Scale of Intelligence; WISC: Wechsler Intelligence Scale for Children; WMIC: working memory and inhibitory control; WPPSI: Wechsler Primary and Preschool Scale of Intelligence

vii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii Adj: adjusted; ASQ: Ages and Stages Questionnaire; BSID: Bayley Scales of Infant Development; CDI: Communicative Development Inventory; CELF(-P2): Clinical Evaluation of Language Fundamentals (Preschool, second edition); CI: confidence interval; CLAMS: Clinical Linguistic and Auditory Milestone Scale; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; ETA: eicosatetranoic acid; INFAT: The Impact of the Nutritional Fatty Acids During Pregnancy and Lactation for Early Human Adipose Tissue Development; KUDOS: Kansas University DHA Outcomes Study; MSCA: McCarthy Scales of Children’s Abilities; NR: not reported; PPVT: Peabody Picture Vocabulary Test; RCT: randomized controlled trial; TOPEL: Test of Preschool Early Literacy; WPPSI-R: Wechsler Primary and Preschool Scale of Intelligence-Revised

ix A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x Adj: adjusted; ARA: arachidonic acid; ASQ: Ages and Stages Questionnaire; BSID: Bayley Scales of Infant Development; CI: confidence interval; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; ETA: eicosatetranoic acid; FO: fish oil; K-ABC: Kaufman Assessment Battery for Children; MSCA: McCarthy Scales of Children’s Abilities; MND: minor neurological dysfunction; MTHF: methyl tetrahydrofolate; NOS: neurological optimality score; NR: not reported; NUHEAL: Nutraceuticals for a Healthier Life; POSGRAD: Prenatal Omega 3 Supplementation on child Growth and Development; RCT: randomized controlled trial

xi A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xii Adj: adjusted; CI: confidence interval; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; NR: not reported; OR: odds ratio; POSGRAD: Prenatal Omega 3 Supplementation on child Growth and Development; RCT: randomized controlled trial; SE: standard error; VEP: visual evoked potentials

xiii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xiv Adj: adjusted; ASQ: Ages and Stages Questionnaire; BASC: Behavioral Assessment System for Children; BSID: Bayley Scales of Infant Development; CBCL: Child Behavior Checklist; CI: confidence interval; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; ETA: eicosatetranoic acid; FFSF: Face-to-Face Still-Face task; INFAT: The Impact of the Nutritional Fatty Acids During Pregnancy and Lactation for Early Human Adipose Tissue Development; NBAS: Neonatal Behavioral Assessment Scale; NR: not reported; POSGRAD: Prenatal Omega 3 Supplementation on child Growth and Development; RCT: randomized controlled trial; SDQ: Strengths and Difficulties Questionnaire

xv A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xvi ADD: attention deficit disorder; ADHD: attention-deficit/hyperactivity disorder; Adj: adjusted; ASD: autism spectrum disorder; CI: confidence interval; DHA: docosahexaenoic acid; DOMInO: DHA to Optimize Mother Infant Outcome; EPA: eicosapentaenoic acid; MARBLES: Markers of Autism Risk in Babies-Learning Early Signs; NR: not reported; PCS: prospective cohort study; RCT: randomized controlled trial; WRAT-4: Wide Range Achievement Test Fourth Edition

xvii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xviii Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

xix Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )