# List of abbreviations

Abbreviation: Full name
ALSPAC: Avon Longitudinal Study of Parents and Children
DP: Dietary pattern
DII: Dietary Inflammation Index
FFQ: Food frequency questionnaire
HEI: Healthy Eating Index
HDI: Human Development Index
HHS: Department of Health and Human Services
IgE: Immunoglobulin E
NESR: Nutrition Evidence Systematic Review
NRCT: Non-randomized controlled trial
RCT: Randomized controlled trial
SES: Socioeconomic status
USDA: United States Department of Agriculture