# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xxii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 2. Food, Beverage, and Nutrient Consumption During Pregnancy and Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1: Analytic frameworkFigure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on maternal diet during pregnancy and lactation and risk of child food allergies and atopic allergic diseases. For this systematic review, the target population considered for the intervention/exposure was women during pregnancy and/or during lactation; healthy and/or at risk for chronic disease. The target population considered for the outcome was infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years) for food allergies, allergic rhinitis, atopic dermatitis and children and adolescents (ages 2-18 years) for asthma. The interventions or exposures considered were dietary intake of a food(s) or food group(s) and their comparators were no food or different amount of dietary intake of the same food(s) or food group(s). The outcomes considered were food allergies, allergic rhinitis, atopic dermatitis, and asthma (2 years and older). The key confounders were maternal age, race/ethnicity, socioeconomic status, smoking, family history of atopic allergic diseases, gestational age at birth, birth weight, mode of delivery, human milk feeding practices (intensity, duration), timing of introduction of complementary foods and beverages (CFB), types of CFB, urban/rural environment, and animals/pets/farming exposure. Other factors to be considered were child sex, maternal substance use (alcohol, drug use), and indoor/outdoor environment.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 9 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Dietary intake of a food(s) or food group(s)
Comparator | - Different amount of dietary intake of the same food(s) or food group(s) | - No comparator
Outcomes | - Food allergies; - Atopic dermatitis; - Allergic rhinitis; - Asthma (≥2 years old) | - Food allergy when diagnosis was based solely on food allergen sensitization (i.e., skin prick test, or serum IgE measure) (i.e., without an oral food challenge or parental report of clinical history); - Asthma when diagnosis was based solely on report of wheeze
Date of publication | - January 1980 to January 2020 | - Articles published before January 1980 or after January 2020
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xxiii^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants | - Non-human participants (e.g., animal or in-vitro models)
Life stage of study participants - intervention or exposure | - Women during pregnancy OR women during both pregnancy and lactation, regardless of human milk feeding status; - Women during lactation who are exclusively or predominantly feeding human milk | - Studies conducted exclusively in non-lactating women or in lactating women who are not exclusively or predominantly feeding human milk.
Life stage of study participants - outcomes: | Food allergies, atopic dermatitis, and allergic rhinitis:; - Infants and toddlers (birth – 24 months); All outcomes:; - Children and adolescents (2 – 18 years) | Asthma:; - Infants and toddlers (birth – 24 months); All outcomes:; - Adults (19 – 64 years); - Older adults (65 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some children diagnosed with a disease or with the health outcome of interest:; ○ Food allergies; ○ Atopic dermatitis; ○ Allergic rhinitis; ○ Asthma | - Studies that exclusively enroll mothers who gave birth to preterm (<37 weeks and 0/7 days) infants; - Studies that exclusively enroll mothers diagnosed with a chronic disease, including severe undernutrition or hospitalized with an illness or injury

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date searched: January 21, 2020
- Date range searched: January 1, 1980 – January 21, 2020
- Search terms:
  - #1 - Diet [Mesh] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR food*[tiab] OR foods[tiab] OR “Food”[Mesh] OR “Eating”[Mesh] OR (maternal tiab] AND intake[tiab])
  - #2 - ((“Allergy and Immunology”[Mesh:NoExp] OR allerg*[tiab] OR Hypersensitiv*[tiab] OR atopic[tiab]) AND (food*[tiab] OR peanut*[tiab] OR nut[tiab] OR nuts[tiab] OR egg*[tiab] OR eggs[tiab] OR milk[tiab] OR shellfish[tiab] OR fish[tiab] OR fishes[Mesh] OR seafood[Mesh] OR wheat[tiab] OR gluten*[tiab] OR glutens[Mesh] OR dairy[tiab] OR dairy products[Mesh] OR eggs[Mesh] OR nuts[Mesh] OR soy foods[mh] OR soy*[tiab])) OR “Food Hypersensitivity”[Mesh] OR asthma*[tiab] OR asthma[Mesh] OR “Rhinitis, Allergic”[Mesh] OR (allerg*[tiab] AND rhiniti*[tiab]) OR “Dermatitis, Atopic”[Mesh] OR atopic dermatitis*[tiab] OR eczema*[tiab] OR eczema[Mesh] OR “Immunoglobulin E”[Mesh] OR “Immunoglobulin E”[tiab] OR IgE[tiab]
  - #3- (“Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother*[tiab] OR “Mothers”[Mesh] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestat*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpart*[tiab] OR post-part*[tiab] OR pre-parturition[tiab] OR postnatal[tiab] OR post-natal[tiab] OR post delivery[tiab] OR postdelivery[tiab] OR after birth[tiab] OR afterbirth[tiab] OR Lactation[Mesh] OR lactati*[tiab] OR breast feeding[Mesh] OR breastfe*[tiab] OR breast fe*[tiab] OR Milk, Human [Mesh] OR breastmilk[tiab] OR “breast milk”[tiab] OR “human milk”[tiab] OR “maternal milk”[tiab] OR “nursing women”[tiab]))
  - #4- #1 AND #2 AND #3
  - #5- #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])

Filters: Publication date from 1980/01/01 to 2020/01/21; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date searched: January 21, 2020
- Date range searched: January 1, 1980 – January 21, 2020
- Search terms:
  - #1- [mh “Diet”] OR diet OR diets OR dietary OR food* OR foods OR [mh “Food”] OR [mh “Eating”] OR (maternal NEAR/4 intake)
  - #2- [mh ^“Allergy and Immunology”] OR ((allerg* OR Hypersensitivit*) NEAR/4 (food* OR peanut* OR nut OR nuts OR egg* OR milk OR shellfish OR seafood* OR wheat OR gluten* OR dairy OR fish OR soy*)) OR [mh “Food Hypersensitivity”] OR asthma* OR [mh “Rhinitis, Allergic”] OR (allerg* NEAR/4 Rhiniti*) OR [mh “Dermatitis, Atopic”] OR ((Dermatiti* OR eczema) NEAR/4 Atopic) OR (Infant* NEAR/4 Eczema) OR [mh “Immunoglobulin E”] OR “Immunoglobulin E”
  - #3- [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR (pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother* OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestat* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”):ti,ab,kw
  - #4- #1 AND #2 AND #3

Filters: Publication Year from 1980 to 2020, in Trials

#### Embase

- Provider: Elsevier
- Date searched: January 21, 2020
- Date range searched: January 1, 1980 – January 21, 2020
- Search terms:
  - #1- ‘diet’/exp OR ‘food’/exp OR ‘eating’/exp OR diet:ti,ab OR diets:ti,ab OR dietary:ti,ab OR food:ti,ab OR foods:ti,ab OR (maternal NEAR/4 intake*) OR eating:ti,ab OR eat:ti,ab
  - #2- ‘allergic asthma’/exp OR ‘food allergy’/exp OR ‘allergic rhinitis’/exp OR ‘dermatitis’/exp OR ‘eczema’/exp OR ‘skin allergy’/exp OR ((allerg* OR hypersensitivity*) NEAR/4 (food OR peanut* OR nut OR nuts OR egg OR eggs OR milk OR shellfish OR seafood* OR wheat OR gluten* OR fish OR dairy OR soy*)) OR ‘immunoglobulin e’/exp OR ‘immunoglobulin e’:ti,ab
  - #3 - pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR lactation:ab,ti OR lactating:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti OR ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/exp/mj OR ‘maternal nutrition’/mj OR ‘lactation’/mj OR ‘breast feeding’/exp/mj OR ‘breast milk’/exp/mj
  - #4- #1 AND #2 AND #3
  - #5- #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date searched: January 21, 2020
- Date range searched: January 1, 1980 – January 21, 2020
- Search terms:
  - #1 - (mh “Diet”) OR diet OR diets OR dietary OR food OR foods[tiab] OR (mh “Food”) OR (mh “Eating”) OR (maternal N4 intake*)
  - #2- (mh “Allergy and Immunology”) OR ((allerg* OR Hypersensitivit*) N4 (food* OR peanut* OR nut OR nuts OR egg* OR milk OR shellfish OR seafood OR wheat OR gluten* OR dairy OR fish OR soy*)) OR (mh “Food Hypersensitivity+”) OR asthma* OR (mh “Rhinitis, Allergic”) OR (allerg* N4 Rhiniti*) OR (mh “Dermatitis, Atopic”) OR ((Dermatiti* OR eczema) N4 Atopic)) OR (Infant* N5 Eczema) OR (mh “Immunoglobulin E”) OR “Immunoglobulin E”
  - #3- postpartum OR post-partum OR MH “Postpartum Period” OR postpartal OR post-partal OR postnatal OR post-natal OR “post deliver*” OR “after birth” OR MH pregnancy OR MH “pregnancy complications” OR MH “Prenatal Exposure Delayed Effects” OR MH “Maternal Exposure” OR MH “pregnant women” OR pregnan* OR pre-pregnancy OR prepregnancy OR prenatal OR antenatal OR maternal OR mother OR mothers OR perinatal OR peri-natal OR peri-conception OR periconception OR MH “Peripartum Period” OR peripartum OR peri-partum OR gestation* OR natal OR puerperium OR MH “Maternal Nutritional Physiological Phenomena” OR MH “Breast Feeding”OR breastfeeding OR breast-feeding OR MH “Milk, Human” OR “human milk” OR MH Lactation OR lactation OR lactating OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed* OR “nursing women” OR “nursing mother*”
  - #4- #1 AND #2 AND #3
  - #5- #4 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication)

Filters: Published Date: 19800101 – 20200121, English Language, Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 10 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between maternal diet during pregnancy and lactation and infant and child food allergies and atopic allergic diseases. The literature search yielded 4,529 articles. During title screening, 2,431 articles were screened out. During abstract screening, 425 articles were screened out. During full-text screening, 72 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 38 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes columns for the categories of inclusion and exclusion criteria (see Table 9) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 10 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1. | Abrams, EM, Sicherer, SH. Maternal peanut consumption and risk of peanut allergy in childhood. Cmaj. 2018. 190:E814–e815. doi:10.1503/cmaj.180563.29986856 29986856 | Study design
2. | Alvarez Zallo, N, Aguinaga-Ontoso, I, Alvarez-Alvarez, I, Marin-Fernandez, B, Guillen-Grima, F, Azcona-San Julian, C. Influence of the Mediterranean diet during pregnancy in the development of wheezing and eczema in infants in Pamplona, Spain. Allergol Immunopathol (Madr). 2018. 46:9–14. doi:10.1016/j.aller.2017.02.009.28629669 | Study design; Outcome
3. | Arshad, SH, Bateman, B, Sadeghnejad, A, Gant, C, Matthews, SM. Prevention of allergic disease during childhood by allergen avoidance: the Isle of Wight prevention study. J Allergy Clin Immunol. 2007. 119:307–13. doi:10.1016/j.jaci.2006.12.621.17291851 | Population; Not 100% human milk feeding
4. | Baiz, N, Just, J, Chastang, J, Forhan, A, de Lauzon-Guillain, B, Magnier, AM, Annesi-Maesano, I. Maternal diet before and during pregnancy and risk of asthma and allergic rhinitis in children. Allergy Asthma Clin Immunol. 2019. 15:40. doi:10.1186/s13223-019-0353-2.31285746 | Exposure assessed after delivery
5. | Bedard, A, Northstone, K, Henderson, AJ, Shaheen, SO. Maternal intake of sugar during pregnancy and childhood respiratory and atopic outcomes. Eur Respir J. 2017. 50. doi:10.1183/13993003.00073-2017. | Intervention/Exposure
6. | Berdi, M, de Lauzon-Guillain, B, Forhan, A, Castelli, FA, Fenaille, F, Charles, MA, Heude, B, Junot, C, Adel-Patient, K. Immune components of early breastmilk: Association with maternal factors and with reported food allergy in childhood. Pediatr Allergy Immunol. 2019. 30:107–116. doi:10.1111/pai.12998.30368940 | Outcome
7. | Binkley, KE, Leaver, C, Ray, JG. Antenatal risk factors for peanut allergy in children. Allergy Asthma Clin Immunol. 2011. 7:17. doi:10.1186/1710-1492-7-17.21970733 | Study design
8. | Bisgaard, H, Stokholm, J, Chawes, BL, Vissing, NH, Bjarnadottir, E, Schoos, AM, Wolsk, HM, Pedersen, TM, Vinding, RK, Thorsteinsdottir, S, Folsgaard, NV, Fink, NR, Thorsen, J, Pedersen, AG, Waage, J, Rasmussen, MA, Stark, KD, Olsen, SF, Bonnelykke, K. Fish Oil-Derived Fatty Acids in Pregnancy and Wheeze and Asthma in Offspring. N Engl J Med. 2016. 375:2530–9. doi:10.1056/NEJMoa1503734.28029926 | Intervention/Exposure
9. | Calvani, M, Alessandri, C, Sopo, SM, Panetta, V, Pingitore, G, Tripodi, S, Zappala, D, Zicari, AM. Consumption of fish, butter and margarine during pregnancy and development of allergic sensitizations in the offspring: role of maternal atopy. Pediatr Allergy Immunol. 2006. 17:94–102. doi:10.1111/j.1399-3038.2005.00367.x.16618358 | Study design
10. | Castro-Rodriguez, JA, Garcia-Marcos, L, Sanchez-Solis, M, Perez-Fernandez, V, Martinez-Torres, A, Mallol, J. Olive oil during pregnancy is associated with reduced wheezing during the first year of life of the offspring. Pediatr Pulmonol. 2010. 45:395–402. doi:10.1002/ppul.21205.20306538 | Study design; Population
11. | Castro-Rodriguez, JA, Ramirez-Hernandez, M, Padilla, O, Pacheco-Gonzalez, RM, Perez-Fernandez, V, Garcia-Marcos, L. Effect of foods and Mediterranean diet during pregnancy and first years of life on wheezing, rhinitis and dermatitis in preschoolers. Allergol Immunopathol (Madr). 2016. 44:400–9. doi:10.1016/j.aller.2015.12.002.27087566 | Study design; Intervention/Exposure
12. | Celik, V, Beken, B, Yazicioglu, M, Ozdemir, PG, Sut, N. Do traditional fermented foods protect against infantile atopic dermatitis. Pediatr Allergy Immunol. 2019. 30:540–546. doi:10.1111/pai.13045.30801810 | Study design
13. | Chandra, RK, Puri, S, Suraiya, C, Cheema, PS. Influence of maternal food antigen avoidance during pregnancy and lactation on incidence of atopic eczema in infants. Clin Allergy. 1986. 16:563–9. doi:10.1111/j.1365-2222.1986.tb01995.x.3791630 | Retracted
14. | Chapman, DJ. Does maternal diet contribute to colic among breastfed infants?. J Hum Lact. 2006. 22:236–7. doi:10.1177/0890334406287108.16684916 | Study design; Outcome
15. | Chatzi, L, Torrent, M, Romieu, I, Garcia-Esteban, R, Ferrer, C, Vioque, J, Kogevinas, M, Sunyer, J. Mediterranean diet in pregnancy is protective for wheeze and atopy in childhood. Thorax. 2008. 63:507–13. doi:10.1136/thx.2007.081745.18198206 | Outcome
16. | Dean, T, Venter, C, Pereira, B, Grundy, J, Clayton, CB, Higgins, B. Government advice on peanut avoidance during pregnancy--is it followed correctly and what is the impact on sensitization?. J Hum Nutr Diet. 2007. 20:95–9. doi:10.1111/j.1365-277X.2007.00751.x.17374021 | Intervention/Exposure; Outcome
17. | Dotterud, CK, Storro, O, Simpson, MR, Johnsen, R, Oien, T. The impact of pre- and postnatal exposures on allergy related diseases in childhood: a controlled multicentre intervention study in primary health care. BMC Public Health. 2013. 13:123. doi:10.1186/1471-2458-13-123.23394141 | Study design; Comparator; Cross-sectional data for control cohort
18. | Dubakiene, R, Rudzeviciene, O, Butiene, I, Sezaite, I, Petronyte, M, Vaicekauskaite, D, Zvirbliene, A. Studies on early allergic sensitization in the Lithuanian birth cohort. ScientificWorldJournal. 2012. 2012:909524. doi:10.1100/2012/909524.22606067 | Exposure-outcome analysis not clear, data not reported
19. | Erkkola, M, Nwaru, BI, Kaila, M, Kronberg-Kippila, C, Ilonen, J, Simell, O, Veijola, R, Knip, M, Virtanen, SM. Risk of asthma and allergic outcomes in the offspring in relation to maternal food consumption during pregnancy: a Finnish birth cohort study. Pediatr Allergy Immunol. 2012. 23:186–94. doi:10.1111/j.1399-3038.2012.01272.x.22432883 | Study design; Diet assessed after birth
20. | Erratum: effect of combined maternal and infant food-allergen avoidance on development of atopy in early infancy: a randomized study (Zeiger et al (1989) 84 (72)). Journal of allergy and clinical immunology. 1989. 84:677-. | Erratum
21. | Falth-Magnusson, K, Kjellman, NI. Allergy prevention by maternal elimination diet during late pregnancy--a 5-year follow-up of a randomized study. J Allergy Clin Immunol. 1992. 89:709–13. doi:10.1016/0091-6749(92)90378-f.1545092 | Outcome
22. | Falth-Magnusson, K. Breast milk antibodies to foods in relation to maternal diet, maternal atopy and the development of atopic disease in the baby. Int Arch Allergy Appl Immunol. 1989. 90:297–300. doi:10.1159/000235041.2592118 | Outcome
23. | Fitzsimon, N, Fallon, U, O’Mahony, D, Loftus, BG, Bury, G, Murphy, AW, Kelleher, CC. Mothers’ dietary patterns during pregnancy and risk of asthma symptoms in children at 3 years. Ir Med J. 2007. 100:suppl 27-32. | Study design; Population
24. | Frazier, AL, Camargo, CA, Jr, Malspeis, S, Willett, WC, Young, MC. Prospective study of peripregnancy consumption of peanuts or tree nuts by mothers and the risk of peanut or tree nut allergy in their offspring. JAMA Pediatr. 2014. 168:156–62. doi:10.1001/jamapediatrics.2013.4139.24366539 | Population
25. | Fukuda, Y, Yamamoto, S, Kameda, M. Association Between Lifestyle Characteristics and Body Mass Index of Mothers of Children With Allergic Diseases. J Clin Med Res. 2019. 11:780–788. doi:10.14740/jocmr3976.31803322 | Study design; Health Status
26. | Gao, X, Yan, Y, Zeng, G, Sha, T, Liu, S, He, Q, Chen, C, Li, L, Xiang, S, Li, H, Tan, S, Yan, Q. Influence of prenatal and early-life exposures on food allergy and eczema in infancy: a birth cohort study. BMC Pediatr. 2019. 19:239. doi:10.1186/s12887-019-1623-3.31315604 | Study design; Diet assessed after birth
27. | Hansen, S, Strom, M, Maslova, E, Dahl, R, Hoffmann, HJ, Rytter, D, Bech, BH, Henriksen, TB, Granstrom, C, Halldorsson, TI, Chavarro, JE, Linneberg, A, Olsen, SF. Fish oil supplementation during pregnancy and allergic respiratory disease in the adult offspring. J Allergy Clin Immunol. 2017. 139:104–111.e4. doi:10.1016/j.jaci.2016.02.042.27246522 | Intervention/Exposure;
28. | Harris, JM, Cullinan, P, Williams, HC, Mills, P, Moffat, S, White, C, Newman Taylor, AJ. Environmental associations with eczema in early life. Br J Dermatol. 2001. 144:795–802. doi:10.1046/j.1365-2133.2001.04135.x.11298539 | Intervention/Exposure; Population
29. | Hattevig, G, Kjellman, B, Sigurs, N, Bjorksten, B, Kjellman, NI. Effect of maternal avoidance of eggs, cow’s milk and fish during lactation upon allergic manifestations in infants. Clin Exp Allergy. 1989. 19:27–32. doi:10.1111/j.1365-2222.1989.tb02339.x.2702510 | Population; Human milk feeding practices unclear
30. | Hattevig, G, Kjellman, B, Sigurs, N, Grodzinsky, E, Hed, J, Bjorksten, B. The effect of maternal avoidance of eggs, cow’s milk, and fish during lactation on the development of IgE, IgG, and IgA antibodies in infants. J Allergy Clin Immunol. 1990. 85:108–15. doi:10.1016/0091-6749(90)90231-r.2299096 | Outcome
31. | Hattevig, G, Sigurs, N, Kjellman, B. Effects of maternal dietary avoidance during lactation on allergy in children at 10 years of age. Acta Paediatr. 1999. 88:7–12.10090539 | Population; Human milk feeding practices unclear
32. | Hoppu, U, Kalliomaki, M, Isolauri, E. Maternal diet rich in saturated fat during breastfeeding is associated with atopic sensitization of the infant. Eur J Clin Nutr. 2000. 54:702–5. doi:10.1038/sj.ejcn.1601079.11002382 | Intervention/Exposure;
33. | Jonsson, K, Barman, M, Moberg, S, Sjoberg, A, Brekke, HK, Hesselmar, B, Johansen, S, Wold, AE, Sandberg, AS. Fat intake and breast milk fatty acid composition in farming and nonfarming women and allergy development in the offspring. Pediatr Res. 2016. 79:114–23. doi:10.1038/pr.2015.187.26389822 | Outcome; Composite outcome
34. | Jonsson, K, Barman, M, Moberg, S, Sjoberg, A, Brekke, HK, Hesselmar, B, Sandberg, AS, Wold, AE. Serum fatty acids in infants, reflecting family fish consumption, were inversely associated with allergy development but not related to farm residence. Acta Paediatr. 2016. 105:1462–1471. doi:10.1111/apa.13592.27637371 | Intervention/Exposure; Outcome; Exp-outcome not tested
35. | Kelleher, CC, Viljoen, K, Khalil, H, Somerville, R, O’Brien, J, Shrivastava, A, Murrin, C. Longitudinal follow-up of the relationship between dietary intake and growth and development in the Lifeways cross-generation cohort study 2001-2013. Proc Nutr Soc. 2014. 73:118–31. doi:10.1017/s002966511300373x.24300176 | Study design
36. | Kemp, AS, Ponsonby, AL, Dwyer, T, Cochrane, JA, Pezic, A, Jones, G. Maternal antenatal peanut consumption and peanut and rye sensitization in the offspring at adolescence. Clin Exp Allergy. 2011. 41:224–31. doi:10.1111/j.1365-2222.2010.03668.x.21129049 | Study design; Outcome
37. | Kim, YH, Kim, KW, Lee, SY, Koo, KO, Kwon, SO, Seo, JH, Suh, DI, Shin, YH, Ahn, K, Oh, SY, Lee, S, Sohn, MH, Hong, SJ. Maternal Perinatal Dietary Patterns Affect Food Allergy Development in Susceptible Infants. J Allergy Clin Immunol Pract. 2019. 7:2337–2347.e7. doi:10.1016/j.jaip.2019.03.026.30930272 | Outcome; Did not require skin prick test; No obvious food challenge
38. | Kusmierek, M, Sardecka, I, Los-Rycharska, E, Krogulska, A. The impact of immunomodulatory factors from maternal diet during pregnancy on cow’s milk allergy in offspring - A pilot study in the paediatric population of the Kuyavian-Pomeranian Voivodship. Allergol Immunopathol (Madr). 2019. 47:570–578. doi:10.1016/j.aller.2019.04.007.31477402 | Study design; Health Status
39. | Levin, ME, Botha, M, Basera, W, Facey-Thomas, HE, Gaunt, B, Gray, CL, Kiragu, W, Ramjith, J, Watkins, A, Genuneit, J. Environmental factors associated with allergy in urban and rural children from the South African Food Allergy (SAFFA) cohort. J Allergy Clin Immunol. 2020. 145:415–426. doi:10.1016/j.jaci.2019.07.048.31606483 | Study design; Population
40. | Lilja, G, Dannaeus, A, Foucard, T, Graff-Lonnevig, V, Johansson, SG, Oman, H. Effects of maternal diet during late pregnancy and lactation on the development of IgE and egg- and milk-specific IgE and IgG antibodies in infants. Clin Exp Allergy. 1991. 21:195–202. doi:10.1111/j.1365-2222.1991.tb00830.x. | Outcome
41. | Linnamaa, P, Nieminen, K, Koulu, L, Tuomasjukka, S, Kallio, H, Yang, B, Tahvonen, R, Savolainen, J. Black currant seed oil supplementation of mothers enhances IFN-gamma and suppresses IL-4 production in breast milk. Pediatr Allergy Immunol. 2013. 24:562–6. doi:10.1111/pai.12110.23980846 | Intervention/Exposure; Outcome
42. | Linnamaa, P, Savolainen, J, Koulu, L, Tuomasjukka, S, Kallio, H, Yang, B, Vahlberg, T, Tahvonen, R. Blackcurrant seed oil for prevention of atopic dermatitis in newborns: a randomized, double-blind, placebo-controlled trial. Clin Exp Allergy. 2010. 40:1247–55. doi:10.1111/j.1365-2222.2010.03540.x.20545710 | Intervention/Exposure
43. | Losol, P, Rezwan, FI, Patil, VK, Venter, C, Ewart, S, Zhang, H, Arshad, SH, Karmaus, W, Holloway, JW. Effect of gestational oily fish intake on the risk of allergy in children may be influenced by FADS1/2, ELOVL5 expression and DNA methylation. Genes Nutr. 2019. 14:20. doi:10.1186/s12263-019-0644-8.31244960 | Intervention/Exposure; Outcome; No exp-outcome test
44. | Ludvigsson, J. Cow-milk-free diet during last trimester of pregnancy does not influence diabetes-related autoantibodies in nondiabetic children. Ann N Y Acad Sci. 2003. 1005:275–8. doi:10.1196/annals.1288.042.14679075 | Outcome
45. | Lumia, M, Luukkainen, P, Tapanainen, H, Kaila, M, Erkkola, M, Uusitalo, L, Niinisto, S, Kenward, MG, Ilonen, J, Simell, O, Knip, M, Veijola, R, Virtanen, SM. Dietary fatty acid composition during pregnancy and the risk of asthma in the offspring. Pediatr Allergy Immunol. 2011. 22:827–35. doi:10.1111/j.1399-3038.2011.01202.x.21929596 | Study design; Diet assessed after birth
46. | Martin-Munoz, MF, Pineda, F, Garcia Parrado, G, Guillen, D, Rivero, D, Belver, T, Quirce, S. Food allergy in breastfeeding babies. Hidden allergens in human milk. Eur Ann Allergy Clin Immunol. 2016. 48:123–8.27425167 | Study design
47. | Miyake, Y, Tanaka, K, Yasutake, A, Sasaki, S, Hirota, Y. Lack of association of mercury with risk of wheeze and eczema in Japanese children: the Osaka Maternal and Child Health Study. Environ Res. 2011. 111:1180–4. doi:10.1016/j.envres.2011.07.003.21807364 | Intervention/Exposure;
48. | Nascimento, JXPT, Ribeiro, CCC, Batista, RFL, de Britto Alves, MTSS, Simoes, VMF, Padilha, LL, Cardoso, VC, Vianna, EO, Bettiol, H, Barbieri, MA, Silva, AAMD. The First 1000 Days of Life Factors Associated with “Childhood Asthma Symptoms”: Brisa Cohort, Brazil. Sci Rep. 2017. 7:16028. doi:10.1038/s41598-017-16295-4.29167579 | Outcome; <2y old
49. | Neild, V. Diet and atopic eczema. Mod Midwife. 1994. 4:22.7788368 | Study design; Not a study
50. | Ngamphaiboon, J, Chatchatee, P, Thongkaew, T. Cow’s milk allergy in Thai children. Asian Pac J Allergy Immunol. 2008. 26:199–204.19317338 | Country; Health Status
51. | Nwaru, BI, Ahonen, S, Kaila, M, Erkkola, M, Haapala, AM, Kronberg-Kippila, C, Veijola, R, Ilonen, J, Simell, O, Knip, M, Virtanen, SM. Maternal diet during pregnancy and allergic sensitization in the offspring by 5 yrs of age: a prospective cohort study. Pediatr Allergy Immunol. 2010. 21:29–37. doi:10.1111/j.1399-3038.2009.00949.x.20003068 | Outcome
52. | Nwaru, BI, Erkkola, M, Ahonen, S, Kaila, M, Lumia, M, Prasad, M, Haapala, AM, Kronberg-Kippila, C, Veijola, R, Ilonen, J, Simell, O, Knip, M, Virtanen, SM. Maternal diet during lactation and allergic sensitization in the offspring at age of 5. Pediatr Allergy Immunol. 2011. 22:334–41. doi:10.1111/j.1399-3038.2010.01114.x.21223376 | Outcome
53. | Nwaru, BI, Erkkola, M, Lumia, M, Kronberg-Kippila, C, Ahonen, S, Kaila, M, Ilonen, J, Simell, O, Knip, M, Veijola, R, Virtanen, SM. Maternal intake of fatty acids during pregnancy and allergies in the offspring. Br J Nutr. 2012. 108:720–32. doi:10.1017/s0007114511005940.22067943 | Study design; Diet assessed after birth
54. | Oien, T, Storro, O, Johnsen, R. Do early intake of fish and fish oil protect against eczema and doctor-diagnosed asthma at 2 years of age? A cohort study. J Epidemiol Community Health. 2010. 64:124–9. doi:10.1136/jech.2008.084921.19666630 | Study design; Population
55. | Olsen, SF, Osterdal, ML, Salvig, JD, Mortensen, LM, Rytter, D, Secher, NJ, Henriksen, TB. Fish oil intake compared with olive oil intake in late pregnancy and asthma in the offspring: 16 y of registry-based follow-up from a randomized controlled trial. Am J Clin Nutr. 2008. 88:167–75. doi:10.1093/ajcn/88.1.167.18614738 | Intervention/Exposure;
56. | Ozawa, N, Shimojo, N, Suzuki, Y, Ochiai, S, Nakano, T, Morita, Y, Inoue, Y, Arima, T, Suzuki, S, Kohno, Y. Maternal intake of Natto, a Japan’s traditional fermented soybean food, during pregnancy and the risk of eczema in Japanese babies. Allergol Int. 2014. 63:261–6. doi:10.2332/allergolint.13-OA-0613.24759553 | Diet assessed after birth
57. | Pele, F, Bajeux, E, Gendron, H, Monfort, C, Rouget, F, Multigner, L, Viel, JF, Cordier, S. Maternal fish and shellfish consumption and wheeze, eczema and food allergy at age two: a prospective cohort study in Brittany, France. Environ Health. 2013. 12:102. doi:10.1186/1476-069x-12-102.24295221 | Population; Diet assessed before pregnancy
58. | Romieu, I, Torrent, M, Garcia-Esteban, R, Ferrer, C, Ribas-Fito, N, Anto, JM, Sunyer, J. Maternal fish intake during pregnancy and atopy and asthma in infancy. Clin Exp Allergy. 2007. 37:518–25. doi:10.1111/j.1365-2222.2007.02685.x.17430348 | Study design; Population
59. | Salam, MT, Li, YF, Langholz, B, Gilliland, FD. Maternal fish consumption during pregnancy and risk of early childhood asthma. J Asthma. 2005. 42:513–8. doi:10.1081/jas-67619.16293548 | Study design; Diet during pregnancy assessed after diagnosis
60. | Sausenthaler, S, Koletzko, S, Schaaf, B, Lehmann, I, Borte, M, Herbarth, O, von Berg, A, Wichmann, HE, Heinrich, J. Maternal diet during pregnancy in relation to eczema and allergic sensitization in the offspring at 2 y of age. Am J Clin Nutr. 2007. 85:530–7. doi:10.1093/ajcn/85.2.530.17284754 | Study design; Diet assessed after birth
61. | Sewell, DA, Hammersley, VS, Robertson, A, Devereux, G, Stoddart, A, Weir, CJ, Worth, A, Sheikh, A. A pilot randomised controlled trial investigating a Mediterranean diet intervention in pregnant women for the primary prevention of allergic diseases in infants. J Hum Nutr Diet. 2017. 30:604–614. doi:10.1111/jhn.12469.28211106 | Outcome
62. | Sicherer, SH, Wood, RA, Stablein, D, Lindblad, R, Burks, AW, Liu, AH, Jones, SM, Fleischer, DM, Leung, DYM, Sampson, HA. Maternal consumption of peanut during pregnancy is associated with peanut sensitization in atopic infants. Journal of Allergy and Clinical Immunology. 2010. 126:1191–1197. doi:10.1016/j.jaci.2010.08.036. | Study design; Health Status; Diet during pregnancy assessed retrospectively
63. | Sigurs, N, Hattevig, G, Kjellman, B. Maternal avoidance of eggs, cow’s milk, and fish during lactation: effect on allergic manifestations, skin-prick tests, and specific IgE antibodies in children at age 4 years. Pediatrics. 1992. 89:735–9.1557270 | Population; Human milk feeding practices unclear
64. | Stenius, F, Swartz, J, Lilja, G, Borres, M, Bottai, M, Pershagen, G, Scheynius, A, Alm, J. Lifestyle factors and sensitization in children - the ALADDIN birth cohort. Allergy. 2011. 66:1330–8. doi:10.1111/j.1398-9995.2011.02662.x.21651566 | Intervention/Exposure; No results reported on association btw diet and sensitization
65. | Storro, O, Oien, T, Dotterud, CK, Jenssen, JA, Johnsen, R. A primary health-care intervention on pre- and postnatal risk factor behavior to prevent childhood allergy. The Prevention of Allergy among Children in Trondheim (PACT) study. BMC Public Health. 2010. 10:443. doi:10.1186/1471-2458-10-443.20667103 | Outcome
66. | Stratakis, N, Roumeliotaki, T, Oken, E, Ballester, F, Barros, H, Basterrechea, M, Cordier, S, de Groot, R, den Dekker, HT, Duijts, L, Eggesbo, M, Fantini, MP, Forastiere, F, Gehring, U, Gielen, M, Gori, D, Govarts, E, Inskip, HM, Iszatt, N, Jansen, M, Kelleher, C, Mehegan, J, Molto-Puigmarti, C, Mommers, M, Oliveira, A, Olsen, SF, Pele, F, Pizzi, C, Porta, D, Richiardi, L, Rifas-Shiman, SL, Robinson, SM, Schoeters, G, Strom, M, Sunyer, J, Thijs, C, Vrijheid, M, Vrijkotte, TGM, Wijga, AH, Kogevinas, M, Zeegers, MP, Chatzi, L. Fish and seafood consumption during pregnancy and the risk of asthma and allergic rhinitis in childhood: a pooled analysis of 18 European and US birth cohorts. Int J Epidemiol. 2017. 46:1465–1477. doi:10.1093/ije/dyx007.28338907 | Study design; Meta-analysis
67. | Tuokkola, J, Luukkainen, P, Tapanainen, H, Kaila, M, Vaarala, O, Kenward, MG, Virta, LJ, Veijola, R, Simell, O, Ilonen, J, Knip, M, Virtanen, SM. Maternal diet during pregnancy and lactation and cow’s milk allergy in offspring. Eur J Clin Nutr. 2016. 70:554–9. doi:10.1038/ejcn.2015.223.26757832 | Study design; Population; Outcome
68. | Ushiyama, Y, Matsumoto, K, Shinohara, M, Wakiguchi, H, Sakai, K, Komatsu, T, Yamamoto, S. Nutrition during pregnancy may be associated with allergic diseases in infants. J Nutr Sci Vitaminol (Tokyo). 2002. 48:345–51. doi:10.3177/jnsv.48.345.12656206 | Study design; Intervention/Exposure; Outcome; Diet assessed retrospectively
69. | Vance, GH, Grimshaw, KE, Briggs, R, Lewis, SA, Mullee, MA, Thornton, CA, Warner, JO. Serum ovalbumin-specific immunoglobulin G responses during pregnancy reflect maternal intake of dietary egg and relate to the development of allergy in early infancy. Clin Exp Allergy. 2004. 34:1855–61. doi:10.1111/j.1365-2222.2004.02111.x.15663559 | Outcome
70. | Venter, C, Pereira, B, Voigt, K, Grundy, J, Clayton, CB, Higgins, B, Arshad, SH, Dean, T. Factors associated with maternal dietary intake, feeding and weaning practices, and the development of food hypersensitivity in the infant. Pediatr Allergy Immunol. 2009. 20:320–7. doi:10.1111/j.1399-3038.2008.00832.x.19220769 | Statistical tests do not converge
71. | von Ehrenstein, OS, Aralis, H, Flores, ME, Ritz, B. Fast food consumption in pregnancy and subsequent asthma symptoms in young children. Pediatr Allergy Immunol. 2015. 26:571–7. doi:10.1111/pai.12433.26109272 | Study design
72. | Warstedt, K, Furuhjelm, C, Falth-Magnusson, K, Fageras, M, Duchen, K. High levels of omega-3 fatty acids in milk from omega-3 fatty acid-supplemented mothers are related to less immunoglobulin E-associated disease in infancy. Acta Paediatr. 2016. 105:1337–1347. doi:10.1111/apa.13395.26970335 | Intervention/Exposure; Outcome; No Exp-outcome test

xxii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xxiii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).