# List of abbreviations

Abbreviation: Full name
AMDR: Acceptable Macronutrient Distribution Range
CHO: Carbohydrate
DHA: Docosahexaenoic acid
EPA: Eicosapentaenoic acid
HDI: Human Development Index
HHS: Department of Health and Human Services
MUFA: Monounsaturated fatty acid
NESR: Nutrition Evidence Systematic Review
PUFA: Polyunsaturated fatty acid
PRO: Protein
RCT: Randomized controlled trial
SAT: Saturated fat
SES: Socioeconomic status
sIgA: Secretory immunoglobulin A
USDA: United States Department of Agriculture