# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xvii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed during lactation and human milk composition and quantity. For this systematic review, the target population considered was women during lactation; healthy and/or at risk of chronic disease. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern; different levels of consumption and/or adherence to a dietary pattern. The outcomes considered were human milk composition assessed in milk collected at least 14 days postpartum, including macronutrients, water soluble vitamins, minerals, human; human milk oligosaccharides, and bioactive proteins; human milk quantity assessed in milk collected at least 14 days postpartum. The key confounders were age, race/ethnicity, socioeconomic status, anthropometry, smoking, parity, gestational age, and supplement intake during lactation.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 7 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Cross-sectional studies | - Uncontrolled trials; - Case-control studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a; 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] including, at a minimum, a description of the foods and beverages in the pattern; and/or | - Studies that; 1a Do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed)
Intervention/exposure | - 2 Diet based on macronutrient distribution outside of the AMDR and; - Include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; - Include at least one macronutrient outside of the acceptable macronutrient distribution range (AMDR^xviii^) | - 2a Examine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | Dietary patterns described by foods and beverages consumed:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; Diets described by macronutrient distribution:; - Different macronutrient distribution of carbohydrate, fat, and protein | - No comparator; - Macronutrient proportion(s) of interest also outside the AMDR
Outcomes | - Human milk composition assessed in milk collected ≥ 14 days postpartum; ○ Macronutrients: Fatty acids, total protein; ○ Water soluble vitamins: B, C, and choline; ○ Fat soluble vitamins: A, D, E, K; ○ Minerals: Iodine and Selenium; ○ Human milk oligosaccharides; ○ Bioactive components; - Human milk quantity assessed in milk collected ≥14 days postpartum
Date of publication | - January 2000 to November 2019 | - Articles published before January 2000 or after November 2019
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peerreviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xix^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human milk composition: Women during lactation; - Human milk quantity: Exclusively or predominantly human milk feeding women | - Animal and in vitro models; - Studies that ONLY enroll multiple gestation pregnancies or present ONLY combined analyses of singleton and multiple gestations (human milk quantity outcome only)
Health status of study participants | - Studies that enroll mothers who are healthy and/or at risk for chronic disease; - Studies that enroll some mothers diagnosed with a disease; - Studies that enroll some mothers who were severely undernourished prior to pregnancy; - Studies that enroll some or all mothers classified as underweight, or obese prior to pregnancy | - Studies that ONLY enroll mothers who gave birth to preterm (gestational age <37 weeks and 0/7 days); - Studies that ONLY enroll mothers diagnosed with a disease, including severe undernutrition, or hospitalized with an illness or injury

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: November 13, 2019
- Date range searched: January 1, 2000 – November 13, 2019
- Search Terms:
  - #1- “Lactation”[Mesh] OR lactation[tiab] OR lactating[tiab] OR “Breast Feeding”[Mesh] OR breastfeeding[tiab] OR breast-feeding[tiab] OR breast feed* OR breast-feed*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed* OR nursing women[tiab]
  - #2 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality[tiab] OR eating habit*[tiab] OR dietary habit* OR diet habit* OR food habit* OR “Feeding Behavior”[Mesh] OR feeding behavior*[tiab] OR beverage consumption[tiab] OR beverage habit*[tiab] OR beverage intake*[tiab] OR dietary profile* OR food profile[tiab] OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake[tiab] OR food intake[tiab] OR food consumption[tiab] OR dietary consumption[tiab] OR eating frequenc* OR food frequenc*[tiab] OR eating style*[tiab] OR dietary change*[tiab] OR dietary choice*[tiab] OR food choice*[tiab] OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR high-fat diet* [tiab] OR low fat diet*[tiab] OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR (“Guideline Adherence”[Mesh] AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage[tiab])) OR (diet score* OR diet quality score* OR diet quality index* OR dietary habits score* OR kidmed OR diet index* OR dietary index* OR Food-based Index* OR diet quality index* OR food index* OR food score* OR Mediterranean diet score* OR MedDietScore OR healthy eating index[tiab] OR food frequency questionnaire* OR food frequency survey* OR “Nutrition Surveys”[Mesh] OR nutrition survey*[tiab] OR diet survey*[tiab] OR food survey* OR dietary questionnaire[tiab]) OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #3 - “human milk composition”[tiab] OR “Milk, Human”[Mesh] OR “milk composition”[tiab] OR “Nutrients”[Mesh:NoExp] OR macronutrient*[tiab] OR “Vitamins”[Mesh] OR “Vitamins” [Pharmacological Action] OR vitamin*[tiab] OR “Milk Proteins”[Mesh] OR total protein*[tiab] OR “milk protein*”[tiab] OR lactoferrin*[tiab] OR lactalbumin[tiab] OR casein*[tiab] OR whey protein*[tiab] OR “alpha 1-Antitrypsin”[Mesh] OR alpha 1-antitrypsin*[tiab] OR “alpha 1-Antitrypsin Deficiency”[Mesh] OR “alpha 1-Antitrypsin Deficien*”[ tiab] OR “Osteopontin”[Mesh] OR osteopontin*[tiab] OR “IgA Deficiency”[Mesh] OR “Immunoglobulin A”[Mesh] OR iga[tiab] OR “iga 1”[tiab] OR “iga 2”[tiab] OR lysozyme*[tiab] OR “Muramidase”[Mesh]
  - #4 - fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR pufa[tiab] OR pufas[tiab] OR alpha-Linolenic Acid[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh]
  - #5 - “Vitamin B Complex”[Mesh] OR “Vitamin B Complex” [Pharmacological Action] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR “vitamin b”[tiab] OR “vitamin c”[tiab] OR “Ascorbic Acid”[Mesh] OR “ascorbic acid*”[tiab] OR choline[tiab] OR “Choline”[Mesh] OR “vitamin A”[tiab] OR “vitamin E”[tiab] OR “vitamin D”[tiab] OR “vitamin K”[tiab] OR “Vitamin A”[Mesh] OR retinol[tiab] OR “Vitamin A Deficiency”[Mesh] OR “Ascorbic Acid Deficiency”[Mesh] OR “Vitamin E”[Mesh] OR “Vitamin E Deficiency”[Mesh] OR tocopherol*[tiab] OR “Vitamin D”[Mesh] OR “Vitamin D Deficiency”[Mesh] OR “Cholecalciferol”[Mesh] OR cholecalciferol*[tiab] OR “Ergocalciferols”[Mesh] OR ergocalciferol*[tiab] OR “Vitamin K”[Mesh] OR “Vitamin K Deficiency”[Mesh] OR “Iodine”[Mesh] OR iodine*[tiab] OR “Selenium”[Mesh] OR selenium[tiab] OR “Oligosaccharides”[Mesh] OR oligosaccharide*[tiab] OR (milk[tiab] AND (amount[tiab] OR quantity[tiab] OR quality[tiab]))
  - #6 - #1 AND #2
  - #7 - #3 OR #4 OR #5
  - #8 - #6 AND #7
  - #9 - #8 NOT ((“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])

Filters: Publication date from 2000/01/01 to 2019/11/13; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: November 14, 2019
- Date range searched: January 1, 2000 – November 14, 2019
- Search Terms:
  - #1 - [mh Lactation] OR lactation OR lactating OR [mh “breast feeding”] OR breastfeeding OR “breast feed” OR “breast feeds” OR breast-feed OR breast-feeds OR breastfed OR breast-fed OR breastfeed OR breastfeeds OR “nursing women” OR “nursing mother*
  - #2 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR [mh “Feeding Behavior”] OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake” OR “food intake” OR “food consumption”):ti,ab OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR “food choice*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “high fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low sodium diet*” OR “low salt diet*” OR (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR (diet OR diets OR consumption OR intake OR supplement*)) OR (“guideline adherence”) NEAR (diet OR dietary OR food OR beverage)) OR (“diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “dietary habits score” OR kidmed OR “diet index” OR “dietary index” OR “Food-based Index” OR “diet quality index” OR “food index” OR “food score” OR “food scores” OR “Mediterranean diet score” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire” OR “food frequency questionnaires” OR “food frequency survey” OR “food frequency surveys” OR [mh “Nutrition Surveys”] OR “nutrition survey” OR “nutrition surveys” OR “diet survey” OR “diet surveys” OR “food survey” OR “food surveys” OR “dietary questionnaire”):ti,ab,kw OR ((pattern OR patterns OR consumption OR habit*) NEAR ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages))):ti,ab,kw
  - #3 - ([mh “milk, human”] OR “breast milk” OR “human milk” OR “mother’s milk” OR breastmilk OR “human milk” OR “maternal milk” OR (milk NEAR/6 composition) OR [mh “nutrients”] OR macronutrient* OR [mh ”vitamins”] OR vitamin* OR [mh “milk proteins”] OR “total protein” OR “total proteins” OR “milk protein*” OR lactoferrin* OR lactalbumin* OR casein* OR “whey protein*” OR “alpha 1 antitrypsin*” OR [mh osteopontin] OR osteopontin* OR [mh “IgA Deficiency”] OR [mh “Immunoglobulin A”] OR iga1 OR iga2 OR iga OR lysozyme* OR [mh muramidase]):ti,ab,kw
  - #4 - (“fatty acid*” OR [mh ^“Fatty Acids”] OR [mh ^“Fatty Acids, Unsaturated”] OR “Arachidonic acid*” OR “linolenic acid*” OR “linoleic acid*” OR “Docosahexaenoic Acid*” OR “Eicosapentaenoic Acid*” OR gamma-linolenic acid* OR [mh “Arachidonic Acids”] OR [mh “Fatty Acids, Essential”] OR [mh “Fatty Acids, Omega-3”] OR [mh “Fatty Acids, Omega-6”] OR “omega-6 fatty acid*” OR “omega-3 fatty acid*” OR “omega 6 fatty acid*” OR “omega 3 fatty acid*” OR pufa OR pufas OR “alpha-linolenic acid*” OR [mh “Fatty Acids, Essential”] OR [mh “Linolenic Acids”] OR [mh “Trans Fatty Acids”] OR [mh “Fatty Acids, Monounsaturated”]):ti,ab
  - #5 - ([mh “vitamin b complex”] OR [mh “Vitamin B 12”] OR “Vitamin B 12” OR “Vitamin B12” OR [mh “Vitamin B 12 Deficiency”] OR “vitamin b” OR “vitamin c” OR [mh “ascorbic acid”] OR “ascorbic acid*” OR choline OR [mh choline] OR “vitamin A” OR “vitamin E” OR “vitamin D” OR “vitamin K” OR [mh “vitamin A”] OR retinol OR [mh “vitamin A deficiency”] OR [mh “ascorbic acid deficiency”] OR [mh “vitamin E”] OR [mh “vitamin E deficiency”] OR tocopheral* OR [mh “Vitamin D”] OR [mh “vitamin D deficiency”] OR [mh cholecalciferol] OR cholecalciferol* OR [mh ergocalciferols] OR ergocalciferol* OR [mh “vitamin K”] OR [mh “vitamin K deficiency”] OR [mh iodine] OR iodine* OR [mh selenium] OR selenium OR [mh oligosaccharides] OR oligosaccharide* OR (milk NEAR/5 (amount OR quantity))):ti,ab
  - #6 - #1 AND #2
  - #7 - #3 OR #4 OR #5
  - #8 - #6 AND #7

Filters: Publication Year from 2000 – 2019, Trials

#### Embase

- Provider: Elsevier
- Date(s) Searched: November 13, 2019
- Date range searched: January 1, 2000 – November 13, 2019
- Search Terms:
  - #1 - (‘breast feeding’/exp OR ‘lactation’/exp OR lactation:ti,ab OR lactating:ti,ab OR breastfeeding:ti,ab OR ‘breast feed’:ti,ab OR breastfed:ti,ab OR ‘breast fed’:ti,ab OR breastfeed*:ti,ab OR ‘nursing women’:ti,ab OR ‘nursing mother*’:ti,ab)
  - #2 - ‘feeding behavior’/exp OR ‘mediterranean diet’/de OR ‘dash diet’/de OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘beverage consumption’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘beverage intake*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake’:ab,ti OR ‘food intake’:ab,ti OR ‘food consumption’:ab,ti OR ‘dietary consumption’:ab,ti OR ‘eating frequenc*’:ab,ti OR ‘food frequenc*’:ab,ti OR ‘eating style*’:ab,ti OR ‘dietary change*’:ab,ti OR ‘dietary choice*’:ab,ti OR ‘food choice*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR (((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR ‘hypo caloric’) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*)):ab,ti) OR ((‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage)):ab,ti) OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘dietary habits score*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food-based index*’:ab,ti OR ‘diet quality index*’:ab,ti OR ‘food index*’:ab,ti OR ‘food score*’:ab,ti OR ‘mediterranean diet score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti OR ‘food frequency questionnaire*’:ab,ti OR ‘food frequency survey*’:ab,ti OR ‘nutrition survey*’:ab,ti OR ‘diet survey*’:ab,ti OR ‘food survey*’:ab,ti OR ‘dietary questionnaire’:ab,ti OR (((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti)
  - #3 - (‘breast milk’/exp OR ‘breast milk’:ti,ab OR ‘human milk’:ti,ab OR ‘mothers milk’:ti,ab OR breastmilk:ti,ab OR ‘maternal milk’:ti,ab) OR (milk NEAR/5 composition) OR ‘nutrient’/exp OR macronutrient*:ti,ab OR ‘vitamin’/exp OR vitamin*:ti,ab OR ‘milk protein’/exp OR total) AND protein*:ti,ab OR ‘milk protein*’:ti,ab OR ‘milk protein’/exp OR ‘lactoferrin’/exp OR lactoferrin*:ti,ab OR ‘lactalbumin’/exp OR lactalbumin:ti,ab OR casein*:ti,ab OR ‘whey protein*’:ti,ab OR ‘alpha 1 antitrypsin*’:ti,ab OR ‘alpha 1 antitrypsin’/exp OR ‘alpha 1 antitrypsin deficiency’/exp OR ‘osteopontin’/exp OR osteopontin*:ti,ab OR iga:ti,ab OR ‘iga 1’:ti,ab OR ‘iga 2’:ti,ab OR lysozyme*:ti,ab OR ‘immunoglobulin a deficiency’/exp OR ‘immunoglobulin a’/exp OR ‘immunoglobulin a’:ti,ab OR ‘lysozyme’/exp
  - #4 - ‘fatty acid*’:ti,ab OR ‘fatty acid’/de OR ‘unsaturated fatty acid’/de OR ‘arachidonic acid’/exp OR ‘arachidonic acid*’:ti,ab OR ‘linolenic acid*’:ti,ab OR ‘linoleic acid*’:ti,ab OR ‘docosahexaenoic acid*’:ti,ab OR ‘eicosapentaenoic acid*’:ti,ab OR ‘gamma linolenic acid*’:ti,ab OR ‘omega 3 fatty acid’/exp OR ‘omega 3 fatty acid*’:ti,ab OR ‘omega-6 fatty acid’/exp OR ‘omega 6 fatty acid*’:ti,ab OR pufa:ti,ab OR pufas:ti,ab OR ‘alpha linolenic acid*’:ti,ab OR ‘monounsaturated fatty acid’/exp OR ‘essential fatty acid’/exp OR ‘linolenic acid’/exp OR ‘trans fatty acid’/exp OR ‘trans fatty acid*’:ti,ab OR ‘essential fatty acid*’:ti,ab OR ‘monounsaturated fatty acid*’:ti,ab
  - #5 - ‘vitamin b 12’:ti,ab OR ‘vitamin b12’:ti,ab OR ‘vitamin b’:ti,ab OR ‘vitamin c’:ti,ab OR ‘ascorbic acid*’:ti,ab OR choline:ti,ab OR ‘vitamin a’:ti,ab OR ‘vitamin e’:ti,ab OR ‘vitamin d’:ti,ab OR ‘vitamin k’:ti,ab OR retinol:ti,ab OR tocopherol*:ti,ab OR cholecalciferol*:ti,ab OR ergocalciferol*:ti,ab OR iodine*:ti,ab OR selenium:ti,ab OR oligosaccharide*:ti,ab OR (milk NEAR/5 (amount OR quantity OR quality)) OR ‘vitamin b complex’/exp OR ‘cyanocobalamin’/exp OR ‘b12 deficiency’/exp OR ‘ascorbic acid’/exp OR ‘choline’/exp OR ‘retinol’/exp OR ‘retinol deficiency’/exp OR ‘ascorbic acid deficiency’/exp OR ‘alpha tocopherol’/exp OR ‘alpha tocopherol deficiency’/exp OR ‘vitamin d’/exp OR ‘vitamin d deficiency’/exp OR ‘colecalciferol’/exp OR ‘ergocalciferol’/exp OR ‘vitamin k group’/exp OR ‘iodine’/exp OR ‘selenium’/exp OR ‘oligosaccharide’/exp
  - #6 - #1 AND #2
  - #7 - #3 OR #4 OR #5
  - #8 - #6 AND #7
  - #9 - #8 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: November 14, 2019
- Date range searched: January 1, 2000 – November 14, 2019
- Search Terms:
  - #1 - MH “Breast Feeding” OR breastfeeding OR breast-feeding OR MH Lactation OR lactation OR lactating OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed* OR “nursing women” OR “nursing mother*”
  - #2 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR MH “Eating Behavior+” OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “food intake*” OR “food consumption” OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR “food choice*” OR MH “Diet, Mediterranean” OR “Mediterranean Diet*” OR MH “Dietary Approaches To Stop Hypertension” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR MH “Diet, Gluten-Free” OR “Gluten Free diet*” OR “prudent diet*” OR MH “Diet, Paleolithic” OR “Paleolithic Diet*” OR MH “Diet, Vegetarian” OR “vegetarian diet*” OR “vegan diet*” OR MH “Healthy Diet” OR “plant based diet*” OR MH “Diet, Western” OR “western diet*” OR MH “Diet, Carbohydrate-Restricted” OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR MH “Diet, Fat-Restricted” OR MH “Diet, High-Fat” OR MH “Diet, High-Protein” OR “high protein diet*” OR “high-fat diet*” OR “low fat diet*” OR MH “Diet, Protein-Restricted” OR “low protein diet*” OR MH “Diet, Sodium-Restricted” OR “low-sodium diet*” OR “low salt diet*” OR ((MH “Dietary Proteins” OR “dietary protein*” OR MH “Dietary Carbohydrates” OR “dietary carbohydrate*” OR MH “Dietary Fats” OR “dietary fat*” OR hypocaloric OR hypo-caloric) AND (diet OR diets OR consumption OR intake OR supplementation)) OR (MH “Guideline Adherence” AND (diet OR dietary OR food OR beverage)) OR (“diet score*” OR “diet quality score*” OR “diet quality index*” OR “dietary habits score*” OR kidmed OR “diet index*” OR “dietary index*” OR “Food-based Index*” OR “diet quality index*” OR “food index*” OR “food score*” OR “Mediterranean diet score*” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire*” OR “food frequency survey*” OR MH “Nutrition Surveys” OR “nutrition survey*” OR “diet survey*” OR “food survey*” OR “dietary questionnaire*”) OR ((pattern OR patterns OR consumption OR habit*) AND (MH “Diet” OR diet OR diets OR dietary OR MH “Food” OR food OR foods OR MH “Beverages” OR beverage OR beverages))
  - #3 - MH “Milk, Human” OR “breast milk” OR breast-milk OR “human milk” OR “mother’s milk” OR “mothers milk” OR “human milk composition” OR (milk n5 composition) OR (MH “Nutrients”) OR “macronutrients” OR (MH “Vitamins”) OR “vitamin*” OR (MH “milk proteins”) OR “total protein*” OR “milk protein*” OR lactoferrin* OR lactalbumin* OR casein* OR “whey protein*” OR “alpha 1-antitrypsin*” OR osteopontin* OR iga OR “iga 1” OR “iga 2” OR “immunoglobulin a” OR lysozyme* OR muramidase*
  - #4 - (MH “Fatty Acids”) OR “fatty acid*” OR (MH “Fatty Acids, Omega-6+”) OR (MH “Fatty Acids, Omega-3+”) OR (MH “Fatty Acids, Unsaturated+”) OR (MH “Fatty Acids, Monounsaturated+”) OR (MH “Trans Fatty Acids+”) OR (MH “Fatty Acids, Essential+”) OR “fatty acids” OR “arachidonic acid*” OR “linolenic acid” OR “linoleic acid” OR “linoleic acids” OR “docosahexaenoic acid*” OR “Eicosapentaenoic Acid*” OR “gamma-Linolenic Acid*” OR (MH “Arachidonic Acids+”) OR (MH “Ascorbic Acid Deficiency+”) OR pufa OR pufas OR “alpha-linolenic acid*” OR (MH “alpha-Linolenic Acid”) OR (MH “Linolenic Acids+”)
  - #5 - (MH “Vitamins”) OR (MH “Vitamin B6 Deficiency”) OR (MH “Vitamin B Deficiency”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Vitamin D Deficiency”) OR (MH “Vitamin A Deficiency”) OR (MH “Vitamin K Deficiency”) OR (MH “Vitamin E Deficiency”) OR (MH “Riboflavin Deficiency”) OR (MH “Ascorbic Acid Deficiency”) OR (MH “Vitamin K”) OR (MH “Vitamin B Complex”) OR (MH “Vitamin B12”) OR (MH “Vitamin A”) OR (MH “Ascorbic Acid”) OR (MH “Vitamin D”) OR (MH “Vitamin E”) OR (MH “Vitamin K”) OR (MH “Cholecalciferol”) OR (MH “Ergocalciferols”) OR (MH “Iodine”) OR (MH “Iodine Deficiency”) OR (MH “Selenium”) OR (MH “Oligosaccharides”) OR “Vitamin B Complex” OR “vitamin b12” OR “vitamin b 12” OR “vitamin b” OR “vitamin c” OR “vitamin d” OR “ascorbic acid*” OR choline OR “vitamin a” OR “vitamin e” OR “vitamin d” OR “vitamin k” OR retinol* OR tocopherol* OR cholecalciferol* OR ergocalciferol* OR ergocalciferol* OR iodine OR selenium OR oligosaccharide* OR (milk N5 (amount OR quantity OR quality))
  - #6 - #1 AND #2
  - #7 - #3 OR #4 OR #5
  - #8 - #6 AND #7
  - #9 - #8 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication )

Filters: Published Date: 20000101 - 20191114, English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. After the initial electronic database search (January 2000-July 2019), an updated search was conducted to also capture macronutrient distribution articles (January 2000-November 2019). The results of both electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria for the systematic review question depicted. Refer to Table 8 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the combined literature search and screening results for articles examining the relationship between dietary patterns consumed during lactation and human milk composition and quantity. The literature search yielded 6,484 articles, and 3,241 articles after duplicates were removed. During title screening, 2,524 articles were screened out. During abstract screening, 547 articles were screened out. During full-text screening, 163 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 7 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes rationale for the categories of inclusion and exclusion criteria (see Table 7) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 8 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1. | Agostoni, C, Marangoni, F, Grandi, F, Lammardo, AM, Giovannini, M, Riva, E, Galli, C. Earlier smoking habits are associated with higher serum lipids and lower milk fat and polyunsaturated fatty acid content in the first 6 months of lactation. European Journal of Clinical Nutrition. 2003. 57:1466–1472. doi:10.1038/sj.ejcn.1601711.14576760 14576760 | Comparator
2. | Alberti-Fidanza, A, Burini, G, Perriello, G. Total antioxidant capacity of colostrum, and transitional and mature human milk. J Matern Fetal Neonatal Med. 2002. 11:275–9. doi:10.1080/jmf.11.4.275.279.12375685 | Intervention/Exposure
3. | Ali, MA, Strandvik, B, Palme-Kilander, C, Yngve, A. Lower polyamine levels in breast milk of obese mothers compared to mothers with normal body weight. J Hum Nutr Diet. 2013. 26 Suppl 1:164–70. doi:10.1111/jhn.12097.23627874 | Intervention/Exposure
4. | Alien, CM, Smith, AM, Clinton, SK, Schwartz, SJ. Tomato consumption increases lycopene isomer concentrations in breast milk and plasma of lactating women. J Am Diet Assoc. 2002. 102:1257–62. doi:10.1016/s0002-8223(02)90278-6.12792623 | Intervention/Exposure
5. | Andersen, SL. Iodine status in pregnant and breastfeeding women: a Danish regional investigation. Dan Med J. 2015. 62. | Study Design; Intervention/Exposure
6. | Anderson, NK, Beerman, KA, McGuire, MA, Dasgupta, N, Griinari, JM, Williams, J, McGuire, MK. Dietary fat type influences total milk fat content in lean women. J Nutr. 2005. 135:416–21. doi:10.1093/jn/135.3.416.15735072 | Comparator
7. | Antonakou, A, Chiou, A, Andrikopoulos, NK, Bakoula, C, Matalas, AL. Breast milk tocopherol content during the first six months in exclusively breastfeeding Greek women. Eur J Nutr. 2011. 50:195–202. doi:10.1007/s00394-010-0129-4.20721564 | Intervention/Exposure
8. | Antonakou, A, Skenderi, KP, Chiou, A, Anastasiou, CA, Bakoula, C, Matalas, AL. Breast milk fat concentration and fatty acid pattern during the first six months in exclusively breastfeeding Greek women. Eur J Nutr. 2013. 52:963–73. doi:10.1007/s00394-012-0403-8.22752261 | Intervention/Exposure; Comparator
9. | Arora, M, Ettinger, AS, Peterson, KE, Schwartz, J, Hu, H, Hernández-Avila, M, Tellez-Rojo, MM, Wright, RO. Maternal dietary intake of polyunsaturated fatty acids modifies the relationship between lead levels in bone and breast milk. Journal of Nutrition. 2008. 138:73–79. | Intervention/Exposure
10. | Aumeistere, L, Ciprovica, I, Zavadska, D, Andersons, J, Volkovs, V, Celmalniece, K. Impact of Maternal Diet on Human Milk Composition Among Lactating Women in Latvia. Medicina (Kaunas). 2019. 55. doi:10.3390/medicina55050173. | Intervention/Exposure
11. | Aumeistere, L, Ciproviča, I, Zavadska, D, Volkovs, V. Fish intake reflects on DHA level in breast milk among lactating women in Latvia. International Breastfeeding Journal. 2018. 13:N.PAG-N.PAG. doi:10.1186/s13006-018-0175-8. | Intervention/Exposure
12. | Azad, MB, Robertson, B, Atakora, F, Becker, AB, Subbarao, P, Moraes, TJ, Mandhane, PJ, Turvey, SE, Lefebvre, DL, Sears, MR, Bode, L. Human Milk Oligosaccharide Concentrations Are Associated with Multiple Fixed and Modifiable Maternal Characteristics, Environmental Factors, and Feeding Practices. J Nutr. 2018. 148:1733–1742. doi:10.1093/jn/nxy175.30247646 | Population
13. | Baatenburg de Jong, R, Bekhof, J, Roorda, R, Zwart, P. Severe nutritional vitamin deficiency in a breast-fed infant of a vegan mother. Eur J Pediatr. 2005. 164:259–60. doi:10.1007/s00431-004-1613-8.15645284 | Study Design
14. | Baheiraei, A, Shamsi, A, Khaghani, S, Shams, S, Chamari, M, Boushehri, H, Khedri, A. The effects of maternal passive smoking on maternal milk lipid. Acta Med Iran. 2014. 52:280–5.24901858 | Intervention/Exposure
15. | Barrera, C, Valenzuela, R, Chamorro, R, Bascunan, K, Sandoval, J, Sabag, N, Valenzuela, F, Valencia, MP, Puigrredon, C, Valenzuela, A. The Impact of Maternal Diet during Pregnancy and Lactation on the Fatty Acid Composition of Erythrocytes and Breast Milk of Chilean Women. Nutrients. 2018. 10. doi:10.3390/nu10070839. | Intervention/Exposure
16. | Bascunan, KA, Valenzuela, R, Chamorro, R, Valencia, A, Barrera, C, Puigrredon, C, Sandoval, J, Valenzuela, A. Polyunsaturated fatty acid composition of maternal diet and erythrocyte phospholipid status in Chilean pregnant women. Nutrients. 2014. 6:4918–34. doi:10.3390/nu6114918.25386693 | Intervention/Exposure; Outcome
17. | Bertschi, I, Collomb, M, Rist, L, Eberhard, P, Sieber, R, Bütikofer, U, Wechsler, D, Folkers, G, von Mandach, U. Maternal dietary Alpine butter intake affects human milk: fatty acids and conjugated linoleic acid isomers. Lipids. 2005. 40:581–587.16149737 | Intervention/Exposure
18. | Bobiński, R, Mikulska, M, Mojska, H, Ulman-Włodarz, I, Sodowska, P. Pregnant women’s diet composition and transitional milk fatty acids: factor analysis. Ginekologia polska. 2015. 86:113–118.25807835 | Intervention/Exposure; Outcome
19. | Bode, L. Human Milk Oligosaccharides at the Interface of Maternal-Infant Health. Breastfeed Med. 2018. 13:S7–s8. doi:10.1089/bfm.2018.29073.ljb.29624421 | Study Design
20. | Boniglia, C, Carratu, B, Chiarotti, F, Giammarioli, S, Sanzini, E. Influence of maternal protein intake on nitrogen fractions of human milk. Int J Vitam Nutr Res. 2003. 73:447–52. doi:10.1024/0300-9831.73.6.447.14743549 | Intervention/Exposure
21. | Bopp, M, Lovelady, C, Hunter, C, Kinsella, T. Maternal diet and exercise: effects on long-chain polyunsaturated fatty acid concentrations in breast milk. J Am Diet Assoc. 2005. 105:1098–103. doi:10.1016/j.jada.2005.04.004.15983527 | Intervention/Exposure
22. | Buntuchai, G, Pavadhgul, P, Kittipichai, W, Satheannoppakao, W. Traditional Galactagogue Foods and Their Connection to Human Milk Volume in Thai Breastfeeding Mothers. J Hum Lact. 2017. 33:552–559. doi:10.1177/0890334417709432.28609178 | Intervention/Exposure
23. | Burtseva, T, Solodkova, I, Savvina, M, Dranaeva, G, Shadrin, V, Avrusin, S, Sinelnikova, E, Chasnyk, V. Dietary intakes of energy and macronutrients by lactating women of different ethnic groups living in Yakutia. Int J Circumpolar Health. 2013. 72. doi:10.3402/ijch.v72i0.21519. | Intervention/Exposure
24. | Butts, CA, Hedderley, DI, Herath, TD, Paturi, G, Glyn-Jones, S, Wiens, F, Stahl, B, Gopal, P. Human Milk Composition and Dietary Intakes of Breastfeeding Women of Different Ethnicity from the Manawatu-Wanganui Region of New Zealand. Nutrients. 2018. 10. doi:10.3390/nu10091231. | Intervention/Exposure
25. | Bzikowska-Jura, A, Czerwonogrodzka-Senczyna, A, Jasinska-Melon, E, Mojska, H, Oledzka, G, Wesolowska, A, Szostak-Wegierek, D. The Concentration of Omega-3 Fatty Acids in Human Milk Is Related to Their Habitual but Not Current Intake. Nutrients. 2019. 11. doi:10.3390/nu11071585. | Intervention/Exposure
26. | Bzikowska-Jura, A, Czerwonogrodzka-Senczyna, A, Oledzka, G, Szostak-Wegierek, D, Weker, H, Wesolowska, A. Maternal Nutrition and Body Composition During Breastfeeding: Association with Human Milk Composition. Nutrients. 2018. 10. doi:10.3390/nu10101379. | Intervention/Exposure
27. | Cai, X, Duan, Y, Li, Y, Wang, J, Mao, Y, Yang, Z, Zhao, X, Zhao, Y, Guan, Y, Yin, S. Lactoferrin level in breast milk: a study of 248 samples from eight regions in China. Food Funct. 2018. 9:4216–4222. doi:10.1039/c7fo01559c.29993054 | Intervention/Exposure
28. | Canfield, LM, Clandinin, MT, Davies, DP, Fernandez, MC, Jackson, J, Hawkes, J, Goldman, WJ, Pramuk, K, Reyes, H, Sablan, B, Sonobe, T, Bo, X. Multinational study of major breast milk carotenoids of healthy mothers. Eur J Nutr. 2003. 42:133–41. doi:10.1007/s00394-003-0403-9.12811470 | Intervention/Exposure
29. | Chapman, DJ, Nommsen-Rivers, L. Impact of maternal nutritional status on human milk quality and infant outcomes: an update on key nutrients. Adv Nutr. 2012. 3:351–2. doi:10.3945/an.111.001123.22585911 | Study Design
30. | Chen, GW, Ding, WH, Ku, HY, Chao, HR, Chen, HY, Huang, MC, Wang, SL. Alkylphenols in human milk and their relations to dietary habits in central Taiwan. Food Chem Toxicol. 2010. 48:1939–44. doi:10.1016/j.fct.2010.04.038.20435081 | Intervention/Exposure; Outcome
31. | Choi, YK, Kim, JM, Lee, JE, Cho, MS, Kang, BS, Choi, H, Kim, Y. Association of Maternal Diet With Zinc, Copper, and Iron Concentrations in Transitional Human Milk Produced by Korean Mothers. Clin Nutr Res. 2016. 5:15–25. doi:10.7762/cnr.2016.5.1.15.26839873 | Intervention/Exposure
32. | Clemens, K, Silvia, R. Physiology of oligosaccharides in lactating women and breast fed infants. Adv Exp Med Biol. 2000. 478:241–50. doi:10.1007/0-306-46830-1_22.11065077 | Intervention/Exposure; Publication Status
33. | Da Cunha, J, Macedo Da Costa, TH, Ito, MK. Influences of maternal dietary intake and suckling on breast milk lipid and fatty acid composition in low-income women from Brasilia, Brazil. Early Human Development. 2005. 81:303–311. doi:10.1016/j.earlhumdev.2004.08.004.15814213 | Intervention/Exposure
34. | da Silva Ribeiro, KD, de Araujo, KF, de Souza, HH, Soares, FB, da Costa Pereira, M, Dimenstein, R. Nutritional vitamin A status in northeast Brazilian lactating mothers. J Hum Nutr Diet. 2010. 23:154–61. doi:10.1111/j.1365-277X.2009.01026.x.20113385 | Intervention/Exposure
35. | da Silva, AGCL, de Sousa Reboucas, A, Mendonca, BMA, Silva, DCNE, Dimenstein, R, Ribeiro, KDDS. Relationship between the dietary intake, serum, and breast milk concentrations of vitamin A and vitamin E in a cohort of women over the course of lactation. Matern Child Nutr. 2019. 15:e12772. doi:10.1111/mcn.12772.30578660 | Intervention/Exposure
36. | Daud, AZ, Mohd-Esa, N, Azlan, A, Chan, YM. The trans fatty acid content in human milk and its association with maternal diet among lactating mothers in Malaysia. Asia Pac J Clin Nutr. 2013. 22:431–42. doi:10.6133/apjcn.2013.22.3.09.23945414 | Intervention/Exposure
37. | de Sousa Reboucas, A, Costa Lemos da Silva, AG, Freitas de Oliveira, A, Thalia Pereira da Silva, L, de Freitas Felgueiras, V, Cruz, MS, Silbiger, VN, da Silva Ribeiro, KD, Dimenstein, R. Factors Associated with Increased Alpha-Tocopherol Content in Milk in Response to Maternal Supplementation with 800 IU of Vitamin E. Nutrients. 2019. 11. doi:10.3390/nu11040900. | Intervention/Exposure
38. | Del Prado, M, Villalpando, S, Elizondo, A, Rodriguez, M, Demmelmair, H, Koletzko, B. Contribution of dietary and newly formed arachidonic acid to human milk lipids in women eating a low-fat diet. Am J Clin Nutr. 2001. 74:242–7. doi:10.1093/ajcn/74.2.242.11470727 | Intervention/Exposure
39. | Del Prado, M, Villalpando, S, Lance, A, Alfonso, E, Demmelmair, H, Koletzko, B. Contribution of dietary and newly formed arachidonic acid to milk secretion in women on low fat diets. Adv Exp Med Biol. 2000. 478:407–8. doi:10.1007/0-306-46830-1_50.11065105 | Intervention/Exposure; Publication Status
40. | Deng, J, Li, X, Ding, Z, Wu, Y, Chen, X, Xie, L. Effect of DHA supplements during pregnancy on the concentration of PUFA in breast milk of Chinese lactating mothers. Journal of Perinatal Medicine. 2017. 45:437–441. doi:10.1515/jpm-2015-0438.27235666 | Intervention/Exposure
41. | Denic, M, Sunaric, S, Gencic, M, Zivkovic, J, Jovanovic, T, Kocic, G, Jonovic, M. Maternal age has more pronounced effect on breast milk retinol and beta-carotene content than maternal dietary pattern. Nutrition. 2019. 65:120–125. doi:10.1016/j.nut.2019.02.019.31082789 | Intervention/Exposure
42. | Ding, M, Li, W, Zhang, Y, Wang, X, Zhao, A, Zhao, X, Wang, P, Sheng, QH. Amino acid composition of lactating mothers’ milk and confinement diet in rural North China. Asia Pac J Clin Nutr. 2010. 19:344–9.20805078 | Intervention/Exposure; Comparator
43. | Dingess, KA, Valentine, CJ, Ollberding, NJ, Davidson, BS, Woo, JG, Summer, S, Peng, YM, Guerrero, ML, Ruiz-Palacios, GM, Ran-Ressler, RR, McMahon, RJ, Brenna, JT, Morrow, AL. Branched-chain fatty acid composition of human milk and the impact of maternal diet: the Global Exploration of Human Milk (GEHM) Study. Am J Clin Nutr. 2017. 105:177–184. doi:10.3945/ajcn.116.132464.27903517 | Intervention/Exposure
44. | Essa, AR, Browne, EP, Punska, EC, Perkins, K, Boudreau, E, Wiggins, H, Anderton, DL, Sibeko, L, Sturgeon, SR, Arcaro, KF. Dietary Intervention to Increase Fruit and Vegetable Consumption in Breastfeeding Women: A Pilot Randomized Trial Measuring Inflammatory Markers in Breast Milk. J Acad Nutr Diet. 2018. 118:2287–2295. doi:10.1016/j.jand.2018.06.015.30213617 | Intervention/Exposure
45. | Fidler, N, Salobir, K, Stibilj, V. Fatty acid composition of human milk in different regions of Slovenia. Annals of Nutrition and Metabolism. 2000. 44:187–193. doi:10.1159/000046682.11146322 | Outcome
46. | Fischer, LM, da Costa, KA, Galanko, J, Sha, W, Stephenson, B, Vick, J, Zeisel, SH. Choline intake and genetic polymorphisms influence choline metabolite concentrations in human breast milk and plasma. Am J Clin Nutr. 2010. 92:336–46. doi:10.3945/ajcn.2010.29459.20534746 | Intervention/Exposure
47. | Furman, L. Maternal Vitamin D Supplementation for Breastfeeding Infants: Will it Work?. Pediatrics. 2015. 136:763–4. doi:10.1542/peds.2015-2312.26416926 | Study Design
48. | Gao, C, Gibson, RA, McPhee, AJ, Zhou, SJ, Collins, CT, Makrides, M, Miller, J, Liu, G. Comparison of breast milk fatty acid composition from mothers of premature infants of three countries using novel dried milk spot technology. Prostaglandins Leukot Essent Fatty Acids. 2018. 139:3–8. doi:10.1016/j.plefa.2018.08.003.30471771 | Intervention/Exposure; Population
49. | Glew, RH, Wold, RS, Corl, B, Calvin, CD, Vanderjagt, DJ. Low Docosahexaenoic Acid in the Diet and Milk of American Indian Women in New Mexico. Journal of the American Dietetic Association. 2011. 111:744–748. doi:10.1016/j.jada.2011.02.001.21515123 | Intervention/Exposure
50. | Granot, E, Ishay-Gigi, K, Malaach, L, Flidel-Rimon, O. Is there a difference in breast milk fatty acid composition of mothers of preterm and term infants?. Journal of Maternal-Fetal and Neonatal Medicine. 2016. 29:832–835. doi:10.3109/14767058.2015.1020785.25758615 | Intervention/Exposure
51. | Guan, P, Tajimi, M, Uehara, R, Watanabe, M, Oki, I, Ojima, T, Nakamura, Y. Associations between dietary intake and breast milk dioxin levels in Tokyo, Japan. Pediatr Int. 2005. 47:560–6. doi:10.1111/j.1442-200x.2005.02121.x.16190965 | Intervention/Exposure; Outcome
52. | Hairon, N. Improving vitamin D levels in pregnancy and breastfeeding. Nurs Times. 2008. 104:27–8. | Study Design
53. | Hannan, MA, Faraji, B, Tanguma, J, Longoria, N, Rodriguez, RC. Maternal milk concentration of zinc, iron, selenium, and iodine and its relationship to dietary intakes. Biol Trace Elem Res. 2009. 127:6–15. doi:10.1007/s12011-008-8221-9.18802672 | Intervention/Exposure; Comparator
54. | Hascoët, JM, Chauvin, M, Pierret, C, Skweres, S, Van Egroo, LD, Rougé, C, Franck, P. Impact of Maternal Nutrition and Perinatal Factors on Breast Milk Composition after Premature Delivery. Nutrients. 2019. 11:366. doi:10.3390/nu11020366. | Intervention/Exposure; Health Status
55. | Hoppu, U, Isolauri, E, Laakso, P, Matomaki, J, Laitinen, K. Probiotics and dietary counselling targeting maternal dietary fat intake modifies breast milk fatty acids and cytokines. Eur J Nutr. 2012. 51:211–9. doi:10.1007/s00394-011-0209-0.21626296 | Intervention/Exposure
56. | Iacovou, M, Craig, SS, Yelland, GW, Barrett, JS, Gibson, PR, Muir, JG. Randomised clinical trial: reducing the intake of dietary FODMAPs of breastfeeding mothers is associated with a greater improvement of the symptoms of infantile colic than for a typical diet. Aliment Pharmacol Ther. 2018. 48:1061–1073. doi:10.1111/apt.15007.30306603 | Intervention/Exposure; Outcome
57. | Iacovou, M, Mulcahy, EC, Truby, H, Barrett, JS, Gibson, PR, Muir, JG. Reducing the maternal dietary intake of indigestible and slowly absorbed short-chain carbohydrates is associated with improved infantile colic: a proof-of-concept study. J Hum Nutr Diet. 2018. 31:256–265. doi:10.1111/jhn.12488.28631347 | Study Design; Intervention/Exposure
58. | Iranpour, R, Kelishadi, R, Babaie, S, Khosravi-Darani, K, Farajian, S. Comparison of long chain polyunsaturated fatty acid content in human milk in preterm and term deliveries and its correlation with mothers’ diet. Journal of Research in Medical Sciences. 2013. 18:1–5.23901333 | Intervention/Exposure
59. | Jarvinen, KM. Variations in Human Milk Composition: Impact on Immune Development and Allergic Disease Susceptibility. Breastfeed Med. 2018. 13:S11–s13. doi:10.1089/bfm.2018.29075.kjs.29624425 | Study Design; Intervention/Exposure
60. | Jiang, J, Wu, K, Yu, Z, Ren, Y, Zhao, Y, Jiang, Y, Xu, X, Li, W, Jin, Y, Yuan, J, Li, D. Changes in fatty acid composition of human milk over lactation stages and relationship with dietary intake in Chinese women. Food Funct. 2016. 7:3154–62. doi:10.1039/c6fo00304d.27298082 | Comparator
61. | Jiang, J, Xiao, H, Wu, K, Yu, Z, Ren, Y, Zhao, Y, Li, K, Li, J, Li, D. Retinol and alpha-tocopherol in human milk and their relationship with dietary intake during lactation. Food Funct. 2016. 7:1985–91. doi:10.1039/c5fo01293g.26987293 | Intervention/Exposure
62. | Jin, Y, Coad, J, Weber, JL, Thomson, JS, Brough, L. Selenium Intake in Iodine-Deficient Pregnant and Breastfeeding Women in New Zealand. Nutrients. 2019. 11. doi:10.3390/nu11010069. | Intervention/Exposure
63. | Jirapinyo, P, Densupsoontorn, N, Wiraboonchai, D, Vissavavejam, U, Tangtrakulvachira, T, Chungsomprasong, P, Thamonsiri, N, Wongarn, R. Fatty acid composition in breast milk from 4 regions of Thailand. J Med Assoc Thai. 2008. 91:1833–7.19133517 | Intervention/Exposure
64. | Johansson, S, Wold, AE, Sandberg, AS. Low breast milk levels of long-chain n-3 fatty acids in allergic women, despite frequent fish intake. Clinical and Experimental Allergy. 2011. 41:505–515. doi:10.1111/j.1365-2222.2010.03678.x.21338426 | Intervention/Exposure
65. | Jonsson, K, Barman, M, Moberg, S, Sjöberg, A, Brekke, HK, Hesselmar, B, Johansen, S, Wold, AE, Sandberg, AS. Fat intake and breast milk fatty acid composition in farming and nonfarming women and allergy development in the offspring. Pediatric Research. 2016. 79:114–123. doi:10.1038/pr.2015.187.26389822 | Intervention/Exposure
66. | Kankaanpaa, P, Nurmela, K, Erkkila, A, Kalliomaki, M, Holmberg-Marttila, D, Salminen, S, Isolauri, E. Polyunsaturated fatty acids in maternal diet, breast milk, and serum lipid fatty acids of infants in relation to atopy. Allergy. 2001. 56:633–8.11421921 | Intervention/Exposure
67. | Kelishadi, R, Hadi, B, Iranpour, R, Khosravi-Darani, K, Mirmoghtadaee, P, Farajian, S, Poursafa, P. A study on lipid content and fatty acid of breast milk and its association with mother’s diet composition. Journal of Research in Medical Sciences. 2012. 17:824–827.23826007 | Intervention/Exposure
68. | Kim, H, Kang, S, Jung, BM, Yi, H, Jung, JA, Chang, N. Breast milk fatty acid composition and fatty acid intake of lactating mothers in South Korea. Br J Nutr. 2017. 117:556–561. doi:10.1017/s0007114517000253.28285609 | Intervention/Exposure
69. | Kim, H, Yi, H, Jung, JA, Chang, N. Association between lutein intake and lutein concentrations in human milk samples from lactating mothers in South Korea. Eur J Nutr. 2018. 57:417–421. doi:10.1007/s00394-017-1414-2.28251339 | Intervention/Exposure
70. | Kim, YH, Kim, KW, Lee, SY, Koo, KO, Kwon, SO, Seo, JH, Suh, DI, Shin, YH, Ahn, K, Oh, SY, Lee, S, Sohn, MH, Hong, SJ. Maternal Perinatal Dietary Patterns Affect Food Allergy Development in Susceptible Infants. Journal of Allergy and Clinical Immunology: In Practice. 2019. doi:10.1016/j.jaip.2019.03.026. | Outcome; Dissertation
71. | Kocaadam, B, Köksal, E, Türkyllmaz, C. Are breast milk adipokines affected by maternal dietary factors?. Journal of Pediatric Endocrinology and Metabolism. 2018. 31:1099–1104. doi:10.1515/jpem-2018-0196.30157033 | Intervention/Exposure; Outcome
72. | Lauritzen, L, Halkjær, LB, Mikkelsen, TB, Olsen, SF, Michaelsen, KF, Loland, L, Bisgaard, H. Fatty acid composition of human milk in atopic Danish mothers. American Journal of Clinical Nutrition. 2006. 84:190–196. | Study Design; Intervention/Exposure
73. | Lauritzen, L, Jørgensen, MH, Mikkelsen, TB, Skovgaard, lM, Straarup, EM, Olsen, SF, Høy, CE, Michaelsen, KF. Maternal fish oil supplementation in lactation: effect on visual acuity and n-3 fatty acid content of infant erythrocytes. Lipids. 2004. 39:195–206.15233397 | Intervention/Exposure
74. | Leotsinidis, M, Alexopoulos, A, Kostopoulou-Farri, E. Toxic and essential trace elements in human milk from Greek lactating women: association with dietary habits and other factors. Chemosphere. 2005. 61:238–47. doi:10.1016/j.chemosphere.2005.01.084.16168747 | Intervention/Exposure; Outcome
75. | Li, K, Jiang, J, Xiao, H, Wu, K, Qi, C, Sun, J, Li, D. Changes in the metabolite profile of breast milk over lactation stages and their relationship with dietary intake in Chinese women: HPLC-QTOFMS based metabolomic analysis. Food Funct. 2018. 9:5189–5197. doi:10.1039/c8fo01005f.30259935 | Intervention/Exposure
76. | Liao, KY, Wu, TC, Huang, CF, Lin, CC, Huang, IF, Wu, L. Profile of nucleotides and nucleosides in Taiwanese human milk. Pediatr Neonatol. 2011. 52:93–7. doi:10.1016/j.pedneo.2011.02.012.21524629 | Outcome; Missing data on dietary pattern
77. | Lipkie, TE, Morrow, AL, Jouni, ZE, McMahon, RJ, Ferruzzi, MG. Longitudinal Survey of Carotenoids in Human Milk from Urban Cohorts in China, Mexico, and the USA. PLoS One. 2015. 10:e0127729. doi:10.1371/journal.pone.0127729.26061885 | Intervention/Exposure
78. | Liu, G, Ding, Z, Li, X, Chen, X, Wu, Y, Xie, L. Relationship between polyunsaturated fatty acid levels in maternal diets and human milk in the first month post-partum. J Hum Nutr Diet. 2016. 29:405–10. doi:10.1111/jhn.12337.26419741 | Intervention/Exposure
79. | Liu, MJ, Li, HT, Yu, LX, Xu, GS, Ge, H, Wang, LL, Zhang, YL, Zhou, YB, Li, Y, Bai, MX, Liu, JM. A Correlation Study of DHA Dietary Intake and Plasma, Erythrocyte and Breast Milk DHA Concentrations in Lactating Women from Coastland, Lakeland, and Inland Areas of China. Nutrients. 2016. 8. doi:10.3390/nu8050312. | Intervention/Exposure
80. | Liu, Y, Liu, X, Wang, L. The investigation of fatty acid composition of breast milk and its relationship with dietary fatty acid intake in 5 regions of China. Medicine (Baltimore). 2019. 98:e15855. doi:10.1097/md.0000000000015855.31192916 | Intervention/Exposure
81. | Lu, M, Xiao, H, Li, K, Jiang, J, Wu, K, Li, D. Concentrations of estrogen and progesterone in breast milk and their relationship with the mother’s diet. Food Funct. 2017. 8:3306–3310. doi:10.1039/c7fo00324b.28835965 | Intervention/Exposure; Outcome
82. | Lubetzky, R, Sever, O, Mimouni, FB, Mandel, D. Human Milk Macronutrients Content: Effect of Advanced Maternal Age. Breastfeed Med. 2015. 10:433–6. doi:10.1089/bfm.2015.0072.26171573 | Intervention/Exposure
83. | Luoto, R, Laitinen, K, Nermes, M, Isolauri, E. Impact of maternal probiotic-supplemented dietary counseling during pregnancy on colostrum adiponectin concentration: a prospective, randomized, placebo-controlled study. Early Hum Dev. 2012. 88:339–44. doi:10.1016/j.earlhumdev.2011.09.006.21945174 | Intervention/Exposure; Outcome
84. | Machado, MR, Kamp, F, Nunes, JC, El-Bacha, T, Torres, AG. Breast Milk Content of Vitamin A and E from Early- to Mid-Lactation Is Affected by Inadequate Dietary Intake in Brazilian Adult Women. Nutrients. 2019. 11. doi:10.3390/nu11092025. | Intervention/Exposure
85. | Mahdavi, R, Nikniaz, L, Arefhosseini, SR, Vahed Jabbari, M. Determination of aflatoxin M(1) in breast milk samples in Tabriz-Iran. Matern Child Health J. 2010. 14:141–5. doi:10.1007/s10995-008-0439-9.19093194 | Intervention/Exposure
86. | Mahdavi, R, Taghipour, S, Ostadrahimi, A, Nikniaz, L, Hezaveh, SJ. A pilot study of synbiotic supplementation on breast milk mineral concentrations and growth of exclusively breast fed infants. Journal of trace elements in medicine and biology : organ of the Society for Minerals and Trace Elements (GMS). 2015. 30:25–29. doi:10.1016/j.jtemb.2015.01.007. | Intervention/Exposure
87. | Makela, J, Linderborg, K, Niinikoski, H, Yang, B, Lagstrom, H. Breast milk fatty acid composition differs between overweight and normal weight women: the STEPS Study. Eur J Nutr. 2013. 52:727–35. doi:10.1007/s00394-012-0378-5.22639073 | Population
88. | Malek, L, Makrides, M. 2.8 Nutrition in pregnancy and lactation. World Rev Nutr Diet. 2015. 113:127–33. doi:10.1159/000367872.25906871 | Study Design
89. | Mandel, D, Lubetzky, R, Dollberg, S, Barak, S, Mimouni, FB. Fat and energy contents of expressed human breast milk in prolonged lactation. Pediatrics. 2005. 116:e432–5. doi:10.1542/peds.2005-0313.16140689 | Intervention/Exposure; Outcome
90. | Martin, MA, Lassek, WD, Gaulin, SJ, Evans, RW, Woo, JG, Geraghty, SR, Davidson, BS, Morrow, AL, Kaplan, HS, Gurven, MD. Fatty acid composition in the mature milk of Bolivian foragerhorticulturalists: controlled comparisons with a US sample. Matern Child Nutr. 2012. 8:404–18. doi:10.1111/j.1740-8709.2012.00412.x.22624983 | Intervention/Exposure; Country
91. | Martysiak-Żurowska, D, Kiełbratowska, B, Szlagatys-Sidorkiewicz, A. The content of conjugated linoleic acid and vaccenic acid in the breast milk of women from Gdansk and the surrounding district, as well as in, infant formulas and follow-up formulas. nutritional recommendation for nursing women. Developmental period medicine. 2018. 22:128–134.30056399 | Intervention/Exposure
92. | Martysiak-Zurowska, D, Szlagatys-Sidorkiewicz, A, Zagierski, M. Concentrations of alpha- and gamma-tocopherols in human breast milk during the first months of lactation and in infant formulas. Matern Child Nutr. 2013. 9:473–82. doi:10.1111/j.1740-8709.2012.00401.x.22513202 | Intervention/Exposure
93. | Mastorakou, D, Ruark, A, Weenen, H, Stahl, B, Stieger, M. Sensory characteristics of human milk: Association between mothers’ diet and milk for bitter taste. J Dairy Sci. 2019. 102:1116–1130. doi:10.3168/jds.2018-15339.30594356 | Intervention/Exposure; Outcome
94. | Matamoros, N, Visentin, S, Ferrari, G, Falivene, M, Fasano, V, Gonzalez, HF. Vitamin A content in mature breast milk and its adequacy to the nutritional recommendations for infants. Arch Argent Pediatr. 2018. 116:146–148. doi:10.5546/aap.2018.eng.146.29557610 | Intervention/Exposure
95. | Mekrungcharas, T, Kasemsup, R. Breast milk iodine concentrations in lactating mothers at Queen Sirikit National Institute of Child Health. J Med Assoc Thai. 2014. 97 Suppl 6:S115–9. | Intervention/Exposure; Outcome; Publication Status
96. | Meneses, F, Torres, AG, Trugo, NM. Influence of recent dietary intake on plasma and human milk levels of carotenoids and retinol in Brazilian nursing women. Adv Exp Med Biol. 2004. 554:351–4. doi:10.1007/978-1-4757-4242-8_39.15384599 | Intervention/Exposure
97. | Metcalfe, JR, Marsh, JA, D’Vaz, N, Geddes, DT, Lai, CT, Prescott, SL, Palmer, DJ. Effects of maternal dietary egg intake during early lactation on human milk ovalbumin concentration: a randomized controlled trial. Clin Exp Allergy. 2016. 46:1605–1613. doi:10.1111/cea.12806.27562481 | Intervention/Exposure
98. | Meyer, KM, Mohammad, M, Bode, L, Chu, DM, Ma, J, Haymond, M, Aagaard, K. Maternal diet structures the breast milk microbiome in association with human milk oligosaccharides and gut-associated bacteria. American journal of obstetrics and gynecology. Conference: 37th annual meeting of the society for maternal-fetal medicine: the pregnancy meeting. United states. Conference start: 20170123. Conference end: 20170128. 2017. 216:S15. | Study Design; Publication Status
99. | Meyer, KM, Mohammad, M, Ma, J, Chu, D, Haymond, M, Aagaard, K. Maternal diet alters the breast milk microbiome and microbial gene content. American journal of obstetrics and gynecology. 2016. 214:S47–S48. | Study Design
100. | Minato, T, Nomura, K, Asakura, H, Aihara, A, Hiraike, H, Hino, Y, Isojima, T, Kodama, H. Maternal Undernutrition and Breast Milk Macronutrient Content Are Not Associated with Weight in Breastfed Infants at 1 and 3 Months after Delivery. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16183315. | Intervention/Exposure
101. | Modification of docosahexaenoic acid composition of milk from women who received DHA from a milk formula during the pregnancy and breastfeeding period. Annals of nutrition & metabolism. 2017. Conference: 21st International Congress of Nutrition, ICN 2017. Argentina. 71:506. doi:10.1159/000480486. | Study Design; Conference
102. | Mojska, H, Socha, P, Socha, J, Soplinska, E, Jaroszewska-Balicka, W, Szponar, L. Trans fatty acids in human milk in Poland and their association with breastfeeding mothers’ diets. Acta Paediatr. 2003. 92:1381–7.14971786 | Intervention/Exposure
103. | Moltó-Puigmartí, C, Plat, J, Mensink, RP, Müller, A, Jansen, E, Zeegers, MP, Thijs, C. FADS1 FADS2 gene variants modify the association between fish intake and the docosahexaenoic acid proportions in human milk. American Journal of Clinical Nutrition. 2010. 91:1368–1376. doi:10.3945/ajcn.2009.28789. | Intervention/Exposure
104. | Moro, GE, Bertino, E, Bravi, F, Tonetto, P, Gatta, A, Quitadamo, PA, Salvatori, G, Profeti, C, Di Nicola, P, Decarli, A, Ferraroni, M, Tavani, A, Stahl, B, Wiens, F. Adherence to the Traditional Mediterranean Diet and Human Milk Composition: Rationale, Design, and Subject Characteristics of the MEDIDIET Study. Front Pediatr. 2019. 7:66. doi:10.3389/fped.2019.00066.30931287 | Study Design; Intervention/Exposure
105. | Mueller, A, Steinhart, H, Thijs, C, Rist, L, Simões-Wüst, AP, Huber, M. Trans fatty acids in human milk are an indicator of different maternal dietary sources containing trans fatty acids. Lipids. 2010. 45:245–251. doi:10.1007/s11745-010-3390-7.20148367 | Intervention/Exposure; Population
106. | Nct, . Does a Diet With the Recommended Amount of Polyunsaturated Fatty Acids, Increase Their Proportion in Maternal Milk?. Https://clinicaltrials.gov/show/nct03805997. 2019. | Study Design; Clinical Trial Registry
107. | Nct, . Effect of n-3 Polyunsaturated Fatty Acids Supplementation on Human Milk Composition of Lactating Women. Https://clinicaltrials.gov/show/nct01288313. 2011. | Study Design; Clinical Trial Registry
108. | Nct, . Is Dietary Manipulation of Human Milk Total Fat and Caloric Content Feasible?. Https://clinicaltrials.gov/show/nct00408980. 2006. | Study Design; Clinical Trial Registry
109. | Nct, . The Mediterranean Diet and Lactation Study: a Diet Study in Lactating Women. Https://clinicaltrials.gov/show/nct01459991. 2011. | Study Design; Publication Status
110. | Newburg, DS, Grave, G. Recent advances in human milk glycobiology. Pediatr Res. 2014. 75:675–9. doi:10.1038/pr.2014.24.24522101 | Study Design
111. | Nikniaz, L, Jr, Mahdavi, R, Arefhoesseini, SR, Sowti Khiabani, M. Association between fat content of breast milk and maternal nutritional status and infants’ weight in tabriz, iran. Malays J Nutr. 2009. 15:37–44.22691803 | Intervention/Exposure; Comparator
112. | Nikniaz, L, Mahdavi, R, Ostadrahimi, A, Hejazi, MA, Vatankhah, AM. Effects of synbiotic supplementation on total antioxidant capacity of human breastmilk. Breastfeed Med. 2013. 8:217–22. doi:10.1089/bfm.2012.0078.23398140 | Intervention/Exposure
113. | Nikniaz, L, Mahdavi, R, Ostadrahimi, A, Nikniaz, Z, Aliasgharzadeh, S. Does Maternal Synbiotic Supplementation Affect Conjugated Linoleic Acid Level in Breast Milk? A Randomized Placebo-Controlled Clinical Trial. Breastfeeding Medicine. 2018. 13:81–84. doi:10.1089/bfm.2017.0053.29130749 | Intervention/Exposure
114. | Nishimura, RY, Barbieiri, P, Castro, GS, Jordao, AA, Jr, Perdona GD, S, Sartorelli, DS. Dietary polyunsaturated fatty acid intake during late pregnancy affects fatty acid composition of mature breast milk. Nutrition. 2014. 30:685–9. doi:10.1016/j.nut.2013.11.002.24613435 | Intervention/Exposure
115. | Ohta, S, Ishizuka, D, Nishimura, H, Nakao, T, Aozasa, O, Shimidzu, Y, Ochiai, F, Kida, T, Nishi, M, Miyata, H. Comparison of polybrominated diphenyl ethers in fish, vegetables, and meats and levels in human milk of nursing women in Japan. Chemosphere. 2002. 46:689–96. doi:10.1016/s0045-6535(01)00233-8.11999792 | Intervention/Exposure
116. | Olafsdottir, AS, Thorsdottir, I, Wagner, KH, Elmadfa, I. Polyunsaturated fatty acids in the diet and breast milk of lactating icelandic women with traditional fish and cod liver oil consumption. Ann Nutr Metab. 2006. 50:270–6. doi:10.1159/000091685.16508255 | Comparator
117. | Olafsdottir, AS, Wagner, KH, Thorsdottir, I, Elmadfa, I. Fat-soluble vitamins in the maternal diet, influence of cod liver oil supplementation and impact of the maternal diet on human milk composition. Ann Nutr Metab. 2001. 45:265–72. doi:10.1159/000046737.11786649 | Intervention/Exposure
118. | Otto, SJ, Van Houwelingen, AC, Badart-Smook, A, Hornstra, G. Comparison of the peripartum and postpartum phospholipid polyunsaturated fatty acid profiles of lactating and nonlactating women. American Journal of Clinical Nutrition. 2001. 73:1074–1079. | Intervention/Exposure
119. | Paronen, J, Bjorksten, B, Hattevig, G, Akerblom, HK, Vaarala, O. Effect of maternal diet during lactation on development of bovine insulin-binding antibodies in children at risk for allergy. J Allergy Clin Immunol. 2000. 106:302–6. doi:10.1067/mai.2000.108110.10932074 | Intervention/Exposure
120. | Pawlak, R. To vegan or not to vegan when pregnant, lactating or feeding young children. Eur J Clin Nutr. 2017. 71:1259–1262. doi:10.1038/ejcn.2017.111.28745335 | Study Design
121. | Peng, Y, Zhou, T, Wang, Q, Liu, P, Zhang, T, Zetterström, R, Strandvik, B. Fatty acid composition of diet, cord blood and breast milk in Chinese mothers with different dietary habits. Prostaglandins Leukotrienes and Essential Fatty Acids. 2009. 81:325–330. doi:10.1016/j.plefa.2009.07.004. | Population; Outcome
122. | Qian, J, Chen, T, Lu, W, Wu, S, Zhu, J. Breast milk macro- and micronutrient composition in lactating mothers from suburban and urban Shanghai. J Paediatr Child Health. 2010. 46:115–20. doi:10.1111/j.1440-1754.2009.01648.x.20105254 | Outcome
123. | Quinn, E, Kuzawa, C. A dose-response relationship between fish consumption and human milk DHA content among Filipino women in Cebu City, Philippines. Acta Paediatrica. 2012. 101:e439–45. doi:10.1111/j.1651-2227.2012.02777.x.22759234 | Intervention/Exposure
124. | Quinn, EA, Largado, F, Power, M, Kuzawa, CW. Predictors of breast milk macronutrient composition in Filipino mothers. Am J Hum Biol. 2012. 24:533–40. doi:10.1002/ajhb.22266.22434662 | Intervention/Exposure
125. | Rachmel, A, Steinberg, T, Ashkenazi, S, Sela, BA. Cobalamin deficiency in a breast-fed infant of a vegetarian mother. Isr Med Assoc J. 2003. 5:534–6.12901258 | Study Design
126. | Ramani, S. Multidisciplinary Studies on Rotavirus-Human Milk Oligosaccharide Interactions. Breastfeed Med. 2018. 13:S9–s10. doi:10.1089/bfm.2018.29074.sjr.29624419 | Study Design
127. | Reghu, A, Hosdurga, S, Sandhu, B, Spray, C. Vitamin B12 deficiency presenting as oedema in infants of vegetarian mothers. Eur J Pediatr. 2005. 164:257–8. doi:10.1007/s00431-004-1616-5.15660229 | Study Design
128. | Rist, L, Mueller, A, Barthel, C, Snijders, B, Jansen, M, Simoes-Wust, AP, Huber, M, Kummeling, I, von Mandach, U, Steinhart, H, Thijs, C. Influence of organic diet on the amount of conjugated linoleic acids in breast milk of lactating women in the Netherlands. Br J Nutr. 2007. 97:735–43. doi:10.1017/s0007114507433074.17349086 | Intervention/Exposure
129. | Sabel, KG, Lundqvist-Persson, C, Bona, E, Petzold, M, Strandvik, B. Fatty acid patterns early after premature birth, simultaneously analysed in mothers’ food, breast milk and serum phospholipids of mothers and infants. Lipids in Health and Disease. 2009. 8. doi:10.1186/1476-511X-8-20. | Intervention/Exposure; Population
130. | Samur, G, Topcu, A, Turan, S. Trans fatty acids and fatty acid composition of mature breast milk in turkish women and their association with maternal diet’s. Lipids. 2009. 44:405–13. doi:10.1007/s11745-009-3293-7.19280240 | Intervention/Exposure; Comparator
131. | Sartorelli, DS, Nishimura, RY, Castro, GSF, Barbieri, P, Jordão, AA. Validation of a FFQ for estimating ω-3, ω-6 and trans fatty acid intake during pregnancy using mature breast milk and food recalls. European Journal of Clinical Nutrition. 2012. 66:1259–1264. doi:10.1038/ejcn.2012.127.22990856 | Intervention/Exposure
132. | Scopesi, F, Ciangherotti, S, Lantieri, PB, Risso, D, Bertini, I, Campone, F, Pedrotti, A, Bonacci, W, Serra, G. Maternal dietary PUFAs intake and human milk content relationships during the first month of lactation. Clin Nutr. 2001. 20:393–7. doi:10.1054/clnu.2001.0464.11534933 | Intervention/Exposure; Comparator
133. | Shoff, SM, Lai, HJ. Essential fatty acid content appears low in breast milk and diet of mothers of infants with CF. Pediatric pulmonology. 2016. Conference: 30th Annual North American Cystic Fibrosis Conference. United States. Conference Start: 20161027. Conference End: 20161029. 51:430. doi:10.1002/ppul.23576. | Study Design; Conference/poster
134. | Silva, MA, Soares, MM, Fonseca, PCA, Vieira, SA, Carvalho, CA, Amaral, RM, Franceschini, SDCC, Novaes, JF. Relationship between breastfeeding patterns and intake of vitamin A and iron in children 6-12 months. Cien Saude Colet. 2019. 24:4009–4018. doi:10.1590/1413-812320182411.05782018.31664374 | Intervention/Exposure; Population
135. | Silva, MHL, Silva, MTC, Brandão, SCC, Gomes, JC, Peternelli, LA, Franceschini, SDCC. Fatty acid composition of mature breast milk in Brazilian women. Food Chemistry. 2005. 93:297–303. doi:10.1016/j.foodchem.2004.09.026. | Intervention/Exposure
136. | Snoj Tratnik, J, Falnoga, I, Mazej, D, Kocman, D, Fajon, V, Jagodic, M, Stajnko, A, Trdin, A, Slejkovec, Z, Jeran, Z, Osredkar, J, Sesek-Briski, A, Krsnik, M, Kobal, AB, Kononenko, L, Horvat, M. Results of the first national human biomonitoring in Slovenia: Trace elements in men and lactating women, predictors of exposure and reference values. Int J Hyg Environ Health. 2019. 222:563–582. doi:10.1016/j.ijheh.2019.02.008.30878540 | Intervention/Exposure
137. | Stendell-Hollis, NR, Thompson, PA, West, JL, Wertheim, BC, Thomson, CA. A comparison of mediterranean-style and mypyramid diets on weight loss and inflammatory biomarkers in postpartum breastfeeding women. Journal of Women’s Health. 2013. 22:48–57. doi:10.1089/jwh.2012.3707. | Outcome
138. | Storck Lindholm, E, Strandvik, B, Altman, D, Möller, A, Palme Kilander, C. Different fatty acid pattern in breast milk of obese compared to normal-weight mothers. Prostaglandins Leukotrienes and Essential Fatty Acids. 2013. 88:211–217. doi:10.1016/j.plefa.2012.11.007. | Intervention/Exposure
139. | Stoutjesdijk, E, Schaafsma, A, Dijck-Brouwer, DAJ, Muskiet, FAJ. Iodine status during pregnancy and lactation: a pilot study in the Netherlands. Neth J Med. 2018. 76:210–217.30019676 | Intervention/Exposure
140. | Su, LL, Sk, TC, Lim, SL, Chen, Y, Tan, EA, Pai, NN, Gong, YH, Foo, J, Rauff, M, Chong, YS. The influence of maternal ethnic group and diet on breast milk fatty acid composition. Ann Acad Med Singapore. 2010. 39:675–5.20957301 | Intervention/Exposure
141. | Taghipour, S, Nikniaz, L, Mahavi, R, Ostadrahimi, A, Nikniaz, Z. Synbiotic supplementation is not effective on breast milk selenium concentrations and growth of exclusively breast fed infants: a pilot study. Int J Vitam Nutr Res. 2019. doi:10.1024/0300-9831/a000549. | Intervention/Exposure
142. | Tavares, MP, Devincenzi, MU, Sachs, A, de Vilhena Abrão, ACF. Nutritional status and diet quality of nursing mothers on exclusive breastfeeding. Acta Paulista de Enfermagem. 2013. 26:294–298. | Outcome
143. | Tawfeek, HI, Muhyaddin, OM, al-Sanwi, HI, al-Baety, N. Effect of maternal dietary vitamin C intake on the level of vitamin C in breastmilk among nursing mothers in Baghdad, Iraq. Food Nutr Bull. 2002. 23:244–7. doi:10.1177/156482650202300302.12362586 | Intervention/Exposure; Country
144. | Tiangson, CLP, Gavino, VC, Gavino, G, Panlasigui, LN. Docosahexaenoic acid level of the breast milk of some Filipino women. International Journal of Food Sciences and Nutrition. 2003. 54:379–386. doi:10.1080/0963748031000092152.12907409 | Intervention/Exposure
145. | Urwin, HJ, Miles, EA, Noakes, PS, Kremmyda, LS, Vlachava, M, Diaper, ND, Perez-Cano, FJ, Godfrey, KM, Calder, PC, Yaqoob, P. Salmon consumption during pregnancy alters fatty acid composition and secretory IgA concentration in human breast milk. J Nutr. 2012. 142:1603–10. doi:10.3945/jn.112.160804.22739373 | Intervention/Exposure
146. | Urwin, HJ, Zhang, J, Gao, Y, Wang, C, Li, L, Song, P, Man, Q, Meng, L, Froyland, L, Miles, EA, Calder, PC, Yaqoob, P. Immune factors and fatty acid composition in human milk from river/lake, coastal and inland regions of China. Br J Nutr. 2013. 109:1949–61. doi:10.1017/s0007114512004084.23148871 | Population
147. | Vähämiko, S, Isolauri, E, Poussa, T, Laitinen, K. The impact of dietary counselling during pregnancy on vitamin intake and status of women and their children. International Journal of Food Sciences and Nutrition. 2013. 64:551–560. doi:10.3109/09637486.2013.766153.23373762 | Intervention/Exposure
148. | Valent, F, Horvat, M, Mazej, D, Stibilj, V, Barbone, F. Maternal diet and selenium concentration in human milk from an Italian population. J Epidemiol. 2011. 21:285–92. doi:10.2188/jea.je20100183.21628842 | Intervention/Exposure
149. | Vaysse, C, Simon, N, Tressou, J, Pasteau, S, Buaud, B, Guesnet, P, Couedelo, L, Billeaud, C. Polyunsaturated fatty acids consumption in lactating women in France: The INCA 2 study and evolution of essential fatty acids composition in breast milk from 1997 to 2014. Cahiers de Nutrition et de Dietetique. 2019. 54:35–43. doi:10.1016/j.cnd.2018.11.004. | Not English
150. | Wan, ZX, Wang, XL, Xu, L, Geng, Q, Zhang, Y. Lipid content and fatty acids composition of mature human milk in rural North China. Br J Nutr. 2010. 103:913–6. doi:10.1017/s0007114509992455.19825220 | Intervention/Exposure; Outcome
151. | Williams, JE, Carrothers, JM, Lackey, KA, Beatty, NF, York, MA, Brooker, SL, Shafii, B, Price, WJ, Settles, ML, McGuire, MA, McGuire, MK. Human Milk Microbial Community Structure Is Relatively Stable and Related to Variations in Macronutrient and Micronutrient Intakes in Healthy Lactating Women. J Nutr. 2017. 147:1739–1748. doi:10.3945/jn.117.248864.28724659 | Intervention/Exposure
152. | Wong, VW, Ng, YF, Chan, SM, Su, YX, Kwok, KW, Chan, HM, Cheung, CL, Lee, HW, Pak, WY, Li, SY, Wong, MS. Positive relationship between consumption of specific fish type and omega-3 polyunsaturated fatty acids in milk of Hong Kong lactating mothers. Br J Nutr. 2019. doi:10.1017/s0007114519000801. | Intervention/Exposure
153. | Wu, TC, Lau, BH, Chen, PH, Wu, LT, Tang, RB. Fatty acid composition of Taiwanese human milk. J Chin Med Assoc. 2010. 73:581–8. doi:10.1016/s1726-4901(10)70127-1.21093826 | Intervention/Exposure
154. | Xiang, M, Alfven, G, Blennow, M, Trygg, M, Zetterstrom, R. Long-chain polyunsaturated fatty acids in human milk and brain growth during early infancy. Acta Paediatr. 2000. 89:142–7.10709881 | Intervention/Exposure
155. | Xiang, M, Harbige, LS, Zetterström, R. Breast milk levels of zinc and ω-6 polyunsaturated fatty acids and growth of healthy Chinese infants. Acta Paediatrica, International Journal of Paediatrics. 2007. 96:387–390. doi:10.1111/j.1651-2227.2006.00140.x. | Intervention/Exposure
156. | Xiang, M, Harbige, LS, Zetterstrom, R. Long-chain polyunsaturated fatty acids in Chinese and Swedish mothers: diet, breast milk and infant growth. Acta Paediatr. 2005. 94:1543–9. doi:10.1080/08035250500251601.16303692 | Intervention/Exposure; Country
157. | Xue, Y, Campos-Gimenez, E, Redeuil, KM, Leveques, A, Actis-Goretta, L, Vinyes-Pares, G, Zhang, Y, Wang, P, Thakkar, SK. Concentrations of Carotenoids and Tocopherols in Breast Milk from Urban Chinese Mothers and Their Associations with Maternal Characteristics: A Cross-Sectional Study. Nutrients. 2017. 9. doi:10.3390/nu9111229. | Intervention/Exposure
158. | Yalcin, SS, Yurdakok, K, Yalcin, S, Engur-Karasimav, D, Coskun, T. Maternal and environmental determinants of breast-milk mercury concentrations. Turk J Pediatr. 2010. 52:1–9.20402060 | Intervention/Exposure
159. | Yang, T, Zhang, Y, Ning, Y, You, L, Ma, D, Zheng, Y, Yang, X, Li, W, Wang, J, Wang, P. Breast milk macronutrient composition and the associated factors in urban Chinese mothers. Chin Med J (Engl). 2014. 127:1721–5.24791881 | Intervention/Exposure; Comparator
160. | Yang, Z, Jiang, R, Chen, Q, Wang, J, Duan, Y, Pang, X, Jiang, S, Bi, Y, Zhang, H, Lonnerdal, B, Lai, J, Yin, S. Concentration of Lactoferrin in Human Milk and Its Variation during Lactation in Different Chinese Populations. Nutrients. 2018. 10. doi:10.3390/nu10091235. | Intervention/Exposure
161. | Yu, Y, Tao, S, Liu, W, Lu, X, Wang, X, Wong, M. Dietary intake and human milk residues of hexachlorocyclohexane isomers in two Chinese cities. Environ Sci Technol. 2009. 43:4830–5. doi:10.1021/es900082v.19673272 | Intervention/Exposure; Outcome
162. | Zhao, A, Ning, Y, Zhang, Y, Yang, X, Wang, J, Li, W, Wang, P. Mineral compositions in breast milk of healthy Chinese lactating women in urban areas and its associated factors. Chin Med J (Engl). 2014. 127:2643–8.25043082 | Intervention/Exposure
163. | Zielinska, MA, Hamulka, J, Wesolowska, A. Carotenoid content in breastmilk in the 3rd and 6th month of lactation and its associations with maternal dietary intake and anthropometric characteristics. Nutrients. 2019. 11. doi:10.3390/nu11010193. | Intervention/Exposure; Comparator

xvii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xviii Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: < 45 or > 65 percentage of energy;
- Protein (age 19 years and older): < 10 or > 35 percentage of energy;
- Fat (age 19 years and older): < 20 or > 35 percentage of energy.

Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press; 2002.

xix The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).