# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED DURING LACTATION AND HUMAN MILK COMPOSITION AND QUANTITY?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed during lactation and human milk composition and quantity?

### What is the answer to the question?

- No evidence is available to determine the relationship between maternal dietary patterns during lactation and human milk quantity.
- Insufficient evidence is available to determine the relationship between maternal diets differing in macronutrient distributions during lactation and human milk quantity.
- Insufficient evidence is available to determine the relationship between dietary patterns during lactation and total fat in human milk.
- Limited evidence suggests that maternal consumption of diets higher in fat (>35 percent fat) and lower in carbohydrate during lactation is related to higher total fat in human milk collected in the maternal postprandial period.
- Limited evidence suggests that certain maternal dietary patterns during lactation, including diets based on macronutrient distributions, are related to the relative proportions of saturated fat and monounsaturated fatty acids in human milk, and of polyunsaturated fatty acids in human milk collected in the maternal postprandial period.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and total protein concentration in human milk.
- Insufficient evidence is available to determine the relationship between maternal diets differing in macronutrient distribution during lactation and total protein concentration in human milk.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and bioactive proteins including alpha-lactalbumin, lactoferrin, casein, alpha (1) antitrypsin, osteopontin, secretory immunoglobulin A, lysozyme in human milk.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and human milk oligosaccharides.
- Insufficient evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamin B_12_ concentration in human milk.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamin C, choline and B vitamins (other than vitamin B_12_) in human milk.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamins A, D, E and K in human milk.
- No evidence is available to determine the relationship between maternal dietary patterns during lactation and iodine and selenium in human milk.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Pregnancy and Lactation Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- For the question on dietary patterns and human milk composition, the population of interest is generally healthy, lactating women.
- For the question on dietary patterns and human milk quantity, the population of interest is generally healthy, lactating women who are exclusively or predominantly feeding their child human milk.

### What evidence was found?

- This review includes seven articles published between 2009 and 2019.
- Two studies reported that a maternal diet higher in fat during lactation (i.e., more than 35 percent of total energy from fat, which is greater than the acceptable macronutrient distribution range resulted in higher total fat in human milk).
- Some studies showed that maternal dietary patterns during lactation were related to the relative proportions of saturated fat, monounsaturated fatty acids, and polyunsaturated fatty acids in human milk, which differed depending on whether milk samples were collected in a fed or fasted state.
- The body of evidence is limited in several ways:
  ○ Small sample sizes of the studies.
  ○ Inconsistencies in when and how human milk was collected across studies.
  ○ Concerns about potential bias of the studies, including the possibility that factors other than maternal diet impacted the outcomes.
  ○ Study populations that are not representative of the racial/ethnic or socioeconomic diversity of the U.S.
- There was insufficient or no evidence to assess the relationship between maternal dietary patterns during lactation and several outcomes, including human milk quantity and composition of total protein, water soluble vitamins (B, C, and choline), fat soluble vitamins (A, D, E, and K), minerals (iodine and selenium), human milk oligosaccharides, and bioactive proteins (alpha-lactalbumin, lactoferrin, casein, alpha (1) antitrypsin, osteopontin, secretory immunoglobulin A, and lysozyme).

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to November 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed during lactation and human milk composition and quantity?

### Conclusion statements and grades

No evidence is available to determine the relationship between maternal dietary patterns during lactation and human milk quantity. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between maternal diets differing in macronutrient distributions during lactation and human milk quantity. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between dietary patterns during lactation and total fat in human milk. (Grade: Grade not assignable)

Limited evidence suggests that maternal consumption of diets higher in fat (>35 percent fat) and lower in carbohydrate during lactation is related to higher total fat in human milk collected in the maternal postprandial period. (Grade: Limited)

Limited evidence suggests that certain maternal dietary patterns during lactation, including diets based on macronutrient distributions, are related to the relative proportions of saturated fat and monounsaturated fatty acids in human milk, and of polyunsaturated fatty acids in human milk collected in the maternal postprandial period. (Grade: Limited)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and total protein concentration in human milk. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between maternal diets differing in macronutrient distribution during lactation and total protein concentration in human milk. (Grade: Grade not assignable)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and bioactive proteins including alpha-lactalbumin, lactoferrin, casein, alpha (1) antitrypsin, osteopontin, secretory immunoglobulin A, lysozyme in human milk. (Grade: Grade not assignable)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and human milk oligosaccharides. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamin B_12_ concentration in human milk. (Grade: Grade not assignable)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamin C, choline, and B vitamins (other than vitamin B_12_) in human milk. (Grade: Grade not assignable)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and vitamins A, D, E, and K in human milk. (Grade: Grade not assignable)

No evidence is available to determine the relationship between maternal dietary patterns during lactation and iodine and selenium in human milk. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review includes three randomized controlled trials (RCTs) (four articles)^1–4^ and two cross sectional studies (three articles)^5–7^ published between 2009 and 2019.
- Studies included in this review assessed one of the following maternal interventions or exposures during lactation:
  ○ Dietary patterns (2 studies)
  ○ Diets based on macronutrient distributions outside of the acceptable macronutrient distribution range (AMDR) (3 studies)
- Two of the three RCTs reported that a maternal diet higher in fat during lactation (i.e., >35 percent of total energy from fat, which is greater than the AMDR) resulted in higher total fat in human milk.
- Some, but not all studies showed that maternal dietary patterns during lactation were related to the relative proportions of saturated fat (SAT), monounsaturated fatty acids (MUFAs), and polyunsaturated fatty acids (PUFAs) in human milk, which differed depending on whether milk samples were collected in a fed or fasted state.
- This body of evidence had notable limitations:
  ○ All RCTs had a small sample size (<20 participants) and none reported power analyses.
  ○ The cross-sectional studies did not account for most of the confounders.
  ○ One cross-sectional study reported that the participants differed on supplement intake during lactation, in addition to differing on dietary patterns. However, this was not controlled for in the statistical analysis or accounted for in the interpretation of the study findings.
  ○ The timing and methods of human milk collection were heterogeneous.
  ○ The study populations did not represent the racial/ethnic or socioeconomic diversity of the U.S. population.
- Insufficient or no evidence was available to assess the association between dietary patterns and several other outcomes, including human milk quantity and human milk composition of total protein, water soluble vitamins (B, C, and choline), fat soluble vitamins (A, D, E, and K), minerals (iodine and selenium), human milk oligosaccharides, and bioactive proteins (alpha-lactalbumin, lactoferrin, casein, alpha (1) antitrypsin, osteopontin, secretory immunoglobulin A (sIgA), and lysozyme).

### Description of the evidence

This systematic review included articles that address the relationship between dietary patterns and/or diets based on macronutrient distributions during lactation and human milk composition and quantity. The search included articles from countries categorized as high or very high on the Human Development Index (HDI)^ii^ and published from January 2000 to November 2019. Studies included generally healthy women during lactation at the time of the intervention or exposure. The following study designs were included: RCTs, non-randomized controlled trials, prospective and retrospective cohort studies, nested case-control studies, and cross-sectional studies. Due to changes in human milk composition during the first weeks after delivery, only studies assessing milk composition in mature milk (defined as milk produced ≥14 days postpartum) were included.

Dietary pattern was defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they were habitually consumed. At a minimum, there had to be a description of the foods and beverages in the pattern. It may have been measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials.

Studies assessing diets based on macronutrient distributions outside of the AMDR had to include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and include at least one macronutrient outside of the AMDR. Macronutrient percentages of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: < 45 or > 65 percent of energy;
- Protein for ≥ 19 years: < 10 or > 35 percent of energy;
- Fat for ≥ 19 years: < 20 or > 35 percent of energy

The outcomes considered in this review were human milk composition (specifically, macronutrients (fatty acids and total protein), water soluble vitamins (B, C, and choline), fat soluble vitamins (A, D, E, and K), selected minerals (iodine and selenium), human milk oligosaccharides, selected bioactive proteins (alpha-lactalbumin, lactoferrin, casein, alpha (1) antitrypsin, osteopontin, sIgA, lysozyme) and human milk quantity.

In total, seven articles from five different studies were included in the body of evidence. The evidence in this review is presented based on the exposure: 1) Dietary patterns; 2) Diets based on macronutrient distributions.

#### Dietary patterns

The baseline characteristics and study findings are presented in Table 1 and Table 2. Three articles from two cross-sectional studies assessed the association between dietary patterns during lactation and human milk composition.^5–7^ One study was conducted in the U.S. and produced two articles from the same sample^5,6^ and another study was conducted in China.^7^ The baseline sample sizes in the China^7^ and the U.S. studies^5,6^ were 287 and 74, respectively.

The participants in the U.S. study were predominantly White, well-educated and had a mean age of 32 years.^5,6^ The Chinese study participants had a mean age of 29.8 years, were 100 percent Chinese Han, and were predominantly from middle-to-higher income households. Mean prepregnancy BMI in the Chinese study was 20.6 kg/m^2^. In the U.S. study, the mean prepregnancy BMI was higher, though mostly within the healthy range, and there was a significant difference between the comparison groups, with vegans (22.8 kg/m^2^) having the lowest BMI when compared to vegetarians (23.9 kg/m^2^) and omnivores (25.8 kg/m^2^).

The Chinese study^7^ used a factor/cluster analysis to arrive at the following dietary patterns:

- Pattern 1: Mushroom food and algae, Meat, Marine products
- Pattern 2: Soybean products, Nuts, Dairy
- Pattern 3: Fruit, Vegetables
- Pattern 4: Grain/potato and beans, Eggs

In the U.S. study,^5,6^ during initial screening, participants self-identified their dietary pattern as vegan, vegetarian, or omnivore dietary patterns. Subsequently, a diet survey was administered to the enrolled participants, based on which the following dietary patterns were identified:

- Vegan: Never consumed meat and never or rarely consumed other animal products
- Vegetarian: Never or rarely consumed meat and sometimes or often consumed other animal products
- Omnivores: Consumed meat sometimes or often

All three articles assessed human milk composition. Specifically, two articles^6,7^ assessed fatty acid composition in human milk and one^5^ assessed vitamin B_12_ levels in human milk. None of the articles assessed human milk quantity.

#### Diets based on macronutrient distributions

Three RCTs^1–4^ assessed the association between diets based on macronutrient distributions and human milk composition and quantity. Two studies were conducted in the U.S.^1,2,4^ and one in Canada.^3^ The sample sizes in these studies were small, with < 20 participants in each study.

The mean age of the participants in the RCTs ranged from 27 years^4^ to 31.6 years.^3^ Maternal BMI was mostly within the healthy range, except for the study by Nasser et al,^3^ in which a mean BMI of 26 kg/m^2^ was reported. Only Mohammad et al^1,2^ reported race/ethnicity, noting that the study included 2 White, 2 African American, and 3 Hispanic mothers.

All RCTs that assessed diets based on macronutrient distributions were crossover studies that manipulated macronutrient percentage of energy above or below the AMDR for both fat and carbohydrate^1–3^ or fat^4^ only.

- Mohammad et al^1,2^ (baseline n=7) randomized mothers to a “H-F” diet (30 percent carbohydrate, 55 percent fat, 15 percent protein) or a “H-CHO” diet (60 percent carbohydrate, 25 percent fat, 15 percent protein) for 8 days each with a washout period of 1-2 weeks. In the “H-F” diet group, the percentage of energy from carbohydrate was below the AMDR and energy from fat was above the AMDR, whereas, in the “H-CHO” diet, both carbohydrate and fat were within the percentage of energy ranges of the AMDR.
- Nasser et al^3^ (baseline n=14) randomized mothers to a “high fat” diet (HF: 40.3 percent fat, 45.3 percent carbohydrate, 14.4 percent protein) or “low fat” diet (LF: 17.6 percent fat, 68 percent carbohydrate, 14.4 percent protein) diet for 4 days each, with a washout period of 3 days. In the “high fat” diet, percent of energy from fat was above the AMDR while percentage of energy from carbohydrates was within the AMDR; in the “low fat” diet, percentage of energy from fat was outside the AMDR and percentage of energy from carbohydrate was above the AMDR.
- Yahvah et al^4^ (baseline n=16) randomized mothers to a “low-fat dairy” (24 percent fat) or “full-fat dairy” (36 percent fat) diet for 14 days each with a 14 day washout period. The percentage of energy from fat was above the AMDR in the “full-fat dairy group;” the percentage of energy from fat in the “low-fat dairy” group was within the AMDR and percentage of energy from both carbohydrate and protein were within the AMDR for both dairy groups.

All of the RCTs assessed human milk composition^2–4^ and only one study assessed both human milk composition and quantity.^1^ The studies primarily measured total fat and fatty acid in human milk,^2–4^ although one study also measured protein content.^1^

### Evidence synthesis

With three RCTs^1–4^ and two cross-sectional studies,^5–7^ there is a smaller body of evidence available to examine the relationship between dietary patterns during lactation and human milk composition. Only one study^1^ assessed the relationship between diets based on macronutrient distributions during lactation and human milk quantity. Below, the results are grouped by two types of exposures – dietary patterns and diets based on macronutrient distributions.

#### Dietary patterns

Both studies that assessed dietary patterns were cross-sectional studies. Tian et al^7^ and Perrin et al^6^ assessed the association between dietary patterns and human milk fatty acids (Table 3). Pawlak et al^5^ was the only study that assessed vitamin B_12_ status in human milk. The findings are discussed below.

##### Dietary patterns and human milk fatty acids

Tian et al^7^ noted significant differences in proportions of certain fatty acids in human milk between women adhering to different dietary patterns. For example, women adhering to pattern 2 (soybean products, nuts, dairy) and pattern 4 (grain/potato and beans, eggs) had the same average amount of saturated fatty acids in human milk, which was significantly higher than the average among women who adhered to pattern 3 (fruit, vegetables) (p<0.001). Among the four groups, the proportion of PUFAs in milk was the highest in women adhering to pattern 3 and lowest in those adhering to pattern 2 (p=0.025). Similarly, the proportion of omega-6 fatty acids in milk was highest in mothers adhering to pattern 1 (mushroom food and algae, meat, marine products) and lowest in those adhering to pattern 2 (p=0.038). There were no statistically significant differences in omega-3 fatty acids, omega-6 to omega-3 ratios, or proportion of MUFAs in the milk of mothers adhering to different dietary patterns, although the last of these indices approached significance (p=0.053).

Perrin et al^6^ reported significant differences in human milk composition between mothers adhering to different dietary patterns. Specifically, milk from mothers adhering to a vegan dietary pattern, when compared to that of mothers adhering to vegetarian or non-vegetarian dietary patterns, had significantly higher unsaturated fatty acids (p<0.001) and total omega-3 fatty acids (p<0.001), and lower saturated fat (p<0.001), trans fat (p<0.001), omega-6 to omega-3 ratios (p<0.001) and linoleic acid to α-linolenic acid ratios (p<0.001). The significant difference in omega-3 fatty acids was driven by a higher percentage of α-linolenic acid, with no difference noted in eicosapentaenoic acid (EPA) and docosahexaenoic acid (DHA) across different maternal dietary patterns. Similarly, there were no differences in omega-6 fatty acids (except γ-linolenic acid), total long chain, or total medium chain fatty acids by maternal dietary patterns.

Summary: The studies discussed above were heterogeneous in dietary patterns methodology. Specifically, Tian et al^7^ used factor analysis to arrive at the dietary patterns, whereas Perrin et al^6^ used an ‘other’ method that relied on grouping women into their respective patterns based on their response to a diet survey. Both studies reported that saturated fat and some of the unsaturated fat in human milk varied significantly across dietary patterns, but the heterogeneity between studies in terms of both the dietary patterns and fatty acid assessment preclude a true comparison and pooling of the study findings.

##### Dietary patterns and human milk vitamin B_12_

Pawlak et al^5^ assessed human milk vitamin B_12_ levels in women adhering to who vegan, vegetarian and non-vegetarian dietary patterns. There were no significant differences in the vitamin B_12_ levels in human milk across these three groups. Thirteen of the 74 women had low vitamin B_12_ concentration (< 310 pmol/L) in human milk, although this did not differ by dietary pattern. Similarly, eight women had human milk vitamin B_12_ above the assay detection threshold (> 1122 pmol/L), and there was no significant difference between the groups. An important context to consider is that almost half of the vegan women (46.2 percent) consumed vitamin B_12_ supplements, whereas only 27.3 percent and 3.9 percent of the vegetarian and non-vegetarian women, respectively, consumed supplements (p=0.001). However, this was not accounted for in the analysis.

#### Diets based on macronutrient distributions

All studies that assessed diets based on macronutrient distributions were RCTs. In terms of outcomes, only one study assessed human milk quantity. All three studies looked at the association between macronutrient distribution in the diet and human milk fatty acids and the findings are discussed below by individual study, and followed by the synthesis (Table 4).

Mohammad et al,^1^ the only study that assessed human milk quantity, concluded that there was no significant difference in human milk production in mothers when consuming a “H-CHO” diet (60 percent carbohydrate, 25 percent fat, 15 percent protein) vs. “H-F” diet (30 percent carbohydrates, 55 percent fat and 15 percent protein). There was also no significant effect of the diet on protein in human milk. However, the milk fat concentration and milk fat content per day was significantly higher when consuming “H-F” diet (p<0.05).

Mohammad et al^2^ reported that the total fat in human milk was significantly higher with the “H-F” diet (30 percent carbohydrates, 55 percent fat and 15 percent protein), when compared to the “H-CHO” diet (60 percent carbohydrate, 25 percent fat, 15 percent protein), but this was only observed in the fed state and not after overnight fasting Human milk ∑C2:C14 fatty acid content differed significantly and was mostly higher when women consumed the “H-CHO” vs. “H-F” diet, during both fasted and fed states. Specifically, saturated fatty acids during fed (C4:0, C6:0, C8:0, C10:0, C12:0, C14:0, C16:0 and C18:0) and fasted states (C4:0, C6:0, C8:0, C10:0, C14:0) were higher in the milk of the mothers during the “H-CHO” diet, as opposed to the “H-F” diet. Despite the differences in individual saturated fatty acids, ∑SAT was not significantly higher when women consumed either the “H-CHO” or “H-F” diet, irrespective of being in fed or fasted states. However, the percent total fat of ∑SAT in human milk was significantly higher during the “H-CHO” diet in the fed state only.

Human milk ∑MUFA was significantly higher when women consumed the “H-F” diet as opposed to the “H-CHO” diet, in the fed state. There was, however, no difference in the fasted state. The percent total fat of ∑MUFA was significantly higher during the “H-F” diet in both fed and fasted states. Similarly, women during their “H-F” diet had higher milk ∑PUFA (specifically C20:2, C20:3, C20:4, C20:5, C22:6) when compared to the “H-CHO” diet. This difference was noted only in the fed state and not in the fasted state. No statistically significant differences were observed in the percent total fat of ∑PUFA when consuming “H-CHO” vs. “H-F” diets, in both fed and fasted states.

Nasser et al^3^ noted no significant differences in the mean total concentrations of saturated fatty acids, MUFA, and PUFA when women were consuming the “low fat” (68 percent carbohydrate, 17.6 percent fat, 14.4 percent protein) vs. “high fat” diet (45.3 percent carbohydrate, 40.3 percent fat 14.4 percent protein). However, the concentrations of total medium chain fatty acids (C8:0-C14:0) were significantly higher during the “low fat” vs. “high fat” diet (p=0.01). Similarly, certain n-6 fatty acids (γ-linolenic acid, dihomo- γ-linolenic acid, and arachidonic acid) were significantly higher with the “low fat” diet when compared to the “high fat” diet. α-linolenic acid (C18:3n-3) in milk was higher when mothers consumed the “high fat” vs. “low fat” diet.

Yahvah et al^4^ reported that the total lipids in human milk were significantly higher with a “full-fat dairy” diet (48 percent carbohydrate, 36 percent fat, 17 percent protein) when compared to a “low-fat dairy” diet (57 percent carbohydrates, 24 percent fat, 20 percent protein). Saturated fat was higher in the milk of women consuming a “full-fat dairy” diet vs. “low-fat dairy” diet (specifically, C12:0, C13:0, iso-C14:0, C15:0, iso-C15:0, anteiso-C15:0, C16:0, iso-C16:0, C17:0, iso-C17:0, anteiso-C17:0, C18:0, anteiso 18:0, iso-18:0, C20:0). Many of the MUFAs in the milk did not differ based on the intervention, with the exception of C14:1, C16:1t9, and C18:1t11, which were higher in the milk of women consuming the full-fat dairy diet. Most of the PUFAs varied with the dietary intervention, with C16:2 and C18:2 c9,t11 higher in milk after women had the “full-fat dairy” diet; on the other hand, α-linolenic acid was higher in milk after women had the “low-fat dairy” diet.

Summary: Across four articles, Mohammad et al^1^ was the only study that reported human milk quantity and there was no statistically significant relationship between diet macronutrient distribution and human milk volume. Mohammad et al (2009)^1^ and Mohammad et al (2014)^2^ (both from the same trial) and Yahvah et al^4^ reported that total milk fat was higher after consuming the “H-F” diet or the “full-fat dairy” diet.

- Saturated fatty acid: Both Mohammad et al^2^ and Nasser et al^3^ reported no differences in total saturated fatty acids. However, when mothers consumed a “H-CHO” diet (60 percent carbohydrate, 25 percent fat, 15 percent protein)^2^ or a “low fat” diet (68 percent carbohydrate, 17.6 percent fat, 14.4 percent protein)^3^, their milk was higher in certain individual saturated fatty acids (Table 4). Yahvah et al^4^ did not report total saturated fatty acids, but noted that certain saturated fatty acids were higher when mothers consumed the “low-fat dairy” diet (57 percent carbohydrate, 24 percent fat, 20 percent protein) and others were higher when they consumed the “full-fat dairy” diet (48 percent carbohydrate, 36 percent fat, 17 percent protein).
- MUFAs: Mohammad et al^2^ reported that after the “H-F” diet (30 percent carbohydrates, 55 percent fat and 15 percent protein), human milk was significantly higher in MUFAs. Nasser et al^3^ reported no differences in total MUFAs in milk when mothers consumed the “low fat” (68 percent carbohydrate, 17.6 percent fat, 14.4 percent protein) vs. “high fat” diet (45.3 percent carbohydrate, 40.3 percent fat 14.4 percent protein), but noted that palmitoleic acid (C16:0) was higher during the “low fat” diet and arachidic acid (C20:0) was higher during the “high fat” diet. Yahvah et al^4^ did not report total MUFAs, but noted that when mothers consumed the “full-fat dairy” diet (48 percent carbohydrate, 36 percent fat, 17 percent protein), their milk was higher in certain MUFAs (C14:1, C16:1t, C18:1t11), whereas C12:0 and iso-17:0 was higher with the “low-fat dairy” diet (57 percent carbohydrates, 24 percent fat, 20 percent protein).
- PUFAs: Mohammad et al^2^ reported that after mothers consumed the “H-F” diet (30 percent carbohydrate, 55 percent fat and 15 percent protein), human milk was significantly higher in PUFAs. Nasser et al^3^ reported no differences in total PUFAs in human milk when mothers consumed the “low fat” (68 percent carbohydrate, 17.6 percent fat, 14.4 percent protein) vs. “high fat” diet (45.3 percent carbohydrate, 40.3 percent fat, 14.4 percent protein), but noted that mothers had higher α-linolenic acid (C18:3n-3) in milk when consuming the latter diet. On the other hand, γ-linoleic acid (C18:3n-6), dihomo γ-linoleic acid (C20:3n-6), and arachidonic acid (C20:4n-6) were higher when mothers consumed the “low fat” diet. Yahvah et al^4^ did not report total PUFAs, but noted that the milk of mothers consuming the “low-fat dairy” diet (57 percent carbohydrate, 24 percent fat, 20 percent protein) had higher linoleic acid (C18:2) and α-linolenic acid (C18:3n:3).

#### Assessment of the evidence^iii^

The following conclusion statement was supported by three RCTs and was graded “limited.” The individual grading elements are discussed below and summarized in Table 5.

“Limited evidence suggests that maternal consumption of diets higher in fat (>35 percent fat) and lower in carbohydrate during lactation is related to higher total fat in human milk collected in the maternal postprandial period.”

As outlined and described below, the body of evidence examining diets based on macronutrient distributions during lactation and human milk composition was assessed for the following elements used when grading the strength of evidence.

- Risk of bias was graded as limited
  ○ Study Design: All studies included in this body of evidence were RCTs, but minimal information on participant randomization methods was reported. Other factors such as maternal BMI and nutritional status prior to enrollment could have influenced the study findings, but are not discussed or accounted for in the articles.
  ○ Intervention/Exposure: Although all 3 RCTs were designed to assess the impact of maternal diet (manipulating outside of AMDR) on human milk fat composition, articles reported minimal information on the foods and types of fat in the intervention diets. Little information was provided on supplement use and the potential influence on the study findings.
  ○ Outcome: There was variability across studies in how and when milk was collected. For example, Mohammad et al^1,2^ collected milk when mothers were in fed and fasted states and Mohammad et al^2^ presented the results stratified by those two states. However, none of the other studies clarified the maternal fed state during milk collection, thus making it difficult to compare the study findings. Studies also differed on how milk was collected. For example, Nasser et al^3^ reported that hind milk was collected, Yahvah et al^4^ reported complete extraction of milk from one breast, and Mohammad et al^1,2^ noted that 2.5 milliliters was extracted at the beginning, middle, and end of each feeding.
  ○ Timing: The stage of lactation was somewhat different between the studies. While lactation stage of women in the Mohammad et al^1,2^ and Nasser et al^3^ studies overlapped (6 to 14 weeks and 2 to 6 months postpartum, respectively), Yahvah et al^4^ recruited women who were at least 4 months postpartum and the upper bound was not specified.
- Consistency was graded as moderate. Two of the three RCTs noted a significant relationship between a higher fat diet and higher total fat in human milk. The remaining study^3^ noted that the average fat content (assessed in the hind milk) was non-significantly greater in the higher fat diet, which is consistent with other findings.
- Directness was graded as strong. These RCTs were designed to address the question on the relationship between diets with macronutrient distributions outside of the AMDR and human milk composition and quantity. Thus, the primary objectives of the studies aligned well with the systematic review question.
- Precision was graded as limited. All the three RCTs each had a small sample size (<20 participants) and none reported power analyses. Despite this, the magnitude and direction of the results were consistent across studies (as discussed above). None of the studies unduly influenced the findings of this systematic review and removing a single study from the body of evidence would unlikely change the conclusions.
- Generalizability was graded as limited. The studies included in this body of evidence were conducted in the U.S. and Canada. However, none of them reported the socioeconomic status (SES) of the participants and Nasser et al^3^ and Yahvah et al^4^ did not report the race/ethnicity of participants. Considering the small sample size of the RCTs and lack of information on SES and race/ethnicity, it is unclear whether the studies were representative of the general U.S. population.

The following conclusion statement is supported by three RCTs and two cross-sectional studies. The individual grading elements are discussed below and summarized in Table 5 and Table 6.

“Limited evidence suggests that certain maternal dietary patterns during lactation, including diets based on macronutrient distributions, are related to the relative proportions of saturated fat and monounsaturated fatty acids in human milk, and of polyunsaturated fatty acids in human milk collected in the maternal postprandial period.”

As outlined and described below, the body of evidence examining dietary patterns during lactation, including diets based on macronutrient distributions, and human milk composition was assessed for the following elements used when grading the strength of evidence.

- Risk of bias was graded limited for the RCTs and limited for the cross-sectional studies. The following bullets address the risk of bias for the 2 cross-sectional studies. For the RCTs, the readers are referred to the risk of bias in the previous section, as the same RCTs contributed to the evidence for both conclusion statements.
  ○ Study Design: Both Tian et al^7^ and Perrin et al^6^ selected participants using convenience sampling, which may have introduced selection bias. Related to participant selection, Perrin et al^6^ noted that nearly half of the participants (approximately 43 percent) who were invited to participate did not respond and it is unclear whether their baseline characteristics were different from those of women who participated. The mothers in the Perrin et al^6^ study also differed significantly by diet group in baseline BMI, which could have influenced the study findings. Tian et al^7^ did not adjust for a majority of key confounders and Perrin et al^6^ accounted for none of the key confounders identified in the analytic framework.
  ○ Exposure: Both studies assessed diet at a single time point. In the study by Perrin et al,^6^ participants self-reported their dietary data based on a questionnaire that collected information on certain foods and food groups. Also, it is unclear if the questionnaires used in either study were validated. In the Perrin et al study^6^, there were statistically significant differences in maternal DHA/EPA supplement intake between groups (vegan: 26.9 percent, vegetarian: 9.1 percent, omnivore: 3.9 percent), in addition to consuming different dietary patterns. However, this was not accounted for in the analysis and made it difficult to determine the effect of the dietary pattern.
  ○ Outcome: Milk was collected at a single time point. Although milk was collected mid-morning in both the studies, it is unclear whether mothers were in fed or fasted states at the time of collection. Similar to RCTs, both studies differed on how milk was collected. For example, Perrin et al^6^ noted that participants provided samples by complete expression of a single breast, whereas, Tian et al^7^ reported that 30 milliliters of milk was collected from study participants.
  ○ Timing: The stage of lactation within and between studies varied widely. For example, mothers in the Tian et al^7^ study were 22 days to 6 months postpartum at the time of data collection. Perrin et al^6^ reported a statistically significant difference in the stage of lactation between exposure groups, ranging from 27.5 to 54.6 weeks postpartum.
- Consistency was graded as moderate for the RCTs and the cross-sectional studies were given a ‘grade not assignable’ rating. While the studies consistently noted associations between maternal dietary patterns/diets based on macronutrient distributions and human milk fatty acids, the findings were heterogeneous regarding the magnitude and directionality of associations for saturated fat, MUFAs, and PUFAs. For this reason, this element was rated ‘grade not assignable.’
- Directness was graded as strong for the RCTs and moderate for the cross-sectional studies. As discussed previously, the primary objective of the RCTs aligned well with the systematic review question. For the cross-sectional studies, the study by Tian et al^7^ seems to have been designed to assess the association between maternal dietary patterns during lactation and composition of fatty acids in human milk. However, it is less clear for Perrin et al^6^ because the other article from this study (Pawlak et al^5^) reported that the power calculations were based on detecting differences in vitamin B_12_ in human milk, suggesting that the Perrin et al^6^ article could have been a secondary analysis.
- Precision was graded as limited for both RCTs and cross-sectional studies. The cross-sectional studies each had a reasonable sample size (n=274^7^ and n=74^6^), although neither reported power calculations. The RCTs had small sample sizes (<20 participants). None of the studies unduly influenced the findings of this systematic review and removing one or more studies would not likely influence the conclusions.
- Generalizability was graded as limited for both RCTs and cross-sectional studies. Although the RCTs were conducted in the U.S. and Canada, the studies reported minimal data on SES and race/ethnicity of the participants. The study by Perrin et al^6^ was conducted in the U.S. and most of the participants were highly educated White women. The study by Tian et al^7^ was conducted in China, with 100 percent Han Chinese women from mid-to-upper SES. Based on these characteristics, it is unclear if the findings would apply to a diverse sample of U.S. mothers.

The bodies of evidence that assessed the relationship between 1) maternal dietary patterns and vitamin B_12_ in human milk, 2) maternal diets differing in macronutrient distributions and total protein concentration or human milk quantity were rated ‘grade not assignable’ primarily because only one study met the inclusion criteria.

Publication bias is always a concern; however, given that these studies were smaller in size and many of them had null findings, publication bias did not seem to be a serious concern in this evidence.

### Research recommendations

- Include diverse populations from the U.S. and elsewhere with varying age groups and different racial/ethnic and socioeconomic backgrounds.
- Foster collaborative efforts to score dietary patterns consistently, so that they can be compared and reproduced across studies.
- Assess other nutrients (particularly water- and fat-soluble vitamins), human milk oligosaccharides, and bioactive proteins in human milk.
- Use a consistent methodology for human milk collection and assessment.
- Include well-designed and sufficiently powered RCTs.
- Adjust for key confounding factors in observational studies including age, race/ethnicity, SES, anthropometry, smoking, parity, gestational age, and supplement intake during pregnancy and lactation.

### Included articles

1 Mohammad MA, Sunehag AL, Haymond MW. Effect of dietary macronutrient composition under moderate hypocaloric intake on maternal adaptation during lactation. Am J Clin Nutr. 2009;89(6):1821–1827. doi:10.3945/ajcn.2008.26877 19386740
2 Mohammad MA, Sunehag AL, Haymond MW. De novo synthesis of milk triglycerides in humans. Am J Physiol Endocrinol Metab. 2014;306(7):E838–847. doi:10.1152/ajpendo.00605.2013 24496312
3 Nasser R, Stephen AM, Goh YK, Clandinin MT. The effect of a controlled manipulation of maternal dietary fat intake on medium and long chain fatty acids in human breast milk in Saskatoon, Canada. Int Breastfeed J. 2010;5:3. doi:10.1186/1746-4358-5-3 20170476
4 Yahvah KM, Brooker SL, Williams JE, Settles M, McGuire MA, McGuire MK. Elevated dairy fat intake in lactating women alters milk lipid and fatty acids without detectible changes in expression of genes related to lipid uptake or synthesis. Nutr Res. 2015;35(3):221–228. doi:10.1016/j.nutres.2015.01.004 25661476
5 Pawlak R, Vos P, Shahab-Ferdows S, Hampel D, Allen LH, Perrin MT. Vitamin B-12 content in breast milk of vegan, vegetarian, and nonvegetarian lactating women in the United States. Am J Clin Nutr. 2018;108(3):525–531. doi:10.1093/ajcn/nqy104 29931273
6 Perrin MT, Pawlak R, Dean LL, Christis A, Friend L. A cross-sectional study of fatty acids and brain-derived neurotrophic factor (BDNF) in human milk from lactating women following vegan, vegetarian, and omnivore diets. Eur J Nutr. 2019;58(6):2401–2410. doi:10.1007/s00394-018-1793-z 30051170
7 Tian HM, Wu YX, Lin YQ, . Dietary patterns affect maternal macronutrient intake levels and the fatty acid profile of breast milk in lactating Chinese mothers. Nutrition. 2019;58:83–88. doi:10.1016/j.nut.2018.06.009 30391695

Table 1 Description of evidence on the relationship between dietary patterns during lactation and human milk composition^iv,v^

Study and Participant Characteristics | Intervention/Exposure and Outcomes | Results | Confounding and Study Limitations | Summary of findings
Factor/Cluster Analysis
Tian, 2019^7^; China Cross-sectional Study; Baseline N=287; Analytic N=274 (Attrition: 5%); - Maternal age: Mean ~29.8y; - Race/Ethnicity: 100% Chinese Han; - SES: Family income (yuan/mo; n(%)), P=0.28:; ○ <5000: 46 (16.8); ○ 5000-9999: 154 (56.2); ○ ≥10000: 74 (27.0); - Anthropometry (median), P=0.89:; ○ GWG: ~16.4 kg, P=0.78; ○ Prepregnancy BMI: ~20.6; - GA at birth: ~39.6wk; - Supplement intake during lactation: None | Dietary Pattern(s):; - Pattern 1: Mushroom food and algae, Meat, Marine products (n=66); - Pattern 2: Soybean products, Nuts, Dairy (n=63); - Pattern 3: Fruit, Vegetables (n=73); - Pattern 4: Grain/potato and beans, Eggs (n=72); Dietary assessment methods:; Data was collected using a 24-h dietary recall questionnaire and 176 item FFQ by a trained investigator to estimate dietary patterns.The foods were combined to make 10 groups: grains/potatoes and beans, soy bean products, mushrooms and algae, fruits, vegetables, nuts, meat, eggs, marine products, and dairy products. These groups were assigned to 1 of 4 dietary patterns using a rotated component matrix.; Outcomes:; Human milk composition: Macronutrients: Fatty acid once during 22d to 6mo postpartum; Outcome assessment methods:; After discarding the first few drops, a total of 30 mL of milk was collected.The profile of fatty acid in human milk was detected by capillary gas chromatography and calculated with fatty acid methylesters (FAME) using the internal standard method. | Significant:; Human milk fatty acid proportions (%), Median (25th, 75th); - SAT, Kruksal-Wallis, P<0.001; ○ Pattern 1: 40.38 (37.41, 44.25); ○ Pattern 2: 42.92 (38.61, 49.62); ○ Pattern 3: 39.10 (34.65, 45.04); ○ Pattern 4: 42.92 (40.31, 49.93); - PUFAs, Kruksal-Wallis, P=0.025; ○ Pattern 1: 24.49 (21.73, 28.43); ○ Pattern 2: 22.09 (19.92, 27.08); ○ Pattern 3: 24.63 (20.37, 29.17); ○ Pattern 4: 22.77 (19.49, 26.38); - n-6 PUFAs, Kruksal-Wallis, P=0.038; ○ Pattern 1: 20.71 (18.11, 23.27); ○ Pattern 2: 18.24 (16.41, 22.71); ○ Pattern 3: 20.11 (17.33, 24.22); ○ Pattern 4: 18.49 (16.11, 21.89); Non-significant:; Human milk fatty acid proportions (%), Median (25th, 75th); - MUFAs, Kruksal-Wallis, P=0.053; ○ Pattern 1: 34.40 (31.20, 36.84); ○ Pattern 2: 33.53 (29.91, 36.42); ○ Pattern 3: 34.85 (31.39, 39.58); ○ Pattern 4: 33.45 (29.09, 35.39); - n-3 PUFAs, Kruksal-Wallis, P=0.29; ○ Pattern 1: 3.96 (2.70, 5.01); ○ Pattern 2: 3.55 (2.98, 4.46); ○ Pattern 3: 3.56 (2.32, 4.98); ○ Pattern 4: 3.86 (3.09, 4.56); - n-6/n-3 PUFAs, Kruksal-Wallis, P=0.34; ○ Pattern 1: 4.83 (3.80, 7.32); ○ Pattern 2: 4.76 (4.14, 6.30); ○ Pattern 3: 5.34 (3.74, 9.39); ○ Pattern 4: 4.69 (3.85, 5.74) | Key confounders accounted for:; Race/ethnicity, Anthropometry, GA; Limitations:; - Time of exposure measurement relative to outcome is not clear; - Lactation stage varies (22 d to 6 mo); - Single measurement of exposure and outcome; - Power calculation NR | Maternal dietary patterns were associated with human milk saturated fatty acids, PUFAs, and n-6 PUFA proportions, but not with MUFAs, n-3 PUFAs, or n-6/n-3 PUFA proportions.
Other Dietary Pattern Analysis
Pawlak, 2018^5^; U.S. Cross-sectional Study; Baseline N=74; Analytic N=74 (Attrition: 0%); - Maternal age: Mean ~32y; - Race/Ethnicity:; ○ White=85.1%; ○ Mixed/Other=9.4%; ○ Hispanic=4%; ○ Asian=1.4%; ○ Black=0%; - SES: Education:; ○ HS/GED/other: 2.7%; ○ Some college/ technical: 16.2%; ○ 4y college: 37.8%; ○ Graduate: 43.2%; - Anthropometry: BMI (mean± SD), P=0.02:; ○ Vegan: 22.8± 3.1; ○ Vegetarian: 23.9±3.8; ○ Nonveg: 25.8±4.5; - Parity: ~1.9; - Supplement intake during lactation, n (%); ○ B12, P=0.001: Vegan: 12 (46.2), Veg: 6 (27.3), Nonveg: 1 (3.9); ○ B-complex, P=0.771: Vegan: 2 (7.7), Veg: 0 (0), Nonveg: 1 (3.9); ○ Multivitamin, P=0.083: Vegan: 4 (15.4), Veg: 0 (0), Nonveg: 5 (19.2); ○ Prenatal, P=0.92: Vegan: 14 (53.9), Veg: 13 (59.1), Nonveg: 14 (53.8); ○ Any B-vitamin, P=0.09: Vegan: 24 (92.3), Veg: 16 (72.7), Nonveg: 18 (69.2) | Dietary Pattern(s):; - Vegan: Never consumed meat and never or rarely consumed other animal products (1 time/mo) (n=26); - Vegetarian: Never consumed meat and regularly consumed other animal products (n=22); - Nonvegetarian: Consumed meat sometimes or often (n=26); Dietary assessment methods:; Diet survey: Unclear timing and validation; Outcomes:; Human milk composition: Vitamin B_12_ assessment once at ~38.8wk postpartum; - Vegan: 36.6± 27.7wk; - Vegetarian: 54.6± 46.0wk; - Nonvegetarian: 27.5± 19.8wk; ○ Vegetarian vs Nonvegetarian, P<0.05; Outcome assessment methods:; Completely express the content of 1 breast in the morning (> 2h since the previous feeding). Competitive chemiluminescent enzyme immunoassay. Milk samples with vitamin B12 concentrations above upper detection limit assigned max value (1122 pmol/L) and flagged. | Significant: None; Non-significant:; Human milk B12 (pmol/L), Median (quartile 1, quartile 3):; Unadjusted: ANOVA P=0.89, Kruskal-Wallis P=0.94; - Vegan: 558 (331, 759);; - Vegetarian: 509 (368, 765 pmol/L);; - Nonvegetarian: 444 (355, 777); Adjusted (BMI, lactation stage) ANOVA: P=0.89; Human milk B12 >1122 pmol/L (%), P=0.72; - Vegan: 15.4; - Vegetarian: 9.1; - Nonvegetarian: 7.7; Human milk B12 <310 pmol/L (%), P=1.00; - Vegan: 19.2; - Vegetarian: 18.2; - Nonvegetarian: 15.4 | Key confounders accounted for: Anthropometry; Limitations:; - Baseline differences in maternal BMI, lactation stage and supplement use; - Majority of the participants (77.4%) reported using vitamin B12 supplements; - Only one time point of exposure and outcome measurement; - No validation of exposure assessment; - Unclear why 61 eligible participants did not respond and whether their characteristics were different from the participants that enrolled; - Stage of lactation was significantly different between the three groups | There was no significant difference between vitamin B_12_ levels in human milk between 3 dietary patterns (vegan, vegetarian and nonvegetarian)
Perrin, 2019^6^; U.S. Cross-sectional Study; Baseline N=74; Analytic N=74 (Attrition: 0%); - Maternal age: Mean ~31.95y; - Race/Ethnicity:; ○ White=85.1%; ○ Mixed/Other=9.4%; ○ Hispanic=4%; ○ Asian=1.4%; ○ Black=0%; - SES: Education:; ○ HS/GED/other: 2.7%; ○ Some college/ technical: 16.2%; ○ 4y college: 37.8%; ○ Graduate: 43.2%; - Anthropometry: BMI (mean± SD), P=0.02:; ○ Vegan: 22.8± 3.1; ○ Vegetarian: 23.9±3.8; ○ Nonveg: 25.8±4.5; - Parity: ~1.9; - Supplement intake during lactation, n (%):; ○ B12, P=0.001: Vegan: 12 (46.2), Veg: 6 (27.3), Nonveg: 1 (3.9); ○ B-complex, P=0.771: Vegan: 2 (7.7), Veg: 0 (0), Nonveg: 1 (3.9); ○ Multivitamin, P=0.083: Vegan: 4 (15.4), Veg: 0 (0), Nonveg: 5 (19.2); ○ Prenatal, P=0.92: Vegan: 14 (53.9), Veg: 13 (59.1), Nonveg: 14 (53.8); ○ Any B-vitamin, P=0.09: Vegan: 24 (92.3), Veg: 16 (72.7), Nonveg: 18 (69.2) | Dietary Pattern(s):; - Vegan: Never consumed meat and never or rarely consumed other animal products (1 time/mo) (n=26); - Vegetarian: Never consumed meat and regularly consumed other animal products (n=22); - Nonvegetarian: Consumed meat sometimes or often (n=26); Dietary assessment methods; Diet survey; Unclear timing and validation; Outcomes:; Human milk composition: Fatty acid once at ~38.8wk postpartum; - Vegan: 36.6± 27.7wk; - Vegetarian: 54.6± 46.0wk; - Nonvegetarian: 27.5± 19.8wk; ○ Vegetarian vs Nonvegetarian, P<0.05; Outcome assessment methods:; Completely express the content of 1 breast in the morning (> 2h since the previous feeding). Total fat measured by creamatocrit. The fatty acid present in the samples measured as fatty acid methyl esters according to Bannon et al method | Significant:; Data are median (IQR); Significance P<0.001 % SAT, ANOVA, P<0.001; - Vegan: 33.1 (6.2);; - Vegetarian: 40.0 (8.6);; - Nonvegetarian: 42.3 (8.4); % C15:0, Kruskal-Wallis, P<0.001; - Vegan: 0.06 (0.08); - Vegetarian: 0.24 (0.20); - Nonvegetarian: 0.26 (0.16); % C16:0, ANOVA, P<0.001; - Vegan: 13.32 (2.49); - Vegetarian: 18.57 (5.22); - Nonvegetarian: 20.02 (4.43); % C17:0, Kruskal-Wallis, P<0.001; - Vegan: 0.12 (0.02); - Vegetarian: 0.22 (0.11); - Nonvegetarian: 0.26 (0.07); % C18:0, ANOVA, P<0.001; - Vegan: 3.98 (1.27); - Vegetarian: 5.85 (2.52); - Nonvegetarian: 6.12 (1.72); % Unsaturated fat, ANOVA, P<0.001; - Vegan: 66.0 (6.5); - Vegetarian: 57.8 (9.8); - Nonvegetarian: 56.2 (8.5); % Total n-3 PUFAs, Kruskal-Wallis, P<0.001; - Vegan: 2.29 (0.77); - Vegetarian: 1.55 (0.56); - Nonvegetarian: 1.46 (0.94); % ALA (C18:3 cis), Kruskal-Wallis, P<0.001; - Vegan: 2.09 (0.75); - Vegetarian: 1.40 (0.70); - Nonvegetarian: 1.19 (0.80); % C18:3 cis, y, Kruskal-Wallis, P<0.001; - Vegan: 0.0 (0.0); - Vegetarian: 0.0 (0.15); - Nonvegetarian; 0.08 (0.19); LA:ALA, Kruskal-Wallis, P<0.001; - Vegan: 9.3 (2.1); - Vegetarian: 12.2 (4.9); - Nonvegetarian: 12.7 (6.2); n-6: n-3 PUFAs, Kruskal-Wallis, P<0.001; - Vegan: 8.8 (2.4); - Vegetarian: 11.4 (3.7); - Nonvegetarian: 11.2 (3.8); % C14:1 cis, Kruskal-Wallis, P<0.001; - Vegan: 0.00 (0.07); - Vegetarian: 0.20 (0.13); - Nonvegetarian: 0.23 (0.15); % C16:1 cis 9, Kruskal-Wallis, P<0.001; - Vegan: 1.01 (0.89); - Vegetarian: 1.44 (0.86); - Nonvegetarian: 2.04 (0.63); % C17:1 cis, Kruskal-Wallis, P<0.001; - Vegan: 0.03 (0.08); - Vegetarian: 0.12 (0.09); - Nonvegetarian: 0.16 (0.06); % C18:1 cis, ANOVA, P<0.001; - Vegan: 39.86 (7.56); - Vegetarian: 35.09 (7.96); - Nonvegetarian: 33.09 (8.50); % Total trans fat, Kruskal-Wallis, P<0.001; - Vegan: 0.44 (0.19); - Vegetarian: 0.66 (0.71); - Nonvegetarian: 1.09 (0.55); % C18:1 trans, Kruskal-Wallis, P<0.001; - Vegan: 0.00 (0.07); - Vegetarian: 0.14 (0.61); - Nonvegetarian: 0.62 (0.45); Non-significant:; Data are median (IQR); Significance P<0.001 Total fat (g/dL), Kruskal-Wallis, P=0.041; - Vegan: 3.0 (1.7); - Vegetarian: 4.0 (2.9); - Nonvegetarian: 4.0 (2.9); % C8:0, ANOVA, P=0.052; - Vegan: 0.21 (0.13); - Vegetarian: 0.18 (0.15); - Nonvegetarian: 0.17 (0.18); % C10:0, Kruskal-Wallis, P=0.332; - Vegan: 1.46 (0.71); - Vegetarian: 1.50 (0.74); - Nonvegetarian: 1.65 (0.43); % C12:0, Kruskal-Wallis, P=0.186; - Vegan: 7.12 (3.63); - Vegetarian: 5.88 (2.01); - Nonvegetarian: 6.22 (3.07); % C14:0, Kruskal-Wallis, P=0.571; - Vegan: 5.55 (3.89); - Vegetarian: 6.81 (3.06); - Nonvegetarian: 6.56 (3.36); % C20:0, Kruskal-Wallis, P=0.002; - Vegan: 0.16 (0.14); - Vegetarian: 0.20 (0.16); - Nonvegetarian: 0.09 (0.15); % C22:0, Kruskal-Wallis, P=0.015; - Vegan: 0.06 (0.09); - Vegetarian: 0.05 (0.08); - Nonvegetarian: 0.00 (0.04); % C24:0, Kruskal-Wallis, P=0.765; - Vegan: 0.00 (0.07); - Vegetarian: 0.06 (0.08); - Nonvegetarian: 0.00 (0.08); % EPA (C20:5 cis), Kruskal-Wallis, P=0.057; - Vegan: 0.0 (0.05); - Vegetarian: 0.0 (0.05); - Nonvegetarian: 0.04 (0.18); % DHA (C22:6 cis), Kruskal-Wallis, P=0.543; - Vegan: 0.14 (0.09); - Vegetarian: 0.17 (0.14); - Nonvegetarian: 0.18 (0.18); % Total n-6 PUFAs, ANOVA, P=0.492; - Vegan: 19.65 (2.88); - Vegetarian: 18.69 (6.76); - Nonvegetarian: 17.11 (6.39); % LA (C18:2 cis), ANOVA, P=0.366; - Vegan: 18.86 (2.29); - Vegetarian: 17.98 (6.91); - Nonvegetarian: 16.28 (6.40); % C20:3 cis, Kruskal-Wallis, P=0.106; - Vegan: 0.27 (0.09); - Vegetarian: 0.34 (0.11); - Nonvegetarian: 0.31 (0.13); % AA (C20:4), ANOVA, P=0.014; - Vegan: 0.38 (0.21); - Vegetarian: 0.38 (0.13); - Nonvegetarian: 0.45 (0.16); % C15:1 cis, Kruskal-Wallis, P=0.002; - Vegan: 0.00 (0.00); - Vegetarian: 0.00 (0.05); - Nonvegetarian 0.00 (0.04); % C20:1 cis, Kruskal-Wallis, P=0.003; - Vegan: 0.38 (0.16); - Vegetarian: 0.33 (0.10); - Nonvegetarian: 0.29 (0.12); % C20:2 cis, Kruskal-Wallis, P=0.873; - Vegan: 0.26 (0.15); - Vegetarian: 0.26 (0.08); - Nonvegetarian: 0.27 (0.11) (P=0.873); % C22:1 cis, Kruskal-Wallis, P=0.278; - Vegan: 0.00 (0.09); - Vegetarian: 0.05 (0.07); - Nonvegetarian: 0.00 (0.05) (P=0.278); % C24:1 cis, Kruskal-Wallis, P=0.430; - Vegan: 0.00 (0.01); - Vegetarian: 0.00 (0.03); - Nonvegetarian: 0.00 (0.0); % C14:1 trans, Kruskal-Wallis, P=0.108; - Vegan: 0.00 (0.00); - Vegetarian: 0.00 (0.03); - Nonvegetarian: 0.00 (0.00); % C16:1 trans, ANOVA, P=0.863; - Vegan: 0.36 (0.17); - Vegetarian: 0.34 (0.10); - Nonvegetarian: 0.36 (0.10); % C18:2 trans, Kruskal-Wallis, P=0.021; - Vegan: 0.00 (0.07); - Vegetarian: 0.14 (0.34); - Nonvegetarian: 0.15 (0.29); Medium chain (%), Kruskal-Wallis, P=0.897; - Vegan: 14.9 (6.3); - Vegetarian: 14.6 (5.6); - Nonvegetarian: 14.9 (6.7); Long chain (%), Kruskal-Wallis, 0.906; - Vegan: 85.1 (6.9); - Vegetarian: 85.4 (5.9); - Nonvegetarian: 85.6 (6.7) | Key confounders accounted for: None; Limitations:; - Baseline differences in maternal BMI, lactation stage and supplement use; - Only one time point of exposure and outcome measurement; - No validation of exposure assessment; - Dietary patterns not fully defined using a priori/posteriori methods; - Unclear why 61 eligible participants did not respond and whether their characteristics were different from the participants that enrolled; - Power calculation was based on detecting differences in milk B12 | Human milk from vegans had significantly higher unsaturated fat and total n-3 PUFAs, and lower saturated fatty acids, trans fats, and n-6/n-3 PUFA ratio than their vegetarian and nonvegetarian counterparts. DHA concentrations in human milk were low regardless of maternal dietary pattern, and were reflective of low seafood intake and supplement use.

Table 2 Description of evidence on the relationship between diets based on macronutrient distributions during lactation and human milk composition and quantity^vi,vii^

Study and Participant Characteristics | Intervention/Exposure and Outcomes | Results | Confounding and Study Limitations | Summary of findings
Randomized Controlled Trials
Mohammad, 2014 ^2^ ; U.S.; RCT: Crossover; Baseline N=7; Analytic N=7; (Attrition: 0%); - Maternal age (Mean±SEM): 28.5± 1.2y; - Race/Ethnicity:; ○ 2 African American; ○ 2 White; ○ 3 Hispanic; - Anthropometry: BMI: 22.2± 0.7; - Infant age: 10.0± 2.0wk | Macronutrient Proportion(s):; - ‘H-FAT’: 30% CHO, 55% FAT, 15% PRO; - ‘H-CHO’: 60% CHO, 25% FAT, 15% PRO; for 8d on each diet with 1-2wk washout during 6-14wk postpartum; Dietary assessment methods:; Diets were created to achieve the designed macronutrient composition. Total energy intake and distribution of energy from CHO, FAT, and PRO were analyzed by using NDSR.; Outcomes:; Human milk composition: Fatty acids; Every 3h collected during the 3d inpatient stay.; Outcome assessment methods:; During human milk feeding, once every 3h, 2.5 mL of milk from each breast was collected at the beginning, middle and after the feeding (total of 15 mL). Milk samples for each collection time were pooled for analyses. After human milk feeding, mothers were asked to empty the breast and milk was weighed. The 13C enrichment and quantification of fatty acid in milk performed on samples using the PFBBr derivatization and GC-MS negative chemical ionization. | Significant:; All values are Mean g/L; Total fatty acid; - Feeding: H-CHO: 42.239, H-FAT: 46.893, P<0.05; C4:0; - Fasting: H-CHO: 0.102, H-FAT: 0.071, P<0.05; - Feeding: H-CHO: 0.148, H-FAT: 0.087, P<0.05; C6:0; - Fasting: H-CHO: 0.202, H-FAT: 0.131, P<0.01; - Feeding: H-CHO: 0.333, H-FAT: 0.183, P<0.05; C8:0; - Fasting: H-CHO: 0.357, H-FAT: 0.246, P<0.01; - Feeding: H-CHO: 0.530, H-FAT: 0.381, P<0.01; C10:0; - Fasting: H-CHO: 1.313, H-FAT: 1.112, P<0.05; - Feeding: H-CHO: 1.920, H-FAT: 1.547, P<0.05; C12:0:; - Feeding: H-CHO: 3.569, H-FAT: 3.078, P<0.05; C14:0:; - Fasting: H-CHO: 2.632, H-FAT: 2.320, P<0.01; - Feeding: H-CHO: 3.915, H-FAT: 3.427, P<0.01; Total C2:C14:; - Fasting: H-CHO: 7.230, H-FAT: 6.269, P<0.01; - Feeding: H-CHO: 10.423, H-FAT: 8.712, P<0.01; C16:0:; - Feeding: H-CHO: 4.846, H-FAT: 5.620, P<0.05; C18:0:; - Feeding: H-CHO: 2.944, H-FAT: 4.034, P<0.01; C18:1:; - Feeding: H-CHO: 10.110, H-FAT: 13.230, P<0.01; Total MUFAs:; - Feeding: H-CHO: 13.371, H-FAT: 16.008, P<0.01; C18:2:; - Feeding: H-CHO: 6.317, H-FAT: 7.595, P<0.01; C18:3:; - Feeding: H-CHO: 1.268, H-FAT: 1.836, P<0.01; C20:2:; - Fasting: H-CHO: 0.598, H-FAT: 0.439, P<0.05; C20:3:; - Fasting: H-CHO: 0.616, H-FAT: 0.372, P<0.05; C20:4:; - Fasting: H-CHO: 1.120, H-FAT: 0.820, P<0.05; C20:5:; - Fasting: H-CHO: 0.106, H-FAT: 0.024, P<0.05; C22:6:; - Fasting: H-CHO: 0.664, H-FAT: 0.408, P<0.05; Total PUFAs:; - Feeding: H-CHO: 10.655, H-FAT: 12.519, P<0.05; % Total C2:C14:; - Fasting: H-CHO: 17.096, H-FAT: 15.054, P<0.05; - Feeding: H-CHO: 24.699, H-FAT: 18.613, P<0.01; % Total SAT:; - Feeding: H-CHO: 43.139, H-FAT: 39.142, P<0.05; % Total MUFAs:; - Fasting: H-CHO: 35.459, H-FAT: 38.962, P<0.05; - Feeding: H-CHO: 31.753, H-FAT: 34.289, P<0.05; Non-significant:; All values are Mean g/L; Total FAs; - Fasting: H-CHO: 41.908, H-FAT: 40.833, P=NS; C2:0; - Fasting: H-CHO: 0.007, H-FAT: 0.008, P=NS; - Feeding: H-CHO: 0.008, H-FAT: 0.009, P=NS; C12:0:; - Fasting: H-CHO: 2.618, H-FAT: 2.383, P=NS; C16:0:; - Fasting: H-CHO: 5.326, H-FAT: 5.456, P=NS; C18:0:; - Fasting: H-CHO: 3.157, H-FAT: 3.308, P=NS; Total SAT:; - Fasting: H-CHO: 15.713, H-FAT: 15.033, P=NS; - Feeding: H-CHO: 18.212, H-FAT: 18.366, P=NS; C16:1:; - Fasting: H-CHO: 2.040, H-FAT: 2.125, P=NS; - Feeding: H-CHO: 2.143, H-FAT: 1.760, P=NS; C18:1:; - Fasting: H-CHO: 11.408, H-FAT: 12.748, P=NS; C20:1:; - Fasting: H-CHO: 1.303, H-FAT: 0.909, P=NS; - Feeding: H-CHO: 1.118, H-FAT: 1.018, P=NS; Total MUFAs:; - Fasting: H-CHO: 14.751, H-FAT: 15.783, P=NS; C18:2:; - Fasting: H-CHO: 6.678, H-FAT: 6.471, P=NS; C18:3:; - Fasting: H-CHO: 1.403, H-FAT: 1.335, P=NS; C20:2:; - Feeding: H-CHO: 0.493, H-FAT: 0.532, P=NS; C20:3:; - Feeding: H-CHO: 0.657, H-FAT: 0.563, P=NS; C20:4:; - Feeding: H-CHO: 1.020, H-FAT: 1.173, P=NS; C20:5:; - Feeding: H-CHO: 0.083, H-FAT: 0.056, P=NS; C22:5:; - Fasting: H-CHO: 0.261, H-FAT: 0.148, P=NS; - Feeding: H-CHO: 0.234, H-FAT: 0.229, P=NS; C22:6:; - Feeding: H-CHO: 0.582, H-FAT: 0.535, P=NS; Total PUFAs:; - Fasting: H-CHO: 11.445, H-FAT: 10.017, P=NS; % Total SAT:; - Fasting: H-CHO: 37.198, H-FAT: 36.230, P=NS; % Total PUFAs:; - Fasting: H-CHO: 27.342, H-FAT: 24.809, P=NS; - Feeding: H-CHO: 25.108, H-FAT: 26.569, P=NS | Key confounders accounted for: None; Limitations:; - Unclear baseline imbalances; - No adjustment for multiple comparisons; - No information on randomization, blinding, or carry-over effects; - Power calculation NR | Total milk fat was significantly higher during H-FAT diet, when compared to H-CHO diet. Total MUFAs and PUFAs in human milk was significantly higher during H-FAT diet vs H-CHO diet. These findings were relevant only during (maternal) fed state.
Mohammad, 2009 ^1^ ; U.S.; RCT: Crossover; Baseline N=7; Analytic N=7; (Attrition: 0%); - Maternal age (Mean±SEM): 28.5± 1.2y; - Race/Ethnicity:; ○ 2 African American; ○ 2 White; ○ 3 Hispanic; - Anthropometry: BMI: 23.2± 0.5; - GDM: 0%; - Infant age: 10.0± 2.0wk | Macronutrient Proportion(s):; - ‘H-FAT’: 30% CHO, 55% FAT, 15% PRO; - ‘H-CHO’: 60% CHO, 25% FAT, 15% PRO; for 8d on each diet with 1-2wk washout during 6-14wk postpartum; Dietary assessment methods:; Crossover design: Intervention 1 (8d), Washout (1-2wk), Intervention 2 (8d). Diets created to achieve designed macronutrient composition. Total energy intake and distribution of energy from CHO, FAT, and PRO analyzed using NDSR. During each study period, women consumed study-provided diet for 4d in their homes, and then consumed the same diet for 4d and 3 nights in the research center.; Outcomes:; Human milk composition: Protein, Fat; Every 3h collected during the 3d inpatient stay, which occurred twice during 6-14wk postpartum; Human milk quantity Every 3h collected during the 3d inpatient stay, which occurred twice during 6-14wk postpartum; Outcome assessment methods:; During human milk feeding, once every 3 h, 2.5 mL of milk from each breast was collected at the beginning, middle and after the feeding (total of 15 mL). Milk samples for each collection time were pooled for analyses. After human milk feeding, mothers were asked to empty the breast and the milk was weighed. Total lipid content was quantified gravimetrically; protein was measured by using a bicinchoninic acid protein assay kit.; The daily intake of the infants was determined on the basis of the milk volume consumed and the energy content of the milk. | Significant:; Composition (Mean± SEM), Paired t-test; Fat (g/dL), P<0.05; - H-CHO: 4.3± 0.3; - H-FAT: 4.8± 0.3; Fat (g/d), P<0.05; - H-CHO: 34± 2; - H-FAT: 39± 2; Non-significant:; Composition (Mean± SEM), Paired t-test; Protein (g/dL), P=NS; - H-CHO: 1.8± 0.1; - H-FAT: 1.9± 0.1; Protein (g/d), P=NS; - H-CHO: 15± 0.9; - H-FAT: 16± 0.8; Milk volume (mL/d, Mean± SEM), Paired t-test, P=NS; - H-CHO: 829± 41; - H-FAT: 821± 33 | Key confounders accounted for: None; Limitations:; - No adjustment for multiple comparisons; - Unclear baseline imbalances; - No information on randomization, blinding, or carry-over effects; - Power calculation NR | Consuming a reduced-calorie H-FAT diet compared to an isocaloric, isonitrogenous H-CHO increased total fat milk concentration, but did not affect milk protein concentrations or volume.
Nasser, 2010 ^3^ ; Canada; RCT: Crossover; Baseline N=14; Analytic N=14; (Attrition: 0%); - Maternal age: 31.6 y (range 24-37); - Anthropometry: BMI: 26; - Smoking status: 0%; - Parity: 6 primiparae, 8 multiparae; - GA at birth: 100% Full-term; - Infant age (Mean± SEM): 2.8± 0.9mo (range 2-6mo) | Macronutrient Proportion(s):; - HF: 40.3% FAT, 14.4% PRO, 45.3% CHO; - LF: 17.6% FAT, 14.4% PRO, 68% CHO; for 4d on each diet with 3d washout during 2-6mo postpartum; Dietary assessment methods:; Women randomly assigned to receive each dietary intervention (low fat and high fat), with equal numbers of participants for each order of treatment. Women were provided with prepared meals and snacks meeting their daily energy requirement, as determined by the dietary assessment prior to the period of diet control.; Outcomes:; Human milk composition: fatty acids; Once during 2-6mo postpartum; Outcome assessment methods:; Each mother espressed 20-50mL of human milk between 1-2pm. Milk was pumped from a breast after the baby latched and fed for 2-5 minutes. Average fat content was assessed in the hind milk.; Milk samples were extracted for medium and long chain fatty acids using a modified Folch procedure. | Significant:; Human milk fat composition (g/100 g total fatty acids), Mean± SEM; Capric acid (C10:0), P= 0.01; - LF: 0.87± 0.04; - HF: 0.68± 0.03; Lauric acid (C12:0), P=0.01; - LF: 5.38± 1.16; - HF: 3.98± 0.37; Total medium chain fatty acids, P=0.01; - LF: 13.56± 0.66; - HF: 11.42± 0.86; Stearic acid (C18:0), P=0.01; - LF: 5.00± 0.11; - HF: 6.08± 0.14; Arichidic acid (C20:0), P=0.02; - LF: 0.08± 0.07; - HF: 0.12± 0.01; Palmitoleic acid (C16:1n-7), P=0.046; - LF: 1.95± 0.29; - HF: 1.31± 0.23; Eicosenoic acid (C20:1n-9), P=0.01; - LF: 0.27± 0.02; - HF: 0.38± 0.02; ALA (C18:3n-3), P=0.01; - LF: 1.22± 0.04; - HF:1.69± 0.06; γ-linoenic acid (C18:3n-6), P=0.02; - LF: 0.12± 0.01; - HF: 0.09± 0.01; Dihomo-γ-linolenic acid (C20:3n-6), P=0.03; - LF: 0.27± 0.02; - HF: 0.24± 0.02; AA (C20:4n-6), P=0.02; - LF: 0.34± 0.01; - HF: 0.30± 0.02; Non-significant:; Human milk fat composition (g/100 g total fatty acids), Mean± SEM; Total SAT, P=0.46; - LF: 41.1± 0.82; - HF: 40.40± 0.85; Caprylic acid (C8:0); - LF: Trace; - HF: Trace; Myristic acid (C14:0), P=0.07; - LF: 7.31± 0.35; - HF: 6.76± 0.48; Palmitic acid (C16:0), P=0.43; - LF: 22.70± 0.45; - HF: 23.43± 0.24; Total MUFAs, P=0.10; - LF: 38.70± 0.80; - HF: 39.90± 0.65; Myristoleic acid (C14:1n-5), P=0.27; - LF: 0.35± 0.01; - HF: 0.41± 0.05; Oleic acid (C18:1n-9), P=0.08; - LF: 36.16± 0.86; - HF: 37.81± 0.67; Total PUFAs, P=0.54; - LF: 16.90± 0.66; - HF: 16.40± 0.48; LA (C18:2n-6), P=0.27; - LF: 14.65± 0.62; - HF: 13.82± 0.45; Eicosadienoic acid (C20:2n-6), P=0.51; - LF: 0.19± 0.02; - HF: 0.18± 0.01; EPA (C20:5n-3); - LF: Trace; - HF: Trace; Docasapentaenoic acid (C22:5n-3); - LF: Trace; - HF: Trace; DHA (C22:6n-3), P= 0.77; - LF: 0.12± 0.02; - HF: 0.14± 0.04 | Key confounders accounted for: Smoking Status, GA; Limitations:; - No adjustment for multiple comparisons; - Short study duration; - Power calculation NR | No significant difference in human milk concentrations of total saturated, MUFAs, and PUFAs during high fat or low fat diet.
Yahvah, 2015 ^4^ ; U.S.; RCT: Crossover; Baseline N=16; Analytic N=15; (Attrition: 6%); All baseline characteristics: (N=15, Mean± SEM); - Maternal age: 27± 1y; - Anthropometry: Prepregnancy BMI: 24± 1; - Parity: 1.7± 0.2 | Macronutrient Proportion(s):; - Low-fat dairy (LFD): ~24% FAT, ~20% PRO, ~57% CHO (Ref, n=15);; - Full-fat dairy (FFD): ~36% FAT, ~17% PRO, ~48% CHO (n=15); Maternal intake of 4 full-fat or low-fat dairy products/d for 14d with 14d washout at ≥4mo postpartum; Dietary assessment methods:; Dairy products delivered weekly to participants’ homes with reminders of study guidelines and sampling dates. 3d weighed food records collected for 2 weekdays and 1 weekend day at baseline and first week of each intervention period. Food records analyzed using the ESHA program.; Outcomes:; Human milk composition: Total lipids, fatty acids 3 times every 14d at ≥4mo postpartum; Outcome assessment methods:; Milk was expressed completely from one breast between 6:00-10:00h. Participants were instructed to refrain from human milk feeding and pumping for at least 3h prior to milk sample donation.; Fatty acid extracted from milk and lipid composition by weight determined by gas chromatography. | Significant:; Mean± SEM, Paired t-tests: Total lipids (g/100 g milk), P<0.05; - FFD: 3.35± 0.28; - LFD: 2.41± 0.31; 4:0 (g/100 g lipid), P<0.05 (questioning this p-value); - FFD: 0.05± 0.00; - LFD: 0.05± 0.00; 12:0 (g/100 g lipid), P<0.05; - FFD: 4.58± 0.36; - LFD: 5.26± 0.44; 13:0 (g/100 g lipid), P<0.001; - FFD: 0.04± 0.00; - LFD: 0.02± 0.00; 14:1 c9 (g/100 g lipid), P<0.001; - FFD: 0.26± 0.01; - LFD: 0.15± 0.02; Iso-14:0 (g/100 g lipid), P<0.001; - FFD: 0.03± 0.00; - LFD: 0.01± 0.00; 15:0 (g/100 g lipid), P<0.001; - FFD: 0.40± 0.01; - LFD: 0.23± 0.02; Iso-15:0 (g/100 g lipid), P<0.001; - FFD: 0.07± 0.00; - LFD: 0.03± 0.00; Anteiso-15:0 (g/100 g lipid), P<0.001; - FFD: 0.12± 0.01; - LFD: 0.05± 0.01; 16:0 (g/100 g lipid), P<0.001; - FFD: 21.62± 0.52; - LFD: 19.29± 0.58; Iso-16:0 (g/100 g lipid), P<0.001; - FFD: 0.09± 0.00; - LFD: 0.05± 0.01; 16:1 t9 (g/100 g lipid), P<0.001; - FFD: 0.14± 0.01; - LFD: 0.08± 0.01; 16:2 c9,c12 (g/100 g lipid), P<0.05; - FFD: 0.22± 0.01; - LFD: 0.18± 0.01; 17:0 (g/100 g lipid), P<0.001; - FFD: 0.37± 0.01; - LFD: 0.27± 0.01; Iso-17:0 (g/100 g lipid), P<0.05; - FFD: 0.36± 0.01; - LFD: 0.41± 0.01; Anteiso-17:0 (g/100 g lipid), P<0.001; - FFD: 0.21± 0.01; - LFD: 0.11± 0.01; 18:0 (g/100 g lipid), P<0.001; - FFD: 7.54± 0.27; - LFD: 5.75± 0.27; Anteiso-18:0 (g/100 g lipid), P<0.001; - FFD: 0.05± 0.00; - LFD: 0.03± 0.00; Iso-18:0 (g/100 g lipid), P<0.001; - FFD: 0.05± 0.01; - LFD: 0.03± 0.00; 18:1 c11 (g/100 g lipid), P<0.05; - FFD: 1.17± 0.15; - LFD: 1.32± 0.18; 18:1 t11 (g/100 g lipid), P<0.001; - FFD: 0.54± 0.03; - LFD: 0.34± 0.03; 18:2 c9,c12 (g/100 g lipid), P<0.001; - FFD: 14.27± 0.75; - LFD: 18.80± 0.91; 18:2 c9,t11(CLA) (g/100 g lipid), P<0.001; - FFD: 0.33± 0.01; - LFD: 0.24± 0.01; 18:3 α c9,c12,c15 (g/100 g lipid), P<0.05; - FFD: 1.60± 0.12; - LFD: 1.97± 0.16; 20:0 (g/100 g lipid), P<0.001; - FFD: 0.21± 0.02; - LFD: 0.16± 0.01; Non-significant:; Mean± SEM, Paired t-tests: 6:0 (g/100 g lipid), P=NS; - FFD: 0.08± 0.00; - LFD: 0.08± 0.01; 8:0 (g/100 g lipid), P=NS; - FFD: 0.17± 0.01; - LFD: 0.17± 0.01; 10:0 (g/100 g lipid), P=NS; - FFD: 1.11± 0.06; - LFD: 1.14± 0.06; 14.0 (g/100 g lipid), P=NS; - FFD: 6.37± 0.38; - LFD: 5.94± 0.54; 16:1 c9 (g/100 g lipid), P=NS; - FFD: 2.08± 0.15; - LFD: 2.21± 0.16; 17:1 c9 (g/100 g lipid), P=NS; - FFD: 0.04± 0.00; - LFD: 0.04± 0.00; 18:1 c9 (g/100 g lipid), P=NS; - FFD: 30.77± 0.80; - LFD: 30.51± 0.59; 18:1 c12 (g/100 g lipid), P=NS; - FFD: 0.66± 0.14; - LFD: 0.69± 0.17; 18:1 t7-8 (g/100 g lipid), P=NS; - FFD: 0.31± 0.03; - LFD: 0.29± 0.05; 18:1 t9 (g/100 g lipid), P=NS; - FFD: 0.32± 0.02; - LFD: 0.31± 0.03; 18:1 t10 (g/100 g lipid), P=NS; - FFD: 0.52± 0.05; - LFD: 0.42± 0.05; 18:3 γ c6,c9,c12 (g/100 g lipid), P=NS; - FFD: 0.11± 0.01; - LFD: 0.13± 0.02; 21:0 (g/100 g lipid), P=NS; - FFD: 0.05± 0.00; - LFD: 0.05± 0.01; 22:0 (g/100 g lipid), P=NS; - FFD: 0.07± 0.01; - LFD: 0.06± 0.01 | Key confounders accounted for: None; Limitations:; - No adjustment for multiple comparisons; - No information on randomization, blinding, or carry-over effects; - Power calculation NR | Consuming a diet rich in full-fat versus low-fat dairy products during lactation was associated with different lipid content and fatty acid profiles in human milk.

Table 3 Results from studies that assessed the relationship between dietary patterns during lactation and human milk fatty acid composition^viii^

Articles^ix^ | Total milk fat | Saturated Fat | Monounsaturated fatty acids | Polyunsaturated fatty acids
Tian, 2019^7^; - Pattern 1: Mushroom food and algae, Meat, Marine products; - Pattern 2: Soybean products, Nuts, Dairy; - Pattern 3: Fruit, Vegetables; - Pattern 4: Grain/potato and beans, Eggs | NR | SAT: Pattern 1: 40.38, Pattern 2: 42.92, Pattern 3: 39.10, Pattern 4: 42.92 (p<0.001) | MUFAs: Pattern 1: 34.40, Pattern 2: 33.53, Pattern 3: 34.85, Pattern 4: 33.45 (p=0.053) | PUFAs: Pattern 1: 24.49, Pattern 2: 22.09, Pattern 3: 24.63, Pattern 4: 22.77 (p=0.025); n-6 PUFAs: Pattern 1: 20.71, Pattern 2: 18.24, Pattern 3: 20.11, Pattern 4: 18.49 (p=0.038); n-3 PUFAs: Pattern 1: 3.96, Pattern 2: 3.55, Pattern 3: 3.56, Pattern 4: 3.86 (p=0.29); n-6: n-3 PUFA ratio: Pattern 1: 4.83, Pattern 2: 4.76, Pattern 3: 5.34, Pattern 4: 4.69 (p=0.34)
Perrin, 2019^6^; - Vegan: Never/rarely consumed animal products; - Vegetarian: Never consumed meat; regularly consumed other animal products; - Non-vegetarian: Consumed meat sometimes/often | Total Fat NS; Trans fat higher among women with Non-vegetarian > Vegetarian > Vegan diets (p<0.001) | SAT: Vegan: 33.1, Vegetarian: 40.0, Non-vegetarian: 42.3 (p<0.001); C15:0, C16:0, C17:0, and C18:0 higher among women with Non-vegetarian > Vegetarian > Vegan diets (p<0.001) C8:0, C10:0, C12:0, C14:0, C20:0, C22:0, and C24:0 NS | Data not reported as total MUFAs; C14:1 cis, C16:1 cis, C17:1 cis higher among women with Non-vegetarian > Vegetarian > Vegan diets (p<0.001); C18:1 cis higher among women with Vegan > Vegetarian > Non-vegetarian diets (p<0.001); C15:1 cis, C20:1 cis, C22:1 cis, C24:1 cis, C14:1 trans, C16:1 trans NS | Data not reported as total PUFAs; n-6 PUFAs: Vegan: 19.65, Vegetarian: 18.69, Non-vegetarian: 17.11 (NS); n-3 PUFAs: Vegan: 2.29, Vegetarian: 1.55, Non-vegetarian: 1.46 (p<0.001); n-6: n-3 PUFA ratio: Vegan: 8.8, Vegetarian: 11.4, Non-vegetarian: 11.2 (p<0.001); LA:ALA ratio higher in Non-vegetarian > Vegetarian > Vegan diet; C18:3 cis γ higher in Non-vegetarian > Vegetarian = Vegan; ALA, and unsaturated fat higher among women with Vegan > Vegetarian > Non-vegetarian diets; LA (C18:2 cis), C18:2 trans C20:2 cis, C20:3 cis, AA (C20:4), EPA (C20:5 cis), and DHA (C22:6 cis) NS

Table 4 Results from studies that assessed the relationship between diets based on macronutrient distributions during lactation and human milk composition^x^

Articles | Total milk fat | Saturated fat | Monounsaturated fatty acids | Polyunsaturated fatty acids
Mohammad, 2009 ^1^; High CHO; (60% CHO, 25% FAT, 15% PRO); vs.; High Fat; (30% CHO, 55% FAT, 15% PRO) | Milk fat concentration and milk fat content/day higher after high fat diet (p<0.05) | NR | NR | NR
Mohammad, 2014 ^2^ ^xi^; High CHO; (60% CHO, 25% FAT, 15% PRO); vs.; High Fat; (30% CHO, 55% FAT, 15% PRO) | Total milk fat higher in high fat diet (p<0.05) only in a fed state | ∑SAT: Fasting: H-CHO: 15.71, H-FAT: 15.03 (NS) Feeding: H-CHO: 18.21, H-FAT: 18.37 (NS); Women during H-CHO diet had higher %total SAT (fed only p<0.05) and ∑C2:C14 (both fed and fasting p<0.05); Women during H-CHO diet had higher C4:0, C6:0, C8:0, C10:0, C12:0 (fed only), C14:0, ∑C2:C14, C16:0 (fed only), C18:0 (fed only) in human milk (p<0.05) than H-FAT. C2:0 NS | ∑MUFA: Fasting: H-CHO: 14.75, H-FAT: 15.78 (NS) Feeding: H-CHO: 13.37, H-FAT: 16.01 (p<0.01); Women during H-FAT diet had higher %Total MUFAs (both fed and fasting p<0.05); Women during H-FAT diet had higher C18:1 than HCHO (fed only, p<0.01). C16:1 and C20:1 NS | ∑PUFA: Fasting: H-CHO: 11.45, H-FAT: 10.02 (NS) Feeding: H-CHO: 10.66, H-FAT: 12.52 (p<0.05); %Total PUFAs: NS; Women during H-FAT diet had higher C18:2 and C18:3 (fed only, p<0.01) and C20:2, C20:3, C20:4, C20:5, and C22:6 (fasting only, p<0.05) than H-CHO. C22:5 NS
Nasser, 2010 ^3^ ^xii^; High Fat; (45.3% CHO, 40.3% FAT, 14.4% PRO); vs; Low Fat; (68% CHO, 17.6% FAT, 14.4% PRO) | NR | ∑SAT: Low Fat: 41.1±0.82, High Fat: 40.4±0.85 (p=0.46); Women during low fat diet had higher total medium chain FA, C10:0 and C12:0 (p=0.01) in human milk than high fat. C18:0 and C20:0 higher in high fat diet than low fat diet (p=0.01). C14:0 and C16:0 NS | ∑MUFA: Low Fat: 38.7±0.8, High Fat: 39.9±0.65 (p=0.10); C16:1: Milk from women during low fat diet higher than high fat (p=0.046); C20:1: Milk from women during high fat diet higher than low fat (p=0.01); C14:1 and C18:1 NS | ∑PUFA: Low Fat: 16.9±0.66, High Fat: 16.4±0.48 (p=0.54); Women during low fat diet had higher C18:3n-6, C20:3 and AA (C20:4n-6) in human milk than high fat milk (p<0.05). ALA (C18:3n:3) was higher in milk of mothers with high fat diet (p=0.01); LA (C18:2n-6), C20:2n-6, C22:5n-3, EPA (C20:5n-3), DHA (C22:6n-3) NS
Yahvah, 2015 ^4^ ^xiii^; Low fat dairy; (57% CHO, 24% FAT, 20% PRO); vs; Full-fat dairy (48% CHO, 36% FAT, 17% PRO) | Total lipids was higher after a full-fat dairy diet compared to low-fat dairy diet | Data not reported as total saturated fat; Women during [underlined: full-fat dairy] diet had higher; C13:0, iso-14:0, C15:0, iso-15:0, anteiso-15:0, C16:0, iso-C16:0, C17:0, anteiso 17:0, C18:0, anteiso 18:0, iso-18:0, C20:0 (p<0.05); Women during [underlined: low fat dairy] diet had higher C12:0 and iso-17:0 in their milk (p<0.05); C4:0, C6:0, C8:0, C10:0, C14:0, C21:0, C22:0 NS | Data not reported as total MUFAs; Women during [underlined: full-fat dairy] diet had higher C14:1, C16:1t9, C18:1t11 (p<0.001); Women during [underlined: low-fat dairy] diet had higher C18:1c11 (p<0.05); C16:1, C17:1, C18:1, C18:1, C18:1t7-8, C18:1t9, C18:1t10 NS | Data not reported as total PUFAs; Women during [underlined: full-fat dairy] diet had higher C16:2 and C18:2 c9,t11 (p<0.05) in human milk than low-fat dairy diet; Women during [underlined: low-fat dairy] diet had higher C18:2 c9,c12 and C18:3α c9,c12,c15 than full-fat dairy diet (p<0.05); C18:3 γ c6,c9,c12 NS

Table 5 Risk of bias for randomized controlled trials examining dietary patterns during lactation and human milk composition and quantity^xiv,xv^

| Randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Mohammad, 2014^2^ | Some concerns | Some concerns | Low | Low | Some concerns
Mohammad, 2009^1^ | Some concerns | Some concerns | Low | Low | Some concerns
Nasser, 2010^3^ | Low | Some concerns | Low | Low | Some concerns
Yahvah, 2015^4^ | Some concerns | Some concerns | Low | Low | Some concerns

Table 6 Risk of bias for observational studies examining dietary patterns during lactation and human milk composition and quantity^xvi^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Tian, 2019^7^ | Serious | Serious | Moderate | Low | Low | Low | Moderate
Pawlak, 2018^5^ | Critical | Serious | Serious | Critical | Low | Low | Moderate
Perrin, 2019^6^ | Critical | Serious | Serious | Critical | Low | Low | Moderate

ii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

iii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv ± indicates values of Mean± SD unless otherwise noted

v AA: arachidonic acid, ALA: alpha-linolenic acid, ANOVA: analysis of variance, BMI: body mass index, d: day(s) DHA: docosahexaenoic acid, EPA: eicosapentaenoic acid, FFQ: food frequency questionnaire, GA: gestational age, GWG: gestational weight gain, h: hour, IQR: interquartile range, kg: kilogram(s), LA: linoleic acid, mo: month(s), MUFA: monounsaturated fatty acid, n-#: omega-#, NR: not reported, PUFA: polyunsaturated fatty acid, SAT: saturated fat, SES: socioeconomic status, wk: week(s), y: year(s)

vi ± indicates values of Mean± SD unless otherwise noted

vii AA: arachidonic acid, ALA: alpha-linolenic acid, BMI: body mass index, CHO: carbohydrate, CLA: conjugated linoleic acid, d: day(s), DHA: docosahexaenoic acid, EPA: eicosapentaenoic acid, FA: fatty acid, GA: gestational age, GC-MS: gas chromatography-mass spectrometry, h: hour(s), LA: linoleic acid, mo: month(s), MUFA: monounsaturated fatty acid, n-#: omega-#, NDSR: Nutrition Data System for Research, NR: not reported, NS: non-significant, PUFA: polyunsaturated fatty acid, PRO: protein, RCT: randomized controlled trial, SAT: saturated fat, SEM: standard error of the mean, wk: week(s), y: year(s)

viii AA: arachidonic acid, ALA: alpha-linolenic acid, DHA: docosahexaenoic acid, EPA: eicosapentaenoic acid, LA: linoleic acid, MUFA: monounsaturated fatty acid, n-#: omega-#, NR: not reported, NS: non-significant, PUFA: polyunsaturated fatty acid, SAT: saturated fat

ix Data are Median % fatty acid proportions unless otherwise specified

x AA: arachidonic acid, ALA: alpha-linolenic acid, CHO: carbohydrate, DHA: docosahexaenoic acid, EPA: eicosapentaenoic acid, LA: linoleic acid, MUFA: monounsaturated fatty acid, n-#: omega-#, NR: not reported, NS: non-significant, PRO: protein, PUFA: polyunsaturated fatty acid, SAT: saturated fat,

xi Units g/L

xii Units g/100 g total fatty acids

xiii Units g/100 g lipids

xiv A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xv Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

xvi Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )