# List of abbreviations

Abbreviation: Full name
ADD: Attention deficit disorder
ADHD: Attention-deficit/hyperactivity disorder
ASD: Autism spectrum disorder
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
DHA: Docosahexaenoic acid
EPA: Eicosapentaenoic acid
FA: Folic acid
Fe: Iron
FNS: Food and Nutrition Service
HDI: Human Development Index
HHS: Department of Health and Human Services
MCV: Mean corpuscular volume
MTHF: Methyl tetrahydrofolate
MTHFR: Methylenetetrahydrofolate reductase
NESR: Nutrition Evidence Systematic Review
PCS: Prospective cohort study
RASP: Resiliency Attitudes and Skills Profile
RBC: Red blood cell
RCT: Randomized controlled trial
RDW: Red blood cell distribution width
SDQ: Strengths and Difficulties Questionnaire
TEIQue-CSF: Trait Emotional Intelligence Questionnaire Child Short Form
THF: Tetrahydrofolate
USDA: United States Department of Agriculture