# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xlvii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 2. Food, Beverage, and Nutrient Consumption During Pregnancy and Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1 through Figure 5) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework: Folic acid and micronutrient status

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation on micronutrient status. For this systematic review, the target population considered was women up to 6 months before and during pregnancy and/or lactation who were healthy and/or at risk for chronic disease. The interventions or exposures considered were folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods and their comparators were different levels of exposure to folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods. The outcomes considered were micronutrient status, including folate, vitamin B12, hemoglobin, mean corpuscular volume (MCV), and red blood cell distribution width (RDW). The key confounders were age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy and lactation)), smoking, and parity. Other factors to be considered include substance use (alcohol, drug use), and gestational age.

Figure 2 Analytic framework: Folic acid and risk of gestational diabetes

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy on risk of gestational diabetes. For this systematic review, the target population considered was women up to 6 months before and during pregnancy who were healthy and/or at risk for chronic disease. The interventions or exposures considered were folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods and their comparators were different levels of exposure to folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods. The outcomes considered were incidence and prevalence of gestational diabetes, with intermediate outcomes: fasting glucose, hemoglobin A1C, glucose tolerance/insulin resistance, and oral glucose tolerance test. The key confounders were age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy)), smoking, family history of diabetes or pre-diabetes, and parity. Other factors to be considered include physical activity, substance use (alcohol, drug use), large infant prior (Large for Gestational Age), enrolled in intervention/prevention trial, and gestational age.

Figure 3 Analytic framework: Folic acid and risk of hypertensive disorders during pregnancy

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy on risk of hypertensive disorders during pregnancy. For this systematic review, the target population considered was women up to 6 months before and during pregnancy who were healthy and/or at risk for chronic disease. The interventions or exposures considered were folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods and their comparators were different levels of exposure to folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods. The outcomes considered were eclampsia, preeclampsia, and gestational hypertension. Intermediate outcomes included blood pressure (systolic and diastolic) and proteinuria. The key confounders were age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy)), diagnosis of gestational diabetes, smoking, history/diagnosis of hypertension or CVD, and parity. Other factors to be considered include physical activity, substance use (alcohol, drug use), and gestational age.

Figure 4 Analytic framework: Folic acid and human milk composition

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation on human milk composition. For this systematic review, the target population considered was women up to 6 months before and during pregnancy and/or lactation who were healthy and/or at risk for chronic disease. The interventions or exposures considered were folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods and their comparators were different levels of exposure to folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods. The outcome considered was folic acid content of human milk. The key confounders were age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy and lactation)), smoking, and parity. Other factors to be considered include gestational age.

Figure 5 Analytic framework: Folic acid and developmental milestones, including neurocognitive development, in the child

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question on the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation on developmental milestones including neurocognitive development. For this systematic review, the target population considered was women up to 6 months before and during pregnancy and/or lactation who were healthy and/or at risk for chronic disease. The interventions or exposures considered were folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods and their comparators were different levels of exposure to folic acid from dietary supplements (including multiple-micronutrient supplements) and/or fortified foods. The outcomes considered were Developmental domains, examined via milestone achievement and/or scales/indices, including: Cognitive, Language/communication, Movement/physical, Social-emotional; Academic performance, Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD), Anxiety, Depression, and Autism spectrum disorder (ASD) in Infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years). The key confounders were age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI and gestational weight gain (during pregnancy) or obesity status (before pregnancy and lactation)), smoking, parity, child sex, gestational age, and human milk feeding practices (intensity, duration). Other factors to be considered include maternal substance use (alcohol, drug use), family history/diagnosis of neurocognitive disorders, and complementary feeding.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 24 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Uncontrolled before-and-after studies; - Cross-sectional studies (for outcomes: human milk composition) | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies (for outcomes: micronutrient status, gestational diabetes, hypertensive disorders, developmental milestones, including neurocognitive health); - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/ exposure | - Exposure to, including intake of, folic acid from:; ○ Dietary supplements (including multiple-nutrient supplements); ○ Fortified foods; ○ Dietary supplements + fortified foods; - Folic acid includes all folate species, including 5-MTHF and folinic acid | - Exposure to multiple-micronutrient supplements in which nutrients other than the nutrient of interest vary
Comparator | - Different levels of exposure to, including intake of, folic acid from:; ○ Dietary supplements (including multiple-nutrient supplements); ○ Fortified foods; ○ Dietary supplements + fortified foods | - No comparator; - Exposure to multiple-micronutrient supplements in which nutrients other than the nutrient of interest vary
Outcome:; Micronutrient status | - Including, but not limited to:; ○ Folate: serum folate, RBC folate, etc.; ○ Vitamin B_12_; ○ Hemoglobin; ○ Mean Corpuscular Volume (MCV); ○ Red Blood Cell Distribution Width (RDW), etc. | - N/A
Outcome:; Gestational diabetes | [underlined: Intermediate outcome:]; - Fasting glucose; - Hemoglobin A1C; - Glucose tolerance/insulin resistance; - Oral Glucose Tolerance Test; [underlined: Endpoint outcome:]; - Gestational diabetes | - N/A
Outcome:; Hypertensive disorders | [underlined: Intermediate outcome:]; - Blood pressure (systolic and diastolic) during pregnancy; - Protein in the urine (proteinuria); [underlined: Endpoint outcome:]; - Eclampsia; - Preeclampsia; - Gestational hypertension | - N/A
Outcome:; Human milk composition | - Including, but not limited to:; ○ Folate: total folate, reduced folates, unmetabolized folic acid, etc. | - Human milk from third parties (e.g., banked/donor milk)
Outcome:; Developmental milestones, including neurocognitive development | - Developmental domains, examined via milestone achievement and/or scales/indices, including:; ○ Cognitive,; ○ Language/communication,; ○ Movement/physical,; ○ Social-emotional; - Academic performance; - Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD); - Anxiety; - Depression; - Autism spectrum disorder (ASD) | - N/A
Date of publication (for all outcomes) | - January 1980 – June/July 2019 | - Articles published prior to January 1980
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xlviii^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants | - Non-human participants (e.g., animal or in-vitro models); - Studies that exclusively enroll multiple gestation pregnancies or exclusively present combined analyses of singleton and multiple gestations
Life stage of study participants - intervention or exposure (relevant for all outcomes) | - Women up to 6 months before pregnancy; - Women during pregnancy; - Women during lactation | - N/A
Life stage of study participants - outcomes: micronutrient status | - Women during pregnancy; - Women during lactation | - N/A
Life stage of study participants - outcomes: gestational diabetes | - Women during pregnancy | - N/A
Life stage of study participants - outcomes: hypertensive disorders | - Women during pregnancy | - N/A
Life stage of study participants - outcomes: milk composition | - Women during lactation | - N/A
Life stage of study participants - outcomes: developmental milestones including neurocognitive development | - Infants and toddlers (birth – 24 months); - Children and adolescents (2 – 18 years) | - Adults (19 – 64 years); - Older adults (65 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or with the health outcome of interest:; ○ Gestational diabetes; ○ Hypertensive disorders of pregnancy; ○ Neurocognitive disorders (ADD, ADHD, anxiety, depression, or ASD); ○ Studies that enroll some participants who are deficient in folate; - Studies that enroll some mothers with infants who are born preterm (<37 weeks and 0/7 days gestational age); - Studies that exclusively enroll or enroll some mothers diagnosed with the outcome of interest that is to be examined in the infant/child (developmental milestones, including neurocognitive development) | - Studies that exclusively enroll participants diagnosed with a chronic disease, or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll participants with obesity will not be excluded.); - Studies that exclusively enroll participants with the outcome of interest (gestational diabetes, hypertensive disorders of pregnancy) (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest); - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age

### Electronic databases and search terms

#### Micronutrient status and Human milk composition

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: June 14, 2019
- Date range searched: January 1, 1980 to June 14, 2019
- Search terms:
  - #1 - “Folic Acid”[Mesh] OR folic acid* OR folate* OR folacin*
  - #2 - Dietary supplements[mh] OR diet supplement* OR dietary supplement* OR food supplement* OR nutrition supplement* OR nutritional supplement* OR vitamin supplement*[tiab] OR multivitamin*[tiab] OR prenatal vitamin*[tiab] OR maternal vitamin*[tiab]
  - #3 - “Food, Fortified”[Mesh] OR ((food[mh] OR food[tiab] OR foods[tiab]) AND (fortification[tiab] OR fortified[tiab] OR fortify[tiab] OR fortifies[tiab] OR fortifying[tiab] OR enrich*[tiab])) OR fortified food* OR enriched food* OR enriching food* OR fortifying food* OR food fortification[tiab] OR “folic acid fortified”[tiab] OR folic acid fortified food*
  - #4 - pregnancy[mh] OR pregnancy complications[mh] OR “Prenatal Exposure Delayed Effects”[mesh] OR “Maternal Exposure”[mesh] OR “pregnant women”[mh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother[tiab] OR mothers[tiab] OR mothers[mh] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh]
  - #5 - Lactation[mh] OR lactation[tiab] OR lactating[tiab] OR breast feeding[mh] OR breastfeeding[tiab] OR breast feed* OR breast-feed*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed*
  - #6 - Milk, human[mh] OR “breast milk”[tiab] OR breast-milk[tiab] OR “human milk”[tiab] OR “mother’s milk”[tiab] OR “mothers milk”[tiab] OR breastmilk[tiab] OR “human milk composition”[tiab] OR “milk composition”[tiab]
  - #7 - Micronutrients[mh] OR micronutrient*[tiab] OR vitamin*[tiab] OR vitamins[tiab] OR trace element* OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR anemic[tiab] OR iron deficien*[tiab] OR apoferritin*[tiab] OR ferritins[mh] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin “[tiab] OR “Vitamin B 12”[Mesh] OR “vitamin B complex”[tiab] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR eritron[tiab] OR hydroxocobalamin[mh] OR hydroxocobalamin[tiab] OR hemoglobin*[tiab] OR hemoglobins[mh] OR methemoglobin[tiab] OR oxyhemoglobin*[tiab] OR sulfhemoglobin*[tiab] OR mean corpuscular volume[tiab] OR MCV[tiab] OR red blood cell*[tiab] OR rbc[tiab] OR rbcs[tiab] OR RDW[tiab] OR red blood cell distribution width[tiab] OR erythrocyte indices[mh] OR multimicronutrient* OR multimicronutrient*
  - #8 - #1 AND (#2 OR #3)
  - #9 - #4 OR #5
  - #10 - #6 OR #7
  - #11 - #8 AND #9 AND #10
  - #12 - #11 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])
    Filters: Publication date from 1980/01/01 to 2019/06/14, English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: June 14, 2019
- Date range searched: January 1, 1980 to June 14, 2019
- Search terms:
  - #1 - [mh “folic acid”] OR “folic acid” OR “folic acids” OR folate OR folates OR folacin OR folacins
  - #2 - [mh “Dietary supplements”] OR “diet supplement” OR “diet supplements” OR “dietary supplement” OR “dietary supplements” OR “food supplement” OR “food supplements” OR “nutrition supplement” OR “nutrition supplements” OR “nutritional supplement” OR “nutritional supplements” OR “vitamin supplement” OR “vitamin supplements” OR multivitamin OR multivitamins OR “prenatal vitamin” OR “prenatal vitamins” OR “maternal vitamins” OR “maternal vitamin” OR “pre-natal vitamin” OR “pre-natal vitamins”
  - #3 - [mh “Food, Fortified”] OR (([mh food] OR food OR foods) AND (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich*)) OR “fortified food” OR “fortified foods” OR “enriched food” OR “enriched foods” OR “enriching food” OR “enriching foods” OR “fortifying food” OR “fortifying foods” OR “food fortification” OR “folic acid fortified”
  - #4 - [mh pregnancy] OR [mh “pregnancy complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “pregnant women”] OR pregnan* OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR [mh mothers] OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR [mh “Peripartum Period”] OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR [mh “Maternal Nutritional Physiological Phenomena”]
  - #5 - [mh Lactation] OR lactation OR lactating OR [mh “breast feeding”] OR breastfeeding OR “breast feed” OR “breast feeds” OR breast-feed OR breast-feeds OR breastfed OR breast-fed OR breastfeed OR breastfeeds
  - #6 - [mh “milk, human”] OR “breast milk” OR “human milk” OR “mothers milk” OR breastmilk OR “human milk composition” OR “human milk”
  - #7 - [mh Micronutrients] OR micronutrient* OR vitamin OR vitamins OR “trace element” OR “trace elements” OR [mh Iron] OR iron OR [mh Anemia] OR Anemia OR anemic OR “iron deficiency” OR “iron deficient” OR apoferritin OR apoferritins OR [mh ferritins] OR ferritin OR ferritins OR ferrous OR Transferrin OR [mh “Vitamin B 12”] OR “vitamin B complex” OR “Vitamin B 12” OR “Vitamin B12” OR [mh “Vitamin B 12 Deficiency”] OR Cobamide* OR Cobalamin* OR Cyanocobalamin OR eritron OR [mh hydroxocobalamin] OR hydroxocobalamin OR hemoglobin* OR [mh hemoglobins] OR methemoglobin OR oxyhemoglobin* OR sulfhemoglobin* OR “mean corpuscular volume” OR MCV OR “red blood cell” OR “red blood cells” OR rbc OR rbcs OR RDW OR “red blood cell distribution width” OR [mh “erythrocyte indices”] OR multimicronutrient* OR multi-micronutrient*
  - #8 - #1 AND (#2 OR #3)
  - #9 - #4 OR #5
  - #10 - #6 OR #7
  - #11 - #8 AND #9 AND #10
    Filters: Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

##### Embase

- Provider: Elsevier
- Date(s) searched: June 18, 2019
- Date range searched: January 1, 1980 to June 18, 2019
- Search terms:
  - #1 - (‘folic acid’/exp OR ‘folic acid*’:ti,ab OR folate*:ti,ab OR folacin*:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #2 - (‘diet supplementation’/exp OR ‘dietary supplement’/exp OR ‘diet supplement*’:ti,ab OR ‘dietary supplement*’:ti,ab OR ‘food supplement*’:ti,ab OR ‘nutrition supplement*’:ti,ab OR ‘nutritional supplement*’:ti,ab OR ‘vitamin supplement*’:ti,ab OR multivitamin*:ti,ab OR ‘prenatal vitamin*’:ti,ab OR ‘maternal vitamin*’:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #3 - (‘fortified food’/exp OR ((‘food’/exp OR foods:ti,ab OR food:ti,ab) AND (fortification:ti,ab OR fortified:ti,ab OR fortify:ti,ab OR fortifies:ti,ab OR fortifying:ti,ab OR enrich*:ti,ab)) OR ‘fortified food*’:ti,ab OR ‘enriched food*’:ti,ab OR ‘enriching food*’:ti,ab OR ‘fortifying food*’:ti,ab OR ‘food fortification’:ti,ab OR ‘folic acid fortified’:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #4 - (pregnan*:ti,ab OR ‘pre pregnancy’:ti,ab OR prenatal:ti,ab OR ‘pre natal’:ti,ab OR maternal:ti,ab OR mother:ti,ab OR mothers:ti,ab OR postpartum:ti,ab OR perinatal:ti,ab OR ‘peri natal’:ti,ab OR ‘pre conception’:ti,ab OR preconception:ti,ab OR ‘peri conception’:ti,ab OR periconception:ti,ab OR peripartum:ti,ab OR ‘peri partum’:ti,ab OR gestation*:ti,ab OR natal:ti,ab OR antenatal:ti,ab OR ‘ante natal’:ti,ab OR puerperium:ti,ab OR ‘pregnancy’/exp OR ‘pregnancy complication’/exp OR ‘prenatal exposure’/exp OR ‘pregnant woman’/exp OR ‘mother’/exp OR ‘puerperium’/exp OR ‘perinatal period’/exp OR ‘maternal nutrition’/exp) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #5 - (‘breast feeding’/exp OR ‘lactation’/exp OR lactation:ti,ab OR lactating:ti,ab OR breastfeeding:ti,ab OR ‘breast feed’:ti,ab OR breastfed:ti,ab OR ‘breast fed’:ti,ab OR breastfeed*:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #6 - (‘breast milk’/exp OR ‘breast milk’:ti,ab OR ‘human milk’:ti,ab OR ‘mothers milk’:ti,ab OR breastmilk:ti,ab OR ‘human milk composition’:ti,ab OR ‘milk composition’:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #7 - (‘trace element’/exp OR ‘iron’/exp OR ‘anemia’/exp OR ‘ferritin’/exp OR ‘cyanocobalamin’/exp OR ‘vitamin b complex’/exp OR ‘b12 deficiency’/exp OR ‘hemoglobin’/exp OR ‘iron deficiency’/exp OR ‘apoferritin’/exp OR ‘mean corpuscular volume’/exp OR ‘red blood cell distribution width’/exp OR ‘cobalamin’/exp OR ‘cobinamide’/exp OR ‘hydroxocobalamin’/exp OR ‘oxyhemoglobin’/exp OR micronutrient:ti,ab OR vitamin:ti,ab OR vitamins:ti,ab OR ‘trace element’:ti,ab OR ‘trace elements’:ti,ab OR iron:ti,ab OR anemia:ti,ab OR anemic:ti,ab OR ‘iron deficiency anemia’/exp OR ‘iron deficiency’:ti,ab OR apoferritin:ti,ab OR ferritin:ti,ab OR ferritins:ti,ab OR ferrous:ti,ab OR transferrin:ti,ab OR transferrins:ti,ab OR ‘vitamin b complex’:ti,ab OR ‘vitamin b 12’:ti,ab OR cobamide:ti,ab OR cobalamin:ti,ab OR cyanocobalamin:ti,ab OR eritron:ti,ab OR hydroxocobalamin:ti,ab OR hemoglobin:ti,ab OR hemoglobins:ti,ab OR methemoglobin:ti,ab OR oxyhemoglobin:ti,ab OR oxyhemoglobins:ti,ab OR sulfhemoglobin:ti,ab OR ‘mean corpuscular volume’:ti,ab OR mcv:ti,ab OR ‘red blood cell’:ti,ab OR ‘red blood cells’:ti,ab OR rbc:ti,ab OR rbcs:ti,ab OR rdw:ti,ab OR ‘red blood cell distribution width’:ti,ab OR ‘erythrocyte indices’:ti,ab OR multimicronutrient:ti,ab OR multimicronutrients:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [english]/lim AND [humans]/lim AND [1980-2019]/py
  - #8 - #1 AND (#2 OR #3)
  - #9 - #4 OR #5
  - #10 - #6 OR #7
  - #11 - #8 AND #9 AND #10
  - #12 - #11 AND [article]/lim AND [humans]/lim AND [english]/lim AND [1980-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) searched: June 18, 2019
- Date range searched: January 1, 1980 to June 14, 2019
- Search terms:
  - #1 - (MH “Folic Acid+” OR “folic acid*” OR folate* OR folacin*)
  - #2 - (MH “Dietary Supplements+” OR “diet supplement*” OR “dietary supplement*” OR “food supplement*” OR “nutrition supplement*” OR “nutritional supplement*” OR “vitamin supplement*” OR multivitamin* OR “prenatal vitamin*” OR “maternal vitamin*”)
  - #3 - ((MH “Food, Fortified” OR “fortified food*” OR “enriched food*” OR “enriching food*” OR “fortifying food*” OR “food fortification” OR “folic acid fortified” OR “folic acid fortified food”) ) OR ( (MH “Food+” OR food OR foods) N6 (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich*)) )
  - #4 - (MH “Pregnancy+” OR MH “Pregnancy Complications+” OR MH “Prenatal Exposure Delayed Effects” OR MH “Maternal Exposure” OR MH “Expectant Mothers” OR pregnan* OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR MH “Mothers” OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR MH “Maternal Nutritional Physiology”)
  - #5 - (MH “Lactation” OR lactation OR lactating OR MH “Breast Feeding” OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed*)
  - #6 - (MH “Milk, Human” OR “breast milk” OR breast-milk OR “human milk” OR “mother’s milk” OR “mothers milk” OR breastmilk OR “human milk composition” OR “milk composition”)
  - #7 - (MH “Micronutrients” OR micronutrient* OR vitamin* OR vitamins OR “trace element*” OR MH “Iron” OR iron OR MH “Anemia” OR anemia OR anemic OR “iron deficien*” OR apoferritin* OR MH “Ferritin” OR ferritin* OR ferrous OR transferrin OR MH “Vitamin B Complex” OR “vitamin B complex” OR “Vitamin B 12” OR “Vitamin B12” OR MH “Vitamin B12 Deficiency” OR Cobamide* OR Cobalamin* OR Cyanocobalamin OR eritron OR hydroxocobalamin OR hemoglobin* OR MH “Hemoglobins” OR methemoglobin OR oxyhemoglobin* OR sulfhemoglobin* OR “mean corpuscular volume” OR mcv OR “red blood cell*” OR rbc OR rbcs OR rdw or “red blood cell distribution width” OR “erythrocyte indices” OR multimicronutrient*
  - #8 - #1 AND (#2 OR #3)
  - #9 - #4 OR #5
  - #10 - #6 OR #7
  - #11 - #8 AND #9 AND #10
  - #12 - #11 NOT (( MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication ) )
    Filters: English Language, Human, Published Date: 20000101 - 20190614

#### Gestational diabetes and Hypertensive disorders of pregnancy

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: July 12, 2019
- Date ranged searched: January 1, 1980 to July 12, 2019
- Search terms:
  - #1 - “Folic Acid”[mh] OR folic acid* OR folate* OR folacin* OR folic acid deficiency[mh]
  - #2 - “Food, Fortified”[Mesh] OR ((food[mh] OR food[tiab] OR foods[tiab]) AND (fortification[tiab] OR fortified[tiab] OR fortify[tiab] OR fortifies[tiab] OR fortifying[tiab] OR enrich*[tiab] OR supplement*[tiab])) OR fortified food* OR enriched food* OR enriching food* OR fortifying food* OR food fortification[tiab] OR “folic acid fortified”[tiab] OR folic acid fortified food* OR Dietary supplements[mh] OR diet supplement* OR dietary supplement* OR food supplement* OR nutrition supplement* OR nutritional supplement* OR vitamin supplement*[tiab] OR multivitamin*[tiab] OR prenatal vitamin*[tiab] OR maternal vitamin*[tiab] OR vitamins[mh]
  - #3 - “Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother[tiab] OR mothers[tiab] OR “Mothers”[Mesh] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpartum[tiab] OR post-partum[tiab] OR perinatal OR peri-natal OR puerperium[tiab] OR postpartal OR post-partal OR postnatal OR post delivery[tiab] OR after birth[tiab]
  - #4 - “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND (diabete*[tiab] OR diabetic*[tiab] OR pre-diabet*[tiab] OR prediabet*[tiab] OR blood sugar*[tiab] OR blood glucose[mh])) OR “fasting glucose”[tiab] OR “impaired fasting”[tiab] OR “fasting blood glucose”[tiab] OR “hemoglobin A1C”[tiab] OR “haemoglobin A1c” OR hba1c[tiab] OR “hba 1c”[tiab]OR glycated hemoglobin A[mh] OR glucose toleran* OR glucose intoleran*[tiab] OR glucose intolerance[mh] OR insulin resistance[mh] OR insulin resistan*[tiab] OR dysglycemi*[tiab] OR prediabetic state[mh] OR prediabet*[tiab] OR hyperglycemia[mh] OR hyperglycemi*[tiab] OR hyperinsulinism[mh] OR hyperinsulin*[tiab] OR diabet*[tiab] OR diabetes mellitus[mh:noexp] OR blood sugar*[tiab] OR hypertensi*[tiab] OR “Hypertension”[Mesh:NoExp] OR hypertension, pregnancy induced[mh] OR pregnancy induced hypertens*[tiab] OR “Proteinuria”[Mesh:noexp] OR proteinuri*[tiab] OR albuminuria[mh] OR Albuminuria[tiab] OR “Blood Pressure”[mh] OR “blood pressure”[tiab] OR systolic pressure*[tiab] OR diastolic pressure*[tiab] OR eclampsia*[tiab] OR pre-eclampsia[tiab] OR preeclampsia[tiab] OR pre-eclamptic[tiab] OR preeclamptic[tiab] OR eclamptic[tiab]
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
  - #8 - #7 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])
    Filters: Publication date from 1980/01/01 to 2019/07/12; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: July 12, 2019
- Date ranged searched: January 1, 1980 to July 12, 2019
- Search terms:
  - #1 - [mh “Folic Acid”] OR “folic acid” OR “folic acids” OR folate OR folates OR folacin OR folacins OR [mh “folic acid deficiency”]
  - #2 - [mh “Food, Fortified”] OR (([mh food] OR food OR foods) AND (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich* OR supplement*)) OR “fortified food” OR “fortified foods” OR “enriched food” OR “enriched foods” OR “enriching food” OR “enriching foods” OR “fortifying food” OR “fortifying foods” OR “food fortification” OR “folic acid fortified”
  - #3 - [mh “Dietary supplements”] OR diet supplement* OR dietary supplement* OR food supplement* OR nutrition supplement* OR nutritional supplement* OR vitamin supplement*[tiab] OR multivitamin*[tiab] OR prenatal vitamin*[tiab] OR maternal vitamin*[tiab]
  - #4 - [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR (pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth”):ti,ab,kw
  - #5 - [mh “Diabetes, Gestational”] OR (gestation*NEAR/4 (diabete* OR diabetic* OR pre-diabet*OR prediabet* OR “blood sugar” OR “blood glucose” OR [mh “blood glucose”])) OR “fasting glucose” OR “impaired fasting” OR “fasting blood glucose” OR “hemoglobin A1C” OR “haemoglobin A1c” OR hba1c OR “hba 1c” OR [mh “glycated hemoglobin A”] OR “glucose toleran*” OR “glucose intoleran*” OR [mh “glucose intolerance”] OR [mh “insulin resistance] OR “insulin resistan*” OR dysglycemi* OR [mh “prediabetic state”] OR prediabet* OR [mh “hyperglycemia”] OR hyperglycemi* OR [mh “hyperinsulinism”] OR hyperinsulin* OR diabet* OR “blood sugar*” OR Hypertension OR hypertensive OR [mh “Hypertension”] OR [mh “hypertension, pregnancy induced”] OR “pregnancy induced hypertension” OR [mh “Proteinuria”] OR proteinuri* OR [mh “albuminuria”] OR Albuminuria OR [mh “Blood Pressure”] OR “blood pressure” OR “systolic pressure” OR “diastolic pressure” OR eclampsia* OR pre-eclampsia OR preeclampsia OR pre-eclamptic OR preeclamptic OR eclamptic OR [mh “eclampsia”]
  - #6 - #1 AND (#2 OR #3)
  - #7 - #6 AND #4
  - #8 - #7 AND #5
    Filters: publication year from 2000 to 2019, Trials

##### Embase

- Provider: Elsevier
- Date(s) searched: July 12, 2019
- Date ranged searched: January 1, 1980 to July 12, 2019
- Search terms:
  - #1 - (‘folic acid’/exp OR ‘folic acid*’:ti,ab OR folate*:ti,ab OR folacin*:ti,ab OR ‘folic acid deficiency’/de) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #2 - (‘diet supplementation’/exp OR ‘dietary supplement’/exp OR ‘diet supplement*’:ti,ab OR ‘dietary supplement*’:ti,ab OR ‘food supplement*’:ti,ab OR ‘nutrition supplement*’:ti,ab OR ‘nutritional supplement*’:ti,ab OR ‘vitamin supplement*’:ti,ab OR multivitamin*:ti,ab OR ‘prenatal vitamin*’:ti,ab OR ‘maternal vitamin*’:ti,ab OR ‘fortified food’/exp OR ((‘food’/exp OR foods:ti,ab OR food:ti,ab) AND (fortification:ti,ab OR fortified:ti,ab OR fortify:ti,ab OR fortifies:ti,ab OR fortifying:ti,ab OR enrich*:ti,ab)) OR ‘fortified food*’:ti,ab OR ‘enriched food*’:ti,ab OR ‘enriching food*’:ti,ab OR ‘fortifying food*’:ti,ab OR ‘food fortification’:ti,ab OR ‘folic acid fortified’:ti,ab) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #3 - (pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/exp/mj OR ‘maternal nutrition’/mj) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #4 - (((‘maternal diabetes mellitus’:ti,ab OR (gestation*:ti,ab AND ((diabete*:ti,ab OR diabetic*:ti,ab OR ‘pre diabet*’:ti,ab OR prediabet*:ti,ab OR blood) AND sugar*:ti,ab OR ‘glucose blood level’/exp)) OR ‘fasting glucose’:ti,ab OR ‘impaired fasting’:ti,ab OR ‘fasting blood glucose’:ti,ab OR ‘hemoglobin a1c’:ti,ab OR haemoglobin) AND a1c:ti,ab OR hb) AND alc:ti,ab OR hba1c:ti,ab OR ‘glucose toleran*’:ti,ab OR ‘glucose intoleran*’:ti,ab OR ‘insulin resistan*’:ti,ab OR dysglycemi*:ti,ab OR prediabet*:ti,ab OR hyperglycemi*:ti,ab OR hyperglycaemi*:ti,ab OR hyperinsulin*:ti,ab OR diabet*:ti,ab OR ‘blood sugar*’:ti,ab OR ‘diabetes mellitus gravidarum’:ti,ab OR ‘pregnancy diabetes mellitus’/exp OR ‘hemoglobin a1c’/exp OR ‘glucose intolerance’/exp OR ‘insulin resistance’/exp OR ‘impaired glucose tolerance’/exp OR ‘hyperglycemia’/exp OR ‘hyperinsulinism’/de OR ‘hyperinsulinemia’/de OR ‘diabetes mellitus’/de OR hypertensi*:ti,ab OR ‘pregnancy induced hypertens*’:ti,ab OR proteinuri*:ti,ab OR albuminuria:ti,ab OR ‘blood pressure’:ti,ab OR ‘systolic pressure*’:ti,ab OR ‘diastolic pressure*’:ti,ab OR eclampsia*:ti,ab OR ‘pre eclampsia’:ti,ab OR preeclampsia:ti,ab OR ‘pre eclamptic’:ti,ab OR preeclamptic:ti,ab OR eclamptic:ti,ab OR ‘hypertension’/de OR ‘prehypertension’/de OR ‘maternal hypertension’/exp OR ‘elevated blood pressure’/de OR ‘proteinuria’/exp OR ‘eclampsia and preeclampsia’/exp OR ‘pregnancy toxemia’/de OR ‘pregnancy toxemia*’:ti,ab OR ‘pregnancy toxaemia*’:ti,ab OR ‘toxicosis gravidarum’:ti,ab OR (((pregnancy OR eclampt* OR eclamps* OR gestation* OR gravidarum) NEAR/4 (toxem* OR toxaem*)):ti,ab)) AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
  - #8 - #7 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [1980-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) searched: July 12, 2019
- Date ranged searched: January 1, 1980 to July 12, 2019
- Search terms:
  - #1 - (MH “folic acid”) OR “folic acid” OR “folic acids” OR folate OR folates OR folacin OR folacins OR (MH “Folic Acid Deficiency”)
  - #2 - ( (MH “Food, Fortified” OR “fortified food*” OR “enriched food*” OR “enriching food*” OR “fortifying food*” OR “food fortification” OR “folic acid fortified” OR “folic acid fortified food”) ) OR ( (MH “Food+” OR food OR foods) N6 (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich* OR supplement*))
  - #3 - (MH “Dietary Supplements+” OR “diet supplement*” OR “dietary supplement*” OR “food supplement*” OR “nutrition supplement*” OR “nutritional supplement*” OR “vitamin supplement*” OR multivitamin* OR “prenatal vitamin*” OR “maternal vitamin*” OR (MH “vitamins”)
  - #4 - pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR (MH “Pregnancy+”) OR (MH “Pregnancy Complications”) OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Maternal Exposure”) OR (MH “Expectant Mothers”) OR (MH “Mothers”) OR (MH “Puerperium”) OR (MH “Maternal Nutritional Physiology”) OR (MH “Postnatal Period”)
  - #5 - (MH “Diabetes Mellitus, Gestational”) OR (MH “Hemoglobin A, Glycosylated”) OR (MH “Glucose Intolerance”) OR (MH “Insulin Resistance”) OR (MH “Prediabetic State”) OR (MH “Hyperglycemia”) OR “hyperglycemia” OR (MH “Hyperinsulinism”) OR (MH “Hyperinsulinemia”) OR (MH “Hypertension”) OR (MH “Proteinuria”) OR (MH “Albuminuria”) OR (MH “Blood Pressure”) OR (MH “Eclampsia”) OR (MH “Pre-Eclampsia”) OR (MH “HELLP Syndrome”) OR (gestation* N5 (diabete* OR diabetic* OR pre-diabet* OR prediabet* OR “blood sugar” OR (MH “Blood Glucose”) )) OR “fasting glucose” OR “impaired fasting” OR “fasting blood glucose” OR “hemoglobin A1C” OR “haemoglobin A1c” OR hbalc OR hba1c OR “glucose intoleran*” OR “glucose toleran*” OR “insulin resistance” OR dysglycemic OR dysglycemia OR “prediabetic state” OR prediabet* OR hyperglycemia OR hyperinsulin* OR diabet* OR “blood sugar” OR “blood sugars” OR hypertensi* OR “pregnancy induced hypertension” OR proteinuria OR Albuminuria OR “blood pressure” OR “systolic pressure*” OR “diastolic pressure*” OR eclampsia* OR pre-eclampsia OR preeclampsia OR pre-eclamptic OR preeclamptic OR eclamptic
  - #6 - #1 AND (#2 OR #3)
  - #7 - #6 AND #4
  - #8 - #7 AND #5
  - #9 - #8 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”)
    Filters: English Language, Human, Published Date: 20000101 - 20190712

#### Developmental milestones, including neurocognitive development

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: July 3, 2019
- Date ranged searched: January 1, 1980 to July 3, 2019
- Search terms:
  - #1 - “Folic Acid”[mh] OR folic acid* OR folate* OR folacin* OR folic acid deficiency[mh]
  - #2 - “Food, Fortified”[Mesh] OR ((food[mh] OR food[tiab] OR foods[tiab]) AND (fortification[tiab] OR fortified[tiab] OR fortify[tiab] OR fortifies[tiab] OR fortifying[tiab] OR enrich*[tiab] OR supplement*[tiab])) OR fortified food* OR enriched food* OR enriching food* OR fortifying food* OR food fortification[tiab] OR “folic acid fortified”[tiab] OR folic acid fortified food* OR Dietary supplements[mh] OR diet supplement* OR dietary supplement* OR food supplement* OR nutrition supplement* OR nutritional supplement* OR vitamin supplement*[tiab] OR multivitamin*[tiab] OR prenatal vitamin*[tiab] OR maternal vitamin*[tiab] OR vitamins[mh]
  - #3 - (“Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother[tiab] OR mothers[tiab] OR “Mothers”[Mesh] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpartum[tiab] OR post-partum[tiab] OR perinatal OR peri-natal OR puerperium[tiab] OR postpartal OR post-partal OR postnatal OR post delivery[tiab] OR after birth[tiab] OR “Lactation”[Mesh] OR lactation[tiab] OR lactating[tiab] OR “Breast Feeding”[Mesh] OR breastfeeding[tiab] OR breast-feeding[tiab] OR breast feed* OR breast-feed*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed* OR “Milk, Human”[Mesh] OR human milk[tiab] OR nursing women[tiab]))
  - #4 - “Mental Disorders”[Mesh] OR mental disorder*[tiab] OR “Cognition”[Mesh] OR cognition[tiab] OR cognitive[tiab] OR metacognition[tiab] OR neurocognitive[tiab] OR neurodevelop*[tiab] OR neurological[tiab] OR “Cognitive Dysfunction”[Mesh] OR “Depressive Disorder”[Mesh] OR “Depression”[Mesh] OR depression[tiab] OR “Psychomotor Performance”[Mesh] OR motor skill*[tiab] OR “Executive Function”[Mesh] OR executive function* OR “Attention Deficit and Disruptive Behavior Disorders”[Mesh] OR attention deficit disorder*[tiab] OR ADHD[tiab] OR “Child Behavior Disorders”[Mesh] OR developmental disorder*[tiab] OR “Autism Spectrum Disorder”[Mesh] OR Autism[tiab] OR Asperger[tiab] OR language processing[tiab] OR language delay* OR “Child Development”[Mesh] OR child develop*[tiab] OR “Developmental Disabilities”[Mesh] OR developmental delay[tiab] OR developmental disabilit*[tiab] OR “Motor Skills Disorders”[Mesh] OR motor skill*[tiab] OR “Problem Solving”[Mesh] OR developmental domain* OR academic performance[tiab] OR academic achievement[tiab] OR academic failure[tiab] OR academic success*[tiab] OR Growth[mh:noexp] OR “Growth Charts”[Mesh] OR “growth and development” [Subheading] OR “growth and development”[tiab] OR “Growth and Development”[Mesh:noexp] OR “Growth”[tiab] OR development*[tiab] OR “Child Development”[Mesh] OR movement[mh] OR “Motor Skills”[Mesh] OR “Nonverbal Communication”[Mesh] OR Standing[tiab] OR sitting[tiab] OR walking[tiab] OR crawling[tiab] OR Ages and Stages Questionnaire* OR ASQ[tiab] OR developmental delay[mh] OR “bayley scales”[tiab] OR verbal behavior[mh] OR talk*[tiab]
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
  - #8 - #7 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 1980/01/01 to 2019/07/03; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: July 3, 2019
- Date ranged searched: January 1, 1980 to July 3, 2019
- Search terms:
  - #1 - [mh “Folic Acid”] OR “folic acid” OR “folic acids” OR folate OR folates OR folacin OR folacins OR [mh “folic acid deficiency”]
  - #2 - [mh “Food, Fortified”] OR (([mh food] OR food OR foods) AND (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich* OR supplement*)) OR “fortified food” OR “fortified foods” OR “enriched food” OR “enriched foods” OR “enriching food” OR “enriching foods” OR “fortifying food” OR “fortifying foods” OR “food fortification” OR “folic acid fortified” OR [mh “Dietary supplements”] OR diet supplement* OR dietary supplement* OR food supplement* OR nutrition supplement* OR nutritional supplement* OR vitamin supplement*[tiab] OR multivitamin*[tiab] OR prenatal vitamin*[tiab] OR maternal vitamin*[tiab]
  - #3 - [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR (pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”):ti,ab,kw
  - #4 - [mh ^Growth] OR [mh “Child Development”] OR [mh “Growth Charts”] OR “growth and development” OR [mh ^“Growth and Development”] OR [mh “Child Development”] OR (child NEAR/1 develop*):ti,ab OR [mh movement] OR [mh “Motor Skills”] OR [mh “Nonverbal Communication”] OR “Bayley Scales of Infant Development” OR Standing OR stands OR sits OR sitting OR walk OR walking OR crawling OR crawl OR “Ages and Stages Questionnaire” OR ASQ OR [mh “Mental Disorders”] OR [mh Cognition] OR [mh “Cognitive Dysfunction”] OR [mh “Depressive Disorder”] OR [mh Depression] OR [mh “Psychomotor Performance”] OR [mh “Executive Function”] OR [mh “Attention Deficit and Disruptive Behavior Disorders”] OR [mh “Child Behavior Disorders”] OR [mh “Autism Spectrum Disorder”] OR [mh “Child Development”] OR [mh “Developmental Disabilities”] OR [mh “Motor Skills Disorders”] OR [mh “Problem Solving”] OR (“mental disorder*” OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR depression OR anxiety OR motor skill* OR “attention deficit disorder*” OR ADHD OR “developmental disorder*” OR Autism OR Asperger OR “language processing” OR “language delay*” OR “child develop*” OR “developmental delay” OR “developmental disabilit*” OR “motor skill*” OR “developmental domain*” OR “academic performance” OR “academic achievement” OR “academic failure” OR “academic success*”):ti,ab,kw
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
    Filters: publication year from 2000 to 2019, Trials

##### Embase

- Provider: Elsevier
- Date(s) searched: July 3, 2019
- Date ranged searched: January 1, 1980 to July 3, 2019
- Search terms:
  - #1 - (‘folic acid’/exp OR ‘folic acid*’:ti,ab OR folate*:ti,ab OR folacin*:ti,ab OR ‘folic acid deficiency’/de)
  - #2 - (‘diet supplementation’/exp OR ‘dietary supplement’/exp OR ‘diet supplement*’:ti,ab OR ‘dietary supplement*’:ti,ab OR ‘food supplement*’:ti,ab OR ‘nutrition supplement*’:ti,ab OR ‘nutritional supplement*’:ti,ab OR ‘vitamin supplement*’:ti,ab OR multivitamin*:ti,ab OR ‘prenatal vitamin*’:ti,ab OR ‘maternal vitamin*’:ti,ab) OR (‘fortified food’/exp OR ((‘food’/exp OR foods:ti,ab OR food:ti,ab) AND (fortification:ti,ab OR fortified:ti,ab OR fortify:ti,ab OR fortifies:ti,ab OR fortifying:ti,ab OR enrich*:ti,ab)) OR ‘fortified food*’:ti,ab OR ‘enriched food*’:ti,ab OR ‘enriching food*’:ti,ab OR ‘fortifying food*’:ti,ab OR ‘food fortification’:ti,ab OR ‘folic acid fortified’:ti,ab)
  - #3 - pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR lactation:ab,ti OR lactating:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti OR ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/exp/mj OR ‘maternal nutrition’/mj OR ‘lactation’/mj OR ‘breast feeding’/exp/mj OR ‘breast milk’/exp/mj
  - #4 - ‘mental disorder*’:ab,ti OR cognition:ab,ti OR cognitive:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR neurodevelop*:ab,ti OR neurological:ab,ti OR depression:ab,ti OR ‘motor skill*’:ab,ti OR ‘executive function’:ab,ti OR ‘attention deficit disorder’:ab,ti OR adhd:ab,ti OR ‘developmental disorder’:ab,ti OR ‘language processing’:ab,ti OR ‘language delay*’:ab,ti OR ‘child develop*’:ab,ti OR autism:ab,ti OR asperger:ab,ti OR ‘developmental delay’:ab,ti OR ‘developmental disabilit*or developmental domain*’:ab,ti OR ‘academic performance’:ab,ti OR ‘academic achievement’:ab,ti OR ‘academic failure’:ab,ti OR ‘academic success*’:ab,ti OR ‘mental disease’/exp OR ‘cognition’/exp OR ‘cognitive defect’/exp OR ‘depression’/exp OR ‘anxiety’/exp OR ‘psychomotor performance’/exp OR ‘executive function’/exp OR ‘attention deficit disorder’/exp OR ‘behavior disorder’/exp OR ‘autism’/exp OR ‘child development’/exp OR ‘developmental disorder’/exp OR ‘psychomotor disorder’/exp OR ‘problem solving’/exp OR growth and development:ti,ab OR growth:ti,ab OR develop*:ti,ab OR ‘child develop*’:ti,ab OR standing:ti,ab OR sitting:ti,ab OR walking:ti,ab OR crawling:ti,ab OR crawl:ti,ab OR asq:ti,ab OR ‘ages and stages questionnaire’:ti,ab OR child develop*:ti,ab OR motor develop*:ti,ab OR ‘motor skill*’:ti,ab OR ‘motor function’:ti,ab OR ‘motor ability’:ti,ab OR ‘motor performance’:ti,ab OR ‘postnatal development’:ti,ab OR ‘Ages and Stages Questionnaire’*:ti,ab OR ASQ:ti,ab OR ‘bayley scale*’:ti,ab OR talk*:ti,ab]OR ‘postnatal growth’/exp OR ‘human development’/exp OR ‘postnatal development’/exp OR ‘motor performance’/exp OR ‘nonverbal communication’/exp OR ‘verbal behavior’/exp OR ‘standing’/exp OR ‘sitting’/exp OR ‘walking’/exp OR ‘crawling’/exp OR ‘growth chart’/exp
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
  - #8 - #7 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) searched: July 3, 2019
- Date ranged searched: January 1, 1980 to July 3, 2019
- Search terms:
  - #1 - (MH “folic acid”) OR “folic acid” OR “folic acids” OR folate OR folates OR folacin OR folacins OR (MH “Folic Acid Deficiency”)
  - #2 - ( (MH “Food, Fortified” OR “fortified food*” OR “enriched food*” OR “enriching food*” OR “fortifying food*” OR “food fortification” OR “folic acid fortified” OR “folic acid fortified food”) ) OR ( (MH “Food+” OR food OR foods) N6 (fortification OR fortified OR fortify OR fortifies OR fortifying OR enrich* OR supplement*)) OR (MH “Dietary Supplements+” OR “diet supplement*” OR “dietary supplement*” OR “food supplement*” OR “nutrition supplement*” OR “nutritional supplement*” OR “vitamin supplement*” OR multivitamin* OR “prenatal vitamin*” OR “maternal vitamin*” OR (MH “vitamins”)
  - #3 - pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women” OR (MH “Pregnancy+”) OR (MH “Pregnancy Complications”) OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Maternal Exposure”) OR (MH “Expectant Mothers”) OR (MH “Mothers”) OR (MH “Puerperium”) OR (MH “Maternal Nutritional Physiology”) OR (MH “Postnatal Period”) OR (MH “Lactation”) OR (MH “Breast Feeding”) OR (MH “Milk, Human”)
  - #4 - (MH “Mental Disorders”) OR mental disorder* OR (MH “Cognition”) OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR “cognitive dysfunction” OR “depressive disorders OR (MH “Depression”) OR depression OR (MH “Anxiety”) OR anxiety OR (MH “Psychomotor Performance”) OR motor skill* OR (MH “Executive Function”) OR executive function* OR (MH “Attention Deficit Hyperactivity Disorder”) OR attention deficit disorder* OR ADHD OR (MH “Child Behavior Disorders”) OR developmental disorder* OR (MH “Autistic Disorder”) OR autism OR Asperger OR “language processing” OR language delay* OR (MH “Child Development”) OR child develop* OR (MH “Developmental Disabilities”) OR developmental delay* OR developmental disabilit* OR (MH “Motor Skills Disorders”) OR motor skill* OR (MH “Problem Solving”) OR developmental domain* OR “academic performance” OR “academic achievement” OR “academic failure” OR academic success* OR “growth and development” OR growth OR develop* OR “child develop*” OR movement OR “motor skills” OR “motor development” OR “motor skill*” OR “motor function” OR “motor ability” OR “motor performance” OR “growth chart*” OR “infant development” OR “language development” OR standing OR stands OR sitting OR sits OR walking OR walk OR crawling OR crawl OR “ages and stages questionnaire*” OR ASQ OR “bayley scales of infant development” OR (MH “Growth+”) OR (MH “Human Development+”) OR (MH “Language Development”) OR (MH “Nonverbal Communication+”) OR (MH “Psychomotor Performance+”) OR (MH “Locomotion+”)
  - #5 - #1 AND #2
  - #6 - #5 AND #3
  - #7 - #6 AND #4
  - #8 - #7 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”)
    Filters: English Language, Human, Published Date: 20000101 - 20190703

## LITERATURE SEARCH AND SCREENING RESULTS

The flow charts (Figure 6, Figure 7, and Figure 8) below illustrate the literature search and screening results for articles examining the systematic review questions. One search (Figure 6) simultaneously addressed two systematic reviews to answer the following questions: What is the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation and 1) micronutrient status and 2) human milk composition. A second search (Figure 7) simultaneously addressed two systematic reviews to answer the following questions: What is the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and risk of 1) gestational diabetes and 2) hypertensive disorders of pregnancy. A third search (Figure 8) addressed the systematic review to answer the question: What is the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation and developmental milestones, including neurocognitive development, in the child. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Excluded Articles (Table 25, Table 26, and Table 27) for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 6 Flow chart of literature search and screening results: Micronutrient status and Human milk composition^xlix^

This flow chart illustrates the literature search and screening results for articles examining the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation and 1) micronutrient status and 2) human milk composition. The literature search yielded 7917 articles (4512 after duplicates were removed). During title screening, 2663 articles were screened out. During abstract screening, 1517 articles were screened out. During full-text screening, 316 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 16 articles were included in the systematic review at the end of the search and screening process, including 14 for the micronutrient status review and 4 for the human milk composition review.

Figure 7 Flow chart of literature search and screening results: Gestational diabetes and Hypertensive disorders of pregnancy^l^

This flow chart illustrates the literature search and screening results for articles examining the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and risk of 1) gestational diabetes and 2) hypertensive disorders of pregnancy. The literature search yielded 829 articles (622 after duplicates were removed). During title screening, 411 articles were screened out. During abstract screening, 135 articles were screened out. During full-text screening, 68 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 8 articles were included in the systematic review at the end of the search and screening process, including 1 for the gestational diabetes review and 8 for the hypertension review.

Figure 8 Flow chart of literature search and screening results: Developmental milestones

This flow chart illustrates the literature search and screening results for articles examining the relationship between folic acid from supplements and/or fortified foods consumed before and during pregnancy and lactation and developmental milestones, including neurocognitive development. The literature search yielded 2728 articles (1831 after duplicates were removed). During title screening, 1671 articles were screened out. During abstract screening, 101 articles were screened out. During full-text screening, 53 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 6 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The tables below (Table 25, Table 26, and Table 27) list the articles excluded after full-text screening, and include the categories of inclusion and exclusion criteria (see Table 24) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 25 Articles excluded after full text screening with rationale for exclusion: Micronutrient status and Human milk composition

| Citation | Rationale
1. | Abdollahi, Z, Elmadfa, I, Djazayery, A, Golalipour, MJ, Sadighi, J, Salehi, F, Sadeghian Sharif, S. Efficacy of flour fortification with folic acid in women of childbearing age in Iran. Ann Nutr Metab. 2011. 58:188–96. doi:10.1159/000329726.21757892 21757892 | Population
2. | Adediran, A, Gbadegesin, A, Adeyemo, TA, Akinbami, AA, Akanmu, AS, Osunkalu, V, Ogbenna, AA, Oremosu, A. Haemoglobin and ferritin concentrations of pregnant women at term. Obstet Med. 2011. 4:152–5. doi:10.1258/om.2011.110033.27579114 | Country
3. | Afifi, M. Anemia in pregnancy at South Sharqiya health centers, Oman. J Egypt Public Health Assoc. 2003. 78:39–54.17219910 | Intervention/Exposure; Comparator
4. | Agodi, A, Barchitta, M, Quattrocchi, A, Marchese, AE, Boffetta, P. Folate deficiency is not associated with increased mitochondrial genomic instability: results from dietary intake and lymphocytic mtDNA 4977-bp deletion in healthy young women in Italy. Mutagenesis. 2014. 29:101–6. doi:10.1093/mutage/get065.24419225 | Intervention/Exposure; Outcome
5. | Agodi, A, Barchitta, M, Valenti, G, Quattrocchi, A, Marchese, AE, Oliveri Conti, G, Fallico, R, Sciacca, S, Ferrante, M. Dietary folate intake and blood biomarkers reveal high-risk groups in a mediterranean population of healthy women of childbearing potential. Annals of Nutrition and Metabolism. 2013. 63:179–185. doi:10.1159/000346962.24051386 | Study Design; Population
6. | Albsoul-Younes, AM, Al-Ramahi, RJ, Al-Safi, SA. Frequency of anemia in pregnancy in Northern Jordan. Saudi Medical Journal. 2004. 25:1525–1527.15494849 | Intervention/Exposure; Comparator
7. | Alevizos, AG, Stamatiou, KN, Lacroix, RE, Natzar, MA, Mihas, CC, Bovis, KD, Panagopoulos, PP, Mariolis, AD. Dietary intake in immigrant Arabian pregnant women. Saudi Med J. 2006. 27:1019–21.16830023 | Intervention/Exposure; Outcome
8. | Allen, LH, Peerson, JM. Impact of multiple micronutrient versus iron-folic acid supplements on maternal anemia and micronutrient status in pregnancy. Food & Nutrition Bulletin. 2009. 30:S527–32.20120794 | Study Design
9. | Anderson, CA, Beresford, SA, McLerran, D, Lampe, JW, Deeb, S, Feng, Z, Motulsky, AG. Response of serum and red blood cell folate concentrations to folic acid supplementation depends on methylenetetrahydrofolate reductase C677T genotype: results from a crossover trial. Mol Nutr Food Res. 2013. 57:637–44. doi:10.1002/mnfr.201200108.23456769 | Population
10. | Antal, M. Nutritional status of Hungarian pregnant women. Forum Nutr. 2003. 56:229–31.15806876 | Study Design; Outcome
11. | Arbour, L, Rupps, R, MacDonald, S, Forth, M, Yang, J, Nowdluk, M, Osborne, G. Congenital heart defects in Canadian Inuit: is more folic acid making a difference? Alaska Med. 2007. 49:163–6.17929627 | Study Design; Intervention/Exposure
12. | Ars, CL, Nijs, IM, Marroun, HE, Muetzel, R, Schmidt, M, Steenweg-de Graaff, J, van der Lugt, A, Jaddoe, VW, Hofman, A, Steegers, EA, Verhulst, FC, Tiemeier, H, White, T. Prenatal folate, homocysteine and vitamin B12 levels and child brain volumes, cognitive development and psychological functioning: the Generation R Study. Br J Nutr. 2016. 1–9. doi:10.1017/s0007114515002081. | Study Design
13. | Atukorala, TM, de Silva, LD, Dechering, WH, Dassenaeike, TS, Perera, RS. Evaluation of effectiveness of iron-folate supplementation and anthelminthic therapy against anemia in pregnancy--a study in the plantation sector of Sri Lanka. Am J Clin Nutr. 1994. 60:286–92. doi:10.1093/ajcn/60.2.286.8030609 | Intervention/Exposure; Country
14. | Aydin, H, Arisoy, R, Karaman, A, Erdogdu, E, Cetinkaya, A, Geckinli, BB, Simsek, H, Demirci, O. Evaluation of maternal serum folate, vitamin B12, and homocysteine levels and factor V Leiden, factor II g.20210G>A, and MTHFR variations in prenatally diagnosed neural tube defects. Turk J Med Sci. 2016. 46:489–94. doi:10.3906/sag-1502-128.27511516 | Intervention/Exposure
15. | Baker, H, DeAngelis, B, Holland, B, Gittens-Williams, L, Barrett, T, Jr. Vitamin profile of 563 gravidas during trimesters of pregnancy. J Am Coll Nutr. 2002. 21:33–7.11838885 | Comparator
16. | Baker, H, Frank, O, Deangelis, B, Feingold, S, Kaminetzky, HA. Role of placenta in maternal-fetal vitamin transfer in humans. Am J Obstet Gynecol. 1981. 141:792–6. doi:10.1016/0002-9378(81)90706-7.7198383 | Study Design; Intervention/Exposure
17. | Baker, PN, Wheeler, SJ, Sanders, TA, Thomas, JE, Hutchinson, CJ, Clarke, K, Berry, JL, Jones, RL, Seed, PT, Poston, L. A prospective study of micronutrient status in adolescent pregnancy. American Journal of Clinical Nutrition. 2009. 89:1114–1124. doi:10.3945/ajcn.2008.27097. | Intervention/Exposure
18. | Bank, MR, Kirksey, A, West, K, Giacoia, G. Effect of storage time and temperature on folacin and vitamin C levels in term and preterm human milk. Am J Clin Nutr. 1985. 41:235–42. doi:10.1093/ajcn/41.2.235.3969932 | Intervention/Exposure; Comparator
19. | Barnabe, A, Alessio, AC, Bittar, LF, de Moraes Mazetto, B, Bicudo, AM, de Paula, EV, Hoehr, NF, Annichino-Bizzacchi, JM. Folate, vitamin B12 and Homocysteine status in the post-folic acid fortification era in different subgroups of the Brazilian population attended to at a public health care center. Nutr J. 2015. 14:19. doi:10.1186/s12937-015-0006-3.25886278 | Intervention/Exposure; Comparator
20. | Bar-Oz, B, Koren, G, Nguyen, P, Kapur, BM. Folate fortification and supplementation--are we there yet? Reprod Toxicol. 2008. 25:408–12. doi:10.1016/j.reprotox.2008.04.010.18550330 | Comparator; Population
21. | Barzilay, E, Moon, A, Plumptre, L, Masih, SP, Sohn, KJ, Visentin, CE, Ly, A, Malysheva, O, Croxford, R, Caudill, MA, O’Connor, DL, Kim, YI, Berger, H. Fetal one-carbon nutrient concentrations may be affected by gestational diabetes. Nutr Res. 2018. 55:57–64. doi:10.1016/j.nutres.2018.04.010.29914628 | Intervention/Exposure
22. | Becker, W, Lindroos, AK, Nalsen, C, Warensjo Lemming, E, Ohrvik, V. Dietary habits, nutrient intake and biomarkers for folate, vitamin D, iodine and iron status among women of childbearing age in Sweden. Ups J Med Sci. 2016. 121:271–275. doi:10.1080/03009734.2016.1201176.27560303 | Study Design; Population
23. | Bentley, S, Hermes, A, Phillips, D, Daoud, YA, Hanna, S. Comparative Effectiveness of a Prenatal Medical Food to Prenatal Vitamins on Hemoglobin Levels and Adverse Outcomes: A Retrospective Analysis. Clinical Therapeutics. 2011. 33:204–210. doi:10.1016/j.clinthera.2011.02.010.21440300 | Intervention/Exposure; Comparator
24. | Berg, MJ, Van Dyke, DC, Chenard, C, Niebyl, JR, Hirankarn, S, Bendich, A, Stumbo, P. Folate, zinc, and vitamin B-12 intake during pregnancy and postpartum. J Am Diet Assoc. 2001. 101:242–5.11271698 | Comparator
25. | Berg, MJ, Van Dyke, DC, Chenard, C, Niebyl, JR, Hirankarn, S, Bendich, A, Stumbo, P. Research and professional briefs. Folate, zinc, and vitamin B-12 intake during pregnancy and postpartum. Journal of the American Dietetic Association. 2001. 101:242–245.11271698 | Intervention/Exposure
26. | Bergen, N, Jaddoe, V, Timmermans, S, Hofman, A, Lindemans, J, Russcher, H, Raat, H, Steegers-Theunissen, R, Steegers, E. Homocysteine and folate concentrations in early pregnancy and the risk of adverse pregnancy outcomes: the Generation R Study. BJOG: An International Journal of Obstetrics & Gynaecology. 2012. 119:739–751. doi:10.1111/j.1471-0528.2012.03321.x.22489763 | Study Design
27. | Beveridge, S, Sancak, O, Barella, L, Bieri, G. Multivitamin/multimineral preparation containing folic acid and L-5-methyltetrahydrofolate rapidly increases and sustains RBC folate levels. Annals of nutrition and metabolism.. 2011. 58:383. doi:10.1159/000334393. | Abstract
28. | Bjelakovic, L, Kocic, G, Stojanovic, I, Jevtovic-Stoimenov, T, Najman, S, Sokolovic, D, Stojanovic, S, Bjelakovic, G. Folic acid effect on arginase activity in human colostrum and mature milk. Pteridines. 2012. 23:33–38. doi:10.1515/pteridines.2012.23.1.33. | Outcome
29. | Bjørke-Monsen, AL, Roth, C, Magnus, P, Midttun, O, Nilsen, RM, Reichborn-Kjennerud, T, Stoltenberg, C, Susser, E, Vollset, SE, Ueland, PM. Maternal B vitamin status in pregnancy week 18 according to reported use of folic acid supplements. Mol Nutr Food Res. 2013. 57:645–52. doi:10.1002/mnfr.201200114.23001761 | Study Design
30. | Bjørke-Monsen, AL, Ulvik, A, Nilsen, RM, Midttun, Ø, Roth, C, Magnus, P, Stoltenberg, C, Vollset, SE, Reichborn-Kjennerud, T, Ueland, PM. Impact of Pre-Pregnancy BMI on B Vitamin and Inflammatory Status in Early Pregnancy: An Observational Cohort Study. Nutrients. 2016. 8:776. doi:10.3390/nu8120776. | Study Design; Intervention/Exposure
31. | Blot, I, Rey, A, Kaltwasser, JP, Francoual, J, Papiernik, E, Tchernia, G. Folate and iron deficiencies in mothers and their newborn children. Blut. 1982. 44:297–303.7074229 | Study Design; Intervention/Exposure
32. | Blunden, CH, Inskip, HM, Robinson, SM, Cooper, C, Godfrey, KM, Kendrick, TR. Postpartum depressive symptoms: the B-vitamin link. Ment Health Fam Med. 2012. 9:5–13.23277793 | Comparator; Outcome
33. | Boeke, CE, Baccarelli, A, Kleinman, KP, Burris, HH, Litonjua, AA, Rifas-Shiman, SL, Tarantini, L, Gillman, M. Gestational intake of methyl donors and global LINE-1 DNA methylation in maternal and cord blood: prospective results from a folate-replete population. Epigenetics. 2012. 7:253–60. doi:10.4161/epi.7.3.19082.22430801 | Outcome
34. | Bopape, MM, Mbhenyane, XG, Alberts, M. The prevalence of anaemia and selected micronutrient status in pregnant teenagers of Polokwane Municipality in the Limpopo Province. South African Journal of Clinical Nutrition. 2008. 21:332–336. | Country
35. | Bortolus, R, Blom, F, Filippini, F, van Poppel, MN, Leoncini, E, de Smit, DJ, Benetollo, PP, Cornel, MC, de Walle, HE, Mastroiacovo, P. Prevention of congenital malformations and other adverse pregnancy outcomes with 4.0 mg of folic acid: community-based randomized clinical trial in Italy and the Netherlands. BMC Pregnancy Childbirth. 2014. 14:166. doi:10.1186/1471-2393-14-166.24884885 | Study Design
36. | Bouwland-Both, MI, Steegers, EAP, Lindemans, J, Russcher, H, Hofman, A, Geurts-Moespot, AJ, Sweep, FCGJ, Jaddoe, VWV, Steegers-Theunissen, RPM. Maternal soluble fms-like tyrosine kinase-1, placental growth factor, plasminogen activator inhibitor-2, and folate concentrations and early fetal size: the Generation R study. American Journal of Obstetrics & Gynecology. 2013. 209:121.e1–121.e11. doi:10.1016/j.ajog.2013.04.009.23583216 | Study Design; Intervention/Exposure; Comparator
37. | Boyles, AL, Wilcox, AJ, Taylor, JA, Shi, M, Weinberg, CR, Meyer, K, Fredriksen, A, Ueland, PM, Johansen, AM, Drevon, CA, Jugessur, A, Trung, TN, Gjessing, HK, Vollset, SE, Murray, JC, Christensen, K, Lie, RT. Oral facial clefts and gene polymorphisms in metabolism of folate/one-carbon and vitamin A: a pathway-wide association study. Genet Epidemiol. 2009. 33:247–55. doi:10.1002/gepi.20376.19048631 | Outcome
38. | Brantsaeter, AL, Haugen, M, Hagve, TA, Aksnes, L, Rasmussen, SE, Julshamn, K, Alexander, J, Meltzer, HM. Self-reported dietary supplement use is confirmed by biological markers in the Norwegian Mother and Child Cohort Study (MoBa). Ann Nutr Metab. 2007. 51:146–54. doi:10.1159/000103275.17536192 | Study Design; Intervention/Exposure; Comparator
39. | Braun, JM, Froehlich, T, Kalkbrenner, A, Pfeiffer, CM, Fazili, Z, Yolton, K, Lanphear, BP. Brief Report: Are Autistic-Behaviors in Children Related to Prenatal Vitamin Use and Maternal Whole Blood Folate Concentrations? Journal of Autism & Developmental Disorders. 2014. 44:2602–2607. doi:10.1007/s10803-014-2114-x.24710813 | Outcome
40. | Brough, L, Rees, GA, Crawford, MA, Dorman, EK. Social and ethnic differences in folic acid use preconception and during early pregnancy in the UK: effect on maternal folate status. J Hum Nutr Diet. 2009. 22:100–7. doi:10.1111/j.1365-277X.2008.00936.x.19226351 | Study Design
41. | Brough, L, Rees, GA, Crawford, MA, Morton, RH, Dorman, EK. Effect of multiple-micronutrient supplementation on maternal nutrient status, infant birth weight and gestational age at birth in a low-income, multi-ethnic population. British Journal of Nutrition. 2010. 104:437–445. doi:10.1017/S0007114510000747. | Comparator; Outcome
42. | Brown, JE, Jacobs, DR, Jr, Hartman, TJ, Barosso, GM, Stang, JS, Gross, MD, Zeuske, MA. Predictors of red cell folate level in women attempting pregnancy. Jama. 1997. 277:548–52.9032161 | Study Design; Population
43. | Bruinse, HW, van der Berg, H, Haspels, AA. Maternal serum folacin levels during and after normal pregnancy. Eur J Obstet Gynecol Reprod Biol. 1985. 20:153–8.4054412 | Intervention/Exposure
44. | Bunduki, V, Dommergues, M, Zittoun, J, Marquet, J, Muller, F, Dumez, Y. Maternal-fetal folate status and neural tube defects: a case control study. Biol Neonate. 1995. 67:154–9. doi:10.1159/000244157.7640313 | Study Design; Intervention/Exposure
45. | Butts, CA, Hedderley, DI, Herath, TD, Gopal, P, Paturi, G, Glyn-Jones, S, Wiens, F, Stahl, B. Human Milk Composition and Dietary Intakes of Breastfeeding Women of Different Ethnicity from the Manawatu-Wanganui Region of New Zealand. Nutrients. 2018. 10:1231. doi:10.3390/nu10091231. | Outcome
46. | Bzikowska-Jura, A, Czerwonogrodzka-Senczyna, A, Olędzka, G, Szostak-Węgierek, D, Weker, H, Wesołowska, A. Maternal nutrition and body composition during breastfeeding: Association with human milk composition. Nutrients. 2018. 10. doi:10.3390/nu10101379. | Intervention/Exposure; Outcome
47. | Cawley, S, McCartney, D, Woodside JV, Sweeney, MR, McDonnell, R, Molloy, AM, Turner, MJ. Optimization of folic acid supplementation in the prevention of neural tube defects. Journal of Public Health. 2018. 40:827–834. doi:10.1093/pubmed/fdx137.29059388 | Study Design
48. | Cawley, S, Mullaney, L, Kennedy, R, Farren, M, McCartney, D, Turner, MJ. Duration of periconceptional folic acid supplementation in women booking for antenatal care. Public Health Nutrition. 2017. 20:371–379. doi:10.1017/S1368980016002585.27702424 | Outcome
49. | Celada, A, Busset, R, Gutierrez, J, Herreros, V. Levels of serum ferritin, folate, and vitamin B12 in pregnant women at term who had been supplemented with iron and folate. Int J Biol Res Pregnancy. 1981. 2:142–5.7333699 | Intervention/Exposure; Comparator
50. | Celik, FC, Aygun, C, Gulten, S, Bedir, A, Cetinoglu, E, Kucukoduk, S, Bek, Y. Assessment of different folic acid supplementation doses for low-birth-weight infants. Turk Pediatri Ars. 2016. 51:210–216. doi:10.5152/TurkPediatriArs.2016.4235.28123334 | Study Design; Outcome
51. | Chatzi, L, Papadopoulou, E, Koutra, K, Roumeliotaki, T, Georgiou, V, Stratakis, N, Lebentakou, V, Karachaliou, M, Vassilaki, M, Kogevinas, M. Effect of high doses of folic acid supplementation in early pregnancy on child neurodevelopment at 18 months of age: the mother-child cohort ‘Rhea’ study in Crete, Greece. Public Health Nutr. 2012. 15:1728–36. doi:10.1017/s1368980012000067.22314109 | Outcome
52. | Chen, B, Carrion, P, Grewal, R, Inglis, A, Hippman, C, Morris, E, Andrighetti, H, Albert, A, Austin, J. Short interpregnancy intervals, maternal folate levels, and infants born small for gestational age: a preliminary study in a Canadian supplement-using population. Applied Physiology, Nutrition & Metabolism. 2017. 42:1092–1096. doi:10.1139/apnm-2017-0292. | Intervention/Exposure; Population
53. | Chen, LW, Lim, AL, Colega, M, Tint, MT, Aris, IM, Tan, CS, Chong, YS, Gluckman, PD, Godfrey, KM, Kwek, K, Saw, SM, Yap, F, Lee, YS, Chong, MFF, van Dam, RM. Maternal folate status, but not that of vitamins B-12 or B-6, is associated with gestational age and preterm birth risk in a multiethnic Asian population. Journal of Nutrition. 2015. 145:113–120. doi:10.3945/jn.114.196352. | Intervention/Exposure; Comparator
54. | Chen, S, Li, N, Mei, Z, Ye, R, Li, Z, Liu, J, Serdula, MK. Micronutrient supplementation during pregnancy and the risk of pregnancy-induced hypertension: A randomized clinical trial. Clinical Nutrition. 2019. 38:146–151. doi:10.1016/j.clnu.2018.01.029.29428785 | Comparator; Country
55. | Cheong, M, Xiao, HY, Tay, V, Karakochuk, CD, Liu, YA, Harvey, S, Lamers, Y, Houghton, LA, Kitts, DD, Green, TJ. Folic acid fortified milk increases blood folate to concentrations associated with a very low risk of neural tube defects in Singaporean women of childbearing age. Asia pacific journal of clinical nutrition. 2016. 25:62–70. doi:10.6133/apjcn.2016.25.1.08.26965763 | Population
56. | Christensen, B, Arbour, L, Tran, P, Leclerc, D, Sabbaghian, N, Platt, R, Gilfix, BM, Rosenblatt, DS, Gravel, RA, Forbes, P, Rozen, R. Genetic polymorphisms in methylenetetrahydrofolate reductase and methionine synthase, folate levels in red blood cells, and risk of neural tube defects. Am J Med Genet. 1999. 84:151–7.10323741 | Intervention/Exposure
57. | Clavel, T, Zkik, A, Berdeaux, G, Auges, M, Sanchez, C, Harvey, T. Iron deficiency anemia in pregnant women in France: a prospective cohort study. Value in health. 2016. 19:A401-. | Abstract
58. | Clifford, AJ, Noceti, EM, Block-Joy, A, Block, T, Block, G. Erythrocyte folate and its response to folic acid supplementation is assay dependent in women. J Nutr. 2005. 135:137–43. doi:10.1093/jn/135.1.137.15623845 | Comparator
59. | Clifford, AJ, Noceti, EM, Block-Joy, A, Block, T, Block, G. Erythrocyte folate and its response to folio acid supplementation is assay dependent in women. Journal of Nutrition. 2005. 135:137–143. | Duplicate
60. | Cooperman, JM, Dweck, HS, Newman, LJ, Garbarino, C, Lopez, R. The folate in human milk. Am J Clin Nutr. 1982. 36:576–80. doi:10.1093/ajcn/36.4.576.6896957 | Intervention/Exposure
61. | Crandall, BF, Corson, VL, Goldberg, JD, Knight, G, Salafsky, IS. Folic acid and pregnancy. American Journal of Medical Genetics. 1995. 55:134–135. doi:10.1002/ajmg.1320550133.7702087 | Study Design
62. | Crider, Krista S, Devine, Owen, Ling, Hao, Dowling, Nicole F, Song, Li, Molloy, Anne M, Zhu, Li, Jianghui, Zhu, Berry, Robert J. Population red blood cell folate concentrations for prevention of neural tube defects: bayesian model. BMJ: British Medical Journal. 2014. 349:g4554–g4554. doi:10.1136/bmj.g4554.25073783 | Intervention/Exposure; Outcome; Country
63. | Czeizel, AE, Puhó, E. Maternal use of nutritional supplements during the first month of pregnancy and decreased risk of Down’s syndrome: case-control study. Nutrition. 2005. 21:698–704.15925294 | Outcome
64. | Dante, Giulia, Morani, Letizia, Bronzetti, Daisy, Garutti, Paola, Neri, Isabella, Calapai, Gioacchino, Facchinetti, Fabio. Poor Folate Intake in a North Italian Pregnant Population: an Epidemiological Survey. Paediatric & Perinatal Epidemiology. 2015. 29:501–504. doi:10.1111/ppe.12226.26367522 | Intervention/Exposure; Outcome
65. | Darby, WJ. Folic acid and macrocytic anemias. South Med J. 1983. 76:1341–3.6356376 | Study Design; Human
66. | Dawson, EB, Evans, DR, Conway, ME, McGanity, WJ. Vitamin B12 and folate bioavailability from two prenatal multivitamin/multimineral supplements. American Journal of Perinatology. 2000. 17:193–199.11041441 | Comparator
67. | De Ocampo, MPG, Araneta, MRG, Macera, CA, Alcaraz, JE, Moore, TR, Chambers, CD. Folic acid supplement use and the risk of gestational hypertension and preeclampsia. Women Birth. 2018. 31:e77–e83. doi:10.1016/j.wombi.2017.08.128.28870524 | Outcome
68. | den Dekker, HT, Jaddoe, VWV, Reiss, IK, de Jongste, JC, Duijts, L. Maternal folic acid use during pregnancy, methylenetetrahydrofolate reductase gene polymorphism, and child’s lung function and asthma. Clin Exp Allergy. 2018. 48:175–185. doi:10.1111/cea.13056.29117460 | Study Design
69. | Devlieger, R, Guelinckx, I, Jans, G, Voets, W, Vanholsbeke, C, Vansant, G. Micronutrient levels and supplement intake in pregnancy after bariatric surgery: a prospective cohort study. PLoS One. 2014. 9:e114192. doi:10.1371/journal.pone.0114192.25470614 | Comparator
70. | Diet & nutrition. Good news: caffeine in pregnancy doesn’t affect the baby’s growth…and folic acid seems to prevent cleft lip. Child Health Alert. 2007. 25:5–6. | Comment
71. | Dimperio, DL, Mahan, CS. Influencing pregnancy outcome through nutrition and dietary changes. Md Med J. 1985. 34:997–1002.3852035 | Study Design
72. | Dommisse, J, Du Toit, ED, Nicholson, N. Folic acid -- has it a role in the treatment of severe iron deficiency anaemia in pregnancy? S Afr Med J. 1982. 61:831–2.7079905 | Country
73. | Doyle, W, Srivastava, A, Crawford, MA, Bhatti, R, Brooke, Z, Costeloe, KL. Inter-pregnancy folate and iron status of women in an inner-city population. British Journal of Nutrition. 2001. 86:81–87. | Comparator; Population
74. | Dubois, L, Diasparra, M, Bédard, B, Colapinto, CK, Fontaine-Bisson, B, Morisset, A-S, Tremblay, RE, Fraser, WD. Adequacy of nutritional intake from food and supplements in a cohort of pregnant women in Québec, Canada: the 3D Cohort Study (Design, Develop, Discover). American Journal of Clinical Nutrition. 2017. 106:541–548. doi:10.3945/ajcn.117.155499. | Outcome
75. | Ek, J. Plasma and red cell folate values in newborn infants and their mothers in relation to gestational age. J Pediatr. 1980. 97:288–92.7400900 | Intervention/Exposure
76. | Ek, J. Plasma, red cell, and breast milk folacin concentrations in lactating women. Am J Clin Nutr. 1983. 38:929–35. doi:10.1093/ajcn/38.6.929.6685974 | Comparator
77. | Elmacioglu, F, Surucu, B, Alper, T, Ozenoglu, A, Ugurlu, S. Is adequate and balanced nutrition during pregnancy more effective than iron and folic acid supplements? Central European Journal of Medicine. 2010. 5:235–242. doi:10.2478/s11536-009-0099-1. | Comparator; Country
78. | El-Sherif, HA, Al-Seeni, MN, Osman, NN, Al-Hertani, RR. Micronutrient status in healthy pregnant Saudi women at different gestational periods. Kuwait Medical Journal. 2017. 49:124–128. | Intervention/Exposure
79. | Fadakar, SK, Ghavi, A, Niknami, M, Kazemnejad, LE. Relationship between mothers’ gt<GT> nutritional status and weight gain during pregnancy with low birth weight. Journal of Guilan University of Medical Sciences. 2012. 21:27–35. | Not English
80. | Faintuch, J, Dias, MC, de Souza Fazio, E, de Oliveira, FC, Nomura, RM, Zugaib, M, Cecconello, I. Pregnancy nutritional indices and birth weight after Roux-en-Y gastric bypass. Obes Surg. 2009. 19:583–9. doi:10.1007/s11695-008-9755-9.18953618 | Intervention/Exposure
81. | Fayyaz, F, Wang, F, Jacobs, RL, O’Connor, DL, Bell, RC, Field, CJ. Folate, vitamin B12, and vitamin B6 status of a group of high socioeconomic status women in the Alberta Pregnancy Outcomes and Nutrition (APrON) cohort. Applied Physiology, Nutrition & Metabolism. 2014. 39:1402–1408. doi:10.1139/apnm-2014-0181. | Intervention/Exposure
82. | Felkner, M, Suarez, L, Hendricks, K, Gunter, EW. Blood folate levels on the Texas-Mexico border. Tex Med. 2002. 98:58–60. | Study Design
83. | Feng, Y, Cai, J, Tong, X, Chen, R, Zhu, Y, Xu, B, Mo, X. Non-inheritable risk factors during pregnancy for congenital heart defects in offspring: A matched case-control study. Int J Cardiol. 2018. 264:45–52. doi:10.1016/j.ijcard.2018.04.003.29685690 | Outcome
84. | Fernàndez-Roig, S, Cavallé-Busquets, P, Fernandez-Ballart, JD, Ballesteros, M, Berrocal-Zaragoza, MI, Salat-Batlle, J, Ueland, PM, Murphy, MM. Low folate status enhances pregnancy changes in plasma betaine and dimethylglycine concentrations and the association between betaine and homocysteine. American Journal of Clinical Nutrition. 2013. 97:1252–1259. doi:10.3945/ajcn.112.054189. | Intervention/Exposure; Comparator
85. | Folate delivers head-to-toe health advantages. The B vitamin that benefits unborn babies may also protect the hearts and minds (and colons) of adults. Health News. 2002. 8:1–2. | Not primary data
86. | Folic acid may prevent cleft lip and palate. J Okla Dent Assoc. 2007. 98:19.17802894 | Outcome; Not primary data
87. | Folic acid supplements taken early in pregnancy reduce facial cleft risk. Journal of the American Dental Association (1939). 2007. 138:452. doi:10.14219/jada.archive.2007.0191.17403734 | Study Design; News
88. | Foreman, JC. Anaemias in pregnancy. Practitioner. 1981. 225:175–84.7267568 | Study Design
89. | Fowler, BM, Giuliano, AR, Piyathilake, C, Nour, M, Hatch, K. Hypomethylation in cervical tissue: is there a correlation with folate status? Cancer Epidemiol Biomarkers Prev. 1998. 7:901–6.9796635 | Population
90. | Franke, C, Demmelmair, H, Decsi, T, Campoy, C, Cruz, M, Molina-Font, JA, Mueller, K, Koletzko, B. Influence of fish oil or folate supplementation on the time course of plasma redox markers during pregnancy. British Journal of Nutrition. 2010. 103:1648–1656. doi:10.1017/S0007114509993746. | Outcome
91. | Freeman, M, Sosinsky, A, Moustafa, D, Viguera, A, Cohen, L. Supplement use by women during pregnancy: data from the Massachusetts General Hospital National Pregnancy Registry for Atypical Antipsychotics. Archives of Women’s Mental Health. 2016. 19:437–441. doi:10.1007/s00737-015-0586-0. | Outcome
92. | Fruzzetti, F. Beyaz®: An oral contraceptive fortified with folate. Women’s Health. 2012. 8:13–19. doi:10.2217/whe.11.68. | Study Design; News/review
93. | Furness, D, Fenech, M, Dekker, G, Khong, YT, Roberts, C, Hague, W. Folate, Vitamin B12, Vitamin B6 and homocysteine: impact on pregnancy outcome. Maternal & Child Nutrition. 2013. 9:155–166. doi:10.1111/j.1740-8709.2011.00364.x.22023381 | Study Design
94. | Furness, DL, Yasin, N, Dekker, GA, Thompson, SD, Roberts, CT. Maternal red blood cell folate concentration at 10-12 weeks gestation and pregnancy outcome. Journal of Maternal-Fetal & Neonatal Medicine. 2012. 25:1423–1427. doi:10.3109/14767058.2011.636463.22081889 | Study Design
95. | Gadowsky, SL, Gale, K, Wolfe, SA, Jory, J, Gibson, R, O’Connor, DL. Biochemical folate, B12, and iron status of a group of pregnant adolescents accessed through the public health system in southern Ontario. J Adolesc Health. 1995. 16:465–74. doi:10.1016/1054-139x(94)00001-u.7669797 | Study Design; Intervention/Exposure
96. | Gaskins, AJ, Yu-Han, C, Williams, PL, Ford, JB, Toth, TL, Hauser, R, Chavarro, JE. Association between serum folate and vitamin B-12 and outcomes of assisted reproductive technologies. American Journal of Clinical Nutrition. 2015. 102:943–950. doi:10.3945/ajcn.115.112185. | Study Design; Outcome; Population
97. | Gatford, KL, Houda, CM, Lu, ZX, Coat, S, Baghurst, PA, Owens, JA, Sikaris, K, Rowan, JA, Hague, WM. Vitamin B12 and homocysteine status during pregnancy in the metformin in gestational diabetes trial: responses to maternal metformin compared with insulin treatment. Diabetes Obes Metab. 2013. 15:660–7. doi:10.1111/dom.12080.23402546 | Intervention/Exposure
98. | Gildestad, T, Bjørge, T, Vollset, SE, Klungsøyr, K, Nilsen, RM, Haaland, ØA, Øyen, N. Folic acid supplements and risk for oral clefts in the newborn: a population-based study. British Journal of Nutrition. 2015. 114:1456–1463. doi:10.1017/S0007114515003013. | Outcome
99. | Giugliani, ER, Jorge, SM, Goncalves, AL. Serum vitamin B12 levels in parturients, in the intervillous space of the placenta and in full-term newborns and their interrelationships with folate levels. Am J Clin Nutr. 1985. 41:330–5. doi:10.1093/ajcn/41.2.330.3969940 | Intervention/Exposure
100. | Glorimar, R, Pereira, SE, Trugo, NM. Longitudinal change in plasma total homocysteine during pregnancy and postpartum in Brazilian women and its relation with folate status and other factors. Int J Vitam Nutr Res. 2004. 74:95–101. doi:10.1024/0300-9831.74.2.95.15255446 | Comparator
101. | Gomber, S, Agarwal, KN, Mahajan, C, Agarwal, N. Impact of daily versus weekly hematinic supplementation on anemia in pregnant women. Indian Pediatr. 2002. 39:339–46.11976463 | Comparator; Country
102. | Gómez Roig, MD, Mazarico, E, Ferrero, S, Montejo, R, Ibáñez, L, Grima, F, Vela, A. Differences in dietary and lifestyle habits between pregnant women with small fetuses and appropriate-for-gestational-age fetuses. Journal of Obstetrics & Gynaecology Research. 2017. 43:1145–1151. doi:10.1111/jog.13330. | Outcome
103. | Gringras, M. A comparison of two combined iron-folic acid preparations in the prevention of anaemia in pregnancy. J Int Med Res. 1982. 10:268–70. doi:10.1177/030006058201000413.7117682 | Comparator
104. | Gu, Q, Li, Y, Cui, ZL, Luo, XP. Homocysteine, folate, vitamin B(12) and B(6) in mothers of children with neural tube defects in Xinjiang, China. Acta Paediatrica. 2012. 101:e486–90. doi:10.1111/j.1651-2227.2012.02795.x.22860981 | Intervention/Exposure
105. | Guerra-Shinohara, EM, Pereira, PM, Kubota, AM, Silva, TA, Reis, JL, Miyashita, GS, D’Almeida, V, Allen, RH, Stabler, SP. Increased MMA concentration and body mass index are associated with spontaneous abortion in Brazilian women: a pilot study. Clin Chim Acta. 2010. 411:423–7. doi:10.1016/j.cca.2009.12.014.20036223 | Study Design; Intervention/Exposure
106. | Haggarty, P, Campbell, DM, Duthie, S, Andrews, K, Hoad, G, Piyathilake, C, Fraser, I, McNeill, G. Folic acid use in pregnancy and embryo selection. BJOG: An International Journal of Obstetrics & Gynaecology. 2008. 115:851–856.18485163 | Intervention/Exposure; Outcome
107. | Haggarty, P, Hoad, G, Campbell, DM, Horgan, GW, Piyathilake, C, McNeill, G. Folate in pregnancy and imprinted gene and repeat element methylation in the offspring. American Journal of Clinical Nutrition. 2013. 97:94–99. doi:10.3945/ajcn.112.042572. | Outcome; Exposure & outcome measured at same time
108. | Haggarty, P, McCallum, H, McBain, H, Andrews, K, Duthie, S, McNeill, G, Templeton, A, Haites, N, Campbell, D, Bhattacharya, S. Effect of B vitamins and genetics on success of in-vitro fertilisation: prospective cohort study. Lancet. 2006. 367 North American Edition:1513–1519.16679164 | Study Design; Comparator
109. | Halicioglu, O, Sutcuoglu, S, Koc, F, Ozturk, C, Albudak, E, Colak, A, Sahin, E, Asik Akman, S. Vitamin B(12) and folate statuses are associated with diet in pregnant women, but not with anthropometric measurements in term newborns. Journal of Maternal-Fetal & Neonatal Medicine. 2012. 25:1618–1621. doi:10.3109/14767058.2011.648244.22185230 | Study Design
110. | Hartman, BA, Fazili, Z, Pfeiffer, CM, O’Connor, DL. Neither folic acid supplementation nor pregnancy affects the distribution of folate forms in the red blood cells of women. Journal of Nutrition. 2014. 144:1364–1369. doi:10.3945/jn.113.189233. | Study Design; Comparator
111. | Haruna, M, Shiraishi, M, Matsuzaki, M, Yatsuki, Y, Yeo, SA. Effect of tailored dietary guidance for pregnant women on nutritional status: A double-cohort study. Maternal & Child Nutrition. 2017. 13:n/a-N.PAG. doi:10.1111/mcn.12391. | Intervention/Exposure; Comparator
112. | Hashemi, M, Heshmat-Ghahdarijani, K, Zarean, E, Baktash, F, Mortazavi, ZS. Evaluation of the effect of high-dose folic acid on endothelial dysfunction in pre-eclamptic patients: A randomized clinical trial. Journal of Research in Medical Sciences. 2016. 21. | Outcome
113. | Hauser, GA. Vitamin requirements in human pregnancy. Int J Vitam Nutr Res Suppl. 1985. 27:207–12.3926695 | Comparator
114. | Hay, G, Clausen, T, Whitelaw, A, Trygg, K, Johnston, C, Henriksen, T, Refsum, H. Maternal folate and cobalamin status predicts vitamin status in newborns and 6-month-old infants. Journal of Nutrition. 2010. 140:557–564. doi:10.3945/jn.109.117424. | Study Design; Outcome
115. | Heppe, DHM, Medina-Gomez, C, Hofman, A, Franco, OH, Rivadeneira, F, Jaddoe, VWVW. Maternal first-trimester diet and childhood bone mass: the Generation R Study. American Journal of Clinical Nutrition. 2013. 98:224–232. doi:10.3945/ajcn.112.051052. | Intervention/Exposure; Outcome
116. | Hess, SY, Zimmermann, MB, Brogli, S, Hurrell, RF. A national survey of iron and folate status in pregnant women in Switzerland. Int J Vitam Nutr Res. 2001. 71:268–73. doi:10.1024/0300-9831.71.5.268.11725691 | Study Design; Intervention/Exposure; Comparator
117. | Hibbard, BM. Iron and folate supplements during pregnancy: supplementation is valuable only in selected patients. Bmj. 1988. 297:1324, 1326. doi:10.1136/bmj.297.6659.1324.3144378 | Outcome; Not primary data
118. | Higgins, JR, Quinlivan, EP, McPartlin, J, Scott, JM, Weir, DG, Darling, MR. The relationship between increased folate catabolism and the increased requirement for folate in pregnancy. Bjog. 2000. 107:1149–54.11002960 | Intervention/Exposure
119. | Hindmarsh, PC, Geary, MPP, Rodeck, CH, Jackson, MR, Kingdom, JCP, Hindmarsh, PC, Geary, MP, Rodeck, CH, Jackson, MR, Kingdom, JC. Effect of early maternal iron stores on placental weight and structure. Lancet. 2000. 356 North American Edition:719–723.11085691 | Study Design; Intervention/Exposure
120. | Hininger, I, Favier, M, Arnaud, J, Faure, H, Thoulon, JM, Hariveau, E, Favier, A, Roussel, AM. Effects of a combined micronutrient supplementation on maternal biological status and newborn anthropometrics measurements: a randomized double-blind, placebo-controlled trial in apparently healthy pregnant women. Eur J Clin Nutr. 2004. 58:52–9. doi:10.1038/sj.ejcn.1601745.14679367 | Comparator
121. | Hossein-nezhad, A, Mirzaei, K, Maghbooli, Z, Najmafshar, A, Larijani, B. The influence of folic acid supplementation on maternal and fetal bone turnover. J Bone Miner Metab. 2011. 29:186–92. doi:10.1007/s00774-010-0205-0.20602129 | Comparator
122. | House, JD, March, SB, Ratnam, S, Crowley, M, Friel, JK, House, JamesD, March, SandraB, Ratnam, Msc Sam, Crowley, Marilyn, Friel, JamesK. Improvements in the status of folate and cobalamin in pregnant Newfoundland women are consistent with observed reductions in the incidence of neural tube defects. Canadian Journal of Public Health. 2006. 97:132–135.16620001 | Study Design
123. | Hure, A, Collins, C, Smith, R. A Longitudinal Study of Maternal Folate and Vitamin B12 Status in Pregnancy and Postpartum, with the Same Infant Markers at 6 Months of Age. Maternal & Child Health Journal. 2012. 16:792–801. doi:10.1007/s10995-011-0782-0.21544621 | Intervention/Exposure; Comparator
124. | Hursthouse, NA, Gray, AR, Miller, JC, Rose, MC, Houghton, LA. Folate status of reproductive age women and neural tube defect risk: the effect of long-term folic acid supplementation at doses of 140 microg and 400 microg per day. Nutrients. 2011. 3:49–62. doi:10.3390/nu3010049.22254076 | Population
125. | Hursthouse, NA, Gray, AR, Miller, JC, Rose, MC, Houghton, LA. Folate status of reproductive age women and neural tube defect risk: The effect of long-term folic acid supplementation at doses of 140 μg and 400 μg per day. Nutrients. 2011. 3:49–62. doi:10.3390/nu3010049.22254076 | Population
126. | Iron/folate for iron deficiency anaemia in pregnancy. Australian journal of pharmacy. 2008. 89:76-. | Study Design; Not peer-reviewed
127. | Jackson, E, Mathur, K. Adolescent pregnancy: effects of nutrients on hematocrit and birth weight in Orangeburg County. J S C Med Assoc. 1991. 87:8–11.2002665 | Study Design; Intervention/Exposure; Comparator
128. | Jacquemyn, Y, Ajaji, M, Karepouan, N, Jacquemyn, N, Van Sande, H. Vitamin B12 and folic acid status of term pregnant women and newborns in the Antwerp region, Belgium. Clin Exp Obstet Gynecol. 2014. 41:141–3.24779238 | Intervention/Exposure; Not peer-reviewed
129. | Jain, R, Acharya, AS. Supplemental folic acid in pregnancy and childhood asthma. National Medical Journal of India. 2010. 23:351–352. | Study Design; Outcome; Summary/Commentary
130. | Jans, G, Matthys, C, Bel, S, Ameye, L, Lannoo, M, Van der Schueren, B, Dillemans, B, Lemmens, L, Saey, J-P, van Nieuwenhove, Y, Grandjean, P, De Becker, B, Logghe, H, Coppens, M, Roelens, K, Loccufier, A, Verhaeghe, J, Devlieger, R. AURORA: bariatric surgery registration in women of reproductive age - a multicenter prospective cohort study. BMC Pregnancy & Childbirth. 2016. 16:1–11. doi:10.1186/s12884-016-0992-y.26728010 | Study Design
131. | Jarvenpaa, J, Schwab, U, Lappalainen, T, Pakkila, M, Niskanen, L, Punnonen, K. Mineral water fortified with folic acid and vitamins B6, B12, D and calcium improves folate status and decreases plasma homocysteine concentration in pregnant women. 35th nordic congress of obstetrics and gynecology; 2006 may 23-25; goteburg, Sweden. 2008. 55. | Abstract
132. | Järvenpää, J, Schwab, U, Lappalainen, T, Päkkilä, M, Niskanen, L, Punnonen, K, Ryynänen, M. Fortified mineral water improves folate status and decreases plasma homocysteine concentration in pregnant women. Journal of Perinatal Medicine. 2007. 35:108–114.17302515 | Comparator
133. | Jiang, HL, Cao, LQ, Chen, HY. Blood folic acid, vitamin B12, and homocysteine levels in pregnant women with fetal growth restriction. Genet Mol Res. 2016. 15. doi:10.4238/gmr15048890. | Intervention/Exposure
134. | Joelson, DW, Fiebig, EW, Wu, AH. Diminished need for folate measurements among indigent populations in the post folic acid supplementation era. Arch Pathol Lab Med. 2007. 131:477–80. doi:10.1043/1543-2165(2007)131[477:Dnffma]2.0.Co;2.17516752 | Population
135. | Jwa, SC, Ogawa, K, Kobayashi, M, Morisaki, N, Sago, H, Fujiwara, T. Validation of a food-frequency questionnaire for assessing vitamin intake of Japanese women in early and late pregnancy with and without nausea and vomiting. J Nutr Sci. 2016. 5:e27. doi:10.1017/jns.2016.14.27547390 | Comparator
136. | Kalem, P, Benli, AR, Koroglu, M, Benli, NC, Koyuncu, M, Cesur, O, Dane, PBK. The effect of ferritin, vitamin B12 and folic acid on pregnancy outcomes. International Journal of Clinical and Experimental Medicine. 2016. 9:22413–22417. | Intervention/Exposure; Comparator
137. | Kang, Y, Dang, S, Zeng, L, Wang, D, Li, Q, Wang, J, Ouzhu, L, Yan, H. Multi-micronutrient supplementation during pregnancy for prevention of maternal anaemia and adverse birth outcomes in a high-altitude area: a prospective cohort study in rural Tibet of China. British Journal of Nutrition. 2017. 118:431–440. doi:10.1017/S000711451700229X. | Study Design; Comparator
138. | Kaplan, JS, Iqbal, S, England, BG, Zawacki, CM, Herman, WH. Is pregnancy in diabetic women associated with folate deficiency? Diabetes Care. 1999. 22:1017–21. doi:10.2337/diacare.22.7.1017.10388960 | Intervention/Exposure; Comparator
139. | Karabulut, A, Şevket, O, Acun, A. Iron, folate and vitamin B12 levels in first trimester pregnancies in the Southwest region of Turkey. Journal of the Turkish-German Gynecological Association. 2011. 12:153–156. doi:10.5152/jtgga.2011.36.24591983 | Intervention/Exposure
140. | Karra, MV, Udipi, SA, Kirksey, A, Roepke, JL. Changes in specific nutrients in breast milk during extended lactation. Am J Clin Nutr. 1986. 43:495–503. doi:10.1093/ajcn/43.4.495.3962902 | Intervention/Exposure; Comparator
141. | Khambalia, A, Latulippe, ME, Campos, C, Merlos, C, Villalpando, S, Picciano, MF, O’Connor D, L. Milk folate secretion is not impaired during iron deficiency in humans. J Nutr. 2006. 136:2617–24. doi:10.1093/jn/136.10.2617.16988136 | Comparator
142. | Kharb, S, Aggarwal, D, Bala, J, Nanda, S. Evaluation of Homocysteine, Vitamin B12 and Folic Acid Levels During all the Trimesters in Pregnant and Preeclamptic Womens. Curr Hypertens Rev. 2016. 12:234–238. doi:10.2174/1573402112666161010151632.27748186 | Intervention/Exposure; Country
143. | Kharb, S, Nanda, S. Patterns of Biomarkers in Cord Blood During Pregnancy and Preeclampsia. Curr Hypertens Rev. 2017. 13:57–64. doi:10.2174/1573402113666170126101914.28128050 | Intervention/Exposure; Country
144. | Kiefte-de Jong, JC, Timmermans, S, Jaddoe, VW, Hofman, A, Tiemeier, H, Steegers, EA, de Jongste, JC, Moll, HA. High circulating folate and vitamin B-12 concentrations in women during pregnancy are associated with increased prevalence of atopic dermatitis in their offspring. Journal of Nutrition. 2012. 142:731–738. | Study Design
145. | Kilbride, J, Baker, TG, Parapia, LA, Khoury, SA, Kilbride, J, Baker, TG, Parapia, LA, Khoury, SA. Iron status, serum folate and B(12) values in pregnancy and postpartum: report from a study in Jordan. Annals of Saudi Medicine. 2000. 20:371–376.17264625 | Intervention/Exposure; Country
146. | Koc, A, Kocyigit, A, Soran, M, Demir, N, Sevinc, E, Erel, O, Mil, Z. High frequency of maternal vitamin B12 deficiency as an important cause of infantile vitamin B12 deficiency in Sanliurfa province of Turkey. European Journal of Nutrition. 2006. 45:291–297.16601915 | Intervention/Exposure
147. | Kocic, G, Bjelakovic, L, Bjelakovic, B, Jevtoci-Stoimenov, T, Sokolovic, D, Cvetkovic, T, Kocic, H, Stojanovic, S, Langerholc, T, Jonovic, M. Impact of Folic Acid Supplementation on Single- and Double-Stranded RNA Degradation in Human Colostrum and Mature Milk. Journal of Medicinal Food. 2014. 17:804–809. doi:10.1089/jmf.2013.0093.24650098 | Outcome
148. | Kocylowski, Rafal, Grzesiak, Mariusz, Gaj, Zuzanna, Lorenc, Wiktor, Bakinowska, Ewa, Barałkiewicz, Danuta, von Kaisenberg, ConstantinS, Lamers, Yvonne, Suliburska, Joanna. Associations between the Level of Trace Elements and Minerals and Folate in Maternal Serum and Amniotic Fluid and Congenital Abnormalities. Nutrients. 2019. 11:328. doi:10.3390/nu11020328. | Intervention/Exposure
149. | Koenig, MD, McFarlin, BL, Steffen, AD, Tussing-Humphreys, L, Giurgescu, C, Engeland, CG, Kominiarek, MA, Ciezczak-Karpiel, C, O’Brien, WD, White-Traut, R. Decreased Nutrient Intake Is Associated With Premature Cervical Remodeling. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2017. 46:123–134. doi:10.1016/j.jogn.2016.08.006. | Intervention/Exposure; Outcome
150. | Kokanali, MK, Ozturkkan, D, Unsal, N, Moroy, P, Gungor, T, Mollamahmutoglu, L. Plasma homocysteine, vitamin B12 and folate levels in hydatidiform moles and histopathological subtypes. Arch Gynecol Obstet. 2008. 278:531–4. doi:10.1007/s00404-008-0637-0.18379803 | Intervention/Exposure; Comparator
151. | Koren, G. Preconceptional folate and neural tube defects: Time for rethinking. Canadian Journal of Public Health. 1993. 84:207–208.8358700 | Study Design; Not primary data
152. | Korkmaz, V, Ozkaya, E, Seven, BY, Duzguner, S, Karsli, MF, Kucukozkan, T. Comparison of oxidative stress in pregnancies with and without first trimester iron supplement: a randomized double-blind controlled trial. Journal of Maternal-Fetal & Neonatal Medicine. 2014. 27:1535–1538. doi:10.3109/14767058.2013.863869.24199687 | Outcome
153. | Kösüs, N, Kösüs, A, Hizli, D, Bitirgen, EÜ, Turhan, NÖ. Can serum ferritin, vitamin B(12) and folic acid levels affect serum screening tests during pregnancy? Journal of Maternal-Fetal & Neonatal Medicine. 2012. 25:1674–1677. doi:10.3109/14767058.2012.657276.22273004 | Intervention/Exposure
154. | Krauss-Etschmann, S, Shadid, R, Campoy, C, Hoster, E, Demmelmair, H, Jiménez, M, Gil, A, Rivero, M, Veszprémi, B, Decsi, T, Koletzko, BV. Effects of fish-oil and folate supplementation of pregnant women on maternal and fetal plasma concentrations of docosahexaenoic acid and eicosapentaenoic acid: a European randomized multicenter trial. American Journal of Clinical Nutrition. 2007. 85:1392–1400. | Study Design; Outcome
155. | La Merrill, M, Torres-Sánchez, L, Ruiz-Ramos, R, López-Carrillo, L, Cebrián, ME, Chen, J, La Merrill, Michele, Torres-Sánchez, Luisa, Ruiz-Ramos, Rubén, López-Carrillo, Lizbeth, Cebrián, MarianoE, Chen, Jia. The association between first trimester micronutrient intake, MTHFR genotypes, and global DNA methylation in pregnant women. Journal of Maternal-Fetal & Neonatal Medicine. 2012. 25:133–137. doi:10.3109/14767058.2011.564242.21443409 | Intervention/Exposure
156. | Lacasaña, M, Blanco-Muñoz, J, Borja-Aburto, VH, Aguilar-Garduño, C, Rodríguez-Barranco, M, Sierra-Ramirez, JA, Galaviz-Hernandez, C, Gonzalez-Alzaga, B, Garcia-Cavazos, R. Effect on risk of anencephaly of gene-nutrient interactions between methylenetetrahydrofolate reductase C677T polymorphism and maternal folate, vitamin B12 and homocysteine profile. Public Health Nutrition. 2012. 15:1419–1428. doi:10.1017/S136898001100334X.22230335 | Intervention/Exposure; Outcome
157. | Lamers, Y, Prinz-Langenohl, R, Moser, R, Pietrzik, K. Supplementation with [6S]-5-methyltetrahydrofolate or folic acid equally reduces plasma total homocysteine concentrations in healthy women. American Journal of Clinical Nutrition. 2004. 79:473–478. | Population
158. | Lawrence, JM, Watkins, ML, Chiu, V, Erickson, JD, Petitti, DB. Do racial and ethnic differences in serum folate values exist after food fortification with folic acid? American Journal of Obstetrics & Gynecology. 2006. 194:520–526.16458656 | Study Design
159. | Lehti, KK. Iron, folic acid and zinc intakes and status of low socio-economic pregnant and lactating Amazonian women. Eur J Clin Nutr. 1989. 43:505–13.2598892 | Intervention/Exposure; Country
160. | Li, C, Zeng, L, Wang, D, Yang, W, Dang, S, Zhou, J, Yan, H. Prenatal Micronutrient Supplementation Is Not Associated with Intellectual Development of Young School-Aged Children. J Nutr. 2015. 145:1844–9. doi:10.3945/jn.114.207795.26084366 | Outcome; Country
161. | Li, X, Jiang, J, Xu, M, Xu, M, Yang, Y, Lu, W, Yu, X, Ma, J, Pan, J. Individualized supplementation of folic acid according to polymorphisms of methylenetetrahydrofolate reductase (MTHFR), methionine synthase reductase (MTRR) reduced pregnant complications. Gynecol Obstet Invest. 2015. 79:107–12. doi:10.1159/000367656.25634728 | Outcome
162. | Li, X, Li, S, Mu, D, Liu, Z, Li, Y, Lin, Y, Chen, X, You, F, Li, N, Deng, K, Deng, Y, Wang, Y, Zhu, J. The association between periconceptional folic acid supplementation and congenital heart defects: A case-control study in China. Preventive Medicine. 2013. 56:385–389. doi:10.1016/j.ypmed.2013.02.019.23480969 | Outcome
163. | Li, Z, Mei, Z, Zhang, L, Li, H, Zhang, Y, Li, N, Ye, R, Ren, A, Liu, J-M, Serdula, MK. Effects of Prenatal Micronutrient Supplementation on Spontaneous Preterm Birth: A Double-Blind Randomized Controlled Trial in China. American Journal of Epidemiology. 2017. 186:318–325. doi:10.1093/aje/kwx094.28472219 | Outcome; Country
164. | Li, Z, Ye, R, Zhang, L, Li, H, Liu, J, Ren, A. Folic acid supplementation during early pregnancy and the risk of gestational hypertension and preeclampsia. Hypertension (0194911X). 2013. 61:873–879. doi:10.1161/HYPERTENSIONAHA.111.00230. | Outcome; Country
165. | Li, Z, Ye, R, Zhang, L, Li, H, Liu, J, Ren, A. Periconceptional folic acid supplementation and the risk of preterm births in China: a large prospective cohort study. International Journal of Epidemiology. 2014. 43:1132–1139. doi:10.1093/ije/dyu020.24603317 | Outcome
166. | Little, J, Gilmour, M, Mossey, PA, FitzPatrick, D, Cardy, A, Clayton-Smith, J, Hill, A, Duthie, SJ, Fryer, AE, Molloy, AM, Scott, JM. Folate and clefts of the lip and palate -- a U.K.-based case-control study: part II: biochemical and genetic analysis. Cleft Palate-Craniofacial Journal. 2008. 45:428–438. | Study Design; Comparator
167. | Liu, Jian-Meng, Mei, Zuguo, Ye, Rongwei, Serdula, MaryK, Ren, Aiguo, Cogswell, MaryE. Micronutrient supplementation and pregnancy outcomes: double-blind randomized controlled trial in china. JAMA Internal Medicine. 2013. 173:276–282. doi:10.1001/jamainternmed.2013.1632.23303315 | Intervention/Exposure; Outcome; Country
168. | Liu, S, West, R, Randell, E, Longerich, L, O’Connor, KS, Scott, H, Crowley, M, Lam, A, Prabhakaran, V, McCourt, C. A comprehensive evaluation of food fortification with folic acid for the primary prevention of neural tube defects. BMC Pregnancy and Childbirth. 2004. 4. doi:10.1186/1471-2393-4-20. | Outcome; Population
169. | Livock, M, Anderson, PJ, Lewis, S, Bowden, S, Muggli, E, Halliday, J. Maternal micronutrient consumption periconceptionally and during pregnancy: a prospective cohort study. Public Health Nutrition. 2017. 20:294–304. doi:10.1017/S1368980016002019.27485466 | Outcome
170. | Looman, M, Geelen, A, Samlal, RAK, Heijligenberg, R, Gunnewiek, JMTK, Balvers, MGJ, Wijnberger, LDE, Brouwer-Brolsma, EM, Feskens, EJM. Changes in Micronutrient Intake and Status, Diet Quality and Glucose Tolerance from Preconception to the Second Trimester of Pregnancy. Nutrients. 2019. 11:460. doi:10.3390/nu11020460. | Study Design; Comparator
171. | Lucock, MD, Daskalakis, I, Lumb, CH, Schorah, CJ, Levene, MI. Impaired regeneration of monoglutamyl tetrahydrofolate leads to cellular folate depletion in mothers affected by a spina bifida pregnancy. Mol Genet Metab. 1998. 65:18–30. doi:10.1006/mgme.1998.2738.9787091 | Population
172. | Lymperaki, E, Tsikopoulos, A, Makedou, K, Paliogianni, E, Kiriazi, L, Charisi, C, Vagdatli, E. Impact of iron and folic acid supplementation on oxidative stress during pregnancy. Journal of Obstetrics & Gynaecology. 2015. 35:803–806. doi:10.3109/01443615.2015.1011102.25692315 | Outcome
173. | Ma, AG, Schouten, EG, Sun, YY, Yang, F, Han, XX, Zhang, FZ, Jiang, DC, Kok, FJ. Supplementation of iron alone and combined with vitamins improves haematological status, erythrocyte membrane fluidity and oxidative stress in anaemic pregnant women. British Journal of Nutrition. 2010. 104:1655–1661. | Country
174. | Ma, R, Wang, L, Jin, L, Li, Z, Ren, A. Plasma folate levels and associated factors in women planning to become pregnant in a population with high prevalence of neural tube defects. Birth Defects Res. 2017. 109:1039–1047. doi:10.1002/bdr2.1040.28569432 | Study Design; Population
175. | Mara, M, Zivny, J, Eretova, V, Kvasnicka, J, Kuzel, D, Umlaufova, A, Marova, E. Changes in markers of anemia and iron metabolism and how they are influenced by antianemics in postpartum period. Acta Obstet Gynecol Scand. 2001. 80:142–8.11167209 | Population
176. | Martinez de Villarreal, LE. Should the dose of folic acid be adjusted for Mexican population? The pilot prevention program implemented in Nuevo Leon, Mexico. J Pediatr Rehabil Med. 2017. 10:215–217. doi:10.3233/prm-170445.29125506 | Study Design; No data
177. | Martinussen, MP, Bracken, MB, Triche, EW, Jacobsen, GW, Risnes, KR. Folic acid supplementation in early pregnancy and the risk of preeclampsia, small for gestational age offspring and preterm delivery. European Journal of Obstetrics & Gynecology & Reproductive Biology. 2015. 195:94–99. doi:10.1016/j.ejogrb.2015.09.022.26500184 | Outcome
178. | McAlpine, JM, Scott, R, Scuffham, PA, Perkins, AV, Vanderlelie, JJ. The association between third trimester multivitamin/mineral supplements and gestational length in uncomplicated pregnancies. Women & Birth. 2016. 29:41–46. doi:10.1016/j.wombi.2015.07.185.26319504 | Comparator; Outcome
179. | McGrath, K. Treatment of anaemia caused by iron, vitamin B12 or folate deficiency. Medical Journal of Australia. 1989. 151:693–697. | Study Design; Review
180. | McKay, JA, Groom, A, Potter, C, Coneyworth, LJ, Ford, D, Mathers, JC, Relton, CL. Genetic and non-genetic influences during pregnancy on infant global and site specific DNA methylation: role for folate gene variants and vitamin B12. PLoS One. 2012. 7:e33290. doi:10.1371/journal.pone.0033290.22479380 | Intervention/Exposure
181. | McMullin, MF, White, R, Lappin, T, Reeves, J, MacKenzie, G. Haemoglobin during pregnancy: relationship to erythropoietin and haematinic status. Eur J Haematol. 2003. 71:44–50.12801298 | Comparator
182. | McNulty, B, Pentieva, K, Marshall, B, Ward, M, Molloy, AM, Scott, JM, McNulty, H. Women’s compliance with current folic acid recommendations and achievement of optimal vitamin status for preventing neural tube defects. Hum Reprod. 2011. 26:1530–6. doi:10.1093/humrep/der078.21441543 | Study Design
183. | Megahed, MA, Taher, IM. Folate and homocysteine levels in pregnancy…reprinted from British Journal of Biomedical Science 2004 61(2) with permission of the publisher. Journal of Continuing Education Topics & Issues. 2005. 7:74–78. | Intervention/Exposure
184. | Mei, Z, Serdula, MK, Liu, J-M, Flores-Ayala, RC, Wang, L, Ye, R, Grummer-Strawn, LM. Iron-Containing Micronutrient Supplementation of Chinese Women with No or Mild Anemia during Pregnancy Improved Iron Status but Did Not Affect Perinatal Anemia. Journal of Nutrition. 2014. 144:943–948. doi:10.3945/jn.113.189894. | Comparator; Country
185. | Micheli, V, Taddeo, A, Vanni, AL, Massone, M, Ricci, MG. The influence of anti-anaemic treatments on the distribution of circulating erythrocytes of different ages during pregnancy. J Int Med Res. 1985. 13:163–8. doi:10.1177/030006058501300303.4007252 | Comparator
186. | Mikkelsen, TB, Osler, M, Olsen, SF. Validity of protein, retinol, folic acid and n-3 fatty acid intakes estimated from the food-frequency questionnaire used in the Danish National Birth Cohort. Public Health Nutrition. 2006. 9:771–778.16925883 | Intervention/Exposure; Comparator
187. | Mills, JL, Tuomilehto, J, Yu, KF, Colman, N, Blaner, WS, Koskela, P, Rundle, WE, Forman, M, Toivanen, L, Rhoads, GG. Maternal vitamin levels during pregnancies producing infants with neural tube defects. J Pediatr. 1992. 120:863–71.1593344 | Intervention/Exposure
188. | Milman, N, Byg, KE, Hvas, AM, Bergholt, T, Eriksen, L. Erythrocyte folate, plasma folate and plasma homocysteine during normal pregnancy and postpartum: a longitudinal study comprising 404 Danish women. Eur J Haematol. 2006. 76:200–5. doi:10.1111/j.1600-0609.2005.00606.x.16412135 | Intervention/Exposure
189. | Mitchell, MC, Lerner, E. Maternal hematologic measures and pregnancy outcome. Journal of the American Dietetic Association. 1992. 92:484–486.1556353 | Intervention/Exposure; Comparator
190. | Mizgier, M, Jarząbek-Bielecka, G, Marcinkowska, E, Jakubek, E, Jeszka, J. DIETARY INTERVENTION OR VITAMIN AND MINERAL SUPPLEMENTATION DURING PREGNANCY? Polish Nursing / Pielegniarstwo Polskie. 2016. 62:546–551. doi:10.20883/pielpol.2016.57. | Outcome
191. | Mogaddam, MR, Ardebili, NS, Kariman, N. The relation between the incidence rate of second and third trimester hemoglobin and the incidence of preeclampsia and gestational diabetes: A cohort study. Crescent Journal of Medical and Biological Sciences. 2019. 6:85–90. | Study Design
192. | Molloy, AM, Mills, JL, McPartlin, J, Kirke, PN, Scott, JM, Daly, S. Maternal and fetal plasma homocysteine concentrations at birth: the influence of folate, vitamin B12, and the 5,10-methylenetetrahydrofolate reductase 677C-->T variant. Am J Obstet Gynecol. 2002. 186:499–503. doi:10.1067/mob.2002.121105.11904614 | Intervention/Exposure
193. | Montgomery, J, Pearson, K, Thomas, W, Rhoades, E, Lorenz, D. Folic acid knowledge and multivitamin use among Oklahoma women. J Okla State Med Assoc. 2000. 93:256.10860295 | Outcome
194. | Mooij, PN, Steegers-Theunissen, RP, Thomas, CM, Doesburg, WH, Eskes, TK. Periconceptional vitamin profiles are not suitable for identifying women at risk for neural tube defects. J Nutr. 1993. 123:197–203. doi:10.1093/jn/123.2.197.8429368 | Comparator
195. | Mukherjee, MD, Sandstead, HH, Ratnaparkhi, MV, Johnson, LK, Milne, DB, Stelling, HP. Maternal zinc, iron, folic acid, and protein nutriture and outcome of human pregnancy. Am J Clin Nutr. 1984. 40:496–507. doi:10.1093/ajcn/40.3.496.6475821 | Intervention/Exposure; Comparator
196. | Murto, T, Skoog Svanberg, A, Yngve, A, Nilsson, TK, Altmae, S, Wanggren, K, Salumets, A, Stavreus-Evers, A. Folic acid supplementation and IVF pregnancy outcome in women with unexplained infertility. Reprod Biomed Online. 2014. 28:766–72. doi:10.1016/j.rbmo.2014.01.017.24745837 | Population
197. | Nelen, WL, Blom, HJ, Thomas, CM, Steegers, EA, Boers, GH, Eskes, TK. Methylenetetrahydrofolate reductase polymorphism affects the change in homocysteine and folate concentrations resulting from low dose folic acid supplementation in women with unexplained recurrent miscarriages. J Nutr. 1998. 128:1336–41. doi:10.1093/jn/128.8.1336.9687553 | Population
198. | Neuhouser, ML, Beresford, SA, Hickok, DE, Monsen, ER. Absorption of dietary and supplemental folate in women with prior pregnancies with neural tube defects and controls. J Am Coll Nutr. 1998. 17:625–30.9853543 | Population
199. | Nohr, EA, Olsen, J, Bech, BH, Bodnar, LM, Olsen, SF, Catov, JM. Periconceptional intake of vitamins and fetal death: a cohort study on multivitamins and folate. International Journal of Epidemiology. 2014. 43:174–184. doi:10.1093/ije/dyt214.24453235 | Intervention/Exposure; Outcome
200. | Nouri, K, Walch, K, Weghofer, A, Imhof, M, Egarter, C, Ott, J. The Impact of a Standardized Oral Multinutrient Supplementation on Embryo Quality in in vitro Fertilization/Intracytoplasmic Sperm Injection: A Prospective Randomized Trial. Gynecologic & Obstetric Investigation. 2017. 82:8–14. doi:10.1159/000452662.27832646 | Outcome; Population
201. | Obara, T, Nishigori, H, Nishigori, T, Metoki, H, Ishikuro, M, Tatsuta, N, Mizuno, S, Sakurai, K, Nishijima, I, Murai, Y, Fujiwara, I, Arima, T, Nakai, K, Mano, N, Yaegashi, N, Kuriyama, S. Prevalence and determinants of inadequate use of folic acid supplementation in Japanese pregnant women: the Japan Environment and Children’s Study (JECS). Journal of Maternal-Fetal & Neonatal Medicine. 2017. 30:588–593. doi:10.1080/14767058.2016.1179273.27089039 | Outcome
202. | Obeid, R, Schon, C, Wilhelm, M, Pietrzik, K, Pilz, S. Dietary and lifestyle predictors of folate insufficiency in non-supplemented German women. Int J Food Sci Nutr. 2019. 70:367–376. doi:10.1080/09637486.2018.1511686.30189767 | Intervention/Exposure; Population
203. | Ogunbode, O, Damole, IO. Treatment of anaemia in obstetric patients with sustained-release (Ferrograd Folic 500 Plus) and conventional fersolate and folic acid as separate drugs. Current therapeutic research - clinical and experimental. 1984. 35:1038–1042. | Comparator; Country
204. | Ohrvik, V, Lemming, EW, Nalsen, C, Becker, W, Ridefelt, P, Lindroos, AK. Dietary intake and biomarker status of folate in Swedish adults. Eur J Nutr. 2018. 57:451–462. doi:10.1007/s00394-016-1328-4.27787623 | Study Design; Population
205. | Oliver, E, Grimshaw, K, Schoemaker, A, Keil, T, McBride, D, Sprikkelman, A, Ragnarsdottir, H, Trendelenburg, V, Emmanouil, E, Reche, M, Fiocchi, A, Fiandor, A, Stanczyk-Przyluska, A, Wilczynski, J, Busacca, M, Sigurdardottir, S, Dubakiene, R, Rudzeviciene, O, Vlaxos, G, Beyer, K. Dietary Habits and Supplement Use in Relation to National Pregnancy Recommendations: Data from the EuroPrevall Birth Cohort. Maternal & Child Health Journal. 2014. 18:2408–2425. doi:10.1007/s10995-014-1480-5.24752313 | Outcome
206. | O’Malley, EG, Cawley, S, Kennedy, RAK, Reynolds, CME, Molloy, A, Turner MJ. Maternal anaemia and folate intake in early pregnancy. Journal of Public Health. 2018. 40:e296–e302. doi:10.1093/pubmed/fdy013.29394368 | Intervention/Exposure; Comparator
207. | O’Malley, EG, Cawley, S, Reynolds, CME, Kennedy, RAK, Molloy, A, Turner, MJ. Comparison at the first prenatal visit of the maternal dietary intakes of smokers with non-smokers in a large maternity hospital: a cross-sectional study. BMJ Open. 2018. 8:e021721. doi:10.1136/bmjopen-2018-021721. | Study Design; Comparator
208. | O’Malley, EG, Reynolds, CME, Cawley, S, Woodside, JV, Molloy, AM, Turner, MJ. Folate and vitamin B12 levels in early pregnancy and maternal obesity. European Journal of Obstetrics & Gynecology & Reproductive Biology. 2018. 231:80–84. doi:10.1016/j.ejogrb.2018.10.001.30336308 | Study Design; Intervention/Exposure
209. | O’Rourke, KM, Redlinger, TE, Waller, DK. Declining levels of erythrocyte folate during the postpartum period among Hispanic women living on the Texas-Mexico border. Journal of Women’s Health & Gender-Based Medicine. 2000. 9:397–403. | Study Design
210. | Ortega, RM, Requejo, AM, Lopez-Sobaler, AM, Navia, B, Mena, MC, Basabe, B, Andres, P. Smoking and passive smoking as conditioners of folate status in young women. J Am Coll Nutr. 2004. 23:365–71.15310741 | Population
211. | Osifo, BO, Onifade, A. Effect of folate supplementation and malaria on the folate content of human milk. Nutr Metab. 1980. 24:176–81.7443097 | Country
212. | Ouyang, F, Longnecker, MP, Venners, SA, Johnson, S, Korrick, S, Zhang, J, Xu, X, Christian, P, Wang, M-C, Wang, X. Preconception serum 1,1,1-trichloro-2,2,bis(p-chlorophenyl)ethane and B-vitamin status: independent and joint effects on women’s reproductive outcomes. American Journal of Clinical Nutrition. 2014. 100:1470–1478. doi:10.3945/ajcn.114.088377. | Intervention/Exposure; Country
213. | Page, R, Robichaud, A, Arbuckle, TE, Fraser, WD, MacFarlane, AJ. Total folate and unmetabolized folic acid in the breast milk of a cross-section of Canadian women. American Journal of Clinical Nutrition. 2017. 105:1101–1109. doi:10.3945/ajcn.116.137968. | Comparator
214. | Page, R, Wong, A, Arbuckle, TE, MacFarlane, AJ. The MTHFR 677C>T polymorphism is associated with unmetabolized folic acid in breast milk in a cohort of Canadian women. Am J Clin Nutr. 2019. doi:10.1093/ajcn/nqz056. | Study Design; Outcome
215. | Papadopoulou, E, Stratakis, N, Roumeliotaki, T, Sarri, K, Merlo, D, Kogevinas, M, Chatzi, L. The effect of high doses of folic acid and iron supplementation in early-to-mid pregnancy on prematurity and fetal growth retardation: the mother-child cohort study in Crete, Greece (Rhea study). European Journal of Nutrition. 2013. 52:327–336. doi:10.1007/s00394-012-0339-z.22430980 | Outcome
216. | Pardo, J, Gindes, L, Orvieto, R. Cobalamin (vitamin B12) metabolism during pregnancy. Int J Gynaecol Obstet. 2004. 84:77–8.14698835 | Intervention/Exposure
217. | Parisi, F, Rousian, M, Koning, AHJ, Willemsen, SP, Cetin, I, Steegers-Theunissen, RPM. Periconceptional maternal one-carbon biomarkers are associated with embryonic development according to the Carnegie stages. Human Reproduction. 2017. 32:523–530. doi:10.1093/humrep/dew349.28104698 | Study Design; Outcome
218. | Park, E, Lee, HC, Han, JY, Choi, JS, Hyun, T, Han, Y. Intakes of iron and folate and hematologic indices according to the type of supplements in pregnant women. Clin Nutr Res. 2012. 1:78–84. doi:10.7762/cnr.2012.1.1.78.23430062 | Comparator
219. | Park, E, Wagenbichler, P, Elmadfa, I. Effects of multivitamin/mineral supplementation, at nutritional doses, on plasma antioxidant status and DNA damage estimated by sister chromatid exchanges in lymphocytes in pregnant women. Int J Vitam Nutr Res. 1999. 69:396–402. doi:10.1024/0300-9831.69.6.396.10642897 | Intervention/Exposure; Comparator
220. | Park, H, Kim, YJ, Ha, EH, Kim, KN, Chang, N. The risk of folate and vitamin B12 deficiencies associated with hyperhomocysteinemia among pregnant women. American Journal of Perinatology. 2004. 21:469–476.15580543 | Intervention/Exposure; Population
221. | Peker, E, Demir, N, Tuncer, O, Üstyol, L, Balahoroğlu, R, Kaba, S, Karaman, K. The levels of vitamın B12, folate and homocysteine in mothers and their babies with neural tube defects. Journal of Maternal-Fetal & Neonatal Medicine. 2016. 29:2944–2948. doi:10.3109/14767058.2015.1109620.26479326 | Intervention/Exposure
222. | Pfeiffer, CM, Johnson, CL, Jain, RB, Yetley, EA, Picciano, MF, Rader, JI, Fisher, KD, Mulinare, J, Osterloh, JD. Trends in blood folate and vitamin B-12 concentrations in the United States, 1988-2004. American Journal of Clinical Nutrition. 2007. 86:718–727. | Study Design; Population
223. | Pietrzik, K, Lamers, Y, Bramswig, S, Prinz-Langenohl, R. Calculation of red blood cell folate steady state conditions and elimination kinetics after daily supplementation with various folate forms and doses in women of childbearing age. Am J Clin Nutr. 2007. 86:1414–9. doi:10.1093/ajcn/86.5.1414.17991654 | Population
224. | Pietrzik, K, Prinz, R, Reusch, K, Bung, P, Mallmann, P, Chronides, A. Folate status and pregnancy outcome. Ann N Y Acad Sci. 1992. 669:371–3. doi:10.1111/j.1749-6632.1992.tb17127.x.1444051 | Intervention/Exposure
225. | Pisal, H, Dangat, K, Randhir, K, Khaire, A, Mehendale, S, Joshi, S. Higher maternal plasma folate, vitamin B12 and homocysteine levels in women with preeclampsia. J Hum Hypertens. 2019. 33:393–399. doi:10.1038/s41371-019-0164-4.30647465 | Country
226. | Plumptre, L, Masih, SP, Ly, A, Aufreiter, S, Kyoung-Jin, S, Croxford, R, Lausman, AY, Berger, H, O’Connor, DL, Young-In, K. High concentrations of folate and unmetabolized folic acid in a cohort of pregnant Canadian women and umbilical cord blood. American Journal of Clinical Nutrition. 2015. 102:848–857. doi:10.3945/ajcn.115.110783. | Intervention/Exposure
227. | Prasodjo, A, Pfeiffer, CM, Fazili, Z, Xu, Y, Liddy, S, Yolton, K, Savitz, DA, Lanphear, BP, Braun, JM. Serum cotinine and whole blood folate concentrations in pregnancy. Annals of Epidemiology. 2014. 24:498–503.e1. doi:10.1016/j.annepidem.2014.04.004.24854185 | Study Design; Intervention/Exposure
228. | Qvist, I, Abdulla, M, Jagerstad, M, Svensson, S. Iron, zinc and folate status during pregnancy and two months after delivery. Acta Obstet Gynecol Scand. 1986. 65:15–22.3716775 | Intervention/Exposure; Comparator
229. | Raghavan, R, Riley, AW, Volk, H, Caruso, D, Hironaka, L, Sices, L, Hong, X, Wang, G, Ji, Y, Brucato, M, Wahl, A, Stivers, T, Pearson, C, Zuckerman, B, Stuart, EA, Landa, R, Fallin, DM, Wang, X. Maternal Multivitamin Intake, Plasma Folate and Vitamin B12 Levels and Autism Spectrum Disorder Risk in Offspring. Paediatric & Perinatal Epidemiology. 2018. 32:100–111. doi:10.1111/ppe.12414.28984369 | Study Design; Outcome
230. | Rambouskova, J, Dlouhy, P, Krizova, E, Prochazka, B, Hrncirova, D, Andel, M. Health behaviors, nutritional status, and anthropometric parameters of Roma and non-Roma mothers and their infants in the Czech Republic. Journal of Nutrition Education & Behavior. 2009. 41:58–64. doi:10.1016/j.jneb.2008.04.360.19161922 | Intervention/Exposure; Comparator
231. | Ramlau-Hansen, CH, Moller, UK, Henriksen, TB, Nexo, E, Moller, J. Folate and vitamin B12 in relation to lactation: a 9-month postpartum follow-up study. Eur J Clin Nutr. 2006. 60:120–8. doi:10.1038/sj.ejcn.1602275.16189550 | Comparator
232. | Ratan, SK, Rattan, KN, Pandey, RM, Singhal, S, Kharab, S, Bala, M, Singh, V, Jhanwar, A. Evaluation of the levels of folate, vitamin B12, homocysteine and fluoride in the parents and the affected neonates with neural tube defect and their matched controls. Pediatr Surg Int. 2008. 24:803–8. doi:10.1007/s00383-008-2167-z.18463884 | Country
233. | Relton, CL, Pearce, MS, Parker, L. The influence of erythrocyte folate and serum vitamin B12 status on birth weight. British Journal of Nutrition. 2005. 93:593–599. | Study Design; Intervention/Exposure
234. | Riskin-Mashiah, S, Auslender, R. Periconceptional folic acid and teratogenic drug use in women undergoing fertility treatments. Journal of Maternal-Fetal & Neonatal Medicine. 2012. 25:1899–1903. doi:10.3109/14767058.2012.668586.22372485 | Outcome
235. | Salmenpera, L, Perheentupa, J, Siimes, MA. Folate nutrition is optimal in exclusively breast-fed infants but inadequate in some of their mothers and in formula-fed infants. J Pediatr Gastroenterol Nutr. 1986. 5:283–9.3958855 | Comparator
236. | Sanlikan, F, Tufan, F, Gocmen, A, Kabadayi, C, Sengul, E. The evaluation of homocysteine level in patients with preeclampsia. Ginekol Pol. 2015. 86:287–91.26117988 | Intervention/Exposure
237. | Scholl, TO, Hediger, ML, Schall, JI, Khoo, CS, Fischer, RL. Dietary and serum folate: their influence on the outcome of pregnancy. Am J Clin Nutr. 1996. 63:520–5. doi:10.1093/ajcn/63.4.520.8599315 | Intervention/Exposure; Comparator; Outcome
238. | Schorah, CJ, Habibzadeh, N, Wild, J, Smithells, RW, Seller, MJ. Possible abnormalities of folate and vitamin B12 metabolism associated with neural tube defects. Ann N Y Acad Sci. 1993. 678:81–91. doi:10.1111/j.1749-6632.1993.tb26111.x.8494295 | Intervention/Exposure
239. | Schorah, CJ, Wild, J, Hartley, R, Sheppard, S, Smithells, RW. The effect of periconceptional supplementation on blood vitamin concentrations in women at recurrence risk for neural tube defect. Br J Nutr. 1983. 49:203–11.6830748 | Intervention/Exposure; Comparator
240. | Schulpis, K, Spiropoulos, A, Gavrili, S, Karikas, G, Grigori, C, Vlachos, G, Papassotiriou, I. Maternal -- neonatal folate and vitamin B12 serum concentrations in Greeks and in Albanian immigrants. Journal of Human Nutrition & Dietetics. 2004. 17:443–448.15357698 | Intervention/Exposure
241. | Sen, S, Iyer, C, Meydani, SN. Obesity during pregnancy alters maternal oxidant balance and micronutrient status. Journal of Perinatology. 2014. 34:105–111. doi:10.1038/jp.2013.153.24355940 | Intervention/Exposure
242. | Serapinas, D, Boreikaite, E, Bartkeviciute, A, Bandzeviciene, R, Silkunas, M, Bartkeviciene, D. The importance of folate, vitamins B6 and B12 for the lowering of homocysteine concentrations for patients with recurrent pregnancy loss and MTHFR mutations. Reprod Toxicol. 2017. 72:159–163. doi:10.1016/j.reprotox.2017.07.001.28689805 | Comparator; Population
243. | Serdula, MK, Zhou, Y, Li, H, Liu, JM, Mei, Z. Prenatal iron containing supplements provided to Chinese women with no or mild anemia had no effect on hemoglobin concentration in post-partum women or their infants at 6 and 12 months of age. Eur J Clin Nutr. 2018. doi:10.1038/s41430-018-0365-x. | Study Design; Country
244. | Serrano, NC, Quintero-Lesmes, DC, Becerra-Bayona, S, Guio, E, Beltran, M, Paez, MC, Ortiz, R, Saldarriaga, W, Diaz, LA, Monterrosa, A, Miranda, J, Mesa, CM, Sanin, JE, Monsalve, G, Dudbridge, F, Hingorani, AD, Casas, JP. Association of pre-eclampsia risk with maternal levels of folate, homocysteine and vitamin B12 in Colombia: A case-control study. PLoS One. 2018. 13:e0208137. doi:10.1371/journal.pone.0208137.30521542 | Study Design; Outcome
245. | Shahbazian, N, Jafari, RM, Haghnia, S. The evaluation of serum homocysteine, folic acid, and vitamin B12 in patients complicated with preeclampsia. Electron Physician. 2016. 8:3057–3061. doi:10.19082/3057.27957303 | Intervention/Exposure
246. | Shankar, H, Kumar, N, Sandhir, R, Pandey, S, Singh, S, Rao, D. Differential iron status and trafficking in blood and placenta of anemic and non-anemic primigravida supplemented with daily and weekly Iron folic acid tablets. Haematologica. 2016. 101:847-. | Country
247. | Shaw, GM, Yang, W, Carmichael, SL, Vollset, SE, Hobbs, CA, Lammer, EJ, Ueland, PM. One-carbon metabolite levels in mid-pregnancy and risks of conotruncal heart defects. Birth Defects Res A Clin Mol Teratol. 2014. 100:107–15. doi:10.1002/bdra.23224.24532477 | Intervention/Exposure; Comparator
248. | Shen, M, Chaudhry, SH, MacFarlane, AJ, Gaudet, L, Smith, GN, Rodger, M, White, Ruth R, Walker, MC, Wen, SW. Serum and red-blood-cell folate demonstrate differential associations with BMI in pregnant women. Public Health Nutrition. 2016. 19:2572–2579. doi:10.1017/S1368980016000756.27087411 | Study Design
249. | Shere, M, Kapur, B, O’Connor, D, Koren, G. STEADY-STATE red blood cell and plasma folate levels achieved with 5 MG VS. 1.1 MG folic acid in prenatal multivitamins among pregnant women. Clinical pharmacology and therapeutics.. 2014. 95:S87. doi:10.1038/clpt.2013.249. | Abstract
250. | Shi-an, Y, Zhen-yu, Y, Yin, S-A, Yang, Z-Y. An on-line database for human milk composition in China. Asia Pacific Journal of Clinical Nutrition. 2016. 25:818–825. doi:10.6133/apjcn.092015.47.27702725 | Intervention/Exposure; Outcome
251. | Shibata, K, Fukuwatari, T, Sasaki, S, Sano, M, Suzuki, K, Hiratsuka, C, Aoki, A, Nagai, C. Urinary excretion levels of water-soluble vitamins in pregnant and lactating women in Japan. J Nutr Sci Vitaminol (Tokyo). 2013. 59:178–86.23883688 | Intervention/Exposure
252. | Shrim, A, Kapur, B, Snyder, J, Basso, O, Blank, D, Brown, RN. Maternal predictors of RBC folate levels in an urban Canadian population. Reprod Toxicol. 2015. 53:127–30. doi:10.1016/j.reprotox.2015.04.009.25929819 | Study Design
253. | Siega-Riz, AM, Savita, DA, Zeisel, SH, Thorp, JM, Herring, A. Second trimester folate status and preterm birth. American Journal of Obstetrics & Gynecology. 2004. 191:1851–1857.15592264 | Intervention/Exposure
254. | Simmons, WK, Sinha, DP. Reduction in anaemia in pregnant women in three Caribbean countries. Possible results of different types of interventions. Ecol Food Nutr. 1994. 32:149–55. doi:10.1080/03670244.1994.9991396.12290746 | Country
255. | Smail, SA. Dietary supplements in pregnancy. J R Coll Gen Pract. 1981. 31:707–11.7338863 | Study Design
256. | Smith, AM, Picciano, MF, Deering, RH. Folate supplementation during lactation: maternal folate status, human milk folate content, and their relationship to infant folate status. J Pediatr Gastroenterol Nutr. 1983. 2:622–8.6685760 | Comparator
257. | Sneed, SM, Zane, C, Thomas, MR. The effects of ascorbic acid, vitamin B6, vitamin B12, and folic acid supplementation on the breast milk and maternal nutritional status of low socioeconomic lactating women. Am J Clin Nutr. 1981. 34:1338–46. doi:10.1093/ajcn/34.7.1338.7258124 | Intervention/Exposure; Comparator
258. | Solé-Navais, P, Salat-Batlle, J, Cavallé-Busquets, P, Fernandez-Ballart, J, Ueland, PM, Ballesteros, M, Ornosa-Martín, G, Inglès-Puig, M, Colomina, JM, Murphy, MM. Early pregnancy folate-cobalamin interactions and their effects on cobalamin status and hematologic variables throughout pregnancy. American Journal of Clinical Nutrition. 2018. 107:173–182. doi:10.1093/ajcn/nqx041. | Intervention/Exposure; Comparator
259. | Srisupandit, S, Pootrakul, P, Areekul, S, Neungton, S, Mokkaves, J, Kiriwat, O, Kanokpongsukdi, S. A prophylactic supplementation of iron and folate in pregnancy. Southeast Asian J Trop Med Public Health. 1983. 14:317–23.6658501 | Country
260. | Stamm, RA, March, KM, Karakochuk, CD, Gray, AR, Brown, RC, Green, TJ, Houghton, LA. Lactating Canadian Women Consuming 1000 microg Folic Acid Daily Have High Circulating Serum Folic Acid Above a Threshold Concentration of Serum Total Folate. J Nutr. 2018. 148:1103–1108. doi:10.1093/jn/nxy070.29901753 | Comparator
261. | Stamm, RA, March, KM, Karakochuk, CD, Gray, AR, Brown, RC, Green, TJ, Houghton, LA. Lactating Canadian women consuming 1000 μg folic acid daily have high serum folic acid above a threshold concentration of serum total folate. Journal of Nutrition. 2018. 148:1103–1108. doi:10.1093/jn/nxy070. | Intervention/Exposure; Comparator
262. | Stamm, RA, March, KM, Karakochuk, CD, Gray, AR, Brown, RC, Green, TJ, Houghton, LA. Lactating Canadian Women Consuming 1000 µg Folic Acid Daily Have High Circulating Serum Folic Acid Above a Threshold Concentration of Serum Total Folate. Journal of Nutrition. 2018. 148:1130–1108. doi:10.1093/jn/nxy070. | Intervention/Exposure; Comparator
263. | Stang, J, Brown, J, Jacobs, D, Jr. Effects of iron and folic acid supplements on serum zinc levels among a cohort of pregnant women. Topics in Clinical Nutrition. 2002. 17:15–26. | Outcome
264. | Steegers-Theunissen, RP, Steegers, EA, de Boer, R, Thomas, CM, Kloosterman, MD, Eskes, TK. Elevated folate levels in amniotic fluid after oral supplementation. Eur J Obstet Gynecol Reprod Biol. 1990. 36:283–91.2379664 | Intervention/Exposure; Comparator
265. | Stingone, JA, Luben, TJ, Carmichael, SL, Aylsworth, AS, Botto, LD, Correa, A, Gilboa, SM, Langlois, PH, Nembhard, WN, Richmond-Bryant, J, Shaw, GM, Olshan, AF. Maternal Exposure to Nitrogen Dioxide, Intake of Methyl Nutrients, and Congenital Heart Defects in Offspring. American Journal of Epidemiology. 2017. 186:719–729. doi:10.1093/aje/kwx139.28520847 | Outcome
266. | Suarez, L, Hendricks, K, Felkner, M, Gunter, E. Maternal serum B12 levels and risk for neural tube defects in a Texas-Mexico border population. Annals of Epidemiology. 2003. 13:81–88.12559666 | Intervention/Exposure; Comparator
267. | Sufang, W, Xing, G, Beibei, Z, Yujie, X, Kun, H, Erigene, R, Leijing, M, Sanhuan, H, Shuangqin, Y, Fangbiao, T. Maternal Continuing Folic Acid Supplementation after the First Trimester of Pregnancy Increased the Risk of Large-for-Gestational-Age Birth: A Population-Based Birth Cohort Study. Nutrients. 2016. 8:493. doi:10.3390/nu8080493. | Outcome
268. | Sun, YY, Ma, AG, Yang, F, Zhang, FZ, Luo, YB, Jiang, DC, Han, XX, Liang, H. A combination of iron and retinol supplementation benefits iron status, IL-2 level and lymphocyte proliferation in anemic pregnant women. Asia Pacific Journal of Clinical Nutrition. 2010. 19:513–519.21147712 | Comparator; Outcome; Country
269. | Surén, P, Roth, C, Bresnahan, M, Haugen, M, Hornig, M, Hirtz, D, Lie, KK, Lipkin, WI, Magnus, P, Reichborn-Kjennerud, T, Schjølberg, S, Smith, GD, Øyen, A-S, Susser, E, Stoltenberg, C. Association between maternal use of folic acid supplements and risk of autism spectrum disorders in children. JAMA: Journal of the American Medical Association. 2013. 309:570–577. doi:10.1001/jama.2012.155925.23403681 | Outcome
270. | Sweeney, MR, Staines, A, Daly, L, Traynor, A, Daly, S, Bailey, SW, Alverson, PB, Ayling, JE, Scott, JM. Persistent circulating unmetabolised folic acid in a setting of liberal voluntary folic acid fortification. Implications for further mandatory fortification? BMC Public Health. 2009. 9:295–295. doi:10.1186/1471-2458-9-295.19689788 | Study Design
271. | Taghizadeh, M, Samimi, M, Tabassi, Z, Heidarzadeh, Z, Asemi, Z. Effect of multivitamin-mineral versus multivitamin supplementation on maternal, newborns’ biochemical indicators and birth size: A double-blind randomized clinical trial. Oman Medical Journal. 2014. 29:123–129. doi:10.5001/omj.2014.30.24715940 | Intervention/Exposure; Comparator
272. | Takimoto, H, Hayashi, F, Kusama, K, Kato, N, Yoshiike, N, Toba, M, Ishibashi, T, Miyasaka, N, Kubota, T. Elevated maternal serum folate in the third trimester and reduced fetal growth: a longitudinal study. J Nutr Sci Vitaminol (Tokyo). 2011. 57:130–7.21697631 | Study Design
273. | Takimoto, H, Mito, N, Umegaki, K, Ishiwaki, A, Kusama, K, Abe, S, Yamawaki, M, Fukuoka, H, Ohta, C, Yoshiike, N. Relationship between dietary folate intakes, maternal plasma total homocysteine and B-vitamins during pregnancy and fetal growth in Japan. European Journal of Nutrition. 2007. 46:300–306.17623226 | Intervention/Exposure; Comparator; Outcome
274. | Tamura, T, Goldenberg, RL, Freeberg, LE, Cliver, SP, Cutter, GR, Hoffman, HJ. Maternal serum folate and zinc concentrations and their relationships to pregnancy outcome. Am J Clin Nutr. 1992. 56:365–70. doi:10.1093/ajcn/56.2.365.1636615 | Intervention/Exposure
275. | Tamura, T, Goldenberg, RL, Johnston, KE, Cliver, SP, Hoffman, HJ. Serum concentrations of zinc, folate, vitamins A and E, and proteins, and their relationships to pregnancy outcome. Acta Obstet Gynecol Scand Suppl. 1997. 165:63–70.9219460 | Intervention/Exposure; Comparator
276. | Taylor, TN, Farkouh, RA, Graham, JB, Colligs, A, Lindemann, M, Lynen, R, Candrilli, SD. Potential reduction in neural tube defects associated with use of Metafolin-fortified oral contraceptives in the United States. American Journal of Obstetrics & Gynecology. 2011. 205:460.e1–8.21903192 | Study Design; Human; Mathematical modeling
277. | Tchernia, G, Blot, I, Rey, A, Kaltwasser, JP, Zittoun, J, Papiernik, E. Maternal folate status, birthweight and gestational age. Dev Pharmacol Ther. 1982. 4 Suppl:58–65.7128394 | Comparator; Outcome
278. | Thomas, MR, Sneed, SM, Wei, C, Nail, PA, Wilson, M, Sprinkle, EE, 3rd. The effects of vitamin C, vitamin B6, vitamin B12, folic acid, riboflavin, and thiamin on the breast milk and maternal status of well-nourished women at 6 months postpartum. Am J Clin Nutr. 1980. 33:2151–6. doi:10.1093/ajcn/33.10.2151.7424809 | Comparator
279. | Titaley, CR, Dibley, MJ, Roberts, CL, Agho, K. Combined iron/folic acid supplements and malaria prophylaxis reduce neonatal mortality in 19 sub-Saharan African countries. American Journal of Clinical Nutrition. 2010. 92:235–243. doi:10.3945/ajcn.2009.29093. | Country
280. | Tiwari, AKM, Mahdi, AA, Mishra, S. Study on Impact of Iron and Folic Acid on the Plasma Trace Minerals in Pregnant Anemic Women. Indian J Clin Biochem. 2018. 33:31–37. doi:10.1007/s12291-017-0653-6.29371767 | Intervention/Exposure; Country
281. | Tomedi, LE, Chang, C-CH, Newby, PK, Evans, RW, Luther, JF, Wisner, KL, Bodnar, LM, Newby, PK. Pre-pregnancy obesity and maternal nutritional biomarker status during pregnancy: a factor analysis. Public Health Nutrition. 2013. 16:1414–1418. doi:10.1017/S1368980013000736.23522785 | Study Design; Intervention/Exposure
282. | Trugo, NMF, Donangelo, CM, Seyfarth, BSP, Henriques, C, Andrade, LP. Folate and iron status of non-anemic women during pregnancy: Effect of routine folate and iron supplementation and relation of erythrocyte folate with iron stores. Nutrition Research. 1996. 16:1267–1276. doi:10.1016/0271-5317(96)00136-4. | Country
283. | Tserga, A, Binder, AM, Michels, KB. Impact of folic acid intake during pregnancy on genomic imprinting of IGF2/H19 and 1-carbon metabolism. Faseb j. 2017. 31:5149–5158. doi:10.1096/fj.201601214RR.28778973 | Study Design; Outcome
284. | Udipi, SA, Kirksey, A, West, K, Giacoia, G. Vitamin B6, vitamin C and folacin levels in milk from mothers of term and preterm infants during the neonatal period. Am J Clin Nutr. 1985. 42:522–30. doi:10.1093/ajcn/42.3.522.4041128 | Intervention/Exposure; Comparator
285. | Valera-Gran, D, Navarrete-Munoz, EM, Garcia de la Hera, M, Fernandez-Somoano, A, Tardon, A, Ibarluzea, J, Balluerka, N, Murcia, M, Gonzalez-Safont, L, Romaguera, D, Julvez, J, Vioque, J. Effect of maternal high dosages of folic acid supplements on neurocognitive development in children at 4-5 y of age: the prospective birth cohort Infancia y Medio Ambiente (INMA) study. Am J Clin Nutr. 2017. 106:878–887. doi:10.3945/ajcn.117.152769.28724645 | Outcome
286. | van den Hil, LCL, Taal, HR, de Jonge, LL, Heppe, DHM, Steegers, EAP, Hofman, A, van der Heijden, AJ, Jaddoe, VWV. Maternal first-trimester dietary intake and childhood blood pressure: the Generation R Study. British Journal of Nutrition. 2013. 110:1454–1464. doi:10.1017/S0007114513000676. | Study Design; Outcome
287. | Van Der Woude, DAA, De Vries, J, Van Wijk, EM, Verzijl, JM, Pijnenborg, JMA. A randomized controlled trial examining the addition of folic acid to iron supplementation in the treatment of postpartum anemia. International Journal of Gynecology & Obstetrics. 2014. 126:101–105. doi:10.1016/j.ijgo.2014.02.013.24839916 | Population
288. | van Lee, L, Tint, MT, Aris, IM, Quah, PL, Fortier, MV, Lee, YS, Yap, FK, Saw, SM, Godfrey, KM, Gluckman, PD, Chong, YS, Kramer, MS, Chong, MF-F. Prospective associations of maternal betaine status with offspring weight and body composition at birth: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) cohort study. American Journal of Clinical Nutrition. 2016. 104:1327–1333. doi:10.3945/ajcn.116.138818. | Intervention/Exposure; Outcome
289. | Vanderlelie, J, Scott, R, Shibl, R, Lewkowicz, J, Perkins, A, Scuffham, PA. First trimester multivitamin/mineral use is associated with reduced risk of pre-eclampsia among overweight and obese women. Maternal & Child Nutrition. 2016. 12:339–348. doi:10.1111/mcn.12133.24847942 | Outcome
290. | Varea, A, Malpeli, A, Disalvo, L, Apezteguia, M, Falivene, M, Ferrari, G, Pereyras, S, Carmuega, E, Etchegoyen, G, Vojkovic, M, Gonzalez, HF. Evaluation of the impact of a food program on the micronutrient nutritional status of Argentinean lactating mothers. Biol Trace Elem Res. 2012. 150:103–8. doi:10.1007/s12011-012-9512-8.23111948 | Intervention/Exposure; Comparator
291. | Venn, BJ, Green, TJ, Moser, R, McKenzie, JE, Murray Skeaff, C, Mann, J. Increases in blood folate indices are similar in women of childbearing age supplemented with [6S]-5-methyltetrahydrofolate and folic acid. Journal of Nutrition. 2002. 132:3353–3355. | Population
292. | Verkleij-Hagoort, AC, de Vries, JHM, Stegers, MPG, Lindemans, J, Ursem, NTC, Steegers-Theunissen, RPM. Validation of the assessment of folate and vitamin B12 intake in women of reproductive age: the method of triads. European Journal of Clinical Nutrition. 2007. 61:610–615.17164826 | Intervention/Exposure; Comparator
293. | Verkleij-Hagoort, AC, de Vries, JHM, Ursem, NTC, de Jonge, R, Hop, WCJ, Steegers-Theunissen, RPM. Dietary intake of B-vitamins in mothers born a child with a congenital heart defect. European Journal of Nutrition. 2006. 45:478–486.17124548 | Study Design; Population
294. | Villalpando, S, Latulippe, ME, Rosas, G, Irurita, MJ, Picciano, MF, O’Connor, DL. Milk folate but not milk iron concentrations may be inadequate for some infants in a rural farming community in San Mateo, Capulhuac, Mexico. American Journal of Clinical Nutrition. 2003. 78:782–789. | Intervention/Exposure
295. | Villamor, E, Rifas-Shiman, SL, Gillman, MW, Oken, E, Villamor, E, Rifas-Shiman, SL, Gillman, MW, Oken, E. Maternal intake of methyl-donor nutrients and child cognition at 3 years of age. Paediatric & Perinatal Epidemiology. 2012. 26:328–335. doi:10.1111/j.1365-3016.2012.01264.x.22686384 | Outcome
296. | Visentin, CE, Masih, SP, Plumptre, L, Schroder, TH, Kyoung-Jin, S, Ly, A, Lausman, AY, Berger, H, Croxford, R, Lamers, Y, Young-In, K, O’Connor, DL, Sohn, K-J, Kim, Young-In. Low Serum Vitamin B-12 Concentrations Are Prevalent in a Cohort of Pregnant Canadian Women. Journal of Nutrition. 2016. 146:1035–1042. doi:10.3945/jn.115.226845. | Intervention/Exposure
297. | Vitamin supplements. Medical Letter on Drugs and Therapeutics. 1985. 27:66–68. | Study Design; Outcome; Not primary data
298. | Viteri, FE, Casanueva, E, Tolentino, MC, Diaz-Frances, J, Erazo, AB. Antenatal iron supplements consumed daily produce oxidative stress in contrast to weekly supplementation in Mexican non-anemic women. Reprod Toxicol. 2012. 34:125–32. doi:10.1016/j.reprotox.2012.03.010.22507748 | Comparator
299. | Vujkovic, M, Steegers, EA, van Meurs, J, Yazdanpanah, N, van Rooij, IA, Uitterlinden, AG, Steegers-Theunissen, RP. The maternal homocysteine pathway is influenced by riboflavin intake and MTHFR polymorphisms without affecting the risk of orofacial clefts in the offspring. European Journal of Clinical Nutrition. 2010. 64:266–273. doi:10.1038/ejcn.2009.138.19935819 | Study Design; Intervention/Exposure
300. | Waksmańska, W, Bobiński, R, Ulman-Włodarz, I, Pielesz, A, Mikulska, M. The dietary composition of women who delivered preterm and full-term infants. Applied Nursing Research. 2017. 35:13–17. doi:10.1016/j.apnr.2017.02.013.28532720 | Outcome
301. | Wald, NJ, Hackshaw, A, Stone, R, Densem, J. Serum alpha-fetoprotein and neural tube defects in the first trimester of pregnancy. MRC Vitamin Study Research Group. Prenat Diagn. 1993. 13:1047–50.7511242 | Outcome
302. | Wald, NJ, Hackshaw, AK, Stone, R, Sourial, NA. Blood folic acid and vitamin B12 in relation to neural tube defects. British Journal of Obstetrics and Gynaecology. 1996. 103:319–324.8605127 | Intervention/Exposure
303. | Walker, MC, Finkelstein, SA, Rennicks White, R, Shachkina, S, Smith, GN, Wen, SW, Rodger, M. The Ottawa and Kingston (OaK) Birth Cohort: development and achievements. J Obstet Gynaecol Can. 2011. 33:1124–33.22082786 | Outcome
304. | Wallace, JM, Bonham, MP, Strain, J, Duffy, EM, Robson, PJ, Ward, M, McNulty, H, Davidson, PW, Myers, GJ, Shamlaye, CF, Clarkson, TW, Molloy, AM, Scott, JM, Ueland, PM. Homocysteine concentration, related B vitamins, and betaine in pregnant women recruited to the Seychelles Child Development Study. American Journal of Clinical Nutrition. 2008. 87:391–397. | Study Design; Intervention/Exposure; Outcome
305. | Wang, H, De Steur, H, Chen, G, Zhang, X, Pei, L, Gellynck, X, Zheng, X. Effectiveness of folic acid fortified flour for prevention of neural tube defects in a high risk region. Nutrients. 2016. 8. doi:10.3390/nu8030152. | Country
306. | Wang, Y, Zhao, N, Qiu, J, He, X, Zhou, M, Cui, H, Lv, L, Lin, X, Zhang, C, Zhang, H, Xu, R, Zhu, D, Dang, Y, Han, X, Bai, H, Chen, Y, Tang, Z, Lin, R, Yao, T, Su, J. Folic acid supplementation and dietary folate intake, and risk of preeclampsia. European Journal of Clinical Nutrition. 2015. 69:1145–1150. doi:10.1038/ejcn.2014.295.25626412 | Outcome
307. | Watanabe, H, Fukuoka, H, Sugiyama, T, Nagai, Y, Ogasawara, K, Yoshiike, N. Dietary folate intake during pregnancy and birth weight in Japan. European Journal of Nutrition. 2008. 47:341–347.18709472 | Intervention/Exposure
308. | Watermeyer, SR, Mukherjee, S, Myers, K, Parveen, S, Asaad, K. Severe megaloblastic anaemia compounding pre-eclampsia in a term pregnancy. J Obstet Gynaecol. 2004. 24:928–9. doi:10.1080/01443610400019096.16147659 | Study Design
309. | Wen, SW, Guo, Y, Rodger, M, White, RR, Yang, Q, Smith, GN, Perkins, SL, Walker, MC. Folic Acid Supplementation in Pregnancy and the Risk of Pre-Eclampsia-A Cohort Study. PLoS One. 2016. 11:e0149818. doi:10.1371/journal.pone.0149818.26901463 | Study Design
310. | Wen, SW, White, RR, Rybak, N, Gaudet, LM, Robson, S, Hague, W, Simms-Stewart, D, Carroli, G, Smith, G, Fraser, WD, Wells, G, Davidge, ST, Kingdom, J, Coyle, D, Fergusson, D, Corsi, DJ, Champagne, J, Sabri, E, Ramsay, T, Mol, BWJ, Oudijk, MA, Walker, MC. Effect of high dose folic acid supplementation in pregnancy on pre-eclampsia (FACT): double blind, phase III, randomised controlled, international, multicentre trial. Bmj. 2018. 362:k3478. doi:10.1136/bmj.k3478.30209050 | Outcome
311. | West, AA, Yan, J, Perry, CA, Jiang, X, Malysheva, OV, Caudill, MA. Folate-status response to a controlled folate intake in nonpregnant, pregnant, and lactating women. Am J Clin Nutr. 2012. 96:789–800. doi:10.3945/ajcn.112.037523.22932279 | Comparator
312. | Yang, T, Gu, Y, Wei, X, Liang, X, Chen, J, Liu, Y, Zhang, T, Li, T. Periconceptional folic acid supplementation and vitamin B12 status in a cohort of Chinese early pregnancy women with the risk of adverse pregnancy outcomes. J Clin Biochem Nutr. 2017. 60:136–142. doi:10.3164/jcbn.16-45.28366994 | Study Design
313. | Yaremco, E, Inglis, A, Innis, SM, Hippman, C, Carrion, P, Lamers, Y, Honer, WG, Austin, J. Red blood cell folate levels in pregnant women with a history of mood disorders: a case series. Birth Defects Res A Clin Mol Teratol. 2013. 97:416–20. doi:10.1002/bdra.23144.23760977 | Study Design
314. | Yates, JR, Ferguson-Smith, MA, Shenkin, A, Guzman-Rodriguez, R, White, M, Clark, BJ. Is disordered folate metabolism the basis for the genetic predisposition to neural tube defects? Clin Genet. 1987. 31:279–87.3608213 | Intervention/Exposure
315. | Yila, TA, Araki, A, Sasaki, S, Miyashita, C, Itoh, K, Ikeno, T, Yoshioka, E, Kobayashi, S, Goudarzi, H, Baba, T, Braimoh, T, Minakami, H, Endo, T, Sengoku, K, Kishi, R. Predictors of folate status among pregnant Japanese women: the Hokkaido Study on Environment and Children’s Health, 2002-2012. Br J Nutr. 2016. 115:2227–35. doi:10.1017/s0007114516001628.27121118 | Study Design
316. | Zhang, F, Yi, C, Fang, G, Sakutombo, DN. Dietary intakes and behaviours in pregnant women of Li ethnicity: a comparison of mountainous and coastal populations in southern China. Asia Pacific Journal of Clinical Nutrition. 2010. 19:236–242.20460238 | Study Design; Intervention/Exposure; Country
317. | Zhang, T, Xin, R, Gu, X, Wang, F, Pei, L, Lin, L, Chen, G, Wu, J, Zheng, X. Maternal serum vitamin B12, folate and homocysteine and the risk of neural tube defects in the offspring in a high-risk area of China. Public Health Nutrition. 2009. 12:680–686. doi:10.1017/S1368980008002735.18547453 | Intervention/Exposure; Country
318. | Zhu, X, Wei, L, Cao, D, Liu, C, Tian, J, Long, Y, Huang, S, Ou, L, Yang, X, Mo, Z. Low serum folate status in the second trimester increase the risk of low birthweight in Chinese women. Journal of Obstetrics & Gynaecology Research. 2018. 44:2037–2044. doi:10.1111/jog.13757. | Study Design
319. | Zhu, Z, Cheng, Y, Zeng, L, Elhoumed, M, He, G, Li, W, Zhang, M, Li, W, Li, D, Tsegaye, S, Chang, S, Yan, H, Wang, EY, Wang, D, Jaffar, S, Dibley, MJ. Association of Antenatal Micronutrient Supplementation With Adolescent Intellectual Development in Rural Western China: 14-Year Follow-up From a Randomized Clinical Trial. JAMA Pediatrics. 2018. 172:832–841. doi:10.1001/jamapediatrics.2018.1401.29987336 | Outcome; Country

Table 26 Articles excluded after full text screening with rationale for exclusion: Gestational diabetes and Hypertensive disorders of pregnancy

| Citation | Rationale
1. | A behavioural nutrition intervention for obese pregnant women: effects on diet quality, weight gain and the incidence of gestational diabetes. Australian and new zealand journal of obstetrics and gynaecology. 56 (4) (pp 364-373), 2016. Date of publication: 01 aug 2016.. 2016. #volume#:doi:10.1111/ajo.12474. | Intervention/Exposure
2. | Banhidy, F, Dakhlaoui, A, Dudas, I, Czeizel, AE. Birth outcomes of newborns after folic Acid supplementation in pregnant women with early and late pre-eclampsia: a population-based study. Adv Prev Med. 2011. 2011:127369. doi:10.4061/2011/127369.21991429 | Study Design; Outcome
3. | Barzilay, E, Moon, A, Plumptre, L, Masih, SP, Sohn, KJ, Visentin, CE, Ly, A, Malysheva, O, Croxford, R, Caudill, MA, O’Connor, DL, Kim, YI, Berger, H. Fetal one-carbon nutrient concentrations may be affected by gestational diabetes. Nutr Res. 2018. 55:57–64. doi:10.1016/j.nutres.2018.04.010.29914628 | Intervention/Exposure
4. | Bentley, S, Hermes, A, Phillips, D, Daoud, YA, Hanna, S. Comparative effectiveness of a prenatal medical food to prenatal vitamins on hemoglobin levels and adverse outcomes: a retrospective analysis. Clin Ther. 2011. 33:204–10. doi:10.1016/j.clinthera.2011.02.010.21440300 | Comparator
5. | Bergen, NE, Jaddoe, VW, Timmermans, S, Hofman, A, Lindemans, J, Russcher, H, Raat, H, Steegers-Theunissen, RP, Steegers, EA. Homocysteine and folate concentrations in early pregnancy and the risk of adverse pregnancy outcomes: the Generation R Study. Bjog. 2012. 119:739–51. doi:10.1111/j.1471-0528.2012.03321.x.22489763 | Intervention/Exposure; Outcome
6. | Berglund, SK, Garcia-Valdes, L, Torres-Espinola, FJ, Segura, MT, Martinez-Zaldivar, C, Aguilar, MJ, Agil, A, Lorente, JA, Florido, J, Padilla, C, Altmae, S, Marcos, A, Lopez-Sabater, MC, Campoy, C. Maternal, fetal and perinatal alterations associated with obesity, overweight and gestational diabetes: an observational cohort study (PREOBE). BMC Public Health. 2016. 16:207. doi:10.1186/s12889-016-2809-3.26931143 | Study Design; Comparator
7. | Bouthoorn, SH, Gaillard, R, Hofman, A, Jaddoe, V, Steegers, E, van Lenthe, F, Raat, H. OS036. Ethnic differences in blood pressure and hypertensivecomplications during pregnancy; the generation R Study. Pregnancy Hypertens. 2012. 2:195. doi:10.1016/j.preghy.2012.04.037. | Abstract
8. | Bouthoorn, SH, Gaillard, R, Hofman, A, Jaddoe, V, Steegers, E, van Lenthe, F, Raat, H. OS036. Ethnic differences in blood pressure and hypertensivecomplications during pregnancy; the generation R Study. Pregnancy Hypertens. 2012. 2:195. doi:10.1016/j.preghy.2012.04.037. | Abstract
9. | Bouthoorn, SH, Gaillard, R, Steegers, EA, Hofman, A, Jaddoe, VW, van Lenthe, FJ, Raat, H. Ethnic differences in blood pressure and hypertensive complications during pregnancy: the Generation R study. Hypertension. 2012. 60:198–205. doi:10.1161/hypertensionaha.112.194365.22615112 | Intervention/Exposure
10. | Braekke, K, Ueland, PM, Harsem, NK, Karlsen, A, Blomhoff, R, Staff, AC. Homocysteine, cysteine, and related metabolites in maternal and fetal plasma in preeclampsia. Pediatr Res. 2007. 62:319–24. doi:10.1203/PDR.0b013e318123fba2.17622947 | Intervention/Exposure
11. | Campbell, SK, Lynch, J, Esterman, A, McDermott, R. Pre-pregnancy predictors of diabetes in pregnancy among Aboriginal and Torres Strait Islander women in North Queensland, Australia. Matern Child Health J. 2012. 16:1284–92. doi:10.1007/s10995-011-0889-3.21959925 | Intervention/Exposure
12. | Chen, S, Li, N, Mei, Z, Ye, R, Li, Z, Liu, J, Serdula, MK. Micronutrient supplementation during pregnancy and the risk of pregnancy-induced hypertension: A randomized clinical trial. Clin Nutr. 2019. 38:146–151. doi:10.1016/j.clnu.2018.01.029.29428785 | Country
13. | Cueto, HT, Riis, AH, Hatch, EE, Wise, LA, Rothman, KJ, Mikkelsen, EM. Predictors of preconceptional folic acid or multivitamin supplement use: a cross-sectional study of Danish pregnancy planners. Clin Epidemiol. 2012. 4:259–65. doi:10.2147/clep.S35463.23071405 | Study Design
14. | De Ocampo, MPG, Araneta, MRG, Macera, CA, Alcaraz, JE, Moore, TR, Chambers, CD. Folic acid supplement use and the risk of gestational hypertension and preeclampsia. Women Birth. 2018. 31:e77–e83. doi:10.1016/j.wombi.2017.08.128.28870524 | Intervention/Exposure; Comparator
15. | Dhobale, M, Chavan, P, Kulkarni, A, Mehendale, S, Pisal, H, Joshi, S. Reduced folate, increased vitamin B(12) and homocysteine concentrations in women delivering preterm. Ann Nutr Metab. 2012. 61:7–14. doi:10.1159/000338473.22776827 | Intervention/Exposure; Comparator
16. | Ede, G, Keskin, U, Samur, G. Is there any effect of maternal dietary acid load during pregnancy on arising gestational diabetes mellitus? Journal of pediatric gastroenterology and nutrition. 2018. 66:932-.29135821 | Abstract
17. | Ede, G, Keskin, U, Samur, G. Is there any effect of maternal dietary acid load during pregnancy on arising gestational diabetes mellitus? Journal of pediatric gastroenterology and nutrition. 2018. 66:932-.29135821 | Abstract
18. | Egan, AM, Danyliv, A, Carmody, L, Kirwan, B, Dunne, FP. A Prepregnancy Care Program for Women With Diabetes: Effective and Cost Saving. J Clin Endocrinol Metab. 2016. 101:1807–15. doi:10.1210/jc.2015-4046.26918293 | Intervention/Exposure; Health Status
19. | Evers, IM, de Valk, HW, Visser, GH. Risk of complications of pregnancy in women with type 1 diabetes: nationwide prospective study in the Netherlands. Bmj. 2004. 328:915. doi:10.1136/bmj.38043.583160.EE.15066886 | Intervention/Exposure; Health Status
20. | Furness, D, Fenech, M, Dekker, G, Khong, TY, Roberts, C, Hague, W. Folate, vitamin B12, vitamin B6 and homocysteine: impact on pregnancy outcome. Matern Child Nutr. 2013. 9:155–66. doi:10.1111/j.1740-8709.2011.00364.x.22023381 | Intervention/Exposure; Outcome
21. | Furness, DL, Yasin, N, Dekker, GA, Thompson, SD, Roberts, CT. Maternal red blood cell folate concentration at 10-12 weeks gestation and pregnancy outcome. J Matern Fetal Neonatal Med. 2012. 25:1423–7. doi:10.3109/14767058.2011.636463.22081889 | Intervention/Exposure
22. | Garratt, FN. Pre-eclampsia: a challenge to public health teams worldwide to ensure that maternal diets contain adequate levels of folic acid, n3 polyunsaturated fatty acids and vitamin D at conception. Public Health. 2009. 123:95–6. doi:10.1016/j.puhe.2008.10.004.19058819 | Study Design
23. | Giroux, I, Inglis, SD, Lander, S, Gerrie, S, Mottola, MF. Dietary intake, weight gain, and birth outcomes of physically active pregnant women: a pilot study. Appl Physiol Nutr Metab. 2006. 31:483–9. doi:10.1139/h06-024.17111001 | Intervention/Exposure
24. | Gray-Donald, K, Robinson, E, Collier, A, David, K, Renaud, L, Rodrigues, S. Intervening to reduce weight gain in pregnancy and gestational diabetes mellitus in Cree communities: an evaluation. Cmaj. 2000. 163:1247–51.11107459 | Intervention/Exposure
25. | Heifetz, EM, Birk, RZ. MTHFR C677T polymorphism affects normotensive diastolic blood pressure independently of blood lipids. Am J Hypertens. 2015. 28:387–92. doi:10.1093/ajh/hpu152.25165067 | Intervention/Exposure; Comparator
26. | Hernandez-Diaz, S, Werler, MM, Louik, C, Mitchell, AA. Risk of gestational hypertension in relation to folic acid supplementation during pregnancy. Am J Epidemiol. 2002. 156:806–12. doi:10.1093/aje/kwf129.12396998 | Study Design; Intervention/Exposure
27. | Hernandez-Diaz, S, Wu, XF, Hayes, C, Werler, MM, Ashok, TD, Badovinac, R, Kelsey, KT, Mitchell, AA. Methylenetetrahydrofolate reductase polymorphisms and the risk of gestational hypertension. Epidemiology. 2005. 16:628–34.16135938 | Study Design; Intervention/Exposure
28. | Huang, L, Yu, X, Li, L, Chen, Y, Yang, Y, Yang, Y, Hu, Y, Zhao, Y, Tang, H, Xu, D, Zhao, M. Duration of periconceptional folic acid supplementation and risk of gestational diabetes mellitus. Asia Pac J Clin Nutr. 2019. 28:321–329. doi:10.6133/apjcn.201906_28(2).0014.31192561 | Intervention/Exposure; Comparator;
29. | Idzior-Walus, B, Cyganek, K, Sztefko, K, Seghieri, G, Breschi, MC, Walus-Miarka, M, Kawalec, E, Seretny, M, Sieradzki, J. Total plasma homocysteine correlates in women with gestational diabetes. Arch Gynecol Obstet. 2008. 278:309–13. doi:10.1007/s00404-008-0571-1.18236055 | Intervention/Exposure; Comparator
30. | Johnson, AA, Knight, EM, Edwards, CH, Oyemade, UJ, Cole, OJ, Westney, OE, Westney, LS, Laryea, H, Jones, S. Dietary intakes, anthropometric measurements and pregnancy outcomes. J Nutr. 1994. 124:936s–942s. doi:10.1093/jn/124.suppl_6.936S.8201444 | Intervention/Exposure
31. | Kaplan, JS, Iqbal, S, England, BG, Zawacki, CM, Herman, WH. Is pregnancy in diabetic women associated with folate deficiency? Diabetes Care. 1999. 22:1017–21. doi:10.2337/diacare.22.7.1017.10388960 | Study Design; Intervention/Exposure
32. | Kharb, S, Aggarwal, D, Bala, J, Nanda, S. Evaluation of Homocysteine, Vitamin B12 and Folic Acid Levels During all the Trimesters in Pregnant and Preeclamptic Womens. Curr Hypertens Rev. 2016. 12:234–238. doi:10.2174/1573402112666161010151632.27748186 | Intervention/Exposure
33. | Kim, MW, Ahn, KH, Ryu, KJ, Hong, SC, Lee, JS, Nava-Ocampo, AA, Oh, MJ, Kim, HJ. Preventive effects of folic acid supplementation on adverse maternal and fetal outcomes. PLoS One. 2014. 9:e97273. doi:10.1371/journal.pone.0097273.24842467 | Study Design
34. | Kim, MW, Hong, SC, Choi, JS, Han, JY, Oh, MJ, Kim, HJ, Nava-Ocampo, A, Koren, G. Homocysteine, folate and pregnancy outcomes. J Obstet Gynaecol. 2012. 32:520–4. doi:10.3109/01443615.2012.693984.22779952 | Study Design; Intervention/Exposure
35. | Leeda, M, Riyazi, N, de Vries, JI, Jakobs, C, van Geijn, HP, Dekker, GA. Effects of folic acid and vitamin B6 supplementation on women with hyperhomocysteinemia and a history of preeclampsia or fetal growth restriction. Am J Obstet Gynecol. 1998. 179:135–9. doi:10.1016/s0002-9378(98)70263-7.9704778 | Intervention/Exposure; Comparator; Population
36. | Li, M, Li, S, Chavarro, JE, Gaskins, AJ, Ley, SH, Hinkle, SN, Wang, X, Ding, M, Bell, G, Bjerregaard, AA, Olsen, SF, Mills, JL, Hu, FB, Zhang, C. Prepregnancy Habitual Intakes of Total, Supplemental, and Food Folate and Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study. Diabetes Care. 2019. 42:1034–1041. doi:10.2337/dc18-2198.31010874 | Population; Exposure measured >6 mo before pregnancy
37. | Li, Z, Gueant-Rodriguez, RM, Quilliot, D, Sirveaux, MA, Meyre, D, Gueant, JL, Brunaud, L. Folate and vitamin B12 status is associated with insulin resistance and metabolic syndrome in morbid obesity. Clin Nutr. 2018. 37:1700–1706. doi:10.1016/j.clnu.2017.07.008.28780990 | Intervention/Exposure
38. | Li, Z, Ye, R, Zhang, L, Li, H, Liu, J, Ren, A. Folic acid supplementation during early pregnancy and the risk of gestational hypertension and preeclampsia. Hypertension. 2013. 61:873–9. doi:10.1161/hypertensionaha.111.00230.23399716 | Country
39. | Looman, M, Geelen, A, Samlal, RAK, Heijligenberg, R, Klein Gunnewiek, JMT, Balvers, MGJ, Wijnberger, LDE, Brouwer-Brolsma, EM, Feskens, EJM. Changes in Micronutrient Intake and Status, Diet Quality and Glucose Tolerance from Preconception to the Second Trimester of Pregnancy. Nutrients. 2019. 11:doi:10.3390/nu11020460. | Intervention/Exposure
40. | Looman, M, Schoenaker, Dajm, Soedamah-Muthu, SS, Mishra, GD, Geelen, A, Feskens, EJM. Pre-pregnancy dietary micronutrient adequacy is associated with lower risk of developing gestational diabetes in Australian women. Nutr Res. 2019. 62:32–40. doi:10.1016/j.nutres.2018.11.006.30803505 | Intervention/Exposure
41. | Lopez-Alarcon, M, Montalvo-Velarde, I, Vital-Reyes, VS, Hinojosa-Cruz, JC, Leanos-Miranda, A, Martinez-Basila, A. Serial determinations of asymmetric dimethylarginine and homocysteine during pregnancy to predict pre-eclampsia: a longitudinal study. Bjog. 2015. 122:1586–92. doi:10.1111/1471-0528.13516.26213116 | Intervention/Exposure; Comparator
42. | Lucock, M, Yates, Z, Martin, C, Choi, JH, Boyd, L, Tang, S, Naumovski, N, Furst, J, Roach, P, Jablonski, N, Chaplin, G, Veysey, M. Vitamin D, folate, and potential early lifecycle environmental origin of significant adult phenotypes. Evol Med Public Health. 2014. 2014:69–91. doi:10.1093/emph/eou013.24699387 | Intervention/Exposure; Population
43. | Makedos, G, Papanicolaou, A, Hitoglou, A, Kalogiannidis, I, Makedos, A, Vrazioti, V, Goutzioulis, M. Homocysteine, folic acid and B12 serum levels in pregnancy complicated with preeclampsia. Arch Gynecol Obstet. 2007. 275:121–4. doi:10.1007/s00404-006-0223-2.16941105 | Intervention/Exposure
44. | Mardones, F, Urrutia, MT, Villarroel, L, Rioseco, A, Castillo, O, Rozowski, J, Tapia, JL, Bastias, G, Bacallao, J, Rojas, I. Effects of a dairy product fortified with multiple micronutrients and omega-3 fatty acids on birth weight and gestation duration in pregnant Chilean women. Public Health Nutrition. 2008. 11:30–40. doi:10.1017/S1368980007000110.17565762 | Intervention/Exposure; Comparator
45. | Martinussen, MP, Bracken, MB, Triche, EW, Jacobsen, GW, Risnes, KR. Folic acid supplementation in early pregnancy and the risk of preeclampsia, small for gestational age offspring and preterm delivery. Eur J Obstet Gynecol Reprod Biol. 2015. 195:94–9. doi:10.1016/j.ejogrb.2015.09.022.26500184 | Intervention/Exposure
46. | Meinila, J, Koivusalo, SB, Valkama, A, Rono, K, Erkkola, M, Kautiainen, H, Stach-Lempinen, B, Eriksson, JG. Nutrient intake of pregnant women at high risk of gestational diabetes. Food Nutr Res. 2015. 59:26676. doi:10.3402/fnr.v59.26676.25994096 | Study Design; Intervention/Exposure
47. | Meltzer, HM, Brantsaeter, AL, Nilsen, RM, Magnus, P, Alexander, J, Haugen, M. Effect of dietary factors in pregnancy on risk of pregnancy complications: results from the Norwegian Mother and Child Cohort Study. Am J Clin Nutr. 2011. 94:1970s–1974s. doi:10.3945/ajcn.110.001248.21543541 | Study Design; Intervention/Exposure
48. | Mislanova, C, Martsenyuk, O, Huppertz, B, Obolenskaya, M. Placental markers of folate-related metabolism in preeclampsia. Reproduction. 2011. 142:467–76. doi:10.1530/rep-10-0484.21690209 | Intervention/Exposure
49. | Mogaddam, MR, Ardebili, NS, Kariman, N. The relation between the incidence rate of second and third trimester hemoglobin and the incidence of preeclampsia and gestational diabetes: A cohort study. Crescent Journal of Medical and Biological Sciences. 2019. 6:85–90. | Intervention/Exposure
50. | Oken, E, Ning, Y, Rifas-Shiman, SL, Rich-Edwards, JW, Olsen, SF, Gillman, MW. Diet during pregnancy and risk of preeclampsia or gestational hypertension. Ann Epidemiol. 2007. 17:663–8. doi:10.1016/j.annepidem.2007.03.003.17521921 | Intervention/Exposure
51. | Patrick, TE, Powers, RW, Daftary, AR, Ness, RB, Roberts, JM. Homocysteine and folic acid are inversely related in black women with preeclampsia. Hypertension. 2004. 43:1279–82. doi:10.1161/01.HYP.0000126580.81230.da.15096466 | Intervention/Exposure
52. | Powers, RW, Dunbar, MS, Gallaher, MJ, Roberts, JM. The 677 C-T methylenetetrahydrofolate reductase mutation does not predict increased maternal homocysteine during pregnancy. Obstet Gynecol. 2003. 101:762–6.12681883 | Intervention/Exposure
53. | Ray, JG, Mamdani, MM. Association between folic acid food fortification and hypertension or preeclampsia in pregnancy. Arch Intern Med. 2002. 162:1776–7.12153382 | Study Design
54. | Roland, JM, Murphy, HR, Ball, V, Northcote-Wright, J, Temple, RC. The pregnancies of women with Type 2 diabetes: poor outcomes but opportunities for improvement. Diabet Med. 2005. 22:1774–7. doi:10.1111/j.1464-5491.2005.01784.x.16401329 | Health Status
55. | Salmenhaara, M, Uusitalo, L, Uusitalo, U, Kronberg-Kippila, C, Sinkko, H, Ahonen, S, Veijola, R, Knip, M, Kaila, M, Virtanen, SM. Diet and weight gain characteristics of pregnant women with gestational diabetes. Eur J Clin Nutr. 2010. 64:1433–40. doi:10.1038/ejcn.2010.167.20808329 | Study Design
56. | Sanchez, SE, Zhang, C, Rene Malinow, M, Ware-Jauregui, S, Larrabure, G, Williams, MA. Plasma folate, vitamin B(12), and homocyst(e)ine concentrations in preeclamptic and normotensive Peruvian women. Am J Epidemiol. 2001. 153:474–80. doi:10.1093/aje/153.5.474.11226979 | Intervention/Exposure; Country
57. | Sanlikan, F, Tufan, F, Gocmen, A, Kabadayi, C, Sengul, E. The evaluation of homocysteine level in patients with preeclampsia. Ginekol Pol. 2015. 86:287–91.26117988 | Intervention/Exposure
58. | Shen, M, Smith, GN, Rodger, M, White, RR, Walker, MC, Wen, SW. Comparison of risk factors and outcomes of gestational hypertension and pre-eclampsia. PLoS One. 2017. 12:e0175914. doi:10.1371/journal.pone.0175914.28437461 | Duplicate
59. | Stone, LP, Stone, PM, Rydbom, EA, Stone, LA, Stone, TE, Wilkens, LE, Reynolds, K. Customized nutritional enhancement for pregnant women appears to lower incidence of certain common maternal and neonatal complications: an observational study. Glob Adv Health Med. 2014. 3:50–5. doi:10.7453/gahmj.2014.053.25568832 | Intervention/Exposure; Comparator
60. | Sun, F, Qian, W, Zhang, C, Fan, JX, Huang, HF. Correlation of Maternal Serum Homocysteine in the First Trimester with the Development of Gestational Hypertension and Preeclampsia. Med Sci Monit. 2017. 23:5396–5401. doi:10.12659/msm.905055.29129906 | Intervention/Exposure
61. | Suzuki, Y, Yamamoto, T, Matsuura, A. PP049. Could the supplementation of L-arginine plus folic acid T improve reduced endothelial function seen in preeclampsia? Pregnancy Hypertens. 2012. 2:268. doi:10.1016/j.preghy.2012.04.160. | Abstract
62. | Suzuki, Y, Yamamoto, T, Matsuura, A. PP049. Could the supplementation of L-arginine plus folic acid T improve reduced endothelial function seen in preeclampsia? Pregnancy Hypertens. 2012. 2:268. doi:10.1016/j.preghy.2012.04.160. | Abstract
63. | Theriault, S, Giguere, Y, Masse, J, Lavoie, SB, Girouard, J, Bujold, E, Forest, JC. Absence of association between serum folate and preeclampsia in women exposed to food fortification. Obstet Gynecol. 2013. 122:345–51. doi:10.1097/AOG.0b013e31829b2f7c.23969804 | Intervention/Exposure
64. | Thompson, D, Berger, H, Feig, D, Gagnon, R, Kader, T, Keely, E, Kozak, S, Ryan, E, Sermer, M, Vinokuroff, C. Diabetes and Pregnancy. Canadian Journal of Diabetes. 2013. 37:S168–S183. doi:10.1016/j.jcjd.2013.01.044.24070943 | Study Design
65. | Timmermans, S, Jaddoe, VW, Silva, LM, Hofman, A, Raat, H, Steegers-Theunissen, RP, Steegers, EA. Folic acid is positively associated with uteroplacental vascular resistance: the Generation R study. Nutr Metab Cardiovasc Dis. 2011. 21:54–61. doi:10.1016/j.numecd.2009.07.002.19819678 | Intervention/Exposure
66. | Wang, Y, Zhao, N, Qiu, J, He, X, Zhou, M, Cui, H, Lv, L, Lin, X, Zhang, C, Zhang, H, Xu, R, Zhu, D, Dang, Y, Han, X, Zhang, H, Bai, H, Chen, Y, Tang, Z, Lin, R, Yao, T, Su, J, Xu, X, Liu, X, Wang, W, Ma, B, Liu, S, Qiu, W, Huang, H, Liang, J, Wang, S, Ehrenkranz, RA, Kim, C, Liu, Q, Zhang, Y. Folic acid supplementation and dietary folate intake, and risk of preeclampsia. Eur J Clin Nutr. 2015. 69:1145–1150. doi:10.1038/ejcn.2014.295.25626412 | Intervention/Exposure; Comparator
67. | Watermeyer, SR, Mukherjee, S, Myers, K, Parveen, S, Asaad, K. Severe megaloblastic anaemia compounding pre-eclampsia in a term pregnancy. J Obstet Gynaecol. 2004. 24:928–9. doi:10.1080/01443610400019096.16147659 | Study Design
68. | Wen, SW, Chen, XK, Rodger, M, White, RR, Yang, Q, Smith, GN, Sigal, RJ, Perkins, SL, Walker, MC. Folic acid supplementation in early second trimester and the risk of preeclampsia. Am J Obstet Gynecol. 2008. 198:45.e1–7. doi:10.1016/j.ajog.2007.06.067.18166303 | Duplicate
69. | Wen, SW, White, RR, Rybak, N, Gaudet, LM, Robson, S, Hague, W, Simms-Stewart, D, Carroli, G, Smith, G, Fraser, WD, Wells, G, Davidge, ST, Kingdom, J, Coyle, D, Fergusson, D, Corsi, DJ, Champagne, J, Sabri, E, Ramsay, T, Mol, BWJ, Oudijk, MA, Walker, MC. Effect of high dose folic acid supplementation in pregnancy on pre-eclampsia (FACT): double blind, phase III, randomised controlled, international, multicentre trial. Bmj. 2018. 362:k3478. doi:10.1136/bmj.k3478.30209050 | Intervention/Exposure; Comparator
70. | Williams, MA, Sanchez, SE, Zhang, C, Bazul, V. Methylenetetrahydrofolate reductase 677 C-->T polymorphism and plasma folate in relation to pre-eclampsia risk among Peruvian women. J Matern Fetal Neonatal Med. 2004. 15:337–44. doi:10.1080/14767050410001680037.15280126 | Intervention/Exposure; Country
71. | Yajnik, CS, Deshpande, SS, Jackson, AA, Refsum, H, Rao, S, Fisher, DJ, Bhat, DS, Naik, SS, Coyaji, KJ, Joglekar, CV, Joshi, N, Lubree, HG, Deshpande, VU, Rege, SS, Fall, CH. Vitamin B12 and folate concentrations during pregnancy and insulin resistance in the offspring: the Pune Maternal Nutrition Study. Diabetologia. 2008. 51:29–38. doi:10.1007/s00125-007-0793-y.17851649 | Country; Outcome

Table 27 Articles excluded after full text screening with rationale for exclusion: Developmental milestones, including neurocognitive development

| Citation | Rationale
1. | Ars, CL, Nijs, IM, Marroun, HE, Muetzel, R, Schmidt, M, Steenweg-de Graaff, J, van der Lugt, A, Jaddoe, VW, Hofman, A, Steegers, EA, Verhulst, FC, Tiemeier, H, White, T. Prenatal folate, homocysteine and vitamin B12 levels and child brain volumes, cognitive development and psychological functioning: the Generation R Study. Br J Nutr. 2016. 1–9. doi:10.1017/s0007114515002081. | Intervention/Exposure
2. | Bjork, M, Riedel, B, Spigset, O, Veiby, G, Kolstad, E, Daltveit, AK, Gilhus, NE. Association of Folic Acid Supplementation During Pregnancy With the Risk of Autistic Traits in Children Exposed to Antiepileptic Drugs In Utero. JAMA Neurol. 2018. 75:160–168. doi:10.1001/jamaneurol.2017.3897.29279889 | Comparator
3. | Braun, JM, Froehlich, T, Kalkbrenner, A, Pfeiffer, CM, Fazili, Z, Yolton, K, Lanphear, BP. Brief report: are autistic-behaviors in children related to prenatal vitamin use and maternal whole blood folate concentrations? J Autism Dev Disord. 2014. 44:2602–7. doi:10.1007/s10803-014-2114-x.24710813 | Intervention/Exposure; Comparator
4. | Brown, AS, Susser, ES. Prenatal nutritional deficiency and risk of adult schizophrenia. Schizophr Bull. 2008. 34:1054–63. doi:10.1093/schbul/sbn096.18682377 | Study Design; Review
5. | Chatzi, L, Papadopoulou, E, Koutra, K, Roumeliotaki, T, Georgiou, V, Stratakis, N, Lebentakou, V, Karachaliou, M, Vassilaki, M, Kogevinas, M. Effect of high doses of folic acid supplementation in early pregnancy on child neurodevelopment at 18 months of age: the mother-child cohort ‘Rhea’ study in Crete, Greece. Public Health Nutr. 2012. 15:1728–36. doi:10.1017/s1368980012000067.22314109 | Intervention/Exposure; Comparator
6. | del Rio Garcia, C, Torres-Sanchez, L, Chen, J, Schnaas, L, Hernandez, C, Osorio, E, Portillo, MG, Lopez-Carrillo, L. Maternal MTHFR 677C>T genotype and dietary intake of folate and vitamin B(12): their impact on child neurodevelopment. Nutr Neurosci. 2009. 12:13–20. doi:10.1179/147683009x388913.19178787 | Intervention/Exposure
7. | DeVilbiss, EA, Magnusson, C, Gardner, RM, Rai, D, Newschaffer, CJ, Lyall, K, Dalman, C, Lee, BK. Antenatal nutritional supplementation and autism spectrum disorders in the Stockholm youth cohort: population based cohort study. Bmj. 2017. 359:j4273. doi:10.1136/bmj.j4273.28978695 | Intervention/Exposure; Comparator
8. | Dobo, M, Czeizel, AE. Long-term somatic and mental development of children after periconceptional multivitamin supplementation. Eur J Pediatr. 1998. 157:719–23.9776529 | Comparator
9. | D’Souza, S, Waldie, KE, Peterson, ER, Underwood, L, Morton, SMB. Antenatal and Postnatal Determinants of Behavioural Difficulties in Early Childhood: Evidence from Growing Up in New Zealand. Child Psychiatry Hum Dev. 2019. 50:45–60. doi:10.1007/s10578-018-0816-6.29860616 | Comparator
10. | Eryilmaz, H, Dowling, KF, Huntington, FC, Rodriguez-Thompson, A, Soare, TW, Beard, LM, Lee, H, Blossom, JC, Gollub, RL, Susser, E, Gur, RC, Calkins, ME, Gur, RE, Satterthwaite, TD, Roffman, JL. Association of Prenatal Exposure to Population-Wide Folic Acid Fortification With Altered Cerebral Cortex Maturation in Youths. JAMA Psychiatry. 2018. 75:918–928. doi:10.1001/jamapsychiatry.2018.1381.29971329 | Intervention/Exposure; Population
11. | Forns, J, Torrent, M, Garcia-Esteban, R, Caceres, A, Pilar Gomila, M, Martinez, D, Morales, E, Julvez, J, Grimalt, JO, Sunyer, J. Longitudinal association between early life socio-environmental factors and attention function at the age 11 years. Environ Res. 2012. 117:54–9. doi:10.1016/j.envres.2012.04.007.22608140 | Intervention/Exposure; Comparator
12. | Frye, RE, Slattery, JC, Quadros, EV. Folate metabolism abnormalities in autism: potential biomarkers. Biomark Med. 2017. 11:687–699. doi:10.2217/bmm-2017-0109.28770615 | Study Design; Review
13. | Gatica-Domínguez, G, Rothenberg, SJ, Torres-Sánchez, L, Schnaas, L, Stein, AD, Schmidt, RJ, López-Carrillo, L. The association of prenatal folate and vitamin B12 levels with postnatal neurodevelopment varies by maternal MTHFR 677C>T genotype. International Journal of Behavioral Development. 2019. doi:10.1177/0165025419853379. | Intervention/Exposure
14. | Georgieff, MK. Nutrition and the developing brain: nutrient priorities and measurement. Am J Clin Nutr. 2007. 85:614s–620s. doi:10.1093/ajcn/85.2.614S.17284765 | Study Design; Intervention/Exposure; Not primary research
15. | Glaser, B, Ades, AE, Lewis, S, Emmet, P, Lewis, G, Smith, GD, Zammit, S. Perinatal folate-related exposures and risk of psychotic symptoms in the ALSPAC birth cohort. Schizophr Res. 2010. 120:177–83. doi:10.1016/j.schres.2010.03.006.20418067 | Outcome
16. | Goodrich, AJ, Volk, HE, Tancredi, DJ, McConnell, R, Lurmann, FW, Hansen, RL, Schmidt, RJ. Joint effects of prenatal air pollutant exposure and maternal folic acid supplementation on risk of autism spectrum disorder. Autism Res. 2018. 11:69–80. doi:10.1002/aur.1885.29120534 | Study Design
17. | Husebye, ESN, Gilhus, NE, Riedel, B, Spigset, O, Daltveit, AK, Bjork, MH. Verbal abilities in children of mothers with epilepsy: Association to maternal folate status. Neurology. 2018. 91:e811–e821. doi:10.1212/wnl.0000000000006073.30068633 | Comparator
18. | Irwin, R, Caffrey, A, McLaughlin, M, McNulty, H, Cassidy, T, Pentieva, K, Walsh, C. Beneficial effects on psychosocial and cognitive development observed in children following in utero folic acid supplementation track with changes in their DNA methylation. Ulster medical journal. 2018. 87:56-. | Abstract
19. | Julvez, J, Fortuny, J, Mendez, M, Torrent, M, Ribas-Fito, N, Sunyer, J. Maternal use of folic acid supplements during pregnancy and four-year-old neurodevelopment in a population-based birth cohort. Paediatr Perinat Epidemiol. 2009. 23:199–206. doi:10.1111/j.1365-3016.2009.01032.x.19775381 | Intervention/Exposure; Comparator
20. | Katz, JM, Pacia, SV, Devinsky, O. Current Management of Epilepsy and Pregnancy: Fetal Outcome, Congenital Malformations, and Developmental Delay. Epilepsy Behav. 2001. 2:119–123. doi:10.1006/ebeh.2001.0158.12609194 | Health Status
21. | Lai, JS, Mohamad Ayob, MN, Cai, S, Quah, PL, Gluckman, PD, Shek, LP, Yap, F, Tan, KH, Chong, YS, Godfrey, KM, Meaney, MJ, Broekman, BFP, Rifkin-Graboi, A, Chong, MFF. Maternal plasma vitamin B12 concentrations during pregnancy and infant cognitive outcomes at 2 years of age. Br J Nutr. 2019. 1–26. doi:10.1017/s0007114519000746. | Intervention/Exposure
22. | Li, YM, Shen, YD, Li, YJ, Xun, GL, Liu, H, Wu, RR, Xia, K, Zhao, JP, Ou, JJ. Maternal dietary patterns, supplements intake and autism spectrum disorders: A preliminary case-control study. Medicine (Baltimore). 2018. 97:e13902. doi:10.1097/md.0000000000013902.30593205 | Study Design
23. | Liu, Jian-Meng, Mei, Zuguo, Ye, Rongwei, Serdula, MaryK, Ren, Aiguo, Cogswell, MaryE. Micronutrient supplementation and pregnancy outcomes: double-blind randomized controlled trial in china. JAMA Internal Medicine. 2013. 173:276–282. doi:10.1001/jamainternmed.2013.1632.23303315 | Country
24. | Loftus, CT, Hazlehurst, MF, Szpiro, AA, Ni, Y, Tylavsky, FA, Bush, NR, Sathyanarayana, S, Carroll, KN, Karr, CJ, LeWinn, KZ. Prenatal air pollution and childhood IQ: Preliminary evidence of effect modification by folate. Environ Res. 2019. 176:108505. doi:10.1016/j.envres.2019.05.036.31229778 | Intervention/Exposure
25. | Meador, KJ, Baker, GA, Browning, N, Clayton-Smith, J, Combs-Cantrell, DT, Cohen, M, Kalayjian, LA, Kanner, A, Liporace, JD, Pennell, PB, Privitera, M, Loring, DW. Cognitive function at 3 years of age after fetal exposure to antiepileptic drugs. N Engl J Med. 2009. 360:1597–605. doi:10.1056/NEJMoa0803531.19369666 | Health Status
26. | Meador, KJ, Baker, GA, Browning, N, Cohen, MJ, Bromley, RL, Clayton-Smith, J, Kalayjian, LA, Kanner, A, Liporace, JD, Pennell, PB, Privitera, M, Loring, DW. Fetal antiepileptic drug exposure and cognitive outcomes at age 6 years (NEAD study): a prospective observational study. Lancet Neurol. 2013. 12:244–52. doi:10.1016/s1474-4422(12)70323-x.23352199 | Health Status
27. | Meador, KJ, Baker, GA, Browning, N, Cohen, MJ, Clayton-Smith, J, Kalayjian, LA, Kanner, A, Liporace, JD, Pennell, PB, Privitera, M, Loring, DW. Foetal antiepileptic drug exposure and verbal versus non-verbal abilities at three years of age. Brain. 2011. 134:396–404. doi:10.1093/brain/awq352.21224309 | Health Status
28. | Miyake, Y, Tanaka, K, Okubo, H, Sasaki, S, Arakawa, M. Maternal B vitamin intake during pregnancy and childhood behavioral problems in Japan: The Kyushu Okinawa Maternal and Child Health Study. Nutritional Neuroscience. 2018. doi:10.1080/1028415X.2018.1548139. | Intervention/Exposure; Comparator
29. | Neumann, D, Herbert, SE, Peterson, ER, Underwood, L, Morton, SMB, Waldie, KE. A longitudinal study of antenatal and perinatal risk factors in early childhood cognition: Evidence from Growing Up in New Zealand. Early Hum Dev. 2019. 132:45–51. doi:10.1016/j.earlhumdev.2019.04.001.30974313 | Comparator
30. | Nilsen, RM, Suren, P, Gunnes, N, Alsaker, ER, Bresnahan, M, Hirtz, D, Hornig, M, Lie, KK, Lipkin, WI, Reichborn-Kjennerud, T, Roth, C, Schjolberg, S, Smith, GD, Susser, E, Vollset, SE, Oyen, AS, Magnus, P, Stoltenberg, C. Analysis of self-selection bias in a population-based cohort study of autism spectrum disorders. Paediatr Perinat Epidemiol. 2013. 27:553–63. doi:10.1111/ppe.12077.23919580 | Intervention/Exposure; Comparator
31. | Polanska, K, Muszynski, P, Sobala, W, Dziewirska, E, Merecz-Kot, D, Hanke, W. Maternal lifestyle during pregnancy and child psychomotor development - Polish Mother and Child Cohort study. Early Hum Dev. 2015. 91:317–25. doi:10.1016/j.earlhumdev.2015.03.002.25846841 | Intervention/Exposure; Comparator
32. | Raghavan, R, Riley, AW, Volk, H, Caruso, D, Hironaka, L, Sices, L, Hong, X, Wang, G, Ji, Y, Brucato, M, Wahl, A, Stivers, T, Pearson, C, Zuckerman, B, Stuart, EA, Landa, R, Fallin, MD, Wang, X. Maternal Multivitamin Intake, Plasma Folate and Vitamin B12 Levels and Autism Spectrum Disorder Risk in Offspring. Paediatr Perinat Epidemiol. 2018. 32:100–111. doi:10.1111/ppe.12414.28984369 | Intervention/Exposure; Comparator
33. | Rogers, EJ. Has enhanced folate status during pregnancy altered natural selection and possibly Autism prevalence? A closer look at a possible link. Med Hypotheses. 2008. 71:406–10. doi:10.1016/j.mehy.2008.04.013.18514430 | Study Design; Not primary research
34. | Roza, SJ, van Batenburg-Eddes, T, Steegers, EA, Jaddoe, VW, Mackenbach, JP, Hofman, A, Verhulst, FC, Tiemeier, H. Maternal folic acid supplement use in early pregnancy and child behavioural problems: The Generation R Study. Br J Nutr. 2010. 103:445–52. doi:10.1017/s0007114509991954.19772683 | Comparator
35. | Schlotz, W, Jones, A, Phillips, DI, Gale, CR, Robinson, SM, Godfrey, KM. Lower maternal folate status in early pregnancy is associated with childhood hyperactivity and peer problems in offspring. J Child Psychol Psychiatry. 2010. 51:594–602. doi:10.1111/j.1469-7610.2009.02182.x.19874428 | Intervention/Exposure
36. | Schmidt, RJ, Iosif, AM, Guerrero Angel, E, Ozonoff, S. Association of Maternal Prenatal Vitamin Use With Risk for Autism Spectrum Disorder Recurrence in Young Siblings. JAMA Psychiatry. 2019. doi:10.1001/jamapsychiatry.2018.3901. | Intervention/Exposure
37. | Schmidt, RJ, Kogan, V, Shelton, JF, Delwiche, L, Hansen, RL, Ozonoff, S, Ma, CC, McCanlies, EC, Bennett, DH, Hertz-Picciotto, I, Tancredi, DJ, Volk, HE. Combined Prenatal Pesticide Exposure and Folic Acid Intake in Relation to Autism Spectrum Disorder. Environ Health Perspect. 2017. 125:097007. doi:10.1289/ehp604.28934093 | Study Design
38. | Schmidt, RJ, Schroeder, DI, Crary-Dooley, FK, Barkoski, JM, Tancredi, DJ, Walker, CK, Ozonoff, S, Hertz-Picciotto, I, LaSalle, JM. Self-reported pregnancy exposures and placental DNA methylation in the MARBLES prospective autism sibling study. Environ Epigenet. 2016. 2:doi:10.1093/eep/dvw024. | Intervention/Exposure
39. | Steenweg-de Graaff, J, Ghassabian, A, Jaddoe, VW, Tiemeier, H, Roza, SJ. Folate concentrations during pregnancy and autistic traits in the offspring. The Generation R Study. Eur J Public Health. 2015. 25:431–3. doi:10.1093/eurpub/cku126.25085472 | Comparator
40. | Steenweg-de Graaff, J, Roza, SJ, Steegers, EA, Hofman, A, Verhulst, FC, Jaddoe, VW, Tiemeier, H. Maternal folate status in early pregnancy and child emotional and behavioral problems: the Generation R Study. Am J Clin Nutr. 2012. 95:1413–21. doi:10.3945/ajcn.111.030791.22572645 | Intervention/Exposure; Comparator
41. | Suren, P, Roth, C, Bresnahan, M, Haugen, M, Hornig, M, Hirtz, D, Lie, KK, Lipkin, WI, Magnus, P, Reichborn-Kjennerud, T, Schjolberg, S, Davey Smith, G, Oyen, AS, Susser, E, Stoltenberg, C. Association between maternal use of folic acid supplements and risk of autism spectrum disorders in children. Jama. 2013. 309:570–7. doi:10.1001/jama.2012.155925.23403681 | Comparator
42. | Surén, P, Schjølberg, S, Øyen, AS, Lie, KK, Hornig, M, Bresnahan, M, Bakke, T, Roth, C, Alsaker, E, Schreuder, P, Stenberg, N, Reichborn-Kjennerud, T, Hirtz, D, Susser, E, Magnus, P, Lipkin, WI, Stoltenberg, C. The autism birth cohort (ABC): A study of autism spectrum disorders in MoBa. Norsk Epidemiologi. 2014. 24:39–50. | Intervention/Exposure; Summary of publications from ABC study
43. | Tamura, T, Goldenberg, RL, Chapman, VR, Johnston, KE, Ramey, SL, Nelson, KG. Folate status of mothers during pregnancy and mental and psychomotor development of their children at five years of age. Pediatrics. 2005. 116:703–8. doi:10.1542/peds.2004-2189.16140711 | Intervention/Exposure; Comparator
44. | Valera-Gran, D, Garcia de la Hera, M, Navarrete-Munoz, EM, Fernandez-Somoano, A, Tardon, A, Julvez, J, Forns, J, Lertxundi, N, Ibarluzea, JM, Murcia, M, Rebagliato, M, Vioque, J. Folic acid supplements during pregnancy and child psychomotor development after the first year of life. JAMA Pediatr. 2014. 168:e142611. doi:10.1001/jamapediatrics.2014.2611.25365251 | Comparator
45. | Valera-Gran, D, Navarrete-Munoz, EM, Garcia de la Hera, M, Fernandez-Somoano, A, Tardon, A, Ibarluzea, J, Balluerka, N, Murcia, M, Gonzalez-Safont, L, Romaguera, D, Julvez, J, Vioque, J. Effect of maternal high dosages of folic acid supplements on neurocognitive development in children at 4-5 y of age: the prospective birth cohort Infancia y Medio Ambiente (INMA) study. Am J Clin Nutr. 2017. 106:878–887. doi:10.3945/ajcn.117.152769.28724645 | Comparator; Outcome
46. | Veiby, G, Daltveit, AK, Schjolberg, S, Stoltenberg, C, Oyen, AS, Vollset, SE, Engelsen, BA, Gilhus, NE. Exposure to antiepileptic drugs in utero and child development: a prospective population-based study. Epilepsia. 2013. 54:1462–72. doi:10.1111/epi.12226.23865818 | Intervention/Exposure
47. | Villamor, E, Rifas-Shiman, SL, Gillman, MW, Oken, E. Maternal intake of methyl-donor nutrients and child cognition at 3 years of age. Paediatr Perinat Epidemiol. 2012. 26:328–35. doi:10.1111/j.1365-3016.2012.01264.x.22686384 | Intervention/Exposure
48. | Virk, J, Liew, Z, Olsen, J, Nohr, EA, Catov, JM, Ritz, B. Preconceptional and prenatal supplementary folic acid and multivitamin intake and autism spectrum disorders. Autism. 2016. 20:710–8. doi:10.1177/1362361315604076.26408631 | Intervention/Exposure
49. | Virk, J, Liew, Z, Olsen, J, Nohr, EA, Catov, JM, Ritz, B. Pre-conceptual and prenatal supplementary folic acid and multivitamin intake, behavioral problems, and hyperkinetic disorders: A study based on the Danish National Birth Cohort (DNBC). Nutr Neurosci. 2018. 21:352–360. doi:10.1080/1028415x.2017.1290932.28276257 | Intervention/Exposure; Comparator
50. | Wehby, GL, Murray, JC. The effects of prenatal use of folic acid and other dietary supplements on early child development. Matern Child Health J. 2008. 12:180–7. doi:10.1007/s10995-007-0230-3.17554612 | Intervention/Exposure; Comparator
51. | Yan, J, Zhu, Y, Cao, LJ, Liu, YY, Zheng, YZ, Li, W, Huang, GW. Effects of maternal folic acid supplementation during pregnancy on infant neurodevelopment at 1 month of age: a birth cohort study in China. Eur J Nutr. 2019. doi:10.1007/s00394-019-01986-7. | Study Design; Intervention/Exposure
52. | Zhu, Z, Cheng, Y, Qi, Q, Li, S, Elhoumeda, M, Chang, S, Fawzi, W, Sudfeld, C, Yan, H, Dibley, M, Zeng, L. Infant Cognitive Development Trajectory and Middle Childhood and Adolescent Development Outcomes: A Chinese Birth Cohort Study (P11-144-19). Curr Dev Nutr. 2019. 3:doi:10.1093/cdn/nzz048.P11-144-19. | Abstract
53. | Zhu, Z, Cheng, Y, Zeng, L, Elhoumed, M, He, G, Li, W, Zhang, M, Li, W, Li, D, Tsegaye, S, Chang, S, Yan, H, Wang, EY, Wang, D, Jaffar, S, Dibley, MJ. Association of Antenatal Micronutrient Supplementation With Adolescent Intellectual Development in Rural Western China: 14-Year Follow-up From a Randomized Clinical Trial. JAMA Pediatr. 2018. 172:832–841. doi:10.1001/jamapediatrics.2018.1401.29987336 | Comparator; Country

xlvii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xlviii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).

xlix Two articles were included in both the review for micronutrient status and the review for human milk composition.

l One article was included in both gestational diabetes and hypertensive disorders of pregnancy review.