# List of abbreviations

Abbreviation: Full name
HHS: Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
USDA: United States Department of Agriculture