# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^ii^ Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 3. Food, Beverage, and Nutrient Consumption During Lactation.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed during lactation and developmental milestones, including neurocognitive development, in the child. For this systematic review, the target population considered for the intervention/exposure was women during lactation; healthy and/or at risk for chronic disease. The target population considered for the outcome was infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years). The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern; different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered were 1) developmental domains, examined via milestone achievement and/or scales/indices, including: cognitive, language/communication, movement/physical, and social-emotional, 2) academic performance, 3) attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD), 4) anxiety, 5) depression, and 6) autism spectrum disorder (ASD). The key confounders were maternal age, race/ethnicity, socioeconomic status, smoking, anthropometry, parity, child sex, gestational age at birth, human milk feeding practices (duration, exclusivity). Other factors to be considered were maternal substance use (alcohol, drug use), family history/diagnosis of neurocognitive disorders, and complementary feeding.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study Design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a; 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed] including, at a minimum, a description of the foods and beverages in the pattern; and/or | - Studies that; 1a Do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary pattern, but do not describe the foods and beverages consumed)
Intervention/exposure | - 2 Diet based on macronutrient distribution outside of the AMDR and; - Include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; - Include at least one macronutrient outside of the acceptable macronutrient distribution range (AMDR^iii^) | - 2a Examine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | Dietary patterns described by foods and beverages consumed:; - Consumption of and/or adherence to a different dietary pattern; - Different levels of consumption of and/or adherence to a dietary pattern; Diets described by macronutrient distribution:; - Different macronutrient distribution of carbohydrate, fat, and protein | - No comparator; - Macronutrient proportion(s) of interest also outside the AMDR
Outcomes | - Developmental domains, examined via milestone achievement and/or scales/indices, including:; ○ Cognitive,; ○ Language/communication,; ○ Movement/physical,; ○ Social-emotional; - Academic performance; - Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD); - Anxiety; - Depression; - Autism spectrum disorder (ASD) | - N/A
Date of publication | - January 2000 to January 2020 | - Articles published before January 2000 or after January 2020
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^iv^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants | - Animal and in vitro models
Life stage of study participants - intervention or exposure | - Women during lactation | - N/A
Life stage of study participants - outcome: | - Infants and toddlers (birth - 24 months); - Children and adolescents (2-18 years) | - Adults (19-64 years); - Older adults (65 years and older)
Health status of study participants | - Studies that enroll mothers who are healthy and/or at risk for chronic disease; - Studies that enroll some mothers diagnosed with a disease; - Studies that enroll some mothers who were severely undernourished prior to pregnancy; - Studies that enroll some or all mothers classified as underweight, or obese prior to pregnancy | - Studies that exclusively enroll mothers who gave birth to preterm (< 37 weeks); - Studies that exclusively enroll mothers diagnosed with a disease, including severe undernutrition, or hospitalized with an illness or injury
Temporality | - Studies that assess exposure prior to outcome | - Studies that assess outcome prior to exposure

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date searched: January 29, 2020
- Date range searched: January 1, 2000 – January 29, 2020
- Search terms:
  - #1 - “Lactation”[Mesh] OR lactati*[tiab] OR “Breast Feeding”[Mesh] OR breastfe*[tiab] OR breast fe*[tiab] OR “Milk, Human”[Mesh] OR breastmilk[tiab] OR “breast milk”[tiab] OR “human milk”[tiab] OR “maternal milk”[tiab] OR “nursing women”[tiab]
  - #2 - dietary pattern*[tiab] OR diet pattern*[tiab] OR eating pattern*[tiab] OR food pattern*[tiab] OR “diet quality”[tiab] OR eating habit*[tiab] OR dietary habit*[tiab] OR diet habit*[tiab] OR food habit*[tiab] OR “Feeding Behavior”[Mesh] OR feeding behavior*[tiab] OR beverage consumption[tiab] OR beverage habit*[tiab] OR beverage intake*[tiab] OR dietary profile*[tiab] OR food profile[tiab] OR diet profile*[tiab] OR eating profile*[tiab] OR dietary guideline*[tiab] OR dietary recommendation*[tiab] OR dietary intake*[tiab] OR food intake*[tiab] OR food consumption[tiab] OR dietary consumption[tiab] OR eating frequenc*[tiab] OR food frequenc*[tiab] OR eating style*[tiab] OR dietary change*[tiab] OR dietary choice*[tiab] OR food choice*[tiab] OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet*[tiab] OR DASH diet*[tiab] OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet*[tiab] OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet*[tiab] OR “Healthy Diet”[Mesh] OR plant based diet*[tiab] OR “Diet, Western”[Mesh] OR western diet*[tiab] OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet*[tiab] OR high carbohydrate diet*[tiab] OR Ketogenic Diet*[tiab] OR Nordic Diet*[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR high-fat diet* [tiab] OR low fat diet*[tiab] OR “Diet, Protein-Restricted”[Mesh] OR low protein diet*[tiab] OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet*[tiab] OR low salt diet*[tiab] OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric[tiab] OR hypo-caloric[tiab]) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR (“Guideline Adherence”[Mesh] AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage[tiab])) OR (diet score* OR diet quality score* OR diet quality index* OR dietary habits score* OR kidmed[tiab] OR diet index*[tiab] OR dietary index*[tiab] OR Food-based Index*[tiab] OR diet quality index* OR food index*[tiab] OR food score*[tiab] OR Mediterranean diet score*[tiab] OR MedDietScore[tiab] OR healthy eating index[tiab] OR food frequency questionnaire*[tiab] OR food frequency survey*[tiab] OR “Nutrition Surveys”[Mesh] OR nutrition survey*[tiab] OR diet survey*[tiab] OR food survey*[tiab] OR dietary questionnaire[tiab]) OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food*[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage*[tiab]))
  - #3 - “Mental Disorders”[Mesh] OR mental disorder*[tiab] OR Neuropsychological Tests[MeSH] OR cogniti*[tiab] OR metacogniti*[tiab] OR neurocogniti*[tiab] OR neurodevelop*[tiab] OR neurological[tiab] OR “Depression”[Mesh] OR depress*[tiab] OR anxiety[tiab] OR anxiou*[tiab] OR “Psychomotor Performance”[Mesh] OR psychomotor[tiab] OR motor skill*[tiab] OR executive function*[tiab] OR attention deficit*[tiab] OR ADHD[tiab] OR behavior disorder*[tiab] OR behavior disorder*[tiab] OR behavioral disorder*[tiab] OR developmental disorder*[tiab] OR autis*[tiab] OR asperger*[tiab] OR language processing[tiab] OR language delay*[tiab] OR Language Development[Mesh] OR developmental delay*[tiab] OR developmental disabilit*[tiab] OR problem solv*[tiab] OR developmental domain*[tiab] OR academic[tiab] OR academic performance[mh] OR mental processes[Mesh]
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])

Filters: Publication date from 2000/01/01 to 2020/01/29; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date searched: January 29, 2020
- Date range searched: January 1, 2000 – January 29, 2020
- Search terms:
  - #1 - [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR lact* OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”
  - #2 - “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR [mh “Feeding Behavior”] OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake” OR “food intake” OR “food consumption” OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR “food choice*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Healthy Diet”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”OR (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR (diet OR diets OR consumption OR intake OR supplement*)) OR (“guideline adherence”) NEAR/4 (diet OR dietary OR food OR beverage)) OR (“diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “dietary habits score” OR kidmed OR “diet index” OR “dietary index” OR “Food-based Index” OR “diet quality index” OR “food index” OR “food score” OR “food scores” OR “Mediterranean diet score” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire” OR “food frequency questionnaires” OR “food frequency survey” OR “food frequency surveys” OR [mh “Nutrition Surveys”] OR “nutrition survey” OR “nutrition surveys” OR “diet survey” OR “diet surveys” OR “food survey” OR “food surveys” OR “dietary questionnaire”):ti,ab,kw OR ((pattern OR patterns OR consumption OR habit*) NEAR ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages)):ti,ab,kw
  - #3 - ([mh “Mental Disorders”] OR [mh “Cognition”] OR [mh “Cognitive Dysfunction”] OR [mh “Depressive Disorder”] OR [mh “Depression”] OR [mh “Psychomotor Performance”] OR [mh “Executive Function”] OR [mh “Attention Deficit and Disruptive Behavior Disorders”] OR [mh “Child Behavior Disorders”] OR [mh “Autism Spectrum Disorder”] OR [mh “Developmental Disabilities”] OR [mh “Motor Skills Disorders”] OR [mh “Problem Solving”] OR “mental disorder*” OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR depression OR anxiety OR “motor skill*” OR “executive function*” OR “attention deficit disorder*” OR ADHD OR “developmental disorder*” OR autism OR autistic OR Asperger* OR “language processing” OR “language delay” OR “child develop*” OR “developmental delay” OR “developmental disabilit*” OR “motor skill*” OR “developmental domain*” OR “academic performance” OR [mh “academic performance”] OR “academic achievement” OR “academic failure” OR “academic success*”):ti,ab,kw
  - #4 - #1 AND #2 AND #3

Filters: Publication Year from 2000 – 2020, Trials

#### Embase

- Provider: Elsevier
- Date searched: January 29, 2020
- Date range searched: January 1, 2000 – January 29, 2020
- Search terms:
  - #1 - Lact*:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti OR ‘lactation’/mj OR ‘breast feeding’/exp/mj OR ‘breast milk’/exp/mj
  - #2 - ‘feeding behavior’/exp OR ‘mediterranean diet’/de OR ‘dash diet’/de OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘beverage consumption’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘beverage intake*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake’:ab,ti OR ‘food intake’:ab,ti OR ‘food consumption’:ab,ti OR ‘dietary consumption’:ab,ti OR ‘eating frequenc*’:ab,ti OR ‘food frequenc*’:ab,ti OR ‘eating style*’:ab,ti OR ‘dietary change*’:ab,ti OR ‘dietary choice*’:ab,ti OR ‘food choice*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR (((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR ‘hypo caloric’) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*)):ab,ti) OR ((‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage)):ab,ti) OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘dietary habits score*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food-based index*’:ab,ti OR ‘diet quality index*’:ab,ti OR ‘food index*’:ab,ti OR ‘food score*’:ab,ti OR ‘mediterranean diet score*’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti OR ‘food frequency questionnaire*’:ab,ti OR ‘food frequency survey*’:ab,ti OR ‘nutrition survey*’:ab,ti OR ‘diet survey*’:ab,ti OR ‘food survey*’:ab,ti OR ‘dietary questionnaire’:ab,ti OR (((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti)
  - #3 - ‘mental disease’/exp OR ‘cognition’/exp OR ‘cognitive defect’/exp OR ‘depression’/exp OR ‘psychomotor performance’/de OR ‘executive function’/de OR ‘attention deficit disorder’/de OR ‘autism’/exp OR ‘child development’/de OR ‘developmental disorder’/exp OR ‘psychomotor disorder’/de OR ‘problem solving’/de OR ‘academic performance’/exp OR ‘mental disorder*’:ab,ti OR cognition:ab,ti OR cognitive:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR neurodevelop*:ab,ti OR neurological:ab,ti OR depression:ab,ti OR anxiety:ab,ti OR ‘executive function*’:ab,ti OR ‘attention deficit disorder*’:ab,ti OR adhd:ab,ti OR ‘developmental disorder*’:ab,ti OR autism:ab,ti OR asperger:ab,ti OR ‘language processing’:ab,ti OR ‘language delay’:ab,ti OR ‘developmental delay’:ab,ti OR ‘developmental disabilit*’:ab,ti OR ‘motor skill*’:ab,ti OR ‘developmental domain*’:ab,ti OR ‘academic performance’:ab,ti OR ‘academic achievement’:ab,ti OR ‘academic failure’:ab,ti OR ‘academic success*’:ab,ti
  - #4 - #1 AND #2 AND #3
  - #5 - #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date searched: January 29, 2020
- Date range searched: January 1, 2000 – January 29, 2020
- Search terms:
  - #1 - MH “Breast Feeding” OR breastfeeding OR breast-feeding OR MH “Milk, Human” OR “human milk” OR MH Lactation OR lactation OR lactating OR breastfeeding OR “breast feed*” OR breast-feed* OR breastfed OR breast-fed OR breastfeed* OR “nursing women” OR “nursing mother*”
  - #2- “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR MH “Eating Behavior+” OR “feeding behavior*” OR “beverage consumption” OR “beverage habit*” OR “beverage intake*” OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “food intake*” OR “food consumption” OR “dietary consumption” OR “eating frequenc*” OR “food frequenc*” OR “eating style*” OR “dietary change*” OR “dietary choice*” OR “food choice*” OR MH “Diet, Mediterranean” OR “Mediterranean Diet*” OR MH “Dietary Approaches To Stop Hypertension” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR MH “Diet, Gluten-Free” OR “Gluten Free diet*” OR “prudent diet*” OR MH “Diet, Paleolithic” OR “Paleolithic Diet*” OR MH “Diet, Vegetarian” OR “vegetarian diet*” OR “vegan diet*” OR MH “Healthy Diet” OR “plant based diet*” OR MH “Diet, Western” OR “western diet*” OR MH “Diet, Carbohydrate-Restricted” OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR MH “Diet, Fat-Restricted” OR MH “Diet, High-Fat” OR MH “Diet, High-Protein” OR “high protein diet*” OR “high-fat diet*” OR “low fat diet*” OR MH “Diet, Protein-Restricted” OR “low protein diet*” OR MH “Diet, Sodium-Restricted” OR “low-sodium diet*” OR “low salt diet*” OR ((MH “Dietary Proteins” OR “dietary protein*” OR MH “Dietary Carbohydrates” OR “dietary carbohydrate*” OR MH “Dietary Fats” OR “dietary fat*” OR hypocaloric OR hypo-caloric) AND (diet OR diets OR consumption OR intake OR supplementation)) OR (MH “Guideline Adherence” AND (diet OR dietary OR food OR beverage)) OR (“diet score*” OR “diet quality score*” OR “diet quality index*” OR “dietary habits score*” OR kidmed OR “diet index*” OR “dietary index*” OR “Food-based Index*” OR “diet quality index*” OR “food index*” OR “food score*” OR “Mediterranean diet score*” OR MedDietScore OR “healthy eating index” OR “food frequency questionnaire*” OR “food frequency survey*” OR MH “Nutrition Surveys” OR “nutrition survey*” OR “diet survey*” OR “food survey*” OR “dietary questionnaire*”) OR ((pattern OR patterns OR consumption OR habit*) AND (MH “Diet” OR diet OR diets OR dietary OR MH “Food” OR food OR foods OR MH “Beverages” OR beverage OR beverages))
  - #3 - (MH “Mental Disorders+”) OR “mental disorder*” OR (MH “Cognition+”) OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR “cognitive dysfunction” OR “depressive disorders OR (MH “Depression”) OR depression OR (MH “Anxiety”) OR anxiety OR (MH “Psychomotor Performance”) OR motor skill* OR (MH “Executive Function”) OR executive function* OR (MH “Attention Deficit Hyperactivity Disorder”) OR attention deficit disorder* OR ADHD OR (MH “Child Behavior Disorders”) OR developmental disorder* OR (MH “Autistic Disorder”) OR autism OR Asperger OR “language processing” OR language delay* OR (MH “Developmental Disabilities”) OR developmental delay* OR developmental disabilit* OR (MH “Motor Skills Disorders”) OR motor skill* OR (MH “Problem Solving”) OR developmental domain* OR (MH “academic performance”) OR “academic performance” OR “academic achievement” OR “academic failure” OR academic success*
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication )

Filters: Published Date: 20000101-20200129, English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 2 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns consumed during lactation and child developmental milestones, including neurocognitive development. The literature search yielded 3,562 articles. There were 3,177 articles left once duplicates were removed via EndNote and Distiller. During title screening, 3,087 articles were excluded. During abstract screening, 87 articles were excluded. During full-text screening, 3 articles were excluded. During the hand search, 0 additional articles were identified to include. A total of 0 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes rationale for the categories of inclusion and exclusion criteria (see Table 1) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 2 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1. | Crozier, SR, Godfrey, KM, Calder, PC, Robinson, SM, Inskip, HM, Baird, J, Gale, CR, Cooper, C, Sibbons, CM, Fisk, HL, Burdge, GC. Vegetarian Diet during Pregnancy Is Not Associated with Poorer Cognitive Performance in Children at Age 6-7 Years. Nutrients. 2019. 11. doi:10.3390/nu11123029. | Intervention/Exposure; Population
2. | Krzeczkowski, JE, Boylan, K, Arbuckle, TE, Muckle, G, Poliakova, N, Seguin, JR, Favotto, LA, Savoy, C, Amani, B, Mortaji, N, Van Lieshout, RJ. Maternal Pregnancy Diet Quality Is Directly Associated with Autonomic Nervous System Function in 6-Month-Old Offspring. J Nutr. 2019. doi:10.1093/jn/nxz228. | Population; Outcome
3. | Marques, RC, Garrofe Dorea, J, Rodrigues Bastos, W, de Freitas Rebelo, M, de Freitas Fonseca, M, Malm, O. Maternal mercury exposure and neuro-motor development in breastfed infants from Porto Velho (Amazon), Brazil. Int J Hyg Environ Health. 2007. 210:51–60. doi:10.1016/j.ijheh.2006.08.001.17011234 | Intervention/Exposure

ii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: < 45 or > 65 percent of energy;
- Protein (age 19 years and older): < 10 or > 35 percent of energy;
- Fat (age 19 years and older): < 20 or > 35 percent of energy.

Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington, DC: The National Academies Press; 2002.

iv In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups)