# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED DURING LACTATION AND DEVELOPMENTAL MILESTONES, INCLUDING NEUROCOGNITIVE DEVELOPMENT, IN THE CHILD?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed during lactation and developmental milestones, including neurocognitive development, in the child?

### What is the answer to the question?

- No evidence is available to determine the relationship between maternal dietary patterns during lactation and developmental outcomes, including neurocognitive development, in the child.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Pregnancy and Lactation Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein, whether or not the foods/food groups consumed were provided.

### What is the population of interest?

- For the intervention/exposure, generally healthy, lactating women.
- For the outcome, infants and toddlers (birth to 24 months) and children and adolescents (ages 2-18 years).

### What evidence was found?

- This review identified 0 studies that met the inclusion criteria.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to January 2020.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed during lactation and developmental milestones, including neurocognitive development, in the child?

### Conclusion statement and grade

No evidence is available to determine the relationship between maternal dietary patterns during lactation and developmental outcomes, including neurocognitive development, in the child. (Grade: Grade not assignable)

### Summary of the evidence

- The outcomes for this systematic review included developmental domains (examined through milestone achievement and/or scales/indices, including cognitive, language and communication, movement and physical, and social-emotional), academic performance, attention deficit disorder or attention-deficit/hyperactivity disorder, anxiety, depression, and autism spectrum disorder.
- This review identified 0 studies published between January 2000 and January 2020 that met the inclusion criteria for this systematic review.

### Research recommendations

- More controlled trials and well-conducted observational studies that assess the relationship between maternal dietary patterns during lactation and child developmental milestones are needed.
- Future studies should use dietary patterns consistently so that they can be compared and reproduced across studies.
- Future studies should include diverse populations with varying age groups and different racial/ethnic and socioeconomic backgrounds.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Maternal age, race/ethnicity, socioeconomic status, smoking, anthropometry (obesity status during lactation, gestational weight gain), parity, child sex, gestational age at birth, human milk feeding practices (duration, exclusivity)
  ○ Maternal substance use (alcohol, drug use), family history/diagnosis of neurocognitive disorders, complementary feeding.