# List of abbreviations

Abbreviation: Full name
ALL: Acute lymphoblastic leukemia
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative