# List of abbreviations

Abbreviation: Full name
ESPGHAN: European Society for Paediatric Gastroenterology, Hepatology and Nutrition
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative