# List of abbreviations

Abbreviation: Full name
CVD: cardiovascular disease
HDL: high-density lipoprotein
LDL: low-density lipoprotein
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative