# List of abbreviations

Abbreviation: Full name
IgE: Immunoglobulin E
ISAAC: International Study of Asthma and Allergy in Childhood
KOALA: Child, Parent and Health: Lifestyle and Genetic Constitution
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative