# ACKNOWLEDGEMENTS

Flavor Exposures and Feeding Practices Technical Expert Collaborative (TEC):

- Sara E. Benjamin-Neelon, PhD, MPH, RD, Johns Hopkins University
- Leann Birch, PhD, University of Georgia
- Maureen M. Black, PhD, University of Maryland School of Medicine and RTI International
- Ronette Briefel, DrPH, MPH, RD, Mathematica Policy Institute
- John T. Cook, PhD, MAEd, Boston Medical Center
- Myles S. Faith, PhD, University at Buffalo
- Julie A. Mennella, PhD, Monell Chemical Senses Center

Nutrition Evidence Systematic Review (NESR) Team:

- Maureen K Spill^i^, PhD, Panum Group, Lead analyst
- Emily H Callahan^i^, MS, Panum Group, Analyst (from 11/2016)
- Kirsten Johns^i^, MS, Panum Group, Analyst (until 01/2017)
- Myra J Shapiro^i^, PhD, Panum Group, Analyst (01/2017)
- Joanne M Spahn, MS, USDA, Analyst
- Yat Ping Wong, MLS, MPH, USDA, Librarian
- Nancy Terry, MLS, NIH, Librarian

Project Leads:

- Kellie O Casavale, PhD, RD, HHS
- Joanne M Spahn, MS, RD, FADA USDA
- Eve Essery Stoody, PhD, USDA

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) Liaisons:

- Andrea Farmer, MS, RD, LD, USDA (until 05/2016)
- Heather Hamner, PhD, MS, MPH, CDC (from 05/2016)
- Cria Perrine, PhD, CDC (from 10/2016)

All TEC and NESR team members, Project leads, and FEG-TEC liaisons participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. JMS, EHC, MKS, KJ and YWP developed and conducted the literature search, screened search results, and identified studies for inclusion. JMS, EHC, MKS, and KJ extracted data and assessed risk of bias for included studies. SEB, LB, MMB, RB, JTC, MSF, JAM reviewed and provided substantive feedback on all systematic review materials, including the synthesis of the body of evidence, conclusion statement, and grade of the strength of the evidence. JMS, EHC, and MKS prepared this report and KOC provided oversight. All authors critically reviewed and approved the final report. The authors declare no conflicts of interest.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.