# BACKGROUND

## Flavor is a combination of tastes and odors

Understanding the findings from this body of research requires an understanding of the terms ‘flavor’ and ‘volatiles’. The flavor of a food (which is often misinterpreted as the ‘taste of food’) is a complex combination of tastes (sweet, sour, salty, bitter, umami), textures, and volatile odors which travel to the olfactory receptors when foods or liquids are in the mouth via the retronasal pathway^1^. These odor volatiles can also be detected when inhaling through the nose, commonly referred to as orthonasal olfaction.

Odor volatiles contribute the most to the overall characteristics of the flavor of a food or beverage. While we refer to a particular flavor using a single term (e.g., garlic), it is important to note that every flavor is the consequence of a large number of chemical compounds in its volatile fraction (hence the term flavor volatiles); and, many foods and beverages which are distinct in their ‘taste’, share volatiles. For example, caraway and spearmint contain a common volatile, carvone, and anise and fennel contain a common volatile, anethole.

Measuring sensory responses to a flavor, from a child or adult, can be assessed when eating, through the retronasal perception of flavor volatiles, or when smelling, through the orthonasal perception of volatiles, or both. For the systematic reviews related to amniotic fluid and the review related to breast milk flavor, because they are bodily fluids, sensory panelists did not taste either, but evaluated whether its odor changed based on maternal ingestion. In one case, mothers blindly tasted their own milk samples to evaluate which milk samples tasted different based on time since flavor ingestion.

## A complex question: flavor transmittance, detection, and infant response

To address the systematic review questions related to maternal diet during pregnancy and lactation, amniotic fluid and breast milk flavor, and child’s behavioral response to the flavor and child’s dietary intake, there are three levels of experimental evidence that were explored.

First, studies aimed to determine whether volatiles contained in the foods and beverages of the maternal diet transfer to and flavor amniotic fluid or breast milk. This was determined using chemical or adult sensory analyses of amniotic fluid or breast milk samples after maternal ingestion of a particular food or flavor. To determine whether there is a time-dependent nature to the transmittance of flavor, in some studies milk samples were collected before and at fixed intervals after maternal ingestion of a food or beverage containing those flavor volatiles. As part of the experimental design and rigor, in many studies mothers were put on bland diets that avoid a particular flavor prior to the study to ensure that the volatiles were absent in the baseline sample. Both analytic and sensory tests can indicate if volatiles of a flavor are present in amniotic fluid or breast milk; however, sensory analysis also demonstrates that the flavor is at a concentration level which is detectable by the human olfactory and taste systems.

Second, studies aimed to determine whether experiences with flavors in amniotic fluid or breast milk bias the child’s subsequent responses to the particular flavor. Often a control odor/flavor was included to assess normal olfactory functioning or relative acceptance. The acceptance behaviors were appetitive in nature (or alternatively non-appetitive/aversive) and were measured during smelling when the volatiles are perceived orthonasally (e.g., head orientation toward, mouthing facial expressions of liking) or during feeding when the volatiles are perceived retronasally (e.g., facial expressions, length of feeding, amount consumed, and mother’s perception of infant enjoyment during feeding). Comparisons with response to a control odor or food or control group often yield differential/relative responses. A differential response (or differences when compared to a control group) when the child is re-exposed to flavors ingested by the mother during pregnancy indicates that the human fetus was able to detect and store chemosensory information about the flavors of maternal diet in the prenatal environment. Similarly, a differential response by the infant or child when re-exposed to flavors ingested by the mother during lactation indicates that the child was able to detect and store chemosensory information about the flavor of the maternal diet during breastfeeding. Manipulating the timing of the maternal diet (and hence the timing of the flavor exposure during development) was done in some studies to determine whether the recency of flavor experience relative to testing matters, and/or whether there is a time period when the flavor experience occurs, independent of recency, that may have a stronger influence on acceptance.

Third, studies aimed to determine whether experiences with the flavors of the maternal diet in amniotic fluid or breastmilk impact the patterning and quality of the child’s diet years later. This question poses serious methodological challenges because it is impossible to isolate the impact of flavor experiences only from maternal diet during pregnancy or only from maternal diet during lactation. Mothers’ diet during pregnancy is related to her diet postnatally, and thus the infants can be exposed to flavors in both amniotic fluid and breastmilk. Also, a child’s diet is typically a reflection of the mother’s diet because she feeds her child what she eats; therefore, maternal report of child’s dietary intake is not a good proxy for the child’s food preferences.

In summary, these systematic reviews include studies that examine the relationship between maternal diet during pregnancy and lactation, amniotic fluid and breast milk flavor, and child’s behavioral response to the flavor and child’s dietary intake based on the following assessment methods:

## Chemical analysis (analytic measures)

- To determine if volatiles from flavors ingested by a woman transfer to her amniotic fluid or breast milk
- Assessments quantify the concentration of flavor volatiles in amniotic fluid or breast milk
- Does not indicate if concentration level is detectable by human sensory system
- Commonly used method: gas chromatography-mass spectrometry (GC-MS)
- Commonly used approach: mothers maintain a bland diet devoid of the volatiles several days before the test session to ensure that baseline milk sample is devoid of the flavor volatiles under study and then milk samples are collected immediately before and at fixed intervals after ingestion

## Adult sensory analysis

- To determine if volatiles from flavors ingested by a woman transfer to her amniotic fluid or breast milk at a concentration level that is detectable by the human sensory system; if detected by adults, it is likely that volatiles can be detected by the infant/fetus sensory system
- Tested using established psychophysical methods by having an adult sensory panel blindly evaluate the odor of amniotic fluid or human milk samples (orthonasal olfaction); to assess odor in breast milk samples, samples are collected from each mother before and at fixed intervals (0.5-8 hours) after ingestion of the flavor to determine whether and, if so, when a sensory change in the milk is detectable. In one study mothers tasted samples of their own milk collected at fixed intervals after ingestion (retronasal olfaction) and results were compared with that obtained from adult sensory panel^2^
- Commonly used approach: mothers maintain a bland diet devoid of the volatiles several days before the test session to ensure that baseline milk sample is devoid of the flavor volatiles under study and then milk samples are collected immediately before and at fixed intervals after ingestion

## Infant behavioral response to odor volatiles/flavor

- The research aims to determine whether infants or children, whose mothers ingested a food or beverage containing distinct flavors during pregnancy or lactation, detected the flavor in amniotic fluid or breast milk, respectively, as evidenced by more appetitive responses during exposure to the flavor when compared to infants or children whose mothers did not ingest the flavor during pregnancy or lactation
- A variety of appetitive and aversive responses were measured during the child’s re-exposure to the flavor of the maternal diet during smelling (orthonasal olfaction) or eating
- Depending on the context in which the infants are tested, outcome measures include: food intake, duration of feeding, head orientation, facial & body responses; food acceptability refers to differences in feeding response, specifically: food intake, duration of feeding, facial response, maternal perception of infant liking

## Child overall dietary intake

- To determine if the maternal diet shapes infant/child’s subsequent diet as a result of flavor experience in utero and/or via breast milk.

1 Rozin P. “Taste-smell confusions” and the duality of the olfactory sense. Percept Psychophys 1982;31(4):397–401.7110896

2 Mennella JA, Beauchamp GK. Experience with a flavor in mother’s milk modifies the infant’s acceptance of flavored cereal. Dev Psychobiol 1999;35(3):197–203.10531532