# List of abbreviations

Abbreviation: Full name
BF: Breastfed or breastfeeding
FEG: Federal Expert Group
HHS: Department of Health and Human Services
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
P/B-24: Pregnancy and Birth to 24 Months Project
PICO: Population, Intervention or independent variable, Comparison, Outcome
RCT: Randomized controlled trial
TEC: Technical Expert Collaborative
US: United States of America
USDA: United States Department of Agriculture