# INTRODUCTION

This document describes two systematic reviews conducted to answer the following questions:

- What is the relationship between maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months)?
- What is the relationship between maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months)?

These systematic reviews were conducted as part of the Pregnancy and Birth to 24 Months (P/B-24) Project by USDA’s Nutrition Evidence Systematic Review (NESR).

The purpose of the P/B-24 Project was to conduct a series of systematic reviews on diet and health for women who are pregnant and for infants and toddlers from birth to 24 months of age. This project was a joint initiative led by USDA and HHS, and USDA’s NESR carried out all of the systematic reviews. A Federal Expert Group (FEG), a broadly representative group of Federal researchers and program leaders, also provided input throughout the P/B-24 Project. More information about the P/B-24 Project has been published^ii^ and is available on the NESR website: https://nesr.usda.gov/project-specific-overview-pb-24-0.

NESR, formerly known as the Nutrition Evidence Library (NEL), specializes in conducting food- and nutrition-related systematic reviews using a rigorous, protocol-driven methodology. To conduct each P/B-24 systematic review, NESR’s staff worked with a Technical Expert Collaborative (TEC), which is a group of 7–8 leading subject matter experts.

NESR’s systematic review methodology involves developing and prioritizing systematic review questions, searching for and selecting studies, extracting and assessing the risk of bias of data from each included study, synthesizing the evidence, developing a conclusion statement, grading the evidence underlying the conclusion statement, and recommending future research. A detailed description of the methodology used in conducting systematic reviews for the P/B-24 Project has been published^iii^ and is available on the NESR website: https://nesr.usda.gov/pb-24-project-methodology-0. In addition, starting on page 91, this document includes details about the methodology as it was applied to the systematic reviews described herein. An analytic framework that illustrates the overall scope of the question, including the population, the interventions and/or exposures, comparators, and outcomes of interest, is found on page 99. In addition, the literature search plan, that was used to identify studies included in this systematic review is found on page 99.

ii Stoody EE, Spahn JM, Cassavale KO. The Pregnancy and Birth to 24 Months Project: a series of systematic reviews on diet and health. Am J Clin Nutr. 2019;109(7):685S–697S. doi:10.1093/ajcn/nqy372 30982878

iii Obbagy JE, Spahn JS, Psota TL, Spill MK, Dreibelbis C, Gungor DE, Nadaud PN, Raghavan R, Callahan EH, English LK, Kingshipp BJ, Lapergola CC, Shapiro MJ, Stoody EE. Systematic review methodology used in the Pregnancy and Birth to 24 Months Project. Am J Clin Nutr. 2019;109(7):698S–704S. doi: 10.1093/ajcn/nqy226 30445449