# ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic reviews conducted to examine the relationships between (a) maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months), and (b) maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months).

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between (a) maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months), and (b) maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months). For this systematic review, the target population considered was pregnant and lactating women and their infants and toddlers 0-24 months that were healthy at the time of testing. The interventions or exposures considered were Maternal diet (including alcohol consumption) during pregnancy (all trimesters) and during lactation (postpartum period during first 24 months) and their comparators were a control diet, different dietary pattern(s), different types/amounts of dietary intake or before vs after ingestion of diet/food. The intermediate outcomes considered were amniotic fluid flavor/odor (measured via: sensory panel, volatile measurement, analytical measure), breast milk flavor/odor (measured via: sensory panel, volatile measurement, analytical measure), or time course of flavor change. The outcomes considered were child’s food acceptability (0-24 months; 24+ months), including: infants’ flavor response (detection of flavor), behavior during feeding (e.g. duration of feeding within infant-led feeding paradigm, facial response-- expressions made during feeding of target/novel food), infants’ overall feeding response, e.g. pickiness (as measured by questionnaire), amount of flavor/ target food consumed, measured by research staff or reported by caregiver, amount of novel food (non-exposed food) consumed, measured by research staff or reported by caregiver, caregiver perception of infants’ enjoyment of the feeding of target/novel food and child’s dietary intake (0-24 months; 24+ months) (24hr recall, FFQ, food diaries) which includes: change in food and beverage intake; dietary pattern or a diet quality indicator, e.g. HEI. The key confounders were maternal diet, outside study foods, tobacco and drug use, maternal health (BMI, nutritional status, supplement use (mother or child), race/ethnicity SES (education level, working status, income, etc.), allergies (maternal or child), household composition and parity. Potential mediators include: amniotic fluid flavor exposure, breast milk flavor exposure, complementary food offerings, eating behavior modeling. Potential moderators include: time lapse since flavor experience, age of introduction of complementary foods, infant/child temperament, hunger at time of testing, taste genetics, maternal baseline BMI, maternal baseline diet, and gestational weight gain. Potential covariates include: race/ethnicity, SES (education level, working status, income, etc.), timing of prenatal visits, prenatal care, dietary advice, food security status, exposure to media/marketing, family composition, gestational age, weight of infant (z-score), weight-for-length; weight-for-age, physical activity, diet quality, nutrient adequacy.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review. This table provides the inclusion and exclusion criteria for the systematic review question(s):

- What is the relationship between maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months)?
- What is the relationship between maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months)?

Table 8 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study Design | - Randomized controlled trials; - Within-subject design; - Non-randomized controlled trials; - Prospective cohort studies; - Retrospective cohort studies | - Case-control studies; - Pre/post studies with a control; - Cross-sectional studies; - Uncontrolled studies Pre/post studies without a control; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/Exposure | - Maternal diet during pregnancy or post-partum period; - Amniotic fluid flavor (related to maternal diet exposure); - Breast milk flavor (related to maternal diet exposure) | N/A
Comparator | - Control diet; dietary patterns; - Different types/amounts of dietary intake; - Before vs after ingestion of food/diet | N/A
Date Range | - January 1980 – June 2017 | N/A
Risk of Bias | - All studies regardless of NEL BAT risk of bias rating | N/A
Language | - Studies published in English | - Studies published in languages other than English
Study Setting/Country | - High, Very high | N/A
Study Duration | - No criterion is needed for study duration | N/A
Publication | - Studies published in peer-reviewed journals | - Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Study Subjects | - Human subjects; - Males; - Females; - Pregnant women; - Lactating women; - Non-lactating postpartum women | - Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy mothers and babies
Age of Study | - Mothers Include:; ○ Adolescents (13-18 years); ○ Adults (19 and older); - Children Include (for outcomes):; ○ Infants and Toddlers (0-24 months); ○ Children and adults (24+ months) | - Older adults (65 to 79 years); - Older adults (80+ years)
Size of Study Group | N/A | N/A
Health Status of Study Subjects (Infants/Toddlers, Birth to 24 months) | - Studies done in generally healthy samples; - Studies done in samples where infants were born full-term (≥37 and 0/7 weeks gestational age) | - Studies that exclusively enroll infant subjects with a disease or with the health outcome of interest (intermediate or endpoint health outcomes); - Studies of exclusively preterm babies (gestational age <37 and 0/7 weeks), exclusively babies that have low birth weight (2500g), and/or exclusively babies that are small for gestational age; - Studies done in subjects hospitalized for illness or injury (i.e., this does not include birth and immediate post-partum hospitalization of healthy babies) or malnourished subjects
Health Status of Study Subjects (Mothers, when applicable) | - Studies done in generally healthy samples; - Studies done in samples with elevated chronic disease risk or that enroll some subjects with a disease or with the health outcome of interest (intermediate or endpoint health outcomes); ○ Anemia^1^: hemoglobin (Hg), hematocrit (Hct), or Hb/Hct <5th percentile for age/gender-specific cutoffs; ○ Prediabetes^2^:; ▪ A1C: 5.7-6.4%; ▪ Fasting plasma glucose (FPG): 100-125 mg/dL; ▪ Oral glucose tolerance test (OGTT): 140-199 mg/dL; ○ Prehypertension^3^:; ▪ Systolic blood pressure (SBP): 120-139 mmHg; ▪ Diastolic blood pressure (DBP): 80-89 mmHg; ○ LDL-Cholesterol^4^: above optimal (≥100 mg/dL); ○ Total Cholesterol^4^: above desirable (≥200 mg/dL); ○ Low HDL Cholesterol^4^: <40 mg/dL; ○ Triglycerides^4^: above normal (≥150 mg/dL); - Samples with diagnosed disease states and conditions common during pregnancy in the US (e.g., obesity, diabetes, gestational diabetes, anemia, allergies, pre-eclampsia), and taking associated medications | - Studies that exclusively recruited subjects that have celiac disease and depression; - Studies done in subjects hospitalized for illness or injury (i.e., this does not include birth and immediate post-partum hospitalization of healthy mothers) or malnourished subjects; - Studies of subjects with infectious diseases (e.g. HIV/AIDS)
Source of Foods, Beverages, or Nutrients (IV or DV) | - Whole food sources; - Fortified foods/beverages; - Enriched foods/beverages; - Flavors (essential oils, beverages, spices, seasonings, etc.); - Mother’s own milk (MOM) [specify delivery mode; e.g. at the breast, expressed fresh, or frozen milk]; - Infant formulas (e.g., milk-based, soy, partially-hydrolyzed, extensive-hydrolyzed, amino acid-based); - Baby foods (purees, cereals, etc) | - Vitamin and mineral supplements (e.g., iron drops); - Donor or banked milk; - Medical foods/supplements (e.g. Pedialyte)
Breast milk flavor/Amniotic fluid flavor (DV) | - As measured via:; ○ Analytic measures; ○ Sensory panel; ○ Flavor response (see ‘food response’, below) | N/A
Food Response/Acceptance (DV) | - Infants’ flavor response (detection of flavor); - Behavior during feeding (e.g. duration of feeding within infantled feeding paradigm, facial response- expressions made during feeding of target/novel food); - Infants’ overall feeding response, e.g. pickiness (as measured by questionnaire); - Amount of flavor/ target food consumed, measured by research staff or reported by caregiver; - Amount of novel food (non-exposed food) consumed, measured by research staff or reported by caregiver; - Caregiver perception of infants’ enjoyment of the feeding of target/novel food | N/A
Dietary Intake (DV) | - Change in food intake^5^; - Diet quality indicator, e.g. HEI^5^ | N/A

1 CDC, 1998

2 NIDDK, 2014

3 NHLBI, 2004

4 NHLBI, 2001

5 Measured via 24hr recall, FFQ, food diaries

### Search terms and electronic databases used

#### PubMed

Date(s) Searched: 5/11/16; 6/21/2017

Search date range: 1980-6/2017

Search Terms:

(Maternal OR Mother*[tiab] OR mothers[mesh] OR pregnan*[tiab] OR “Pregnant Women”[Mesh] OR “Pregnancy”[Mesh] OR “Lactation”[Mesh] OR lactat*[tiab] OR natal[tiab] OR postnatal[tiab] OR “Perinatal Care”[Mesh] OR Perinatal[tiab] OR prenatal OR periconception OR gestation*[tiab] OR gravid*[tiab] OR peripartum[tiab])

AND

diet[mh:noexp] OR diet[ti] OR diets[ti] OR food preferences[mh] OR feeding behavior[mh] OR food*[tiab] OR “Food”[mh:noexp] OR “Eating”[mh] OR caloric intake* OR fruit*[tiab] OR vegetable*[tiab] OR dietary intake*[tiab] OR food intake*[tiab] OR food habits[mh] OR dietary habit*[tiab] OR diet habit*[tiab] OR eating habit*[tiab] OR nutrient intake*[tiab] OR food choice*[tiab] OR “diet quality”[tiab] OR dietary choice*[tiab] OR dietary change*[tiab] OR diet records[mh] OR dietary pattern*[tiab] OR eating pattern*[tiab] OR food pattern*[tiab] OR eating habit*[tiab] OR dietary habit*[tiab] OR food habit*[tiab] OR dietary profile*[tiab] OR food profile*[tiab] OR eating profile*[tiab] OR dietary guideline*[tiab] OR dietary recommendation*[tiab] OR food intake*[tiab] OR dietary intake*[tiab] OR eating style*[tiab] OR dietary score*[tiab] OR adequacy index*[tiab] OR kidmed[tiab] OR Food Score*[tiab] OR Diet Score*[tiab] OR MedDietScore[tiab] OR “healthy eating index”[tiab] OR ((index*[ti] OR score*[ti] OR indexes[ti] OR scoring[ti] OR indices[ti]) AND (dietary[ti] OR nutrient*[ti] OR eating[tiab] OR food[ti] OR food[mh] OR diet[ti] OR diet[mh]) AND (pattern* OR habit* OR profile*))

OR

(beverage*[tiab] OR beverages[mh] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR bread[mh] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR honey[mh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh:noexp] OR “egg white”[mh] OR egg yolk[mh] OR nut[ti] OR nuts[ti] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR candy[mh] OR condiments[mh] OR condiment*[tiab] OR “Fast Foods”[Mesh] OR meat[mh] OR molasses[mh] OR nuts[mh] OR “Raw Foods”[Mesh] OR seeds[mh])

FA search:

taste OR flavor* OR flavour* OR accepta* OR preference* OR enjoy* OR choice* OR habit* OR discriminat* OR aversion* OR avert* OR (“Facial Expression”[Mesh] OR ((facial[tiab] OR face[tiab]) AND (expression* OR response* OR react*))) OR (reject* OR dislike* OR disliking OR neophobi*) OR odor* OR smell*

AND

(food OR dietary OR diet OR eating OR beverage* OR food*[tiab] OR “Food and Beverages”[Mesh] OR beverage*[tiab] OR cereal*[tiab] OR Cereal* OR bread*[tiab] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR rice OR soup OR snack*[tiab] OR meals OR meal)

OR “Taste”[Mesh] OR gustat*[tiab] OR taste sense*[tiab] OR “Taste Threshold”[Mesh] OR “Taste Perception”[Mesh] OR flavor* OR flavor* OR distaste OR hedoni* OR palatab* OR unpalatab*

AND

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR early year*[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR “head start”[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling* OR “first two years” OR “first 2 years”

(includes age filter: Filters: Infant: birth-23 months)

(“Study Characteristics” [Publication Type] OR “clinical trial”[ptyp] OR random*[tiab] OR “Epidemiologic Studies”[Mesh] OR “Support of Research”[ptyp] OR cohort[tiab] OR observational[tiab] OR retrospective[tiab] OR longitudinal[tiab] OR controlled trial*[tiab] OR trial[tiab] OR trials[tiab] OR epidemiolog*) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

For prior to 2009; just NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb]) (don’t do: doesn’t exclude that many more.)

#### Embase

Date(s) Searched: 5/16/16; 6/22/2017

Search Terms:

(‘maternal nutrition’/exp OR mother/exp OR ‘pregnancy’/exp OR ‘pregnant woman’/exp OR ‘lactation’/exp OR ‘prenatal period’/exp OR ‘perinatal period’/exp)

AND ((‘dietary intake’/de OR ‘feeding behavior’/exp OR ‘eating habit’/de OR ‘food preference’/de OR ‘food intake’/exp OR ‘fruit’/exp OR ‘vegetable’/exp OR ‘food’/exp OR ‘portion size’/de OR ‘caloric intake’/exp OR ‘alcohol consumption’/exp OR ‘fluid intake’/exp OR ‘diet restriction’/exp OR ‘fluid intake’/exp) NOT (‘postprandial state’/exp OR ‘enteric feeding’/exp OR ‘parenteral nutrition’/exp))

OR ((food/exp NOT (‘animal food’/exp OR ‘dietary fiber’/exp OR ‘fat’/exp OR ‘food color’/exp OR ‘food contamination’/exp OR ‘food drug interaction’/exp OR ‘functional food’/exp OR ‘genetically modified food’/exp)) OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(Maternal OR mother* OR pregnan* OR lactat* OR natal OR postnatal OR Perinatal OR prenatal OR periconception OR gestation* OR gravid* OR peripartum) NEAR/3

(Diet OR diets OR dietary OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR ‘sea food’ OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetable OR vegetable* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR snack* OR meal* OR beans OR legume*)

(‘amnion fluid’/exp OR ((amnio* OR allantoi* OR amnii) NEAR/1 (liquid OR fluid*)))

OR

(‘breast milk’/exp OR ‘human milk’:ab,ti OR ‘breast milk’:ti,ab OR breast-milk:ti,ab OR breastmilk:ti,ab OR ((mother* OR maternal OR human) NEAR/1 milk):ti,ab)

AND

(taste OR flavor* OR flavour* OR accepta* OR preference* OR enjoy* OR choice* OR habit* OR discriminat* OR aversion* OR avert* OR distaste OR hedonic OR palatab* OR unpalatab* OR “Facial Expression”/exp OR ((facial OR face OR physiogno*) AND (expression* OR response* OR react*)) OR smile* OR smiling OR reject* OR dislike* OR disliking OR neophobi* OR odor* OR smell* OR odour* OR aroma* OR gustat* OR ‘smelling and taste’/exp)

OR ((nutrient* NEAR/3 dense*) OR (nutrient* NEAR/3 rich*)) AND (food* OR beverage*):ti,ab ?

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR “early years”:ti,ab OR pre-school:ti,ab OR ‘preschool child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling:ti,ab (postnatal, perinatal?)

OR ([newborn]/lim OR [infant]/lim OR [child]/lim OR [preschool]/lim) not needed (got same # as just doing the infant search.)

AND ([in process]/lim OR [article]/lim OR [article in press]/lim)

NOT [medline]/lim

‘clinical article’/exp OR ‘clinical trial’:ti,ab OR ‘controlled study’:ti,ab OR ‘clinical study’:ti,ab OR ‘randomized controlled’:ti,ab OR ‘clinical study’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR ‘types of study’/exp OR

((‘article’/it OR ‘article in press’/it) AND (‘case report’/de OR ‘clinical article’/de OR ‘clinical trial’/de OR ‘cohort analysis’/de OR ‘comparative study’/de OR ‘controlled clinical trial’/de OR ‘controlled study’/de OR ‘human’/de OR ‘human experiment’/de OR ‘longitudinal study’/de OR ‘major clinical study’/de OR ‘normal human’/de OR ‘observational study’/de OR ‘prospective study’/de OR ‘randomized controlled trial’/de OR ‘retrospective study’/de))

Dietary intake/diet/foods

diet*:ti OR ‘caloric intake’:ab, ti OR ‘dietary intake’:ab, ti OR ‘dietary quality’:ab, ti OR ‘eating pattern’:ab, ti OR ‘food pattern’:ab,ti OR ‘dietary habit’:ab,ti OR ‘food habit’:ab,ti OR ‘food intake’:ab,ti OR ‘food choice’:ab, ti OR ‘diet quality’:ab, ti OR ‘dietary profile’:ab, ti OR ‘food profile’:ab, ti OR ‘diet profile’:ab, ti OR ‘eating profile’:ab, ti OR ‘eating style’:ab, ti OR ‘dietary score’:ab, ti OR kidmed:ab, ti OR ‘food score’:ab, ti OR ‘diet score’:ab, ti OR ‘meddietscore’:ab, ti OR ‘dietary pattern score’:ab, ti OR ‘healthy eating index’:ab, ti OR (index:ab, ti OR score:ab, ti OR scoring:ab, ti OR indices:ab, ti AND (dietary:ab, ti OR nutrient:ab, ti OR eating:ab, ti OR food:ab, ti OR diet:ab, ti) AND (pattern:ab, ti OR habit:ab, ti OR profile:ab, ti) OR

“food consumption” OR “food ingestion” OR “food uptake” OR “meal ingestion” OR ((‘dietary intake’/de OR ‘feeding behavior’/exp OR ‘eating habit’/de OR ‘food preference’/de OR ‘food intake’/exp OR ‘fruit’/exp OR ‘vegetable’/exp OR ‘food’/exp OR ‘portion size’/de OR ‘caloric intake’/exp OR ‘alcohol consumption’/exp OR ‘fluid intake’/exp OR ‘diet restriction’/exp OR ‘fluid intake’/exp)

NOT (‘postprandial state’/exp OR ‘enteric feeding’/exp OR ‘parenteral nutrition’/exp))

OR ((food/exp NOT (‘animal food’/exp OR ‘dietary fiber’/exp OR ‘fat’/exp OR ‘food color’/exp OR ‘food contamination’/exp OR ‘food drug interaction’/exp OR ‘functional food’/exp OR ‘genetically modified food’/exp)) OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR ‘sea food’ OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetable OR vegetable* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR snack* OR meal* OR beans OR legume*):ti,ab

#### Cochrane

Date(s) Searched: 5/24/16; 6/23/2017

Search Terms:

((maternal OR mother* OR pregnan* OR lactat* OR natal OR postnatal OR perinatal OR prenatal OR periconception OR gestation* OR gravid* OR peripartum) AND (infant*:ti,ab OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR preschool*:ti,ab OR “early years”:ti,ab OR pre-school:ti,ab OR “early childhood”:ti,ab OR pre-k:ti,ab OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling:ti,ab)) NEAR/3 (diet:ti OR diets:ti OR dietary:ti OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR ‘sea food’ OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetable OR vegetable* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR snack* OR meal* OR beans OR legume* OR ‘caloric intake’:ab,ti OR ‘dietary intake’:ab,ti OR ‘dietary quality’:ab,ti OR ‘eating pattern’:ab,ti OR‘food pattern’:ab,ti OR ‘dietary habit’:ab,ti OR ‘food habit’:ab,ti OR ‘food intake’:ab,ti OR ‘food choice’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary profile’:ab,ti OR ‘food profile’:ab,ti OR ‘diet profile’:ab,ti OR ‘eating profile’:ab,ti OR ‘eating style’:ab,ti OR ‘dietary score’:ab,ti OR kidmed:ab,ti OR ‘food score’:ab,ti OR’ diet score’:ab,ti OR ‘meddietscore’:ab,ti OR ‘dietary pattern score’:ab,ti OR ‘healthy eating index’:ab,ti OR ((index:ab,ti OR score:ab,ti OR scoring:ab,ti OR indices:ab,ti) AND (dietary:ab,ti ORnutrient:ab,ti OR eating:ab,ti OR food:ab,ti OR diet:ab,ti) AND (pattern:ab,ti OR habit:ab,ti OR profile:ab,ti)) OR “food consumption” OR “food ingestion” OR “food uptake” OR “meal ingestion”) 20; imported; 12 unique

(maternal OR mother* OR pregnan* OR lactat* OR natal OR postnatal OR perinatal OR prenatal OR periconception OR gestation* OR gravid* OR peripartum OR infant*:ti,ab OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR preschool*:ti,ab OR “early years”:ti,ab OR pre-school:ti,ab OR “early childhood”:ti,ab OR pre-k:ti,ab OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling:ti,ab) NEAR/3 (diet:ti OR diets:ti OR dietary:ti OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR ‘sea food’ OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetable OR vegetable* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR snack* OR meal* OR beans OR legume* OR ‘caloric intake’:ab,ti OR ‘dietary intake’:ab,ti OR ‘dietary quality’:ab,ti OR ‘eating pattern’:ab,ti OR‘food pattern’:ab,ti OR ‘dietary habit’:ab,ti OR ‘food habit’:ab,ti OR ‘food intake’:ab,ti OR ‘food choice’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary profile’:ab,ti OR ‘food profile’:ab,ti OR ‘diet profile’:ab,ti OR ‘eating profile’:ab,ti OR ‘eating style’:ab,ti OR ‘dietary score’:ab,ti OR kidmed:ab,ti OR ‘food score’:ab,ti OR’ diet score’:ab,ti OR ‘meddietscore’:ab,ti OR ‘dietary pattern score’:ab,ti OR ‘healthy eating index’:ab,ti OR ((index:ab,ti OR score:ab,ti OR scoring:ab,ti OR indices:ab,ti) AND (dietary:ab,ti ORnutrient:ab,ti OR eating:ab,ti OR food:ab,ti OR diet:ab,ti) AND (pattern:ab,ti OR habit:ab,ti OR profile:ab,ti)) OR “food consumption” OR “food ingestion” OR “food uptake” OR “meal ingestion”)

((amnio* OR allantoi* OR amnii) NEAR/1 (liquid OR fluid*))

OR

(‘human milk’:ab,ti OR ‘breast milk’:ti,ab OR breast-milk:ti,ab OR breastmilk:ti,ab OR ((mother* OR maternal OR human) NEAR/1 milk):ti,ab)

AND

(taste OR gustatory OR flavor* OR flavour* OR accepta* OR preference* OR enjoy* OR choice* OR habit* OR discrimination* OR aversion* OR avert* OR distaste OR hedonic OR palatab* OR unpalatab* OR ((facial OR face OR physiogno*) AND (expression* OR response* OR react*)) OR smile* OR smiling OR reject* OR dislike* OR disliking OR neophobi* OR odor* OR smell* OR aroma* OR odour* OR gustat*)

((food* OR beverage* OR diet* OR eating OR taste* OR tasty OR tastiness OR gustatory OR flavo*r* OR distaste*) NEAR/3 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR enjoy* OR avert* OR avers* OR facial OR face OR reject* OR dislik* OR neophobi* OR hedoni*))

((Face OR facial) NEAR/4 (react* OR respons* OR expressi*)):ti,ab need?

OR

((‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice* OR beans OR legume* OR snack* OR meal*) NEAR/7 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR enjoy* OR avert* OR aversion* OR facial OR face OR reject* OR dislik* OR neophobi* OR hedoni* OR distaste* OR taste* OR tasty OR tastiness OR odor* OR smell odour* OR aroma*))

(Palatab* OR unpalatab*):ti,ab

AND

infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*

#### CINAHL (Plus)

Date(s) Searched: 6/7/16; 6/23/2017;

Search Terms:

((MH “Food Intake+”) OR “dietary intake” OR (MH “Infant Feeding+”) OR

((MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Meals+”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) OR (MH “Facial Expression”))

(MH “Expectant Mothers”) OR (MH “Adolescent Mothers”) OR (MH “Mothers”)

DI AND maternal and child Done; imported 46

AF/BM 96 results; imported 5

((MH “Milk, Human”) AND (taste OR gustatory OR flavor* OR flavour* OR accepta* OR preference* OR enjoy* OR choice* OR discrimination* OR aversion* OR avert* OR distaste OR hedonic OR palatab* OR unpalatab* OR reject* OR dislike* OR disliking OR neophobi* OR odor* OR smell* OR odour* OR aroma* OR gustat*)) OR (MH “Amniotic Fluid”)

OR (MH “Food Preferences”) OR (MH “Food Habits”) dupes; 1 imported.

Limit to “all infant” OR

(MH “Infant”) OR (MH “Infant, Newborn”) OR (MH “Infant Behavior”) OR (MH “Infant Feeding”) OR (MH “Infant Feeding Schedules”) OR (MH “Child, Preschool”)

((Mother* OR maternal) AND (infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*)) n3 (food* OR beverage* OR diet* OR eating OR taste* OR gustatory OR flavo#r* OR‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog#urt* OR cheese* OR juice* OR snack* OR meal OR meals)

OR (infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*) NEAR/3

#### FSTA/BIOSIS/CAB

Date(s) Searched: 6/2016

Search Terms:

((food* OR beverage* OR diet* OR eating OR taste* OR gustatory OR flavor* OR flavor*) NEAR/7 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR aversion* OR avert* OR face OR facial OR reject* OR dislik* OR neophobi* OR react* OR respons* OR expressi* OR hedoni* OR distaste* OR tasty OR tastiness))

Imported one from FSTA; none from BIOSIS/CAB; dupes/irrelevant/not able to limit to humans/non conference

(“whole grain” OR “whole grains” OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yogurt* OR yoghurt* OR cheese* OR juice* OR snack* OR meal OR meals) NEAR/7 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR enjoy* OR aversion* OR avert* OR face OR facial OR reject* OR dislik* OR neophobi* OR react* OR respons* OR expressi* OR distaste* OR taste* OR tasty OR tastiness)

infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*

#### Web of science

Date(s) Searched: 6/2016

Search Terms:

((food OR beverage OR diet OR eating OR taste OR gustatory OR flavor) w/3 (accepta* OR prefer* OR choice OR habit* OR discriminat* OR select* OR like* OR enjoy* OR avert* OR aversion OR face OR facial OR dislike OR reject OR neophobi* OR respons* OR react*))

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR eggs OR meat OR poultry OR seafood OR fruit OR milk OR fish OR poultry OR vegetables OR peas OR nuts OR cereal OR beverage OR bread OR seafood OR yogurt OR cheese OR juice) w/3 (accepta* OR prefer* OR choice OR habit* OR discriminat* OR select* OR like OR enjoy* OR avert* OR aversion OR face OR facial OR dislike OR distaste OR reject OR neophobi* OR respons* OR react*)

AND

(infant* OR (baby OR babies OR toddler OR newborn OR nurser*) OR preschool* OR pre-school OR “early childhood” OR pre-k OR prekindergarten OR pre-kindergarten OR “early years” OR weanling)

#### APA PsycNET (PsycInfo/PsycArticles)

Date(s) Searched: 6/9/2016; 6/23/17

Search Terms:

({Food Intake} OR {Food Preferences} OR {Food Refusal} OR {Diets} OR {Food} OR {Beverages (Nonalcoholic)} OR {Appetite} OR {Taste Buds} OR {Eating Behavior} OR {Taste Perception} OR Palatab* OR unpalatab* OR food* OR beverage* OR diet* OR eating OR taste* OR gustatory OR flavor* OR flavour* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yogurt* OR cheese* OR juice* OR snack* OR meal OR meals)

AND ({Expectant Mothers} OR {Mothers} OR {Adolescent Mothers} OR {Pregnancy} OR {Human Females} OR maternal OR mother*) OR/AND (infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*)

(infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR “early years” OR pre-k OR prekindergarten OR pre-kindergarten OR weanling*) NEAR/3

(food* OR beverage* OR diet* OR eating OR taste* OR gustatory OR flavor* OR flavour* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yogurt* OR cheese* OR juice* OR snack* OR meal OR meals)

{Amniotic Fluid} OR ((Breast NEAR/3 milk) AND (taste OR gustatory OR flavor* OR flavour* OR accepta* OR preference* OR enjoy* OR choice* OR discrimination* OR aversion* OR avert* OR distaste OR hedonic OR palatab* OR unpalatab* OR reject* OR dislike* OR disliking OR neophobi* OR odor* OR smell* OR favor* OR gustat*))

#### PsycNET

Date(s) Searched: 2/4/2016;

Search terms: see above for update:

(food* OR beverage* OR diet* OR eating OR taste* OR tasty OR tastiness OR gustatory OR flavo*) NEAR/3 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR enjoy* OR avert* OR avers* OR facial OR face OR reject* OR dislik* OR neophobi* OR hedoni*) 520

((‘whole grain’ OR ‘whole grains’ OR dairy OR egg* OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR vegetables* OR pea OR nut OR cereal OR beverage* OR bread* OR seafood OR yogurt* OR yoghurt* OR cheese* OR juice* OR beans OR legume* OR snack* OR meal*) NEAR/3 (accepta* OR prefer* OR choice* OR habit* OR discriminat* OR select* OR liking OR like* OR enjoy* OR avert* OR aversion* OR facial OR face OR reject* OR dislik* OR neophobic* OR hedoni* OR distaste* OR taste* OR tasty OR tastiness)) 9 none selected

#### ScienceDirect

Date(s) searched: 6/2016

Search terms:

(docsubtype(FLA) and pub-date > 1979 and (food OR beverage OR diet OR eating OR taste OR gustatory OR flavor) w/3 (accepta* OR prefer* OR choice OR habit* OR discriminat* OR select* OR like OR enjoy* OR avert* OR aversion OR face OR facial OR dislike OR distaste OR reject OR neophobi* OR respons* OR react*) AND LIMIT-TO(cids, “271256”,“Food Quality and Preference”)) AND (pub-date > 1979 and (infant* OR (baby OR babies OR toddler OR newborn OR nurser*) OR preschool* OR pre-school OR “early childhood” OR pre-k OR prekindergarten OR pre-kindergarten OR “early years” OR weanling) AND docsubtype(FLA))

((food OR beverage OR diet OR eating OR taste OR gustatory OR flavor) w/3 (accepta* OR prefer* OR choice OR habit* OR discriminat* OR select* OR like OR enjoy* OR avert* OR aversion OR face OR facial OR dislike OR distaste OR reject OR neophobi* OR respons* OR react*)) AND NOT (‘whole grain’ OR ‘whole grains’ OR dairy OR eggs OR meat OR poultry OR seafood OR fruit OR milk OR fish OR poultry OR vegetables OR peas OR nuts OR cereal OR beverage OR bread OR seafood OR yogurt OR cheese OR juice)

AND

(pub-date > 1979 and (infant* OR (baby OR babies OR toddler OR newborn OR nurser*) OR preschool* OR pre-school OR “early childhood” OR pre-k OR prekindergarten OR pre-kindergarten OR “early years” OR weanling) AND docsubtype(FLA) LIMIT-TO(cids, “271256”,“Food Quality and Preference”)

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationships between maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months), and maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months). The literature search yielded 20,749 articles. During title screening, 17,969 articles were screened out. During abstract screening, 2,606 articles were screened out. During full-text screening, 156 articles were screened out. During the hand search, 5 additional articles were identified to include. 11 articles total were included in the systematic review on maternal diet during pregnancy and 15 articles total were included in the systematic review on maternal diet during lactation at the end of the search and screening process. 1 article was included in both systematic reviews.

This flow chart illustrates the literature search and screening results for articles examining the relationships between maternal diet during pregnancy on flavor transfer to amniotic fluid, child’s behavioral response, and dietary intake (0-24 months, 24+ months), and maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake (0-24 months, 24+ months). The results of the electronic database searches were screened independently by two NESR analysts in a step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on maternal diet during pregnancy included 11 articles, and the systematic review on maternal diet during lactation included 15 articles.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, and may not reflect all possible reasons.

Table 9 Excluded articles

| Citation | Rationale
1 | Aksoy Okan, M.,Gunduz, M.,Okur, M.,Akgun, C.,Esin, K.. Does maternal diet affect infantile colic?. J Matern Fetal Neonatal Med. 2015;1-3. | Dependent variable
2 | Amir LH, Donath SM. Maternal diet and breastfeeding: a case for rethinking physiological explanations for breastfeeding determinants. Breastfeeding Review. 2013;21:52-52 1p. | Study design
3 | Andersen, L. B.,Molgaard, C.,Michaelsen, K. F.,Carlsen, E. M.,Bro, R.,Pipper, C. B.. Indicators of dietary patterns in Danish infants at 9 months of age. Food Nutr Res. 2015;59:27665. | Study design, Independent variable
4 | Antoniou, E. E.,Roefs, A.,Kremers, S. P. J.,Jansen, A.,Gubbels, J. S.,Sleddens, E. F. C.,Thijs, C.. Picky eating and child weight status development: a longitudinal study. Journal of Human Nutrition & Dietetics. 2016;29:298-307 10p. | Independent variable, Age
5 | Apple RD. An Unexpected but Fruitful Combination. Nurs Hist Rev. 2016;24:76-80. | Study design
6 | Ashman AM,Collins CE,Weatherall L,Brown LJ,Rollo ME,Clausen D,Blackwell CC,Pringle KG,Attia J,Smith R,Lumbers ER,Rae KM. A cohort of Indigenous Australian women and their children through pregnancy and beyond: the Gomeroi gaaynggal study. J Dev Orig Health Dis. 2016;1-12. | Study design, Dependent variable
7 | Barroso CS,Roncancio A,Moramarco MW,Hinojosa MB,Davila YR,Mendias E,Reifsnider E. Food security, maternal feeding practices and child weight-for-length. Appl Nurs Res. 2016;29:31-6. | Study design
8 | Beauchamp, G. K.,Mennella, J. A.. Early flavor learning and its impact on later feeding behavior. Journal of Pediatric Gastroenterology & Nutrition. 2009;48:S25-30 1p. | Study design
9 | Betoko A,Charles MA,Hankard R,Forhan A,Bonet M,Saurel-Cubizolles MJ,Heude B,de Lauzon-Guillain B. Infant feeding patterns over the first year of life: influence of family characteristics. Eur J Clin Nutr. 2013;67:631-7. | Independent variable
10 | Biering-Sorensen, F.,Hilden, J.,Biering-Sorensen, K.. Breast-feeding in Copenhagen, 1938-1977. Data on more than 365,000 infants. Dan Med Bull. 1980;27:42-8. | Study design
11 | Bingham PM,Stevens-Tuttle D,Lavin E,Acree T. Odorants in breast milk. Arch Pediatr Adolesc Med. 2003;157:1031. | Study design
12 | Blankenbaker, R. G.. WIC: a food program intended to improve nutritional status. J Indiana State Med Assoc. 1981;74:748. | Study design
13 | Breastfeeding for the health of baby and mother. Nurs J India. 2011;102:179. | Study design
14 | Carruth, B. R.,Skinner, J. D.,Moran, J. D., III,Coletta, F.. Preschoolers’ food product choices at a simulated point of purchase and mothers’ consumer practices. Journal of Nutrition Education. 2000;32:146-151 6p. | Independent variable, Age
15 | Catalano, P. M.. Diabetic pregnancy: is it time to enjoy the fruits of our labors?. Diabetes Care. 1988;11:292-3. | Study design
16 | Caton SJ,Ahern SM,Hetherington MM. Vegetables by stealth. An exploratory study investigating the introduction of vegetables in the weaning period. Appetite. 2011;57:816-25. | Study design, Age
17 | Chapman DJ,Nommsen-Rivers L. Impact of maternal nutritional status on human milk quality and infant outcomes: an update on key nutrients. Adv Nutr. 2012;3:351-2. | Study design
18 | Chatoor I,Egan J,Getson P,Menvielle E,O’Donnell R. Mother-infant interactions in infantile anorexia nervosa. J Am Acad Child Adolesc Psychiatry. 1988;27:535-40. | Independent variable, Health Status
19 | Chen GW,Ding WH,Ku HY,Chao HR,Chen HY,Huang MC,Wang SL. Alkylphenols in human milk and their relations to dietary habits in central Taiwan. Food Chem Toxicol. 2010;48:1939-44. | Independent variable, Dependent variable
20 | Chen, X. C.,Liu, D. S.,Fu, A. Z.,Yan, H. C.,Yin, T. A.,Jing, Y. S.,Xu, Q. M.. A longitudinal study on infant growth during the first sixth months of life, in relation to the nutrition of the lactating mothers and to the breastmilk output. Prog Food Nutr Sci. 1989;13:113-37. | Dependent variable
21 | Chien YC,Huang YJ,Hsu CS,Chao JC,Liu JF. Maternal lactation characteristics after consumption of an alcoholic soup during the postpartum ‘doing-the-month’ ritual. Public Health Nutr. 2009;12:382-8. | Dependent variable
22 | Collins, L. J.,Lacy, K. E.,Campbell, K. J.,McNaughton, S. A.. The Predictors of Diet Quality among Australian Children Aged 3.5 Years. J Acad Nutr Diet. 2016. | Independent variable
23 | Conover B. Exposures during pregnancy and lactation. Nebr Med J. 1992;77:65-7. | Study design
24 | Contreras, C. M.,Gutierrez-Garcia, A. G.,Mendoza-Lopez, R.,Rodriguez-Landa, J. F.,Bernal-Morales, B.,Diaz-Marte, C.. Amniotic fluid elicits appetitive responses in human newborns: fatty acids and appetitive responses. Dev Psychobiol. 2013;55:221-31. | Independent variable
25 | Cooke L,Wardle J,Gibson EL. Relationship between parental report of food neophobia and everyday food consumption in 2-6-year-old children. Appetite. 2003;41:205-6. | Study design, Independent variable
26 | Cooke, L.,Fildes, A.. The impact of flavour exposure in utero and during milk feeding on food acceptance at weaning and beyond. Appetite. 2011;57:808-811. | Study design
27 | Corbett, M. A.,Burst, H. V.. Nutritional intervention in pregnancy. J Nurse Midwifery. 1983;28:23-9. | Study design, Dependent variable
28 | de Barse, L. M.,Tharner, A.,Micali, N.,Jaddoe, V. V.,Hofman, A.,Verhulst, F. C.,Franco, O. H.,Tiemeier, H.,Jansen, P. W.. Does maternal history of eating disorders predict mothers’ feeding practices and preschoolers’ emotional eating?. Appetite. 2015;85:1-7. | Independent variable
29 | Deming, Denise M.,Briefel, Ronette R.,Reidy, Kathleen C.. Infant Feeding Practices and Food Consumption Patterns of Children Participating in WIC. Journal of Nutrition Education & Behavior. 2014;S29-37 1p. | Study design
30 | Dennison BA,Erb TA,Jenkins PL. Predictors of dietary milk fat intake by preschool children. Prev Med. 2001;33:536-42. | Independent variable, Age
31 | Dieting okay for breastfeeding mothers. J Natl Med Assoc. 2000;92:A14. | Study design
32 | Dobe, M.. Optimal infant feeding in rural areas-the missing agenda of communication needs. Indian J Public Health. 2002;46:145-50. | Country
33 | Dondero, Molly,Van Hook, Jennifer. Generational status, neighborhood context, and mother-child resemblance in dietary quality in Mexican-origin families. Social Science & Medicine. 2016;150:212-220. | Age
34 | Doucet, Sébastien,Soussignan, Robert,Sagot, Paul,Schaal, Benoist. The “smellscape” of mother’s breast: Effects of odor making and selective unmasking on neonatal arousal, oral, and visual responses. Developmental Psychobiology. 2007;49:129-138. | Independent variable
35 | Dunn C,Kolasa K,Dunn PC,Ogle MB. Dietary intake of pregnant adolescents in a rural southern community. J Am Diet Assoc. 1994;94:1040-1. | Independent variable, Dependent variable
36 | Durao C,Severo M,Oliveira A,Moreira P,Guerra A,Barros H,Lopes C. Association of maternal characteristics and behaviours with 4-year-old children’s dietary patterns. Matern Child Nutr. 2016. | Age
37 | Dusdieker LB,Stumbo PJ,Kross BC,Dungy CI. Does increased nitrate ingestion elevate nitrate levels in human milk?. Archives of pediatrics & adolescent medicine. 1996;150:311-4. | Independent variable, Dependent variable
38 | Emmett PM,Jones LR,Golding J. Pregnancy diet and associated outcomes in the Avon Longitudinal Study of Parents and Children. Nutrition Reviews. 2015;73:154-174 21p. | Study design, Dependent variable
39 | Emmett, P. M.,Jones, L. R.,Northstone, K.. Dietary patterns in the Avon Longitudinal Study of Parents and Children. Nutr Rev. 2015;73 Suppl 3:207-30. | Study design, Independent variable
40 | Emmett, P. M.. Dietary Patterns during Complementary Feeding and Later Outcomes. Nestle Nutr Inst Workshop Ser. 2016;85:145-54. | Independent variable
41 | Emmett, Pauline M.,Jones, Louise R.. Diet, growth, and obesity development throughout childhood in the Avon Longitudinal Study of Parents and Children. Nutrition Reviews. 2015;73:175-206 32p. | Study design, Independent variable
42 | Fangupo LJ,Heath AL,Williams SM,Somerville MR,Lawrence JA,Gray AR,Taylor BJ,Mills VC,Watson EO,Galland BC,Sayers RM,Hanna MB,Taylor RW. Impact of an early-life intervention on the nutrition behaviors of 2-y-old children: a randomized controlled trial. Am J Clin Nutr. 2015;102:704-12. | Independent variable
43 | Fetal effects of maternal alcohol use. Jama. 1983;249:2517-21. | Study design
44 | Fewtrell, M.. 2.4 Complementary foods. World Rev Nutr Diet. 2015;113:109-12. | Study design
45 | Fisk CM,Crozier SR,Inskip HM,Godfrey KM,Cooper C,Robinson SM. Influences on the quality of young children’s diets: the importance of maternal food choices. Br J Nutr. 2011;105:287-96. | Age
46 | Flanders-Stepans, M. B.. Breast milk from mothers who smoke and drink smells!. J Perinat Educ. 1999;8:45-6. | Study design
47 | Font, L.. “Incidental” maternal dietary intake and infant refusal to nurse. J Hum Lact. 1990;6:9. | Study design
48 | Forbes, R.. Alcohol-related birth defects. Public Health. 1984;98:238-41. | Study design
49 | Forestell CA,Mennella JA. Early determinants of fruit and vegetable acceptance. Pediatrics. 2007;120:1247-54. | Independent variable
50 | Forestell CA. The Development of Flavor Perception and Acceptance: The Roles of Nature and Nurture. Nestle Nutr Inst Workshop Ser. 2016;85:135-43. | Study design
51 | Forsum E,Lonnerdal B. Effect of protein intake on protein and nitrogen composition of breast milk. Am J Clin Nutr. 1980;33:1809-13. | Dependent variable
52 | Gentry, J. A.,Luiselli, J. K.. Treating a child’s selective eating through parent implemented feeding intervention in the home setting. Journal of Developmental & Physical Disabilities. 2008;20:63-70 8p. | Study design
53 | Gerrard, J. W.. Allergies in breastfed babies to foods ingested by the mother. Clin Rev Allergy. 1984;2:143-9. | Study design
54 | Gopalan S,Puri RK,Sachdev HP. Adequacy of vegetarian diets for optimal nutrition of mother and child. Indian Pediatr. 1993;30:1379-86. | Study design, Independent variable
55 | Gregory JE,Paxton SJ,Brozovic AM. Maternal feeding practices predict fruit and vegetable consumption in young children. Results of a 12-month longitudinal study. Appetite. 2011;57:167-72. | Independent variable
56 | Gross, R. S.,Mendelsohn, A. L.,Gross, M. B.,Scheinmann, R.,Messito, M. J.. Randomized Controlled Trial of a Primary Care-Based Child Obesity Prevention Intervention on Infant Feeding Practices. J Pediatr. 2016. | Independent variable, Dependent variable
57 | Hackney, A. R.. Breast feeding. Am J Nurs. 1990;90:70. | Study design
58 | Haftel L,Berkovich Z,Reifen R. Elevated milk beta-carotene and lycopene after carrot and tomato paste supplementation. Nutrition. 2015;31:443-5. | Dependent variable
59 | Hetherington, M. M.,Schwartz, C.,Madrelle, J.,Croden, F.,Nekitsing, C.,Vereijken, C. M.,Weenen, H.. A step-by-step introduction to vegetables at the beginning of complementary feeding. The effects of early and repeated exposure. Appetite. 2015;84:280-90. | Independent variable
60 | Hjern A,Kocturk-Runefors T,Jeppson O. Food habits and infant feeding in newly resettled refugee families from Chile and the Middle East. Scand J Prim Health Care. 1990;8:145-50. | Independent variable
61 | Horan, M. K.,Donnelly, J. M.,McGowan, C. A.,Gibney, E. R.,McAuliffe, F. M.. The association between maternal nutrition and lifestyle during pregnancy and 2-year-old offspring adiposity: analysis from the ROLO study. Z Gesundh Wiss. 2016;24:427-436. | Dependent variable
62 | Howard, A. J.,Mallan, K. M.,Byrne, R.,Magarey, A.,Daniels, L. A.. Toddlers’ food preferences. The impact of novel food exposure, maternal preferences and food neophobia. Appetite. 2012;59:818-25. | Study design, Independent variable
63 | Hudson P,Buckley R. Vegetarian diets. Are they good for pregnant women and their babies?. Pract Midwife. 2000;3:22-3. | Study design, Independent variable
64 | Huffman, S. L.,Dewey, K. G.,Schofield, D.. Moving ahead with maternal, infant, and young child nutrition: need to integrate actions. Food Nutr Bull. 2010;31:S99. | Study design
65 | Jacobson, H. N.. Roundtable. V. Diet therapy and the improvement of pregnancy outcomes. Birth. 1983;10:29-31. | Study design
66 | Jelliffe, D. B.,Patrice-Jelliffe, E. F.. Maternal nutrition, breast-feeding, and contraception. Br Med J (Clin Res Ed). 1982;285:806-7. | Study design
67 | Johnson, Samantha,Matthews, Ruth,Draper, Elizabeth S.,Field, David J.,Manktelow, Bradley N.,Marlow, Neil,Smith, Lucy K.,Boyle, Elaine M.. Eating difficulties in children born late and moderately preterm at 2 y of age: a prospective population-based cohort study. American Journal of Clinical Nutrition. 2016;103:406-414 9p. | Study design, Independent variable
68 | Kilanowski JF. Patterns and correlates of nutrition among migrant farm-worker children. West J Nurs Res. 2012;34:396-416. | Age
69 | Kirsch F,Buettner A. Characterisation of the metabolites of 1,8-cineole transferred into human milk: Concentrations and ratio of enantiomers. Metabolites. 2012;3:47-71. | Duplicate of Findings
70 | Kirsch F,Buettner A. Characterisation of the metabolites of 1,8-cineole transferred into human milk: concentrations and ratio of enantiomers. Metabolites. 2013;3:47-71. | Duplicate of Findings
71 | Kirsch F,Horst K,Röhrig W,Rychlik M,Buettner A. Tracing metabolite profiles in human milk: Studies on the odorant 1,8-cineole transferred into breast milk after oral intake. Metabolomics. 2013;9:483-496. | Duplicate of Findings
72 | Klohe-Lehman DM,Freeland-Graves J,Clarke KK,Cai G,Voruganti VS,Milani TJ,Nuss HJ,Proffitt JM,Bohman TM. Low-income, overweight and obese mothers as agents of change to improve food choices, fat habits, and physical activity in their 1-to-3-year-old children. J Am Coll Nutr. 2007;26:196-208. | Age
73 | Kocturk T. Infant feeding pattern in three districts of Istanbul. J Trop Pediatr. 1988;34:193-7. | Study design, Independent variable
74 | Koletzko, B.. 1.5 Early nutrition and long-term health. World Rev Nutr Diet. 2015;113:72-7. | Study design
75 | Kravitz, E.,Pollack, R. L.,Mueller, D. H.. Nutrition during pregnancy, infancy, childhood, and adolescence. J Pedod. 1983;7:182-95. | Study design
76 | Kristiansen AL,Lande B,Sexton JA,Andersen LF. Dietary patterns among Norwegian 2-year-olds in 1999 and in 2007 and associations with child and parent characteristics. Br J Nutr. 2013;110:135-44. | Study design, Independent variable, Age
77 | Lambert, E. J.,Hall, M. A.. Infant nutrition. Part 1: Preweaning (0-4 months). Br J Hosp Med. 1995;53:567-9. | Study design
78 | Laster, L. E.,Lovelady, C. A.,West, D. G.,Wiltheiss, G. A.,Brouwer, R. J.,Stroo, M.,Ostbye, T.. Diet quality of overweight and obese mothers and their preschool children. J Acad Nutr Diet. 2013;113:1476-83. | Independent variable, Age
79 | Lee SY, Hoerr SL, Schiffman RF. Screening for infants’ and toddlers’ dietary quality through maternal diet. MCN Am J Matern Child Nurs. 2005;30(1):60-6. PMID: 15622151. | Independent variable
80 | Lee Y,Birch LL. Diet quality, nutrient intake, weight status, and feeding environments of girls meeting or exceeding the American Academy of Pediatrics recommendations for total dietary fat. Minerva Pediatr. 2002;54:179-86. | Study design, Age
81 | Lee, Y.,Joo, N.. The awareness level and needs for education on reducing sugar consumption among mothers with preschool children. Nutr Res Pract. 2016;10:229-36. | Independent variable, Dependent variable, Age
82 | Linderborg KM,Kalpio M,Makela J,Niinikoski H,Kallio HP,Lagstrom H. Tandem mass spectrometric analysis of human milk triacylglycerols from normal weight and overweight mothers on different diets. Food Chem. 2014;146:583-90. | Independent variable, Dependent variable
83 | Loos HM,Doucet S,Soussignan R,Hartmann C,Durand K,Dittrich R,Sagot P,Buettner A,Schaal B. Responsiveness of human neonates to the odor of 5alpha-androst-16-en-3-one: a behavioral paradox?. Chem Senses. 2014;39:693-703. | Independent variable
84 | Magarey, A.,Mauch, C.,Mallan, K.,Perry, R.,Elovaris, R.,Meedeniya, J.,Byrne, R.,Daniels, L.. Child dietary and eating behavior outcomes up to 3.5 years after an early feeding intervention: The NOURISH RCT. Obesity (Silver Spring). 2016;24:1537-45. | Independent variable
85 | Marlier, L.,Schaal, B.,Soussignan, R.. Bottle-fed neonates prefer an odor experienced in utero to an odor experienced postnatally in the feeding context. Dev Psychobiol. 1998;33:133-45. | Independent variable
86 | Marlier, L.,Schaal, B.,Soussignan, R.. Neonatal responsiveness to the odor of amniotic and lacteal fluids: a test of perinatal chemosensory continuity. Child Dev. 1998;69:611-23. | Independent variable
87 | Marlier, L.,Schaal, B.,Soussignan, R.. Orientation responses to biological odours in the human newborn. Initial pattern and postnatal plasticity. C R Acad Sci III. 1997;320:999-1005. | Independent variable
88 | Mason, M.. Women, infants, and children supplemental food program: its impact on infant nutrition. Nebr Med J. 1982;67:58-9. | Study design
89 | McEachan RR,Santorelli G,Bryant M,Sahota P,Farrar D,Small N,Akhtar S,Sargent J,Barber SE,Taylor N,Richardson G,Farrin AJ,Bhopal RS,Bingham DD,Ahern SM,Wright J. The HAPPY (Healthy and Active Parenting Programmme for early Years) feasibility randomised control trial: acceptability and feasibility of an intervention to reduce infant obesity. BMC Public Health. 2016;16:211. | Study design, Dependent variable
90 | McGowan, L.,Croker, H.,Wardle, J.,Cooke, L. J.. Environmental and individual determinants of core and non-core food and drink intake in preschool-aged children in the United Kingdom. Eur J Clin Nutr. 2012;66:322-8. | Age
91 | Mennella JA,Garcia PL. Children’s hedonic response to the smell of alcohol: effects of parental drinking habits. Alcohol Clin Exp Res. 2000;24:1167-71. | Independent variable, Age
92 | Mennella, J. A.,Beauchamp, G. K.. Mothers’ milk enhances the acceptance of cereal during weaning. Pediatr Res. 1997;41:188-92. | Study design, Independent variable
93 | Mennella, J. A.,Forestell, C. A.,Morgan, L. K.,Beauchamp, G. K.. Early milk feeding influences taste acceptance and liking during infancy. Am J Clin Nutr. 2009;90:780s-788s. | Independent variable
94 | Mennella, J. A.. Infants’ suckling responses to the flavor of alcohol in mothers’ milk. Alcohol Clin Exp Res. 1997;21:581-5. | Study design, Independent variable
95 | Mesirow, M. S.,Cecil, C.,Maughan, B.,Barker, E. D.. Associations between Prenatal and Early Childhood Fish and Processed Food Intake, Conduct Problems, and Co-Occurring Difficulties. J Abnorm Child Psychol. 2017;45:1039-1049. | Dependent variable
96 | Mizuno, K.,Ueda, A.. Antenatal olfactory learning influences infant feeding. Early Hum Dev. 2004;76:83-90. | Independent variable
97 | Moding, K. J.,Stifter, C. A.. Stability of food neophobia from infancy through early childhood. Appetite. 2016;97:72-8. | Independent variable
98 | Moses, R. G.,Luebke, M.,Petocz, P.,Brand-Miller, J. C.. Maternal diet and infant size 2 y after the completion of a study of a low-glycemic-index diet in pregnancy. American journal of clinical nutrition. 2007;86:1806. | Study design, Dependent variable
99 | Mosley SA,Shahin AM,Williams J,McGuire MA,McGuire MK. Supplemental conjugated linoleic acid consumption does not influence milk macronutrient contents in all healthy lactating women. Lipids. 2007;42:723-9. | Dependent variable
100 | Mothers influence the milk-drinking habits of their daughters. Mayo Clin Womens Healthsource. 2001;5:3. | Study design
101 | Naja F,Nasreddine L,Al Thani AA,Yunis K,Clinton M,Nassar A,Farhat Jarrar S,Moghames P,Ghazeeri G,Rahman S,Al-Chetachi W,Sadoun E,Lubbad N,Bashwar Z,Bawadi H,Hwalla N. Study protocol: Mother and Infant Nutritional Assessment (MINA) cohort study in Qatar and Lebanon. BMC Pregnancy Childbirth. 2016;16:98. | Study design
102 | Nguyen TT,Risbud RD,Chambers CD,Thomas JD. Dietary Nutrient Intake in School-Aged Children With Heavy Prenatal Alcohol Exposure. Alcohol Clin Exp Res. 2016;40:1075-82. | Dependent variable, Age
103 | Nguyen, A. N.,de Barse, L. M.,Tiemeier, H.,Jaddoe, V. W.,Franco, O. H.,Jansen, P. W.,Voortman, T.. Maternal history of eating disorders: Diet quality during pregnancy and infant feeding. Appetite. 2017;109:108-114. | Independent variable, Dependent variable
104 | Northstone K,Emmett P. The associations between feeding difficulties and behaviours and dietary patterns at 2 years of age: the ALSPAC cohort. Matern Child Nutr. 2013;9:533-42. | Independent variable
105 | Nutrition for mother and child. Nurs J India. 1990;81:181-8. | Study design
106 | Oski, F. A.. What we eat may determine who we can be. Nutrition. 1997;13:220-1. | Study design
107 | Ostbye T,Malhotra R,Stroo M,Lovelady C,Brouwer R,Zucker N,Fuemmeler B. The effect of the home environment on physical activity and dietary intake in preschool children. Int J Obes (Lond). 2013;37:1314-21. | Independent variable, Age
108 | Ovaskainen ML,Nevalainen J,Uusitalo L,Tuokkola JJ,Arkkola T,Kronberg-Kippila C,Veijola R,Knip M,Virtanen SM. Some similarities in dietary clusters of pre-school children and their mothers. Br J Nutr. 2009;102:443-52. | Independent variable
109 | Palmer DJ,Gold MS,Makrides M. Effect of maternal egg consumption on breast milk ovalbumin concentration. Clin Exp Allergy. 2008;38:1186-91. | Dependent variable
110 | Papas, M. A.,Hurley, K. M.,Quigg, A. M.,Oberlander, S. E.,Black, M. M.. Low-income, African American adolescent mothers and their toddlers exhibit similar dietary variety patterns. J Nutr Educ Behav. 2009;41:87-94. | Study design, Dependent variable
111 | Pereira, M. A.,Gillman, M. W.. Maternal Consumption of Artificially Sweetened Beverages and Infant Weight Gain: Causal or Casual?. JAMA Pediatr. 2016. | Study design
112 | Pilgrim A,Barker M,Jackson A,Ntani G,Crozier S,Inskip H,Godfrey K,Cooper C,Robinson S. Does living in a food insecure household impact on the diets and body composition of young children? Findings from the Southampton Women’s Survey. J Epidemiol Community Health. 2012;66:e6. | Independent variable, Dependent variable
113 | Piperata BA,Schmeer KK,Hadley C,Ritchie-Ewing G. Dietary inequalities of mother-child pairs in the rural Amazon: evidence of maternal-child buffering?. Soc Sci Med. 2013;96:183-91. | Independent variable, Age
114 | Pobocik RS,Heathcote GM,Spiers JB,Otto CT. Nutritional and anthropometric assessment of a sample of pregnant women and young children in Palau. Asia Pac J Clin Nutr. 2000;9:102-14. | Independent variable, Age
115 | Prentice, A. M.,Cole, T. J.,Whitehead, R. G.. Food supplementation in pregnant women. Eur J Clin Nutr. 1988;42:87-91. | Study design
116 | Radzyminski, Sharon. Mother’s Beliefs, Attitudes, and Decision Making Related to Infant Feeding Choices. Journal of Perinatal Education. 2016;25:18-28 11p. | Study design
117 | Rauber F,da Costa Louzada ML,Feldens CA,Vitolo MR. Maternal and family characteristics associated with the Healthy Eating Index among low socioeconomic status Brazilian children. J Hum Nutr Diet. 2013;26:369-79. | Independent variable
118 | Rauber F,Hoffman DJ,Vitolo MR. Diet quality from pre-school to school age in Brazilian children: a 4-year follow-up in a randomised control study. Br J Nutr. 2014;111:499-505. | Independent variable, Age
119 | Robinson, S.,Marriott, L.,Poole, J.,Crozier, S.,Borland, S.,Lawrence, W.,Law, C.,Godfrey, K.,Cooper, C.,Inskip, H.. Dietary patterns in infancy: the importance of maternal and family influences on feeding practice. Br J Nutr. 2007;98:1029-37. | Independent variable, Age
120 | Romaszko E,Wiczkowski W,Romaszko J,Honke J,Piskula MK. Exposure of breastfed infants to quercetin after consumption of a single meal rich in quercetin by their mothers. Mol Nutr Food Res. 2014;58:221-8. | Dependent variable
121 | Roset-Salla M,Ramon-Cabot J,Salabarnada-Torras J,Pera G,Dalmau A. Educational intervention to improve adherence to the Mediterranean diet among parents and their children aged 1-2 years. EniM clinical trial. Public Health Nutr. 2016;19:1131-44. | Independent variable, Dependent variable
122 | Rosso, P.. Nutrition and maternal-fetal exchange. Am J Clin Nutr. 1981;34:744-55. | Study design, Dependent variable
123 | Rudloff S,Pohlentz G,Borsch C,Lentze MJ,Kunz C. Urinary excretion of in vivo (1)(3)C-labelled milk oligosaccharides in breastfed infants. Br J Nutr. 2012;107:957-63. | Independent variable, Dependent variable
124 | Ryan C,Dwyer J,Ziegler P,Yang E,Moore L,Song WO. What Do Infants Really Eat?. Nutr Today. 2002;37:50-56. | Study design
125 | Salvatori, P.,Andrei, F.,Neri, E.,Chirico, I.,Trombini, E.. Pattern of mother-child feeding interactions in preterm and term dyads at 18 and 24 months. Front Psychol. 2015;6:1245. | Independent variable
126 | Schaal B,Marlier L,Soussignan R. Olfactory function in the human fetus: evidence from selective neonatal responsiveness to the odor of amniotic fluid. Behav Neurosci. 1998;112:1438-49. | Independent variable
127 | Scott, J. A.,Chih, T. Y.,Oddy, W. H.. Food variety at 2 years of age is related to duration of breastfeeding. Nutrients. 2012;4:1464-74. | Independent variable
128 | Shrivastava A,Murrin C,Kelleher CC. Preschoolers’ parent-rated health disparities are strongly associated with measures of adiposity in the Lifeways cohort study children. BMJ Open. 2014;4:e005328. | Study design, Independent variable
129 | Skinner, J. D.,Carruth, B. R.,Bounds, W.,Ziegler, P.,Reidy, K.. Do food-related experiences in the first 2 years of life predict dietary variety in school-aged children?. J Nutr Educ Behav. 2002;34:310-5. | Independent variable, Age
130 | Sparks JW. Fetal growth and diet. Mead Johnson Symp Perinat Dev Med. 1984;21-7. | Study design, Dependent variable
131 | Stimming, M.,Mesch, C. M.,Kersting, M.,Libuda, L.. Fish and rapeseed oil consumption in infants and mothers: dietary habits and determinants in a nationwide sample in Germany. Eur J Nutr. 2015;54:1069-80. | Study design
132 | Streissguth AP,Barr HM,Martin DC. Alcohol exposure in utero and functional deficits in children during the first four years of life. Ciba Found Symp. 1984;105:176-96. | Study design, Dependent variable
133 | Streissguth AP,Martin DC,Martin JC,Barr HM. The Seattle longitudinal prospective study on alcohol and pregnancy. Neurobehav Toxicol Teratol. 1981;3:223-33. | Dependent variable
134 | Sylvetsky AC,Gardner AL,Bauman V,Blau JE,Garraffo HM,Walter PJ,Rother KI. Nonnutritive Sweeteners in Breast Milk. J Toxicol Environ Health A. 2015;78:1029-32. | Independent variable
135 | Talvia S,Rasanen L,Lagstrom H,Pahkala K,Viikari J,Ronnemaa T,Arffman M,Simell O. Longitudinal trends in consumption of vegetables and fruit in Finnish children in an atherosclerosis prevention study (STRIP). Eur J Clin Nutr. 2006;60:172-80. | Study design, Independent variable
136 | Taveras, E. M.. Childhood Obesity Risk and Prevention: Shining a Lens on the First 1000 Days. Child Obes. 2016;12:159-61. | Study design
137 | Trout, K. K.,McGrath, J.,Flanagan, J.,Costello, M. C.,Frey, J. C.. A pilot study to increase fruit and vegetable intake in pregnant latina women. J Prim Care Community Health. 2012;3:2-5. | Dependent variable
138 | Trout, K. K.,Wetzel-Effinger, L.. Flavor learning in utero and its implications for future obesity and diabetes. Current Diabetes Reports. 2012;12:60-66 7p. | Study design
139 | Tull, M. W.,Brown, A. L.. Pediatric drug information: effects of caffeine on pregnancy and lactation. Pediatr Nurs. 1981;7:51-2. | Study design
140 | Varendi, H.,Porter, R. H.,Winberg, J.. Natural odour preferences of newborn infants change over time. Acta Paediatr. 1997;86:985-90. | Independent variable
141 | Vitolo MR,Bortolini GA,Campagnolo PD,Hoffman DJ. Maternal dietary counseling reduces consumption of energy-dense foods among infants: a randomized controlled trial. J Nutr Educ Behav. 2012;44:140-7. | Independent variable
142 | Vitolo MR,Rauber F,Campagnolo PD,Feldens CA,Hoffman DJ. Maternal dietary counseling in the first year of life is associated with a higher healthy eating index in childhood. J Nutr. 2010;140:2002-7. | Independent variable
143 | Wallace, J. P.,Inbar, G.,Ernsthausen, K.. Infant acceptance of postexercise breast milk. Pediatrics. 1992;89:1245-7. | Independent variable
144 | Wallis, J.. Positive role of breastfeeding during the first six weeks. Midwives. 2012;15:31. | Study design
145 | Walsh, A. D.,Cameron, A. J.,Crawford, D.,Hesketh, K. D.,Campbell, K. J.. Dietary associations of fathers and their children between the ages of 20 months and 5 years. Public Health Nutr. 2016;1-7. | Independent variable
146 | Walsh, A. D.,Cameron, A. J.,Hesketh, K. D.,Crawford, D.,Campbell, K. J.. Associations between dietary intakes of first-time fathers and their 20-month-old children are moderated by fathers’ BMI, education and age. Br J Nutr. 2015;114:988-94. | Independent variable
147 | Watt TT,Appel L,Lopez V,Flores B,Lawhon B. A Primary Care-Based Early Childhood Nutrition Intervention: Evaluation of a Pilot Program Serving Low-Income Hispanic Women. J Racial Ethn Health Disparities. 2015;2:537-47. | Dependent variable
148 | Whichelow, M. J.,Doddridge, M. C.. Lactation in diabetic women. Br Med J (Clin Res Ed). 1983;287:649-50. | Study design, Health Status
149 | Whitehead, R. G.. Nutritional aspects of human lactation. Lancet. 1983;1:167-9. | Study design
150 | Winkelstein, M. L.. Overfeeding in infancy: the early introduction of solid foods. Pediatr Nurs. 1984;10:205-8, 236. | Study design, Independent variable
151 | Worobey H,Ostapkovich K,Yudin K,Worobey J. Trying versus liking fruits and vegetables: correspondence between mothers and preschoolers. Ecol Food Nutr. 2010;49:87-97. | Age
152 | Yoshida M,Shinohara H,Sugiyama T,Kumagai M,Muto H,Kodama H. Taste of milk from inflamed breasts of breastfeeding mothers with mastitis evaluated using a taste sensor. Breastfeed Med. 2014;9:92-7. | Independent variable, Dependent variable
153 | Yuan, W. L.,Nicklaus, S.,Lioret, S.,Lange, C.,Forhan, A.,Heude, B.,Charles, M. A.,de Lauzon-Guillain, B.. Early factors related to carbohydrate and fat intake at 8 and 12 months: results from the EDEN mother-child cohort. Eur J Clin Nutr. 2017;71:219-226. | Dependent variable
154 | Yuan, W. L.,Rigal, N.,Monnery-Patris, S.,Chabanet, C.,Forhan, A.,Charles, M. A.,de Lauzon-Guillain, B.. Early determinants of food liking among 5y-old children: a longitudinal study from the EDEN mother-child cohort. Int J Behav Nutr Phys Act. 2016;13:20. | Independent variable
155 | Zhang J,Shi L,Chen D-f,Wang J,Wang Y. Effectiveness of an educational intervention to improve child feeding practices and growth in rural China: updated results at 18 months of age. Maternal & Child Nutrition. 2013;9:118-129 12p. | Independent variable
156 | Zhang, Gen-Hua,Chen, Meng-Ling,Liu, Si-Si,Zhan, Yue-Hua,Quan, Ying,Qin, Yu-Mei,Deng, Shao-Ping. Effects of mother’s dietary exposure to acesulfame-K in pregnancy or lactation on the adult offspring’s sweet preference. Chemical Senses. 2011;36:763-770. | Study design