# RESEARCH RECOMMENDATIONS

In order to better understand the impact of what mother’s eat during pregnancy and lactation on the infant or child’s acceptance of flavors and their overall dietary intake, further research addressing these topics should:

- More research is needed to determine whether flavors from other foods and beverages transmit to and flavor amniotic fluid, the amount needed to be consumed by the mother to elicit a flavor change, and how often the fetus needs to be exposed to the flavor to modify subsequent sensory responses.
- Further examine the timing and duration of exposure to flavors in amniotic fluid and/or breastmilk on subsequent acceptance of a particular food or foods during infancy. Specifically, when does the exposure to a particular flavor need to occur (timing) for the infant to develop a preference for that flavor? What is the minimum amount of exposure (duration, repetition) required for infants to develop a preference for that flavor? Does the child need repeated exposures to the food after weaning to maintain the preference, especially since the flavor is first experienced in a liquid (amniotic fluid and/or breast milk) and the flavor experienced in a solid food is more complex in texture and other sensory properties.
- Conduct research to explore how early flavor experience interacts with variation in taste and flavor genetics in how accepting the child is of flavors and foods after weaning. Specifically, do some children require a different type or prolonged exposure to learn to like the taste of healthy foods (e.g. vegetables) based, for example, on variation in their sensitivity to bitter tastes?
- Evaluate how long the flavor memory that is formed prenatally in amniotic fluid or during breastfeeding lasts and whether such flavor experiences impact food acceptance of the infant at weaning and the rate of acceptance of the foods/flavors following repeated exposure, particularly if the infant is formula fed and there is a lack of continuity in flavor experienced postnatally with that experienced prenatally.
- Conduct randomized controlled trials with longitudinal follow-up at multiple time points from infancy through childhood and into adulthood to assess changes in food and flavor acceptability and dietary intake that include direct measurements of acceptance and liking by the child.
- Evaluate whether there is an optimal time to intervene to improve the diet of both mothers and their children.
- Improve data collection methods, specifically for dietary assessment of mother and child, and food and flavor response measures in the birth to 24 month population. Dietary intake measures of children should not solely rely on maternal report. Investigations into what children eat and what they like to eat should include direct measurements of children.
- Assess the impact of duration of breastfeeding, formula feeding, and a combination of the two on acceptance of foods and flavors during and after weaning to include evaluation of picky eating, willingness to try new foods, and the variety of the child’s diet.
- Evaluate the relationship between maternal eating behaviors (e.g. pickiness, low variety) and what she feeds on her child, and her child’s eating behaviors, specifically, food/flavor acceptability, picky eating, willingness to try new foods, and amount of variety in their diet.