# OBSERVATIONS ACROSS SYSTEMATIC REVIEWS

Results from these systematic reviews are in accordance with one another and combined provide evidence that flavors from the maternal diet are present in amniotic fluid and breast milk, and are detected by the fetus or infant. Studies across both reviews showed that 4 flavors—alcohol, anise, carrot, and garlic—transferred and were later recognized by infants. The results are supported by a combination of analytic methods (chemical, sensory, and infant behavioral analyses). One study was designed to examine maternal consumption during both maternal time-periods and found that at 6 mo of age carrot flavor was detected by infants after maternal ingestion of carrot juice during pregnancy or during lactation. Evidence investigating garlic in both reviews demonstrated a continuation of findings over these early life stages. Garlic flavors transferred to amniotic fluid and breast milk and infants and children responded differently to the odor and taste of garlic, if their mothers ate garlic during the last month of pregnancy or ate garlic while breastfeeding. Further, experiences with garlic flavor during the last month of pregnancy resulted in greater acceptance of garlic-flavored foods by the child 8–9 y later. The convergence of this evidence highlights the importance of the maternal diet during pregnancy and lactation on infants’ responses to flavors and the potential to influence subsequent dietary intake and quality.