# WHAT IS THE RELATIONSHIP BETWEEN MATERNAL DIET DURING LACTATION ON FLAVOR TRANSFER TO BREAST MILK, CHILDREN’S BEHAVIORAL RESPONSE, AND DIETARY INTAKE?

## PLAIN LANGUAGE SUMMARY

### What is the question

- The question is: what is the relationship between maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake?

### What is the answer to the question?

- Moderate evidence indicates that flavor volatiles originating from the maternal diet during lactation transmit to and flavor breast milk in a time-dependent manner as determined by chemical and sensory measures. Evidence indicates flavor transfer to human breast milk occurs after lactating mothers ingest alcohol, anise, caraway, carrots, eucalyptus, garlic, and mint flavors.
- Moderate evidence also indicates that infants can detect diet-transmitted flavors in mother’s milk as evidenced by differential response to flavors they have previously been exposed to through their mother’s milk when compared with infants who did not have previous exposure. Differential infant behavioral response was found: 1) within hours of a single maternal ingestion of flavor (alcohol, garlic, vanilla); 2) within days after their lactating mothers ingested a flavor (garlic, carrot juice) repeatedly (daily for 3 or 7 days); and 3) several months after their lactating mothers ingested the flavor (variety of vegetable juices including carrot) during 1 to 4 months postpartum.
- No conclusion can be drawn to describe the relationship between maternal diet during lactation and toddler dietary intake, since there was no research identified to answer this question.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative.

### What is the population of interest?

- Generally healthy lactating women and their healthy infants and toddlers who were ages 0-24 months. The child’s food acceptability and dietary intake was examined through the lifespan.

### What evidence was found?

- This systematic review included 15 controlled trials which examined the relationship between maternal diet during lactation, breast milk flavor, and/or infant response to a flavor.
- The flavor of a food is a complex combination of tastes (sweet, sour, salty, bitter, umami), textures, and volatile odors which travel to the olfactory receptors when foods or liquids are in the mouth and when odor volatiles are inhaled through the nose.
- The foods, beverages, or supplements ingested by lactating mothers investigated in this review include: alcohol; garlic extract; raw garlic; carrot juice; vegetable juices including carrot, celery, beet, and mixed vegetable; fennel-anise-caraway tea; vanilla extract; fish oil supplements, d-carvone supplement; trans-anethole supplement (associated with anise, licorice, fennel flavors); and 1,8-cineole (associated with eucalyptus flavor).
- Ten studies analyzed breast milk samples, via chemical or sensory analysis methods, to determine whether there were time-dependent changes in the flavor of breast milk after when compared to before maternal flavor ingestion.
  ○ Eight of ten studies provide evidence that flavor volatiles found in alcohol, anise, caraway, carrots, eucalyptus, garlic, and mint originating from the maternal diet during lactation, transfer and flavor breast milk. Transmission of flavor from fish oil supplements, fennel-anise-caraway tea and 3-methylbutyl acetate was not demonstrated, which may have been due to limitations in experimental design.
    ■ Volatile levels or changes in the perceived odor of the breast milk were evident 30 minutes to 1 hour after alcohol ingestion and 2 to 3 hours after ingestion of raw garlic or encapsulated garlic extract, carrot juice or capsules containing caraway, mint and anise flavor and dissipated over the following 3 to 8 hours.
    ■ When both chemical and sensory analyses were conducted, there was concordance in the findings; when a change in the flavor volatile concentration was detected by chemical analysis, a change in the flavor of the breast milk was also detected by sensory evaluation analysis.
- Ten studies evaluated the infants’ behavioral responses, which was assessed 1 of 3 ways: a) during breastfeeding, within hours of a single maternal ingestion of flavor; b) within days after their lactating mothers’ ingested the flavor repeatedly for 3 or 7 days; or c) several months after their lactating mothers ingested the flavor for 1 to 3 months.
  ○ Evidence from 5 studies displayed that infants could detect a flavor change as evidenced by differential behavioral response 1 to 3 hours after mothers ingested the flavor.
  ○ Evidence from 2 of 3 studies on repeated maternal ingestion of flavor and infant response days after maternal ingestion of the flavor found that repeated ingestion of carrot juice or garlic by lactating mothers impacted their infant’s acceptance of similarly flavored breast milk or cereal days later when compared to a non-exposed control group.
  ○ Two studies revealed that repeated ingestion of carrot and other vegetable juices by lactating mothers during the first 2 to 4 months of lactation modifies their infants’ acceptance of carrot flavored cereal several months later.
- Evidence indicates that the timing may be more important than duration of exposure.

### How up-to-date is this review?

- This review includes literature from 01/1980 to 06/2017.

## TECHNICAL ABSTRACT

### Background

- This systematic review was conducted as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.
- The goal of this systematic review was to examine the following question: what is the relationship between maternal diet during lactation on flavor transfer to breast milk, child’s behavioral response, and dietary intake?
- The flavor of a food is a complex combination of tastes (sweet, sour, salty, bitter, umami), textures, and volatile odors which travel to the olfactory receptors when foods or liquids are in the mouth and when odor volatiles are inhaled through the nose.

### Conclusion Statement and Grades

- Moderate evidence indicates that flavor volatiles originating from the maternal diet during lactation transmit to and flavor breast milk in a time-dependent manner as determined by chemical and sensory measures. Evidence indicates flavor transfer to human breast milk occurs after lactating mothers ingest alcohol, anise, caraway, carrots, eucalyptus, garlic, and mint flavors. Grade: Moderate
- Moderate evidence also indicates that infants can detect diet-transmitted flavors in mother’s milk as evidenced by differential response to flavors they have previously been exposed to through their mother’s milk when compared with infants who did not have previous exposure. Differential infant behavioral response was found: 1) within hours of a single maternal ingestion of flavor (alcohol, garlic, vanilla); 2) within days after their lactating mothers ingested a flavor (garlic, carrot juice) repeatedly (daily for 3 or 7 days); and 3) several months after their lactating mothers ingested the flavor (variety of vegetable juices including carrot) during 1 to 4 months postpartum. Grade: Moderate
- No conclusion can be drawn to describe the relationship between maternal diet during lactation and toddler dietary intake, since there was no research identified to answer this question. Grade: Grade Not Assignable

### Methods

- The systematic review was conducted by a team of staff from the Nutrition Evidence Systematic Review in collaboration with a Technical Expert Collaborative.
- Literature searches were conducted using 10 databases to identify studies that evaluated the relationship among maternal diet during lactation, breast milk flavor; and children’s food acceptability and overall dietary intake. A manual search was conducted to identify articles that may not have been included in the electronic databases searched. Articles were screened by two authors independently for inclusion based on pre-determined criteria.
- Data from each included article were extracted, risks of bias were assessed, and both were checked for accuracy. The body of evidence was qualitatively synthesized, a conclusion statement was developed, and the strength of the evidence (grade) was assessed using pre-established criteria including evaluation of the internal validity/risk of bias, adequacy, consistency, impact, and generalizability of available evidence.

### Summary of Evidence

- This systematic review included 15 controlled trials, which examined the relationship between maternal diet during lactation, breast milk flavor, and/or infant response to a flavor (odor or food stimulus).
- The foods, beverages, or supplements ingested by lactating mothers investigated in this review include: alcohol; garlic extract; raw garlic; carrot juice; vegetable juices including carrot, celery, beet, and mixed vegetable; fennel-anise-caraway tea; vanilla extract; fish oil supplements, d-carvone supplement; trans-anethole supplement (associated with anise, licorice, fennel flavors); and 1,8-cineole (associated with eucalyptus flavor).
- Ten studies analyzed breast milk samples, via chemical or sensory analysis methods, to determine whether there were time-dependent changes in the flavor of breast milk after when compared to before maternal flavor ingestion.
  ○ Eight of ten studies provide evidence that flavor volatiles found in alcohol, anise, caraway, carrots, eucalyptus, garlic, and mint originating from the maternal diet during lactation, transfer and flavor breast milk. Transmission of flavor from fish oil supplements, fennel-anise-caraway tea and 3-methylbutyl acetate was not demonstrated, which may have been due to limitations in experimental design.
    ■ Volatile levels or changes in the perceived odor of the breast milk were evident 30 minutes to 1 hour after alcohol ingestion and 2 to 3 hours after ingestion of raw garlic or encapsulated garlic extract, carrot juice or capsules containing caraway, mint and anise flavor and dissipated over the following 3 to 8 hours.
    ■ When both chemical and sensory analyses were conducted, there was concordance in the findings; when a change in the flavor volatile concentration was detected by chemical analysis, a change in the flavor of the breast milk was also detected by sensory evaluation analysis.
- Ten studies evaluated the infants’ behavioral responses, which was assessed 1 of 3 ways: a) during breastfeeding, within hours of a single maternal ingestion of flavor; b) within days after their lactating mothers’ ingested the flavor repeatedly for 3 or 7 days; or c) several months after their lactating mothers ingested the flavor for 1 to 3 months.
  ○ Evidence from 5 studies displayed that infants could detect a flavor change as evidenced by differential behavioral response 1 to 3 hours after mothers ingested the flavor.
  ○ Evidence from 2 of 3 studies on repeated maternal ingestion of flavor and infant response days after maternal ingestion of the flavor found that repeated ingestion of carrot juice or garlic by lactating mothers impacted their infant’s acceptance of similarly flavored breast milk or cereal days later when compared to a non-exposed control group.
  ○ Two studies revealed that repeated ingestion of carrot and other vegetable juices by lactating mothers during the first 2 to 4 months of lactation modifies their infants’ acceptance of carrot flavored cereal several months later.
- Evidence indicates that the timing may be more important than duration of exposure.

## FULL REVIEW

### Systematic review question

What is the relationship among maternal diet in breastfeeding women, breast milk flavor and food acceptability and dietary intake?

### Conclusion statement

Moderate evidence indicates that flavor volatiles originating from the maternal diet during lactation transmit to and flavor breast milk in a time-dependent manner as determined by chemical and/or sensory measures. Evidence indicates flavor transfer to breast milk occurs after mothers ingest alcohol, anise, caraway, carrots, eucalyptus, garlic, or mint flavors.

Moderate evidence indicates that infants can detect diet-transmitted flavors in mother’s milk as demonstrated by differential response to flavors they have previously been exposed to through their mother’s milk when compared with infants who did not have previous exposure. Differential infant behavioral response was found: a) within hours of a single maternal ingestion of flavor (alcohol, garlic, vanilla); b) within days after their lactating mothers ingested a flavor (garlic, carrot juice) multiple times (daily for 3 or 7 days); and c) several months after their lactating mothers ingested the flavor for 1 to 4 months postpartum (carrot juice alone or with a variety of vegetable juices).

No conclusion can be drawn to describe the relationship between maternal overall diet (e.g., food group intake, dietary pattern, or diet quality) during lactation and toddler dietary intake, since there was no research identified to answer this question. Grade not assignable

### Grade

Moderate: Relationship between maternal diet during lactation and breast milk flavor

Moderate: Relationship between maternal diet during lactation and child’s behavioral response to flavor

Grade not assignable: Relationship between maternal overall diet during lactation and toddler dietary intake

### Summary

- This systematic review included 15 controlled trials which examined the relationship between maternal diet during lactation, breast milk flavor, and/or infant response to a flavor (odor or food stimulus).
- The foods, beverages, or supplements ingested by lactating mothers investigated in this review include: alcohol; garlic extract; raw garlic; carrot juice; vegetable juices including carrot, celery, beet, and mixed vegetable; fennel-anise-caraway tea; vanilla extract; fish oil supplements, d-carvone supplement; trans-anethole supplement (associated with anise, licorice, fennel flavors); and 1,8-cineole (associated with eucalyptus flavor).
- Ten studies analyzed breast milk samples, via chemical or sensory analysis methods, to determine whether there were time-dependent changes in the flavor of breast milk after when compared to before maternal flavor ingestion.
  ○ Eight of ten studies provide evidence that a wide range of flavor volatiles found in alcohol, anise, caraway, carrots, eucalyptus, garlic, and mint originating from the maternal diet during lactation, transfer and flavor breast milk. Transmission of flavor from fish oil supplements, fennel-anise-caraway tea and 3-methylbutyl acetate was not demonstrated, but may have been due to limitation in experimental design.
    ■ Evidence indicates flavor transmission occurs in a time dependent manner. Volatile levels or changes in the perceived odor of the breast milk were evident 30 minutes to 1 hour after alcohol ingestion and 2 to 3 hours after ingestion of raw garlic or encapsulated garlic extract, carrot juice or capsules containing caraway, mint and anise flavor and dissipated over the following 3 to 8 hours.
    ■ When both chemical and sensory analyses were conducted, there was concordance in the findings; when a change in the flavor volatile concentration was detected by chemical analysis, a change in the flavor of the breast milk was also detected by sensory evaluation analysis.
- Ten studies evaluated the infants’ behavioral responses, which was assessed 1 of 3 ways: a) during breastfeeding, within hours of a single maternal ingestion of flavor; b) within days after their lactating mothers’ ingested the flavor repeatedly for 3 or 7 days; or c) several months after their lactating mothers ingested the flavor for 1 to 3 months.
  ○ Evidence on lactating mothers one-time ingestion of flavor on their infants’ immediate (within hours) breastfeeding behavioral response indicates that infants could detect the flavor change as evidenced by differential behavioral response 1 to 3 hours after mothers ingested the flavor. This time frame parallels the time-dependent changes identified in the chemical and sensory properties of the milk following maternal ingestion.
    ■ Differential behavioral responses detected included sucking more frequently (alcohol and garlic), increased time attached to the mother’s nipple (garlic and vanilla) and increased intake of flavored milk (vanilla).
  ○ Evidence from 2 of 3 studies on repeated maternal ingestion of flavor and infant response days after maternal ingestion of the flavor found that repeated ingestion of carrot juice (300mL/day for 1 week) or garlic (1.5 g/d for 3 days) by lactating mothers impacted their infant’s acceptance of similarly flavored breast milk or cereal days later when compared to a non-exposed control group.
    ■ Infants were more accepting of the test flavor (garlic) when they did not have recent experience with the flavor (control group) compared to infants whose mothers had ingested the flavor for several days prior to testing.
    ■ One study, did not find repeated maternal ingestion of d-carvone in hummus impacted their infants’ acceptance of caraway-flavored potato puree; however no sensory testing was done to assess whether the amount of volatile transmitted to breastmilk was detectable by the human sensory system.
  ○ Two RCTs exploring the effect of maternal ingestion of a flavor during the first few months of lactation on infants’ acceptance of the flavor when tested several months later revealed that repeated ingestion of carrot and other vegetable juices by lactating mothers during the first 2 to 4 months of lactation modifies their infants’ acceptance of carrot flavored cereal several months later.
- Evidence indicates that the timing may be more important than duration of exposure.

### Description of the evidence

The 15 included papers were published in peer-reviewed journals from January 1980 to June 2017. The search included articles from countries with a high or very high Human Developmental Index (United Nations Development Program, 2014) to be generalizable to the U.S. population. Studies included generally healthy women who were breastfeeding at the time of the intervention or exposure assessment and their generally healthy infants. Outcomes were measured in both mothers (breastmilk analysis) and infants. Studies were not included if they exclusively enrolled infants with gestational age at birth of less than 37 weeks or infants who were small for gestational age (<2500g).

Included studies examined whether flavor volatiles in the diet of breastfeeding women were transmitted to breast milk in a time-dependent manner as evidenced by: a) chemical analysis; b) sensory analysis; and/or c) changes in the infants’ behavioral responses to breast milk or a food containing the flavor ingested by their lactating mothers. Table 5 lists the type of method or methods used in each included study.

Table 5 Type of study outcomes found to assess the relationship between maternal diet during lactation on flavor transfer to breast milk and the breastfed children’s behavioral responses

Flavor ingested by mothers^1^ | Reference | Chemical analysis of breast milk | Sensory analysis of breast milk | Children’s behavioral response to flavor^2^
Alcohol | Mennella et al., 1991 | X | X | X^3^
Alcohol | Mennella et al., 1993 | X | X | X
Alcohol | Mennella et al., 2001 | ––– | ––– | X^3^
Garlic | Mennella et al., 1991 | ––– | X | X^3^
Garlic | Mennella et al., 1993 | ––– | ––– | X^4^
Garlic | Scheffler et al., 2016 | X | X | –––
Carrot | Mennella et al., 1999 | ––– | X | X^4^
Carrot | Mennella et al., 2001 | ––– | ––– | X^5^
Variety of vegetables | Mennella et al., 2017 | ––– | ––– | X^5^
Caraway | Hausner et al., 2010 | X | ––– | X^4^
Vanilla | Mennella et al., 1996 | ––– | ––– | X^3^
Eucalyptus | Kirsch et al., 2012 | X | X | –––
Anise,; Caraway,; Mint,; Fruit | Hausner et al., 2008 | X; X; X; X | –––; –––; –––; ––– | –––; –––; –––; –––
Fish oil | Sandgruber et al., 2011 | X | X | –––
Fennel-anise-caraway tea | Denzer et al., 2015 | X | X | –––

1 Predominant flavor of the maternal dietary intervention, see Tables 6 and 7 for more details

2 Children’s behavioral response to flavor in breast milk or solid food

3 Children’s behavioral responses measured during breastfeeding immediately after (3-4 hours) maternal ingestion of flavor

4 Children’s behavioral responses measured within days (1-5 days) after mothers repeated ingestion of the flavor (for 3 or 7 days) when compared to control group;

5 Children’s behavioral responses measured approximately 4-6 months after mothers’ repeated ingestion of the flavor for 1-3 months when compared to control group

Chemical and sensory analyses were conducted on breast milk samples collected before (baseline) and at intervals up to 8 hours after maternal ingestion of flavor. Infants’ behavioral responses were measured: a) during the breast feedings that occurred 0.5 to 16 hours after maternal ingestion of a flavor on one occasion and/or a placebo on another; b) 1-5 days following repeated maternal ingestion of the flavor of an exposure period of (3-10 days) or following no maternal ingestion (control group); or c) 4-6 months following repeated maternal ingestion of the flavor that lasted 1-3 months or following no ingestion (control group).

#### Study details: (see Tables 6 and 7)

- Study designs: all studies were controlled trials (Note: Mennella, 1999 reported on two studies):
  ○ 6 randomized controlled trials (RCT): Mennella, 1993b; Mennella, 1999 (Study 2); Mennella, 2001b; Hausner, 2010; Sandgruber, 2011; Mennella, 2017
  ○ 5 controlled crossover studies: Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1996; Mennella, 2001a
  ○ 5 controlled trials (CT) (single group, within-subject design): Mennella, 1999 (Study 1); Hausner, 2008; Kirsch, 2012; Denzer, 2015; Scheffler, 2016
- Sample size: There were no inclusion criteria related to sample size and sample size varied.
  ○ Chemical analysis: Within the 8 studies that used chemical analysis, the number of women who provided breast milk samples to be evaluated ranged from 5 (Denzer, 2015; within-subject controlled trial) to 40 (Hausner, 2010; within- and between-subject RCT).
  ○ Sensory analysis: Within the 8 studies that used sensory analysis, breast milk samples were collected from a range of 1 (Denzer, 2015; within-subject controlled trial) to 23 (Sandgruber, 2011; between-subject RCT) mothers. Sensory panels ranged in size from 6 (Mennella, 1991a; Mennella, 1993) to 13 adults (Denzner, 2015); in one study, 5 lactating women evaluated (tasted) their own breast milk samples.
  ○ Infant behavioral response: Within the 10 studies that evaluated infant behavioral response, the number of participating mother-infant dyads ranged from 8 (Mennella, 1991b; crossover RCT) to 75 (Mennella, 2017; within- & between-subject RCT).
- Country: 9 of 15 papers reported on studies conducted in the United States.
  ○ United States: Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1996; Mennella, 1999 (both studies); Mennella, 2001a; Mennella, 2001b; Mennella, 1993b; Mennella, 2017
  ○ Denmark: Hausner, 2008; Hausner, 2010
  ○ Germany: Sandgruber, 2011; Kirsch, 2012; Denzer, 2015; Scheffler, 2016
- Sample characteristics:
  ○ Maternal age: At the start of the studies, mean maternal age ranged from 27 to 34 years.
  ○ Parity: Twelve studies reported parity. Within these studies, women ranged from 8% to 80% primiparous prior to the pregnancy of the infant included in the study.
  ○ Race and ethnicity of mothers: The majority of studies did not report race and ethnicity. Mennella, 1996 described 8 of the participants as black, 3 as white, and 1 as Hispanic. Mennella, 1999 (study 1) described the race or ethnicity of mothers: 60% white, 20% black, and 20% Hispanic, whereas Mennella, 1999 (study 2) reported: 61% white, 21% black, 6% Hispanic, 3% Asian, and 9% other. Mennella, 2001a described 10 of the participants as white, and 2 as black. Mennella, 2001b described the race or ethnicity of mothers: 85% white, 9% black, 4% Hispanic, and 2% Asian. Mennella, 2017 described the race or ethnicity of mothers: 55% white, 27% black, 3% Asian, and 16% more than one race reported.
  ○ Socioeconomic status (SES): Only 2 studies reported SES. Mennella, 2017 reported that 66% of participants had a college education, 11% had an income of <$10,000 per year, 36% had an income of $10,000-49,000 per year, and 53% had an income of $50,000 per year. Hausner, 2010 reported that study groups did not differ in social class or educational level, but did not report details.
  ○ Maternal weight characteristics: Only 4 studies described maternal weight status. Mennella, 1993a and Hausner, 2008 reported mean maternal pre-pregnancy weight of 64.1 ± 2.8 kg and 65.2 ± 7.4 kg, respectively. Hausner, 2010 reported mean maternal pre-pregnancy BMI as 22.8 ± 0.8 kg/m2 and Sandgruber, 2011 reported a range of maternal BMI at the time of conception of 23-32 kg/m2.
  ○ Smoking status: Only 5 studies reported smoking status and all 5 reported that mothers were healthy, non-smokers (Hausner, 2008; Mennella, 1993b; Mennella, 1996; Mennella, 1999 (study 1); Mennella, 2001a).
  ○ Infant sex: Nine of 10 studies that assessed infants’ behavioral responses reported infant sex, which ranged from 39 (Mennella, 2001b) to 75% (Mennella, 1993a) female (Mennella, 1991a; Mennella, 1993a; Mennella, 1993b; Mennella, 1996; Mennella, 1999 (study 2); Mennella, 2001a; Mennella, 2001b; Hausner, 2010; Mennella, 2017).
  ○ Infant age at outcome assessment: Of the 10 studies that tested infant response, infant ages ranged from as young as 25 days in Mennella, 1991a (which had an age range of 25 – 216 days) to as old as 8 months old in Mennella, 2017 (which had an age range of 6 – 8 months).

#### Experimental Manipulation of Maternal Diet

In general, when conducting chemical or sensory analytics on breast milk samples or when studying infant behavioral responses during breastfeeding following a single maternal ingestion of flavor, lactating mothers were asked to avoid eating certain foods, beverages, or supplements or avoid using cosmetics containing the experimental flavor for several days to a week prior to testing. This was done to ensure that the baseline milk sample was devoid of the flavor and that infants did not have recent exposure to the flavor under study. During testing, what lactating mothers ingested and in what form (encapsulated, beverage, food) was chosen to ensure that mothers ingested the same amount within a fixed period of time so that time-dependent changes in her breast milk (chemical and sensory analysis) or in the behaviors of her infant during feeding could be determined. In the majority of studies, the collection of breast milk samples and evaluation of infant behavioral response included a control day of testing that controlled for time of day (since breast milk intake varies with time of day) and time at which mothers’ ingested a placebo.

In general, for studies that manipulated maternal diet over a number of days or months, mothers were asked to ingest the flavor 0.5-2 hours prior to breastfeeding during the intervention period to ensure infants breastfed during the time the flavor was transmitted to breast milk. After the period of maternal diet manipulation, testing occurred. In general, infants breastfed or fed at their regular pace during testing. The time of day that testing occurred was controlled since lactation performance and infant intake varies with time of day. A control food and/or control group of mothers who ingested the placebo/water during the intervention period were also included to determine specificity of responses.

In what follows, we list the beverages, encapsulated flavors, or foods ingested by the mother.

- Alcohol: in orange juice, 0.3 g ethanol/kg body weight (Mennella, 1991a); in beer, 0.3g ethanol/kg body weight (Mennella, 1993a; Mennella 2001a)
- Garlic: encapsulated garlic extract, 1.5 g, 1 time (Mennella, 1991b); 1.5 g/d for 3 days (Mennella, 1993b), or raw garlic, 3 g , one time (Scheffler, 2016)
- Carrot juice: 500 mL 1 time (Mennella, 1999 [study 1]); 300 mL/day for 1 week (Mennella, 1999 [study 2]); 300 mL/day for 4 days/week for 3 consecutive weeks (Mennella, 2001b)
- Mixed Vegetable juices including carrot, celery, beet, and mixed vegetable: 118 mL/d, 24 times/month for 1 or 3 months (Mennella, 2017)
- Fennel-anise-caraway tea: 950 mL one time; Key flavor volatiles measured in tea samples ingested by mothers were: Trans-anethole (volatile found in foods including anise, licorice, fennel): 858 ± 1973 μg/L; carvone (volatile found in caraway): 238 ± 308 μg/L; limonene (associated with citrus flavor): 8.36 ± 4.83 μg/L); and 1,8-cineole (volatile found in eucalyptus):1.24 ± 0.53 μg/L) (Denzer, 2015)
- Vanilla: extract, 10 mL (Mennella, 1996)
- Fish oil supplements: 3000 mg tuna fish oil/day during pregnancy (starting at 14-16 weeks gestation) through the first 4 months of lactation (Sandgruber, 2011)
- Caraway: encapsulated d-carvone (flavor volatile found in foods/spices including caraway, spearmint, some citrus fruit), 100 mg (Hausner, 2008); d-carvone, 30 mg, in hummus every third day for 28 days (Hausner, 2010)
- Mint: encapsulated l-menthol (flavor volatile found in mint), 100 mg (Hausner, 2008)
- Fruit: encapsulated 3-methylbutyl acetate (flavor volatile found in fruits such as banana, pear), 100 mg (Hausner, 2008)
- Anise: encapsulated trans-anethole, 100 mg (Hausner, 2008)
- Eucalyptus: encapsulated 1,8-cineole (100 mg) (Kirsch, 2012)

#### Outcomes: Studies on the transmission of flavor from the maternal diet to breast milk: Chemical and sensory analysis (Table 6)

Ten studies analyzed breast milk samples, via chemical or sensory analysis methods, to determine whether there were time-dependent changes in the flavor of breast milk after when compared to before maternal ingestion (or when compared to the same time of day during the control session) (Mennella, 1991a; Mennella, 1993a; Mennella, 1991b; Scheffler, 2016; Mennella, 1999; Kirsch, 2012; Hausner, 2008; Hausner, 2010; Denzer, 2015; Sandgruber, 2011. Seven of these studies were designed to assess the pattern of flavor change over time (Mennella, 1991a; Mennella, 1993a; Mennella, 1991b; Mennella, 1999; Scheffler, 2016; Hausner, 2008; Denzer, 2015).

- Eight studies used chemical analysis, either conducted by nicotinamide adenine dinucleotide-alcohol dehydrogenase enzymatic assay for determination of alcohol (Mennella, 1991a; Mennella, 1993a) or by gas chromatography−mass spectrometry for determination of odor volatiles (Hausner, 2008; Hausner, 2010; Sandgruber, 2011; Kirsch, 2012; Denzer, 2015; Scheffler, 2016).
- Eight studies used adult sensory analysis (Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Sandgruber, 2011; Mennella, 1999 (study 1); Kirsch, 2012; Denzer, 2015; Scheffler, 2016).
- Six studies used both chemical and sensory analysis methods (Mennella, 1991a; Mennella, 1993a; Denzer, 2012; Kirsch, 2012; Scheffler, 2016; Sandgruber, 2016).

Table 6 Summary of the evidence-base of the effect of maternal diet during lactation on flavor transfer to breast milk: chemical and sensory analysis^1^

Reference;; Country;; Study design;; Participants | Intervention and analysis methods | Outcomes
Reference;; Country;; Study design;; Participants | Intervention and analysis methods | Chemical analysis | Adult sensory analysis
Flavor: Alcohol
Mennella et al., 1991;; US;; Crossover study;; 12 lactating women; 17 adult sensory panelists (6-8 panelists were presented with samples) | Mothers drank 0.3 g ethanol/kg BW, in orange juice (15% vol/vol) on one d and orange juice alone (control) on another d; order counterbalanced; Milk collected before and 0.5, 1, 2, 3 h post ingestion;; Chemical analysis: nicotinamide adenine dinucleotide-alcohol dehydrogenase enzymatic assay;; Sensory panel: Panelists were randomly presented with all possible pairs of breast milk samples from each mother_twice; asked which of the pair smelled “more like alcohol” or “stronger”. | Ethanol content in breast milk peaked 30 mins to 1 h after alcohol consumption when compared to baseline and then decreased thereafter. No ethanol was detected when mothers ingested orange juice alone.; Changes in the ethanol content of milk paralleled changes in the odor of the milk on the d mothers ingested alcohol in orange juice (p< 0.0001). | Changes in the odor of the milk detected 30 mins to 1 h after alcohol ingestion and then decreased thereafter (p< 0.0001).; Breast milk odor changes peaked 30 mins to 1 h after alcohol consumption then decreased (p< 0.001); no perceived odor change after consumption of orange juice without ethanol.
Mennella et al., 1993;; US;; Crossover study;; 11 lactating women; 17 adult sensory panelists (6-8 panelists were presented with samples) | Mothers drank 0.3 g alcohol/kg BW, alcoholic beer (4.5% vol/vol) on one d and non-alcoholic beer (< 0.05% vol/vol alcohol) (control) on another d; order counterbalanced; Milk collected before and 1, 2, 3 and 4 h post ingestion;; Chemical analysis: nicotinamide adenine dinucleotide-alcohol dehydrogenase enzymatic assay;; Sensory panel: Panelists were randomly presented with all possible pairs of breast milk samples from each mother twice; asked which of the pair smelled “more like alcohol” or “stronger”. | Alcoholic beer: ethanol content changed as a function of time after beer consumption (p< 0.001).; Nonalcoholic beer: no ethanol was detected, NS.; Changes in the ethanol content of milk paralleled sensory changes in milk on the d mothers consumed alcoholic beer. | Alcoholic beer: significant change in perceived odor of breast milk during h after consumption of alcoholic beer for all women (p< 0.01); odor intensity peaked at 1 h after beer consumption then decreased.; Nonalcoholic beer: small but significant change in odor of milk samples following consumption of nonalcoholic beer in 5 of 11 women (p< 0.05).
Mennella et al., 1991;; US;; Crossover study;; 8 lactating women; 11 adult sensory panelists | Mothers ingested a 1.5 g garlic extract capsule on one d and placebo capsules (control) on another; milk collected before and 0, 1, 2 and 3 h post ingestion;; Sensory panel: Panelists were randomly presented with all possible pairs of breast milk samples from each mother twice; asked to indicate which of the pair smelled “stronger” on “more like garlic.” | NA | There was no noticable difference in the 5 milk samples taken from a woman on the d she ingested the placebo.; There was a significant difference in perceived odor of the milk samples taken after when compared to before garlic ingestion.; Odor change was first detected in breast milk collected 2 h after mothers ingested garlic, and in 3 of 8 samples at 3 h post-ingestion.; The percentage of intervention samples that were chosen over control samples in the paired forced-choice procedure at each time point was (mean ± SE): −1 h (30.7 ± 3.1%), 0 h (35.2 ± 3.5%), 1 h (48.0 ± 4.4%), 2 h (78.6 ± 3.6%), 3 h (57.3 ± 6.9%).
Scheffler et al., 2016;; Germany;; CT (within-subject);; 6 lactating women, sensory panelists n: NR | All mothers ingested 3 g raw garlic; Milk collected before and at two intervals (2-3 and 4-5 h) post ingestion.; Chemical analysis: GC-MS; Sensory panel: Trained panel of adults smelled and rated the intensity of previously determined breast milk aroma characteristics and added ‘garlic-like’ and ‘cabbage-like’, rated from 0 (no perception) to 3 (strong perception). | Time-intensity: High interindividual differences in metabolism/excretion rates of garlic metabolites; 2/6 increased over test period (∼5 h) while 4/6 peaked (∼2-3 h) then decreased. | Garlic and cabbage-like odors were not perceived in any milk samples prior to garlic ingestion, but 3 to 5 h after ingestion breast mik was pereived to have “slight to average” odor intensities (0.5-2.0 on a scale from 0 [no perception] to 3 [strong perception].
Flavor: Carrot
Mennella et al., 1999;; US;; Study 1: CT (within-subject);; Study 1 = 5 lactating women, 11 adult sensory panelists | All mothers ingested 500 mL carrot juice; Milk collected before and 1, 2, and 3 h post ingestion.; Sensory panel: evaluated milk samples collected from 4 of 5 mothers; panelists were randomly presented with all possible pairs of breast milk samples from each mother twice; asked to indicate which of the pair smelled “more like carrots” or “stronger”.; Maternal detection of flavor: mothers were randomly presented with pairs of their breast milk samples and asked to indicate which of the pair tasted “more like carrots” or “stronger. Repeated 2-3 times for each pair. | NA | Detection of change in the odor of breast milk collected after, when compared to before, consumption of carrot juice.; Odor change peaked 2 h after ingestion of carrot juice.; Mothers perceived the breast milk collected 3 h after ingestion of carrot juice as more like carrot when compared to baseline sample collected before ingestion (percent chosen = 85.7%, p< 0.001); no difference between baseline and samples at 1 h or 2 h after carrot juice ingestion.
Flavor: Eucalyptus
Kirsch et al., 2012;; Germany;; CT (within-subject);; 12 lactating women, 8 adult sensory panelists | Ingestion of 100 mg 1,8-cineole (eucalyptus) capsule; Milk collected only after mothers perceived eucalyptic-like odor on their breath; some women repeated the experiment and some expressed more than one sample after capsule intake (21 samples).; Chemical analysis: GC-MS.; Sensory panel: evaluated 21 samples obtained from 12 women; panelists rated intensity of aroma of each sample on a scale from 0 (no perception) to 3 (strong perception); subsequent reduced panel of 3-5 judges rated samples as “smelling like eucalyptus” or “not smelling like eucalyptus”. | High amounts of 1,8-cineole were detected in the 14 eucalyptus-smelling samples and only trace amounts were detected in the 7 non-eucalyptus-smelling samples;; Quantification of 1,8-cineole levels showed large variation. Those samples with the eucalyptus odor had concentrations ranging from 70 - 2090 μg/kg milk, most ranged from 100-500 μg/kg. Samples without the eucalyptus smell ranged from ∼1-20 μg/kg. | 14 of 21 samples had distinct eucalyptus smell; 7 samples did not.
Other Flavors: Fennel, Caraway, Mint, Fruit
Hausner et al., 2008;; Denmark;; CT (within-subject);; 18 lactating women | Mothers ingested 4 capsules, 100 mg capsules of each: d-carvone (spearmint, caraway), 1-menthol (mint), 3-methylbutyl acetate (banana, pear), trans-anethole (caraway, anise, fennel) on 3 separate test ds (each separated by at least 3 ds).; Milk collected at home before and 2, 4, 6, 8 h post ingestion on each test d.; Chemical analysis: GC-MS. | d-carvone: milk concentrations peaked ∼2 h post ingestion and returned to baseline by 8 h post-ingestion; Concentration (Conc) (micro-g/L) at 0, 2, 4, 6, 8 h: 1.33 < 7.17 = 5.61 = 4.30 > 2.66 (p<0.05);; trans-anethole: milk concentrations peaked ∼2 h post ingestion and returned to baseline by 8 h post-ingestion; Conc (micro-g/L) at 0, 2, 4, 6, 8 h: 2.00<9.90=9.20=7.26>4.25 (p<0.05);; 1-menthol: volatile first detected 2 h and did not decrease by 8 h post-ingestions; Conc (micro-g/L) at 0, 2, 4, 6, 8 h: 2.11 < 4.85 = 5.87 = 5.82 = 4.14 (p< 0.05);; 3-methylbutyl acetate: not detected in any milk sample; Conc (micro-g/L) at 0, 2, 4, 6, 8 h: not detected.; There was large intra-individual variation in flavor content of each compound among the 3 test ds. Between-person variation of flavor content in milk samples exceeded intra-individual variations. | NA
Hausner et al., 2010;; Denmark;; RCT (within- and between-subjects);; 40 lactating women (20 intervention group, 20 control group) | Mothers ingested either 30 mg d-carvone/75 g hummus or 75 g plain hummus every 3rd d for 28 ds; milk collected 2 h post ingestion on ds 1 and 28.; Chemical analysis: GC-MS | Detection of d-carvone in milk samples: d-carvone was detected in milk samples from 18 of 20 women in the experimental group (in 2 women it was detected in only 1 of 2 milk samples); detection rate was 83% (concentrations not significantly different after the first and tenth exposure); Mean (SEM) d-carvone concentration in breast milk of women who ate caraway hummus: 3.2 ug/L (1.0), range 0-13.2 ug/L; no d-carvone detected in milk samples from women who ate plain hummus. | NA
Denzer et al., 2015;; Germany; CT (within-subject);; Analytic analysis: 5 lactating women;; Sensory analysis: 1 lactating woman, 13 adult sensory panelists | Analytic analysis: Mothers ingested 950 mL of fennel-anise-caraway tea on 3 test ds each separated by at least 6 ds; milk collected at on a control d (prior to ingestion), and at 0.5, 1, and 2 h post ingestion.; Mean concentration of predominant flavor components in 1 L of tea: Limonene (associated with citrus flavor): 8.36 ± 4.83 μg/L); 1,8-cineole:1.24 ± 0.53 μg/L carvone (238 ± 308 μg/L); Trans-anethole: 858 ± 1973 μg/L; There was a significant difference in concentrations across tea samples.; Chemical analysis: GC-MS; Sensory analysis: 1 mother ingested 950 mL of fennel-anise-caraway tea; Milk collected before and 30, 105, 155, and 225 mins post ingestion. Panelists rated the odor of milk samples using a scale of 0 (no perception) to 3 (strong perception) with 0.5 increments. | There were no differences in concentration of flavor volatiles collected before when compared to after tea consumption (p>0.05); large inter- and intra-individual variation in the tea ingested was demonstrated. | No difference in the sensory attributes of the 5 samples of milk collected from one women before and after tea ingestion.
Flavor: Fish Oil
Sandgruber et al., 2011;; Germany;; RCT (between-subjects);; 23 lactation women; 8 adult sensory panelists | Intervention Group: mothers ingested 3 PUFA preparation (1000 mg of tuna fish oil with; 0.3% vitamin E; 0.3% sunflower oil) capsules per d beginning at 14-16 wk gestation through 4 mos postpartum.; Control group: refrained from any fish oil supplementation during pregnancy and lactation.; Milk sampling occurred on an empty stomach after an overnight fast in the morning h on 2 occasions: when women were 4-6 and 16-18 wk postpartum.; Chemical analysis: GC-MS; Sensory panel: Panelists were randomly presented 9 control and 7 intervention group samples; asked todescribe and rate intensities from 0 (no perception) to 3 (strong perception). | No significant difference in mean concentration values of target marker substances between groups; high inter-individual variability between samples was reported for both groups. | Aroma profile analysis: NS between groups.

1 USA, United States of America; BW, body weight; GC-MS, gas chromatography-mass spectrometry; NS, not significant (p>0.05); NA, not applicable; NR, not reported; SE, standard error;

#### Outcomes: Studies on the infants’ behavioral responses to flavor in breast milk or solid food (Table 7)

Ten studies evaluated the infants’ behavioral responses, which was assessed 1 of 3 ways: a) during breastfeeding, within hours of a single maternal ingestion of flavor; b) within days after their lactating mothers’ ingested the flavor repeatedly for 3 or 7 days; or c) several months after their lactating mothers ingested the flavor for 1 to 3 months. Behaviors during breastfeeding or feeding solid foods were videotaped for later coding by trained observers frequently blinded to the condition or group assignment. Mothers who ingested the flavor and who evaluated their infants’ behaviors and enjoyment of the food were blind to the hypotheses being tested.

- Five controlled crossover studies examined infants’ behaviors while breastfeeding during the hours immediately following a single ingestion of the flavor by their mothers to determine whether infants could detect the flavor in breast milk. Infants’ behavioral responses to the flavor were compared to a control day wherein mothers ingested a placebo (breast milk therefore should not contain the flavor) (Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1996; Mennella, 2001a).
  ○ Flavors ingested by lactating mothers included: alcohol in orange juice or beer (Mennella, 1991a; Mennella, 1993a; Mennella, 2001a), encapsulated garlic extract (Mennella, 1991b), and vanilla extract (Mennella, 1996). [Three of these studies confirmed the transmission of the flavor (alcohol and garlic) from the maternal diet to breast milk using sensory analysis (Mennella, 1991b) or both chemical and sensory analysis (Mennella, 1991a; Mennella, 1993a). One study based the time period of observation on previously published findings (Mennella, 2001a).
  ○ A variety of behavioral (appetitive) responses were measured during breastfeeding that occurred within 3-4 hours after maternal ingestion. Breast feedings were videotaped and trained observers blind to condition determined the meal or feeding duration, time attached to the nipple, number of sucks. Infants were weighed before and after feedings to determine breast milk intake. Mothers rated their infants’ behaviors and nursing experience.
  ○ One study extended the time period to measure infant behavioral response to 16 hours, well beyond the expected flavor transmission period. This extension was to study infant self-regulation of intake, not response to flavor (Mennella, 2001a).
- Three RCTs examined how repeated ingestion of a flavor 3 to 10 times by lactating mothers influenced their infants’ acceptance of similarly flavored breast milk (garlic) or foods (carrot, caraway) 1 to 5 days after the last maternal ingestion when compared to a non-exposed control group (Mennella, 1993b; Mennella 1999; Hausner 2010). Across these 3 studies, a variety of behavioral responses were measured to determine whether experience with flavor in breast milk modified the infants’ subsequent response during the immediate days following exposure to the flavor when compared to the control group. Behavioral (appetitive) responses that were measured included breast milk or cereal intake, caloric intake, and mothers’ rating of their infant’s enjoyment of the food. Feedings were videotaped and trained observers determined meal or feeding duration, number of accepted spoons, number of refused spoons and number of feedings.
  ○ Mennella, 1993b examined the effect of the recency of maternal ingestion of 1.5 g encapsulated garlic to the infants’ behavioral assessment during breastfeeding. Following a 4 day washout period, all mothers ingested a placebo and infant behavior responses during breastfeeding were evaluated over 4 hours. Mothers were randomized to 1 of 3 groups that differed in the type and timing of flavor ingestion over the next 6 days. One group (control) did not ingest garlic until the test day (a placebo was ingested during the last 3 days of the intervention period), a second group ingested garlic capsules each day for first 3 days of intervention period and the third group ingested garlic each day during the last 3 days of the intervention period. The following day infant behavioral testing was conducted during breastfeeding, 4 hours following maternal ingestion of a garlic capsule.
  ○ Mennella, 1999 evaluated the effects of repeated ingestion of 300 mL per day of carrot juice or water (control group) for 1 week on infants’ acceptance of carrot flavored and plain cereal 1 to 3 days after the last day of maternal ingestion, when compared to before the intervention period.
  ○ Hausner, 2010 evaluated the effect of repeated ingestion of caraway flavor in a 2-part study. In study 1, lactating mothers consumed (10 times over a 28 day period) caraway-flavored (30 mg d-carvone) or plain hummus (control group) and infant acceptance of the flavor in a potato puree was tested. In study 2, which immediately followed the first, both groups of infants consumed d-carvone flavored potato puree at home for 10 meals on alternate days and infant acceptance of the flavor in a potato puree was tested. Infant testing occurred within approximately 3.6 and 5.4 days after the last day of the intervention period within study 1 and study 2, respectively. After each study, infants participated in two separate test days. They were fed 200 g of caraway-flavored potato puree on 1test day and 200 g plain potato puree on the other day (order was counter-balanced).
- Two RCTs examined how repeated ingestion of a flavor by lactating mothers during the first months of an infant’s life impact infants’ acceptance of similarly flavored food several months after maternal flavor ingestion (Mennella, 2001b; Mennella, 2017). Behavioral responses were measured to determine whether infants’ prior exposure to the flavor in breast milk modified their acceptance of similarly flavored food, as evidenced by more appetitive responses by the exposed group(s) when compared to control food and control group. A variety of behavioral (appetitive) responses were measured. Feedings were videotaped and trained observers blind to conditions and hypotheses determined the durations and rate of feeding, number of spoons accepted or refused and infant facial expressions. Food bowls were weighed before and after feedings to determine intake. Mothers rated their infants’ enjoyment of the foods immediately after each feed.
  ○ Mennella, 2001b evaluated whether repeated maternal ingestion (4 days/week for 3 consecutive weeks) of carrot juice (or water for the control group) during the first 2 months postpartum affected their infants’ acceptance of a carrot-flavored and plain cereal 4 months later (when infants were ~6 months old) when compared to the control group who avoided carrots throughout pregnancy and lactation.
  ○ Mennella, 2017 evaluated the effects of the timing (when during lactation) and duration (for how long during lactation) of maternal ingestion of a variety vegetable juices (carrot, beet, celery, and mixed vegetable juices) on their infants’ acceptance of carrot-flavored (exposed flavor), broccoli-flavored (novel flavor) and plain cereal 4.5 to 6.5 months after the maternal intervention period (depending on the group). Across five groups, mothers drank 118 mL/d of the vegetable juices 24 days/month for 1 month beginning at 0.5, 1.5, or 2.5 months postpartum, for 3 months beginning at 0.5 months postpartum or did not ingest vegetable juices at all for the entire 3 months (control group).

Table 7 Summary of the evidence-base on the effect of maternal diet during lactation on flavor transfer to breast milk: children’s behavioral response^1^

Reference;; Country; | Study design; | Participants | Maternal intervention and child testing methods | Child age at testing^2^ | Effect of maternal diet intervention on children’s behavioral response to flavor
Flavor: Alcohol
Mennella et al., 1991;; US | Crossover study | 12 lactating mother-infant dyads | Lactating mothers drank 0.3 g ethanol/kg BW in orange juice (15% vol/vol) on one test d; equal volume of orange juice alone on another (control) d; test order counter balanced.; Infant’s breastfed as per usual 3 h following maternal ingestion. Intake assessed by weighing infants before and after a breast feed (test weighing) and infant behaviors monitored by videotape. | 25 – 216 d/during breastfeeding | Infants consumed less breast milk during the 3 h after maternal EtOH consumption than orange juice alone (120 ± 9.5 mL, 156.4 ± 8.2 mL, respectively, p<0.001).; Frequency of sucks: infants sucked more frequently during first min of breastfeeds that occurred after maternal EtOH consumption, compared to first min after orange juice alone (p<0.002).; No significant difference in number of feedings; time attached to nipple and number of sucks.
Mennella et al., 1993;; US | Crossover 11 study | 11 lactating Lactating mothers-infants dyads | Lactating mothers drank 0.3 g alcohol/kg BW alcoholic beer (4.5% vol/vol) on one d and non-alcoholic beer (<0.05% vol/vol alcohol) on another (control) d; test order counter balanced.; Infants breast-fed as per usual 4 h following maternal ingestion. Intake assessed by test weighing and infant behaviors monitored by videotape. | 150 d (median)/during breastfeeding | Infants consumed less milk after maternal alcoholic beer consumption when compared to non-alcoholic beer consumption (mean ± SE) (149.5 ± 13.1 mL, 193.1 ± 18.4 mL, p=0.03).; No significant difference in feeding duration (number of feeds and time attached to the nipple at each feed) and maternal perception of enjoyment.
Mennella et al., 2001;; US | Crossover study | 12 lactating mother-infant dyads | Lactating mothers drank 0.3 g ethanol/kg BW in orange juice (15% vol/vol) on one d; control: orange juice alone on another d; test order counter balanced.; Infants breast fed as per usual 4 h following maternal ingestion in lab; Intake assessed by test weighing and infant behaviors monitored by videotape.; For the next 16 h infant milk intake was assessed via test weighting at home by mothers to study infant self regulation of breast milk intake. | 1.8 – 5.0 mo/during breastfeeding | Breast milk intake: 0-4 h after ingestion, infants consumed less milk after maternal alcohol consumption when compared to after orange juice alone (147.4 ± 17.7 mL, vs. 200.6 ± 24.4 mL, respectively, p=0.04); (149.1 ± 17.4 mL, 117.8 ± 16.9 mL, respectively, p=0.05); 8-12 h after ingestion, infants consumed more milk after maternal alcohol consumption than after orange juice alone (149.1 ± 17.4 mL, 117.8 ± 16.9 mL, respectively, p=0.05); No significant difference 12-16 h and 0-16 h after alcohol ingestion compared to after orange juice alone.; Number of feeds: 8-12 h after ingestion, infants had a greater number of feeds after maternal alcohol consumption compared to after orange juice alone (2.1 ± 0.3, 1.5 ± 0.2, respectively, p=0.04), indicating that infants compensated for the decreasesd milk intake that occurred 0-4 h post maternal alcohol consumption. No significant difference in number of feedings: 0-4 h, 4-8 h, 12-16 h, and 0-16 h after alcohol ingestion compared to after orange juice alone.; No significant difference in mothers’ perception of infant behavior during the feedings following ingestion of alcohol compared to orange juice alone.
Flavor: Garlic
Mennella et al., 1991;; US | Crossover study | 8 lactating mother-infant dyads | Lactating mothers ingested a 1.5g garlic extract capsule on one d and a placebo capsule (control) on another d; test order counter balanced.; Infant’s breast-fed as per usual 3 h following maternal ingestion. Intake assessed by test weighing and infant behaviors monitored by videotape. | 90 – 121 d/during breastfeeding | Time attached to nipple: infants spent more time attached to the nipple during the 4 h after mothers ingested garlic compared to after mothers ingested placebo, (32.8 ± 6.6 mins vs 27.4 ± 5.2 min, respectively, p<0.02).; Interaction between treatment (garlic vs placebo) and time (before or after the odors first appeared in milk), p<0.005. There was no difference in time suckling during feeds that occured within 1.5 h from capsule ingestion (placebo vs garlic, NS), indicating the infants were at similar baseline levels in the 2 d of testing.; However, in the breast feeds that occurred 1.5 to 3 h after garlic capsule ingestion, when the sensory panelists detected that the milk smelled stronger and more like garlic, there was a difference between treatment: infants spent more time attached to nipple 1.5-3 h after maternal garlic ingestion when compared to 1.5-3 h after maternal placebo ingestion (garlic vs placebo: 18.8 ± 3.6 min vs 12.4 ± 2.6 min, p< 0.005).; Number of sucks: Infants sucked more frequently during the feeds that occurred 1.5-3 h post-maternal garlic ingestion when compared to maternal placebo ingestion( garlic vs placebo: 946 ± 208.9 vs 637.6 ± 164.5, p= 0.007).; No significant difference between treatment (maternal garlic or placebo ingestion) in amount of milk consumed; and number of feeds.
Mennella et al., 1993;; US | RCT (within- and between-subject) | 30 lactating mother-infant dyads | Dyads randomized to 1 of 3 groups.; D 1-3: all groups ate bland diet devoid of sulfur volatiles (e.g., garlic, onion);; D 4, (test session 1): all mothers ingested placebo, and over the next 4 h infants breast fed on demand as customary; breast milk intake was assessed; infant behavior monitored;; D 5-10: groups differed in type and timing of capsule ingestion: Group 1, mothers ingested placebo on d 5-10 (control); Group 2 ingested garlic capsules (1.5 g garlic extract) on d 5-7; Group 3 ingested garlic capsules on d 8-10;; D 11 (test session 2): all mothers ingested garlic capsule; and over the next 4 h infants breast fed on demand as customary. Breast milk intake was assessed via test weighing; infant behavior monitored by videotape. | 124.3 ± 13.6 d (mean)/ during breastfeeding 1 d after, when compared to before maternal intervention | Feeding duration: Between subjects: Infants whose mothers ingested garlic on d 5-7 (group 2) or d 8-10 (group 3) spent less time breastfeeding during the test session in which their mothers consumed garlic than did infants whose mothers maintained a bland diet and ingested the placebo capsule during d 8-10 (group 1)(Group 1: 47.9 ± 5.8 min, Group 2: 24.6 ± 3.7 min, Group 3: 27.8 ± 5.8 min; both p<0.05). Within subjects: Infants whose mothers ingested the placebo (group 1) spent more time attached to the breast during the test session on d 11 where mothers consumed garlic compared to the test session on d 4 where their mothers consumed the placebo(47.9 ± 5.8 min vs 37.6 ± 4.4 min, p=0.009; Groups 2 and 3, NS).; No significant difference in number of feedings per session; and milk intake.
Flavor: Carrot and/or Vegetable Juices (carrot, beet, celery, and mixed vegetable)
Mennella et al., 1999;; US | Study 2: RCT (between- and within-subject) | 38 lactating mother-infant dyads | Dyads randomized to one of two groups; all infants tested on 2 separate ds before the 1-wk intervention period. Mothers fed infants cereal prepared with water on one d and cereal prepared with carrot juice on another d; test order counter balanced. Intake was assessed by test weighing; infant behavior monitored.; After preexposure testing, dyads differed in what mothers ingestion during the 1-wk intervention period.; Group 1: Lactating mothers ingested 300 mL carrot juice every d for 1 wk;; Group 2: Mothers ingested water every d for 1 wk (control);; Within 3 ds after the last d of the 1-wk intervention: mothers fed infants cereal prepared with water on one d and cereal prepared with carrot juice on another d; test order counter balanced. Intake was assessed by test weighing; infant behavior monitored by videotape. | 173.0 ± 8.0 d/during feeding 1-3 d after when compare to before maternal intervention | Intake: Infants whose mothers ingested carrot juice consumed less carrot-flavored cereal compared to plain cereal, (cereal weight in g) p=0.004, calories ingested p=0.05; Infants whose mothers did not ingest carrot juice consumed similar amounts of plain and carrot flavored cereal after, when compared to before the maternal intervention period.; Feeding time: Infants whose mothers ingested carrot juice spent relatively less time eating carrot-flavored cereal compared to plain cereal (p=0.004); There was no significant difference in infants in the control group.; No significant difference in maternal perception on infants enjoyment between groups.
Mennella et al., 2001;; US | RCT (within- and between-subjects) | 31 mother-infant dyads [total from water/carrot group and water/water group only] | Pregnant women randomized to 1 of 3 groups:; Group 1(water/carrot): mothers ingested water (avoided carrots) 4 ds per wk during the last trimester of pregnancy and 300 mL of carrot juice 4 ds per wk for 3 consecutive wk during first 2 mos of lactation;; Group 2 (control: water/water): mothers ingested water during both last trimester of pregnancy and first two mos of lactation and avoided carrots throughout;; Group 3 (carrot/water): mothers ingested carrot juice during last trimester of pregnancy and water (avoided carrots) during first 2 mos of lactation.; All infants exclusively breastfed during the intervention period.; When infants were 5.7 mos (~ 4 mos after maternal intervention of group 1 and 2 and ~ 6 mos for group 3) and had been eating solids for about 4 wk, mothers fed infants cereal prepared with carrot juice on 1 d or with water on another d; testing order counter balanced. Intake was assessed by test weighing; infant behavior monitored by videotape. | 5.7 ± 0.2 mos (mean)/ during feeding mos after maternal intervention period | Facial expressions of distaste: Infants whose mothers drank carrot juice during lactation had less negative facial expressions when eating carrot-flavored cereal compared to plain cereal (3.4 ± 0.6 vs 4.7 ± 0.8, p=0.03) as compared to an unexposed control group. (A similar finding was reported in part 1 among infants whose mothers ingested carrot juice during pregnancy).; No significant difference in length of feed and maternal perception of enjoyment of carrot-flavored vs plain cereal.
Mennella et al., 2017;; US | RCT (within- and between-subjects) | 75 lactating mother-infant dyads | Dyads were randomized to 1 of 5 groups.; Group 1M0.5: lactating mothers ingested 118 mL/d carrot, beet, celery, and mixed vegetable juices from 0.5-1.5 mos postpartum (24 total exposures);; Group 1M1.5: mothers ingested 118 mL/d carrot, beet, celery, and mixed vegetable juices from 1.5-2.5 mos postpartum (24 total exposures);; Group 1M2.5: mothers ingested 118 mL/d carrot, beet, celery, and mixed vegetable juices from 2.5-3.5 mos postpartum (24 total exposures);; Group 3M0.5: mothers ingested 118 mL/d carrot, beet, celery, and mixed vegetable juices from 0.5-3.5 mos postpartum (24 total exposures/mo);; Control Group: mothers ingested equal amounts of water and did not consume vegetable juices (24 total exposures/mos). When infants were ~8 mos and had been eating solid foods for about few wk, they were tested on 3 separate ds. At the time of infant vegetable acceptance testing, the time since the maternal intervention period was 6.5 (Group 1M0.5), 5.5 (Group 1M1.5), or 4.5 (Groups 1M2.5 and 3M0.5) mos. Mothers fed infants cereal prepared with water (control) on one d, cereal prepared with broccoli juice (novel vegetable flavor) and cereal prepared with carrot juice (exposed vegetable flavor) on another d; test order counter balanced. Intake was assessed by test weighing; infant behavior was monitored by videotape, and infants’ enjoyment after eating was rated by mothers on a scale of 1 (extreme dislike) to 9 (extreme like). | 6-8 mos/ during feeding 4.5-6.5 mos after maternal intervention | Timing (1 mo of maternal ingestion starting at age 0.5 mos, 1.5 mos, and 2.5 mos compared to control):; Carrot-flavored cereal intake and rate of feeding: infants who consumed vegetable juices from 0.5-1.5 mos (1M0.5 group) consumed more carrot flavored cereal compared to infants whose mothers did not consume vegetable juices (78.2 ± 14.8 g and 41.0 ± 7.6 g, p=0.03 ) and at a faster rate (7.2 ± 1.1 and 3.9 ± 0.6 g/min, p=0.01); no signficant difference in facial expressions; and maternal rating of infant enjoyment between groups.; There were no significant differences in intake, rate of feeding, facial expressions and maternal rating of enjoyment between the groups whose mothers drank the juices for one mo starting 1.5 or 2.5 mos postpartum and the control group.; Duration (1M0.5 vs 3M0.5): Timing was more important than duration.; Intake and rate of feeding: Infants whose mothers drank the juices for 1 mo (1M0.5) ate more carrot-flavored cereal at a greater rate than did infants in the control group, but were no different from those with 3 mos of exposure (3M0.5) (p<0.02).; No significant difference in 1M0.5 and 3M0.5 groups in intake, rate of feeding facial expressions, and maternal rating of infant enjoyment.; Maternal ingestion of the vegetables juices did not affect the relative acceptance of the novel broccoli-flavored food when compared to the control group.
Flavor: Caraway (d-carvone)
Hausner et al., 2010;; Denmark | RCT (within- and between-subjects) | 40 lactating mother-infant dyads [total from BF-E group and BF-Non group only] | Part 1: Group 1 (BF-E): Mothers ingested 30 mg d-carvone/75 g hummus every 3rd d for 28 d; infant acceptance of the flavor in a potato puree was tested.; Group 2 (BF-Non): Mothers ingested 75 g plain hummus every 3rd d for 28 d; infant acceptance of the flavor in a potato puree was tested.; Group 3 (FF): Formula-feeding mothers ingested 30 mg d-carvone/75 g hummus every 3rd d for 28 d; infant acceptance of the flavor in a potato puree was tested.; Part 2: which immediately followed, both groups of infants consumed d-carvone flavored potato puree at home for 10 meals on alternate ds and infant acceptance of the flavor in a potato puree was tested.; Part 1 and 2: In both parts of the study, infant testing occurred within 5.4 d after the last d of the intervention period. Infants fed 200 g of caraway-flavored potato puree on 1 d and 200 g plain potato puree on another d; test order counter balanced. | 7.0 ± 0.1 mos (mean); ~5 d after maternal intervention period | Part 1: No significant difference between or within groups in intake, number of accepted spoons, number of refused spoons, meal duration, and maternal perception of liking.; Part 2: No within or between group differences in intake, meal duration, number of accepted spoons and mothers’ perception of liking.; Within groups: Number of refused spoons: Infants of mothers who consumed plain hummus refused fewer spoons when fed caraway-flavored vs plain puree (8.6 ± 1.1 and 14.2 ± 2.1, p<0.05).
Flavor: Vanilla
Mennella et al., 1996;; US | Crossover study | 12 lactating mother-infant dyads | Mothers ingested 10 mL vanilla extract on one d and a diluent (control) on another d.; Infant’s breast fed as per usual 3 h following maternal ingestion; Intake assessed by weighing and infant behaviors monitored by videotape. | 35 – 138 d/during breastfeeding | Milk intake: Infants consumed more milk during 3 h after their mothers consumed vanilla compared to the diluent (vanilla vs. control: 205.0 ± 15.6 vs 178.2 ± 17.1 mL, p<0.02).; Feeding duration (time attached to nipple): The infants spent significantly more time attached to their mother’s nipple during the 3 h that followed their mother’s ingestion of the vanilla compared to the diluent (vanilla vs. control: 39.0 ± 3.3 vs. 32.9 ± 4.1 mins, p<0.05).; No significant difference in number of feedings per session, mothers perception of infant feeding behavior or lactational performance.

1 US, United States; BW, body weight; 1M0.5, group that ingested juices for 1 mo starting at 0.5 mo; 1M1.5, group that ingested juices for 1 mo starting at 1.5 mo; 1M2.5, group that ingested juices for 1 mo starting at 2.5 mo; 3M0.5, group that ingested juices for 3 mo starting at 0.5 mo; BF-E, group of mothers who ingested flavor while breastfeeding; BF-non, group of mothers who did not ingest flavor while breastfeeding; FF, group of mothers who ingested flavor while formula feeding their children and not breastfeeding; NS, not significant (p>0.05); SE, standard error;

2 Child age at testing including the range and context of the testing

#### Limitations

The NEL Bias Assessment Tool was used to evaluate the internal validity of each included study.

##### Evidence on transmission of flavor from the maternal diet to breast milk from chemical and sensory detection methods

- Denzer, 2015: Low and highly variable volatile content in the fennel-anise-caraway tea ingested by lactating mothers likely limited the ability to detect volatiles via chemical analytic methods. Sensory analyses of milk samples was conducted on samples collected from only 1 woman, eliminating the ability to reach a valid conclusion. Experimental rigor was lacking; mothers prepared the tea and collected the breast milk samples at home and little information was provided on storage of samples prior to analysis.
- Kirsch, 2012: Timing of breast milk collection was based on a mother’s subjective judgement of when her breath smelled of eucalyptus; therefore timing of testing was not uniform and may be a source of detection bias.
- Sandgruber, 2011: Timing of the collection of breast milk, after an overnight fast rather than soon after fish oil supplement ingestion, may explain negative findings in both chemical and sensory analysis, since flavor volatiles from the maternal diet are transmitted to breast milk in a time-dependent manner and dissipate hours after ingestion.

##### Evidence on the infants’ behavioral responses to flavor change in their mother’s milk

- Evidence on the effect of maternal ingestion of alcohol on lactation performance (2010 DGAC Report), confounds studies evaluating infant response to maternal ingestion of alcohol during breastfeeding. For this reason, behavioral response results in these studies (Mennella, 1991a; Mennella, 1993a; Mennella, 2001a) must be interpreted in light of subsequent research findings. The decreased milk intake at the breast following maternal alcohol ingestion is not due to infants rejecting its flavor but rather alcohol had direct effects on lactation performance of mothers. Nevertheless, it was later verified that breastfed infants could detect the flavor of alcohol in breast milk as evidenced from differences in their suckling response (2010 DGAC Report; Mennella, 1997 https://www.ncbi.nlm.nih.gov/pubmed/9194908).

### Evidence synthesis

#### Evidence on the transmission of flavor from the maternal diet to breast milk: Chemical and sensory analysis

Eight studies provide evidence that a wide range of flavor volatiles found in caraway (d-carvone), anise (trans-anethole), mint (l-menthol), eucalyptus (1,8-cineole), garlic, carrots, and alcohol originating from the maternal diet during lactation, transfer and flavor breast milk as determined by chemical and sensory analyses (Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1999; Hausner, 2008; Hausner, 2010; Kirsch, 2012; Scheffler, 2016). The flavors ingested ranged from sulfur-containing volatiles found in garlic to sweet-smelling volatiles in fruits and those found in spices, foods and beverages eaten by various cultures. Seven of these studies (Hausner, 2008; Kirsch, 2012; Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1999; Scheffler, 2016) provide evidence of the time-dependent manner of this transfer. Volatile levels or changes in the perceived odor of the breast milk were evident 30 minutes to 1 hour after alcohol ingestion (Mennella, 1991a; Mennella, 1993a); 2-3 hours after ingestion of raw garlic or encapsulated garlic extract (Mennella, 1991b; Scheffler, 2016), carrot juice (Mennella, 1999) or capsules containing caraway (d-carvone), anise (trans-anethole), (Hausner, 2008); such changes in levels of volatiles in or sensory characteristics of breast milk then dissipated over a few hours. While mint volatiles were first detected 2 hours after maternal ingestion of l-menthol containing capsules, volatiles could still be detected 8 hours later. Kirsh, 2012 demonstrated that changes in the chemical and sensory properties of milk following eucalyptus ingestion paralleled changes in the eucalyptus odor on mothers’ breath.

When both chemical and sensory analyses were conducted (Mennella, 1991a; Mennella, 1993a; Scheffler, 2016; Kirsch, 2012), there was concordance in the findings; when a change in the flavor volatile concentration was detected by chemical analysis, a change in the flavor of the breast milk was also detected by sensory evaluation analysis. Additionally, when both sensory and infant behavioral responses were conducted, there was agreement in the findings; when a change in the flavor of breast milk was detected by sensory evaluation, infant breastfeeding behaviors also differed during the 2-3 hours following maternal ingestion of flavor (Mennella, 1991a; Mennella, 1993a, Mennella, 1991b).

Transmission of flavor from fish oil supplements (Sangruber, 2011), fennel-anise-caraway tea (Denzer, 2015) and 3-methylbutyl acetate (Hausner, 2008) was not demonstrated. The negative findings could be due to any of several reasons, including an insufficient intake of the volatile (concentration), timing of breast milk collection, or selective transmission.

Two crossover studies, examined the time-dependent transmission of alcohol ingested by mothers during lactation (Mennella, 1991a; Mennella, 1993a). Testing occurred on 2 separate days separated by 1 week. Mothers either drank 0.3 g ethanol/kg body weight in orange juice (15% vol/vol) on 1 day (Mennella, 1991a) or 0.3 g alcohol/kg body weight alcoholic beer (4.5% vol/vol) on 1 day and a similar non-alcoholic control beverage on another day (Mennella, 1993a). Milk was collected before and at specific time intervals 0.5 to 3 hours (Mennella, 1991a) or 1-4 hours (Mennella, 1993a) following ingestion. Nicotinamide adenine dinucleotide-alcohol dehydrogenase enzymatic assay was used to measure the alcohol content of breast milk and adult sensory panels evaluated the odor of milk samples. Alcohol was detected by chemical and sensory analysis in milk samples from the experimental groups, but not the control groups. The alcohol content and odor intensity of alcohol in breast milk samples changed as a function of time after alcohol consumption, peaking approximately 1 hour after ingestion and subsequently decreased.

Mennella, 1991b used a similar crossover design to examine the time-dependent transmission of garlic using a sensory panel after maternal ingestion of garlic extract. Eight mothers maintained a diet devoid of sulfur volatiles for several days before testing then ingested 1.5 g encapsulated garlic extract on 1 day and placebo capsules (control) on another (separated by 1 week). Milk was collected before and 0, 1, 2, and 3 hours post ingestion. Evaluation by a sensory panel revealed that there was a time-dependent change in the odor of the milk. Garlic odor was evident 2 hours post garlic ingestion then decreased to baseline values at 3 hours post ingestion. It was noted however that garlic was still evident in the milk collected from 3 of the 8 women 3 hours post ingestion. There was no garlic odor in milk samples prior to garlic ingestion or 1 hour after ingestion.

Scheffler, 2016 conducted a controlled trial to evaluate the time dependency of flavor transmission following a single ingestion of raw garlic. Six lactating women ingested 3 g of raw garlic and milk was collected before and at 2-3 hours and 4-5 hours post ingestion. Analysis with GC-MS found a metabolite with a garlic-like aroma (allyl methyl sulfide) in breast milk from 4 women and the concentration peaked approximately 2 to 3 hours after garlic ingestion and then decreased, while allyl methyl sulfide concentrations in the other 2 women increased over approximately 5 hours. (Other metabolites, allyl methyl sulfoxide and allyl methyl sulfone, were identified, but did not have a detectable odor). A sensory panel reported garlic and cabbage-like odors were not present in breast milk prior to garlic ingestion, but after ingestion, breast milk samples were perceived to have “slight to average” garlic and cabbage like odor intensity. High inter-individual differences in metabolism and excretion rates of garlic volatiles were observed.

Mennella, 1999 (study 12), a within-subject controlled study, evaluated sensory changes to breast milk before compared to after maternal carrot juice consumption, assessed by a sensory panel and by mothers taste testing their own milk samples. Five lactating mothers ingested 500 mL carrot juice on the test day. Milk samples were collected before and 1, 2, and 3 hours post ingestion. A sensory panel evaluated the odor of milk samples from 4 of 5 mothers (1 mother was excluded because the baseline sample had a strong minty odor) and mothers blindly evaluated the taste of a baseline and post-ingestion sample of their own breast milk. Consumption of carrot juice altered the odor and taste of breast milk. The sensory change in the odor of the milk peaked 2 hours after ingestion, and mother’s perceived significant difference in the taste of the breast milk collected 3 hours after ingestion.

Hausner, 2008 used gas chromatography−mass spectrometry (GC-MS) to evaluate the time-dependent transfer of favor volatiles to breast milk following maternal ingestion of capsules containing 4 flavor volatiles, each representing a different food class: 3-methylbutyl acetate (volatile found in fruits), d-carvone (volatile found in caraway), l-menthol (mint volatile) and trans-anethole (volatile found in anise). Eighteen lactating mothers avoided foods containing the flavors 3 days prior to testing. Mothers ingested flavor capsules and breast milk was collected before and 2, 4, 6, and 8 hours post ingestion on each of 3 test days. D-carvone and trans-anethole milk concentrations peaked 2 hours post ingestion (7.17 ug/L and 9.90 ug/L, respectively) and returned to baseline 8 hours after ingestion (2.66 ug/L and 4.25 ug/L) . l-menthol was first detected 2 hours after ingestion when compared to baseline (4.85 ug/L) and remained at this level for the next 8 hours (4.14 ug/L). 3-methylbutyl acetate was not detected in any milk samples during the 8 hours after ingestion. This finding may indicate that volatiles are selectively transmitted in low quantities. There was large intra-individual variation in flavor content of each compound in breast milk samples. Between-person variation of flavor content in milk samples exceeded intra-individual variations. Mother’s weight-adjusted dose (mg/kg/day) did not affect the flavor concentration-time profiles of the milk.

Hausner 2010 examined transmission of caraway (d-carvone) in a RCT, where 40 women ingested either 30 mg d-carvone in hummus or plain hummus every third day for 28 days. Breast milk was collected 2 hours post ingestion after the first and tenth ingestion of hummus. Gas chromatography was used to evaluate the percentage of breast milk samples from the exposed and unexposed groups that contained d-carvone. d-carvone was detected in milk samples from 18 of the 20 women who had ingested d-carvone and was not detected in any milk samples from women who did not consume d-carvone. There was no significant difference in d-carvone concentration following the first and the tenth ingestion of d-carvone, indicating d-carvone flavor is not stored in breast milk.

Kirsch, 2012 evaluated 1,8-cineole (eucalyptus flavor volatile) transmission in 12 lactating women. A preliminary experiment was conducted to inform the timing of milk collection during the study. Time dependency of 1,8-cineole was conducted using milk samples from 1 woman, who on 3 separate days provided a series of samples expressed before and after consuming a 1,8-cineole capsule and plus an additional sample provided 1 morning the day following a serial collection. At regular intervals during this period, the 1,8-cineole content of the mother’s breath gas was measured. Two of the serial milk collections and the morning after sample were evaluated by a sensory panel using a scale of 0 (no perception) to 3 (strong perception). Chemical analysis of milk samples was performed to verify sensory panel findings. Results indicated that breastmilk 1,8-cineole content more or less coincided with its presence in exhaled breath of the mother.

In the second part of the study, 12 lactating women ingested 100 mg 1,8-cineole in a capsule and milk was collected only after mothers perceived eucalyptic-like odor on their own breath. Twenty-one samples were collected in total because some women repeated the experiment and some women expressed more than 1 sample after ingesting a capsule. Based on chemical and sensory evaluation, high amounts of 1,8-cineole were detected in the 14 eucalyptus-smelling samples (70 to an approximately 2090 ug/kg) and only trace amounts were detected in the 7 non-eucalyptus-smelling samples (<20 ug/kg). Quantification of 1,8-cineole levels (ug/kg) revealed large inter- and intra-individual differences; however timing of breast milk collection was not uniform and mother’s judgement of the eucalyptus odor of their breath is subjective.

Denzer, 2015 evaluated a commercial fennel-anise-caraway “nursing tea” popular in Germany. Five women participated in an experiment that had 3, 6 day blocks. The first 4 days were washout days and a control breast milk sample was collected from the mothers on day 4. On day 5, mothers prepared fennel-anise-caraway tea and drank 950 mL of it within 30 minutes. In each block, women provided a sample at a different time point after tea ingestion: 30 min (block 1), 1 hour (block 2), and 2 hours (block 3). However because mothers could decide at what block they provided a milk sample, not all women participated in every block and some women repeated blocks. Flavor volatile concentrations in the tea were low (approximately 1−1000 μg) compared with other included studies and the odorant profile was complex. GC-MS conducted on milk samples from 5 women found no difference in concentration of any tea flavor compounds between before and after tea consumption at any time point. A sensory panel found no difference in the sensory attributes of milk samples collected from 1 woman over time after tea ingestion. Large variation in flavor volatile concentrations was observed across tea samples and in breast milk samples collected before and after tea consumption. It is worth noting that several factors suggest that the study lacked sufficient experimental rigor to test the hypothesis: 1) the tea was prepared by the mother; 2) concentration of flavor volatiles may have been insufficient in the tea to detect flavor transmission (e.g., tea contained 238 ± 308 μg/L carvone, 858 ± 1973 μg/L and trans-anethole compared to 30 mg100mg d-carvone and 100 mg trans-anethole concentrations tested by Hausner, 2008); 3) some of the baseline breast milk samples had higher levels of the flavor volatile that those collected post ingestion; 4) volatile content of the tea ingested varied widely among mothers

Sandgruber, 2011 used a RCT to evaluate flavor transfer from fish oil supplements. The intervention group ingested 3 capsules (1000 mg each) per day beginning at 14-16 weeks gestation through 4 months postpartum, while the control group refrained from any fish oil supplementation. Milk sampling occurred on an empty stomach in morning hours at 4-6 and 16-18 weeks postpartum. No significant differences were detected in flavor volatile concentrations and in breast milk odor between groups. Because milk collection was conducted in the morning on an empty stomach, it is assumed that fish oil supplements were not ingested during the hours before milk collection. This null finding for fish oil is consistent with time-dependent results from other flavors reviewed herein, indicating flavor volatiles are not stored in breast milk, but dissipate within hours of maternal ingestion.

#### Evidence on the infants’ immediate (within hours) behavioral responses to breastfeeding after their lactating mothers one-time ingestion of flavor

Five cross-over controlled studies examined infants’ behaviors while breastfeeding and found that infants’ behaviors at the breast were different during 1-3 hours after their mothers’ ingested a flavor when compared to the same time of day in a control test session (Mennella, 1991a; Mennella, 1991b; Mennella, 1993a; Mennella, 1996; Mennella, 2001a). Flavors and respective controls (placebos) ingested by lactating mothers included: alcohol in orange juice or orange juice alone (Mennella, 1991a; Mennella, 2001a); alcoholic beer or nonalcoholic beer (Mennella, 1993a), encapsulated garlic extract or placebo capsules (Mennella, 1991b), and vanilla extract or placebo diluent (Mennella, 1996).

For each of the 3 flavors (alcohol, garlic, vanilla), it was found that infants could detect the flavor change as evidenced by differential behavioral response during the immediate (1-3 hours) after mothers ingested the flavor; this time frame parallels the time-dependent changes identified in the chemical and sensory properties of the milk following maternal ingestion. In the case of alcohol, as noted earlier, subsequent research findings revealed that the infants were not rejecting their mothers’ milk following maternal alcohol ingestion. While this body of evidence identifies that breastfed infants detected the flavor of alcohol in the breast milk, as evidenced from suckling responses, diminished milk intake was due to alcohols effect on the mother’s lactation performance (2010 DGAC Report; Mennella, 1997; https://www.ncbi.nlm.nih.gov/pubmed/9194908 ).

Two crossover studies found after alcohol ingestion, infants ingested less breast milk during the next 3 hours (120 ± 9.5 mL, 156.4 ± 8.2 mL, respectively, p<0.001) (Mennella, 1991a), or 4 hours (149.5 ± 13.1 mL v. 193.1 ± 18.4 mL, p=0.03) (Mennella, 1993a). Mennella, 1991a found infants sucked more frequently after maternal ingestion of an alcoholic beverage when compared to control beverage (p<0.002). A third crossover study, Mennella, 2001a, replicated the decreased intake at the breast during the 4 hours after maternal alcohol consumption compared with a placebo (147.4±17.7mL, 200.6±24.4mL, respectively, p=0.04) and provided evidence of compensation by the infants 8 to 12 hours later when infants compared to the control condition breastfed more often (2.1 ± 0.3, 1.5 ± 0.2, respectively, p=0.04), and ingested more breast milk (149.1 ± 17.4 mL, 117.8 ± 16.9 mL, respectively, p=0.05).

Mennella 1991b found breastfed infants spent more time attached to their mother’s nipple (garlic vs placebo: 18.8 ±3.6 vs 12.4 ±2.6 min, p< 0.005) and sucked more frequently (garlic vs placebo: 946 ±208.9vs 637.6 ±164.5, p= 0.007) during the 1.5-3 hours after their mothers ingested garlic when compared to when they ingested placebo. The time of the changes in the infants’ behavior during breastfeeding coincided with the time when the sensory panel detected that the breast milk collected from their mothers smelled stronger or more like garlic (p<0.005). There was no difference between groups found with regards to the number of feedings or the amount of milk that was consumed.

In a sample of 12 breastfed infants, Mennella, 1996 found that during the 3 hours after their mothers ingested vanilla, infants ingested more breast milk (vanilla vs placebo: 205.0 ± 15.6 vs 178.2 ± 17.1 mL, p<0.02) and spent longer time attached to the breast (vanilla vs placebo: 39.0 ± 3.3 vs. 32.9 ± 4.1 minutes, p<0.05) when compared to the control session when their mothers ingested a placebo. Breastfed infants were tested on 2 days separated by 1 week. After following a bland diet devoid of vanilla flavors for several days, half the mothers consumed vanilla extract (10 mL) on the first test day and placebo on the second test day; the order was reversed for the other half of mothers. There was no difference between groups with regards to the number of feedings or mother’s perception of infant’s feeding behaviors or lactation performance.

#### Evidence on the infants’ behavioral responses within days of repeated maternal ingestion of flavor

Three RCTs manipulated whether and for how long mothers repeatedly ingest a flavor and then looked at their infants’ response to the flavor in the days following maternal ingestion (Mennella, 1993b; Mennella, 1999; Hausner, 2010). Two of the 3 studies found that repeated ingestion of flavor (carrot juice 1/day for 1 week) or garlic (3 times over 10 days) by lactating mothers impacted their infant’s acceptance of similarly flavored breast milk (Mennella 1993b) or carrot-flavored cereal (Mennella 1999) days later when compared to a non-exposed control group. Infants were more accepting of the test flavor (garlic) when they did not have recent experience with the flavor (control group) compared to infants whose mothers had ingested the flavor for several days prior to testing. One study, Hausner, 2010, did not find repeated maternal ingestion of d-carvone in hummus impacted their infants’ acceptance of caraway-flavored potato puree.

In Mennella, 1993b, 30 mother-infant dyads (mean infant age at testing ~4 months) participated in an 11-day experimental period. After eating a bland diet for 3 days all infants were tested for their acceptance of plain cereal on day 4. Dyads were randomized into 1 of 3 groups which differed in what mother ingested (placebo or 1.5 g garlic extract capsules) and when they ingested the capsules during a 5-day period (placebo capsules on days 8-10; garlic capsules on days 5-7; garlic capsules 8-10). Infants’ acceptance of garlic-flavored cereal was tested on day 11. Confirming prior results mentioned above, the infants whose mothers diets were devoid of garlic during the experimental period spent more time breastfeeding during the test session that infants whose mothers ingested garlic on study days 5-7 (p<0.05) or on days 8-10 (47.9 ± 5.8 minutes, 24.6 ± 3.7 minutes, 27.8 ± 5.8 minutes, p<0.05 respectively).

In Mennella, 1999 (study 2), 38 lactating mothers (mean infant age at testing ~5.5 months) were randomized to drink either 300 mL of carrot juice per day or an equal volume of water over a 1-week period. Immediately before and after the 1-week period (4 days of testing), the infants, (all of whom had been fed cereal for an average of 21.3 days) were tested for their acceptance of cereal prepared with carrot juice on 1 day and cereal prepared with water on another. Within- and between-subject differences were analyzed. Infants whose mothers ingested carrot juice consumed less carrot-flavored cereal compared to plain cereal (cereal intake, g: p=0.004; calories ingested: p=0.05) and spent less time eating carrot-flavored cereal compared to plain cereal (p=0.004). Infants whose mothers did not ingest carrot juice consumed similar amounts of plain and carrot flavored cereal after the maternal ingestion period.

These studies provide further evidence that infants can detect garlic (Mennella, 1993b) or carrot (Mennella, 1999) flavors in breast milk and that the infants response varies depending on recency of exposure; that is whether the flavor had not been experienced by the infants in breast milk during the recent past or whether the infant had repeated, recent experience with the flavor. Results from these studies, in which mothers eat bland diets devoid of a given flavor for a week, generally resulted in greater acceptance (as evidenced by more sucking, longer time spent breastfeeding, or greater intake) to the flavor by the infant during breastfeeding. Infants suck more when they are aroused and so detection of a flavor not experienced in the past week may arouse the infants’ interest, resulting in a change in nursing behavior. However, if mothers had been ingesting the flavor for several days prior to testing and their infants were repeatedly exposed to the flavor in breast milk, the flavor may be less interesting or arousing to the infant. This may represent an early form of sensory specific satiety such that acceptability of a food decreases after recent consumption.

Chemical analysis on breast milk samples demonstrated the transmission of caraway (d-carvone) flavors to breast milk (Hausner, 2008; Hausner, 2010). Hausner, 2010 further explored breastfed infants’ reaction to carawy-flavored foods after their mothers consumed caraway-flavored hummus. In part-one of this study, 40 mother-infant dyads (mean infant age at testing ~7 months) were randomized to ingest either 30 mg d-carvone per 75 g hummus or 75 g plain hummus every third day for 28 days (10 exposures). Infants were tested for their initial acceptance of caraway after the ingestion period. In part-two of the study, which immediately followed, both groups of infants consumed d-carvone-flavored potato puree at home for 10 meals (one meal every other day for 19 days) followed by testing of infant acceptance of the caraway-flavored puree. Infant testing occurred on average 3.6 and 5.4 days after the last day of the intervention period for parts 1 and 2 of the study, respectively. During acceptibility testing, infants were fed 200 g of caraway-flavored potato puree on one day and 200 g plain potato puree on another day and the test order was counter balanced. Intake was assessed by weighing the food and infant behaviors were monitored by videotape. Upon initial exposure to caraway-flavored food, there was no difference in infants reaction to plain and caraway-flavored purees within or between groups. After 10 exposures of the caraway-flavored puree, the only difference was that infants whose mothers did not consume caraway-flavored hummus refused fewer spoons of caraway-flavored puree than plain puree (8.6±1.1 and 14.2±2.1, respectively, p<0.05), while there was no difference in number of refused spoons between caraway-flavored and plain puree within the group of infants whose mothers consumed caraway-flavored hummus. While it has been established that caraway (d-carvone) transfers to breast milk as detected using chemical analysis, it remains unknown whether maternal ingestion of 30 mg of caraway in hummus is enough to produce a detectable flavor in breast milk since no sensory testing was conducted.

#### Evidence on the infants’ behavioral responses to a flavor several months post weaning after their mother’s had ingested the flavor during the first few months of lactation

Two RCTs reveal that repeated ingestion of carrot and other vegetable juices by lactating mother during the first 2-4 months of lactation modifies their infants acceptance of carrot flavored cereal several months later (Mennella, 2001b; Mennella, 2017). Mennella, 2001b found that infants repeated exposure to carrot in mothers’ milk during the first 2 months of lactation resulted in relatively greater acceptance of carrot-flavored cereal 4 months later (versus plain cereal), compared to infants without any prior exposure. Subsequent work revealed that the timing of exposure was more important than duration of exposure (Mennella, 2017). Maternal ingestion of vegetable juices for 1 month, beginning when the infant was 2 weeks of age, had a greater impact on the infant’s acceptance of carrot-flavored cereal after weaning, compared to infants who had one month exposure starting at 1.5 or 2.5 months of age. Also, Infants whose mothers drank the juices for 1 month starting 2 weeks post-partum ate more carrot-flavored cereal and at a faster rate than did infants whose mothers did not drink vegetable juices. Timing of exposure was more important than duration of exposure. There were no differences in acceptability of carrot-flavored cereal between infants whose mothers began drinking vegetable juices at 2 weeks postpartum for either one month or 3 months. Also, flavor learning was specific to the exposed flavor (carrot) and did not generalize to a novel flavor of broccoli in foods.

In Mennella, 2001b, 31 mother-infant dyads were randomized to ingest 300 mL carrot juice or water 4 days per week for 3 consecutive weeks during the first 2 months of lactation. (A third group not described here, ingested carrot juice during pregnancy). Infants were approximately 5.7 months at testing and weaned ~ 4 months after the intervention phase. Testing occurred approximately 4 weeks after introduction of solids. All women breastfed their children during the intervention phase and all but 7 of the women were still breastfeeding at the time of testing. Infants were fed cereal flavored with water on 1 day and with carrot juice on another test day in counterbalanced order. Infants who had been exposed to carrot flavor via maternal ingestion of carrot juice during lactation displayed less negative facial expressions when eating carrot-flavored cereal compared to plain cereal (3.4 ± 0.6 vs 4.7 ± 0.8, p=0.03). Infants in the control group did not demonstrate a difference. There were no differences in the proportional amount consumed, length of feeding, or maternal perception of infant enjoyment between groups.

Building on this finding, the next RCT, Mennella, 2017, focused on the first 3.5 months of lactation and the intervention entailed mothers ingesting a variety of vegetable juices, 1 of which was carrot (i.e., carrot, beet, celery, mixed vegetables). The study was designed to determine the effects of both the timing of maternal ingestion (when mothers drank a variety of vegetable juices, beginning at 0.5, 1.5, 2.5 months) and duration of maternal ingestion (how often she drank a variety of vegetables juices; 0, 1 or 3 months) on the infants’ acceptance of carrot-flavored food (exposed flavor) and broccoli-flavored (novel flavor) food 4.5 to 6.5 months later (depending on the group). The timing of vegetable juice consumption impacted the acceptance of food containing 1 of the exposed flavors, carrot. One month of maternal ingestion of vegetable juice beginning when the infants were 2 weeks postpartum had the greatest effect on relative carrot flavor acceptance several months later when compared to the control group, as measured by intake (78.2 ± 14.8 g and 41.0 ± 7.6 g, p=0.03), and a faster rate of feeding (7.2 ± 1.1 and 3.9 ± 0.6 g/min, p=0.01). Infants whose mothers drank the juices for 1 month starting at 0.5 months lactation ate more carrot-flavored cereal than did infants in the control group, but were no different from those with 3 months of exposure who started the intervention at 0.5 month lactation. There were no significant differences in intake, rate of feeding, facial expressions and maternal rating of enjoyment between the groups whose mothers drank the juices for 1 month starting 1.5 or 2.5 months postpartum and the control group or between infants whose mothers consumed juices for 1 versus 3 months starting 2 weeks postpartum. Maternal ingestion of the vegetables juices did not affect the relative acceptance of the novel broccoli-flavored food when compared to the control group.

#### Assessment of the body of evidence

- Internal validity (determined with NEL Bias Assessment Tool): All studies were controlled trials and have strong internal validity; detection bias identified in studies testing alcohol, fennel-anise-caraway tea, and fish oil supplements; performance bias may exist in the study examining fennel-anise-caraway tea, since mothers prepared their own tea.
- Adequacy: There were 15 papers in this body of evidence, twelve flavors were tested, and each flavor was tested in one to three studies. Adequacy was judged to be moderate.
- Consistency: Results were consistent within flavors, across outcome types, and across research groups. Negative findings from three studies are likely due to methodological details (e.g., timing of sample collection). Consistency was assessed as moderate.
- Impact: Impact is limited because evidence focused on particular flavors in isolation rather than the full maternal diet and long-term effects were not assessed.
- Generalizability: Evidence is specific to flavors tested and therefore may not be generalize to other flavors within the maternal diet; therefore generalizability of the body of evidence was considered to be limited.

### Included articles

1 Mennella JA, Daniels LM, Reiter AR. Learning to like vegetables during breastfeeding: a randomized clinical trial of lactating mothers and infants. Am J Clin Nutr. 2017;106(1):67–76. PMID: 28515063. https://www.ncbi.nlm.nih.gov/pubmed/28515063.28515063
2 Scheffler L, Sauermann Y, Zeh G, Hauf K, Heinlein A, Sharapa C, . Detection of Volatile Metabolites of Garlic in Human Breast Milk. Metabolites. 2016;6(2). PMID: 27275838. https://www.ncbi.nlm.nih.gov/pubmed/27275838.27275838
3 Denzer MY, Kirsch F, Buettner A. Are odorant constituents of herbal tea transferred into human milk? J Agric Food Chem. 2015;63(1):104–11. PMID: 25436940. https://www.ncbi.nlm.nih.gov/pubmed/25436940.25436940
4 Kirsch F, Beauchamp J, Buettner A. Time-dependent aroma changes in breast milk after oral intake of a pharmacological preparation containing 1,8-cineole. Clin Nutr. 2012;31(5):682–92. PMID: 22405404. https://www.ncbi.nlm.nih.gov/pubmed/22405404.22405404
5 Sandgruber S, Much D, Amann-Gassner U, Hauner H, Buettner A. Sensory and molecular characterisation of human milk odour profiles after maternal fish oil supplementation during pregnancy and breastfeeding. Food Chem. 2011;128(2):485–94. PMID: 25212160. https://www.ncbi.nlm.nih.gov/pubmed/25212160.25212160
6 Hausner H, Nicklaus S, Issanchou S, Molgaard C, Moller P. Breastfeeding facilitates acceptance of a novel dietary flavour compound. Clin Nutr. 2010;29(1):141–8. PMID: 19962799. https://www.ncbi.nlm.nih.gov/pubmed/19962799.19962799
7 Hausner H, Bredie WL, Molgaard C, Petersen MA, Moller P. Differential transfer of dietary flavour compounds into human breast milk. Physiol Behav. 2008;95(1–2):118–24. PMID: 18571209. https://www.ncbi.nlm.nih.gov/pubmed/18571209.18571209
8 Mennella JA, Jagnow CP, Beauchamp GK. Prenatal and postnatal flavor learning by human infants. Pediatrics. 2001;107(6):E88. PMID: 11389286. https://www.ncbi.nlm.nih.gov/pubmed/11389286.11389286
9 Mennella JA. Regulation of milk intake after exposure to alcohol in mothers’ milk. Alcohol Clin Exp Res. 2001;25(4):590–3. PMID: 11329500. https://www.ncbi.nlm.nih.gov/pubmed/11329500.11329500
10 Mennella JA, Beauchamp GK. Experience with a flavor in mother’s milk modifies the infant’s acceptance of flavored cereal. Dev Psychobiol. 1999;35(3):197–203. PMID: 10531532. https://www.ncbi.nlm.nih.gov/pubmed/10531532.10531532
11 Mennella JA, Beauchamp GK. The Human Infants’ Response in Mother’s Milk and to Vanilla Flavors Formula. Infant behavior and development. 1996;19:13–9.
12 Mennella JA, Beauchamp GK. The effects of repeated exposure to garlic-flavored milk on the nursling’s behavior. Pediatr Res. 1993;34(6):805–8. PMID: 8108198. https://www.ncbi.nlm.nih.gov/pubmed/8108198.8108198
13 Mennella JA, Beauchamp GK. Beer, breast feeding, and folklore. Dev Psychobiol. 1993;26(8):459–66. PMID: 8293892. https://www.ncbi.nlm.nih.gov/pubmed/8293892.8293892
14 Mennella JA, Beauchamp GK. Maternal diet alters the sensory qualities of human milk and the nursling’s behavior. Pediatrics. 1991;88(4):737–44. PMID: 1896276. https://www.ncbi.nlm.nih.gov/pubmed/1896276.1896276
15 Mennella JA, Beauchamp GK. The transfer of alcohol to human milk. Effects on flavor and the infant’s behavior. N Engl J Med. 1991;325(14):981–5. PMID: 1886634. https://www.ncbi.nlm.nih.gov/pubmed/1886634.1886634