# WHAT IS THE RELATIONSHIP BETWEEN MATERNAL DIET DURING PREGNANCY ON FLAVOR TRANSFER TO AMNIOTIC FLUID, CHILDREN’S BEHAVIORAL RESPONSE, AND DIETARY INTAKE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: what is the relationship between maternal diet during pregnancy on flavor transfer to amniotic fluid, children’s behavioral response, and dietary intake?

### What is the answer to the question?

- Limited but consistent evidence indicates that flavors contained in the foods and beverages in the maternal diet during pregnancy can transfer to and flavor amniotic fluid, and fetal exposure to these flavors increases acceptance of the exposed flavor during infancy and potentially childhood. Flavor transfer to amniotic fluid occurred after pregnant mothers ingested alcohol, anise, carrot, or garlic. These findings may not be generalizable to all foods and beverages in the maternal diet during pregnancy.
- A conclusion cannot be drawn to describe the relationship between maternal diet during pregnancy and children’s dietary intake. Based upon current evidence, it is not feasible to isolate the influence of maternal diet during pregnancy on subsequent infant and child dietary intake.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of staff from the Nutrition Evidence Systematic Review conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative.

### What is the population of interest?

- Generally healthy pregnant women and their healthy infants and toddlers who were ages 0-24 months. The child’s food acceptability and dietary intake was examined through the lifespan.

### What evidence was found?

- This review includes 11 studies published since 1995
- These studies compared maternal diet during pregnancy and: 1) changes in the flavor (odor) of amniotic fluid, 2) how experiences with flavors in amniotic fluid impact the infant’s or child’s behavioral responses during subsequent exposure to the flavor (or odor), and/or 3) dietary intake during childhood.
- The flavor of a food is a complex combination of tastes (sweet, sour, salty, bitter, umami), textures, and volatile odors, which travel to the olfactory receptors when foods or liquids are in the mouth and when odor volatiles are inhaled through the nose.
- Flavors contained in foods or beverages in the maternal diet during pregnancy studied include: alcohol, anise, carrot, and garlic.
- One study showed that when mothers ate garlic during pregnancy there was a change in amniotic fluid odor, as detected by a sensory panel of adults.
- Six studies focused on the relationship between maternal ingestion of particular flavors during pregnancy and their child’s behavioral response to the flavor, during smelling or eating.
  ○ Four studies showed that maternal intake of garlic, anise or alcohol flavors during pregnancy resulted in greater acceptance or more arousal by the infants when re-exposed to the odor, three hours to 10 days after birth compared to infants whose mothers did not ingest the flavor during pregnancy.
  ○ One study demonstrated that after weaning, infants whose mothers drank carrot juice during pregnancy exhibited greater acceptance of carrot-flavored cereal relative to plain cereal when compared to infants whose mothers avoided carrot juice or carrots during pregnancy.
  ○ One study focused on the relationship between maternal ingestion of garlic during pregnancy and the child’s acceptance of garlic when they were 8- to 9-years-old. Children of mothers who consumed garlic during the last 4 weeks of pregnancy ate more garlic-flavored potatoes when compared to children of mothers who did not consume garlic during the last 4 weeks of pregnancy.
- For garlic, the convergence of findings from 3 separate studies revealed: 1) garlic ingestion by pregnant mothers in the second trimester alters the odor of amniotic fluid; 2) newborns respond differently to the odor of garlic, if their mothers ate garlic during the last month of pregnancy; and 3) experiences with garlic flavor during the last month of pregnancy resulted in greater child acceptance of garlic-flavored foods by the child 8-9 years later.
- Four studies found an association between maternal diet during pregnancy and diet quality or dietary patterns of children 9 months to 4 years of age. While this is important research, these studies cannot directly address the impact of maternal diet strictly during pregnancy on their children’s dietary intake due to serious methodological limitations. These limitations include: similarities between maternal prenatal and postpartum diet, maternal influences on what foods are offered to children, and maternal and child dietary measures based on maternal report without direct measurements of children’s acceptance of foods or flavors.

### How up-to-date is this review?

- This review includes literature from 01/1980 to 06/2017.

## TECHNICAL ABSTRACT

### Background

- This systematic review was conducted as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.
- The goal of this systematic review was to examine the following question: what is the relationship between maternal diet during pregnancy on flavor transfer to amniotic fluid, children’s behavioral response, and dietary intake?
- The flavor of a food is a complex combination of tastes (sweet, sour, salty, bitter, umami), textures, and volatile odors, which travel to the olfactory receptors when foods or liquids are in the mouth and when odor volatiles are inhaled through the nose.

### Conclusion Statement and Grades

- Limited but consistent evidence indicates that flavors contained in the foods and beverages in the maternal diet during pregnancy can transfer to and flavor amniotic fluid, and fetal exposure to these flavors increases acceptance of the exposed flavor during infancy and potentially childhood. Flavor transfer to amniotic fluid occurred after pregnant mothers ingested alcohol, anise, carrot, or garlic. These findings may not be generalizable to all foods and beverages in the maternal diet during pregnancy. Grade: Limited
- A conclusion cannot be drawn to describe the relationship between maternal diet during pregnancy and children’s dietary intake. Based upon current evidence, it is not feasible to isolate the influence of maternal diet during pregnancy on subsequent infant and child dietary intake. Grade: Grade Not Assignable

### Methods

- The systematic review was conducted by a team of staff from the Nutrition Evidence Systematic Review in collaboration with a Technical Expert Collaborative.
- Literature searches were conducted using 10 databases to identify studies that evaluated the relationship among maternal diet during pregnancy, amniotic fluid flavor; and children’s food acceptability and overall dietary intake. A manual search was conducted to identify articles that may not have been included in the electronic databases searched. Articles were screened by two authors independently for inclusion based on pre-determined criteria.
- Data from each included article were extracted, risks of bias were assessed, and both were checked for accuracy. The body of evidence was qualitatively synthesized, a conclusion statement was developed, and the strength of the evidence (grade) was assessed using pre-established criteria including evaluation of the internal validity/risk of bias, adequacy, consistency, impact, and generalizability of available evidence.

### Summary of Evidence

- This systematic review includes 11 studies
- The studies used multiple approaches to examine the relationship between maternal ingestion of alcohol, anise, carrot, and garlic during pregnancy and: 1) changes in the flavor (odor) of amniotic fluid, 2) how experiences with flavors in amniotic fluid impact the infant’s or child’s behavioral responses during subsequent exposure to the flavor (or odor), and/or 3) dietary intake during childhood.
- One study demonstrated maternal ingestion of garlic during pregnancy resulted in a change in amniotic fluid odor, as detected by a sensory panel of adults.
- Six studies focused on the relationship between maternal ingestion of particular flavors during pregnancy and their child’s behavioral response to the flavor, during smelling or eating.
  ○ Four studies indicated that maternal intake of garlic, anise or alcohol flavors during pregnancy resulted in greater acceptance or more arousal by the infants when re-exposed to the respective odor from three hours to 10 days after birth compared to infants whose mothers did not ingest the respective flavor during pregnancy.
  ○ One study demonstrated that after weaning, infants whose mothers consumed carrot juice during pregnancy exhibited greater acceptance of carrot-flavored cereal relative to plain cereal compared to infants whose mothers avoided carrot juice or carrots during pregnancy.
  ○ One study found that 8- to 9-year-old children of mothers who consumed garlic during the last 4 weeks of pregnancy ate more garlic-flavored potatoes when compared to children of mothers who were randomly assigned to not consume garlic during the last 4 weeks of pregnancy.
- For at least one commonly consumed flavor (garlic), the convergence of findings from 3 separate studies revealed: 1) garlic ingestion by pregnant mothers in the second trimester alters the sensory properties of amniotic fluid; 2) newborns respond differently to the odor of garlic, if their mothers ate garlic during the last month of pregnancy; and 3) experiences with garlic flavor during the last month of pregnancy resulted in greater child acceptance of a garlic-flavored food by the child 8-9 years later.
- Four longitudinal cohort studies found an association between maternal diet during pregnancy and diet quality or dietary patterns of children 9 months to 4 years of age. While this is important research, these studies cannot directly address the impact of maternal diet strictly during pregnancy on their children’s dietary intake due to serious methodological limitations. These limitations include: similarities between maternal prenatal and postpartum diet, maternal influences on what foods are offered to children, and maternal and child dietary measures based on maternal report without direct measurements of children’s acceptance of foods or flavors.

## FULL REVIEW

### Systematic review question

What is the relationship among maternal diet during pregnancy, amniotic fluid flavor and child food acceptability and dietary intake?

### Conclusion statement

Limited but consistent evidence indicates that flavors contained in the foods and beverages in the maternal diet during pregnancy can transfer to and flavor amniotic fluid, and fetal exposure to these flavors increases acceptance of the exposed flavor during infancy and potentially childhood. Flavor transfer to amniotic fluid occurred after pregnant mothers ingested alcohol, anise, carrot, or garlic. These findings may not be generalizable to all foods and beverages in the maternal diet during pregnancy.

A conclusion cannot be drawn to describe the relationship between maternal diet during pregnancy and children’s dietary intake. Based upon current evidence, it is not feasible to isolate the influence of maternal diet during pregnancy on subsequent infant and child dietary intake. Grade not assignable

### Grade

Limited: Relationship between maternal diet during pregnancy and a) amniotic fluid flavor and/or b) child’s behavioral response to flavor

Grade not assignable: Relationship between maternal diet during pregnancy and child’s dietary intake

### Summary

- Eleven studies examined the relationship between maternal diet during pregnancy and: 1) changes in the flavor (odor) of amniotic fluid, 2) how experiences with flavors in amniotic fluid impact the infant’s or child’s behavioral responses during subsequent exposure to the flavor (or odor), and/or 3) dietary intake during childhood.
- Flavors contained in foods or beverages in the maternal diet during pregnancy studied include: alcohol, anise, carrot, and garlic.
- One randomized controlled trial (RCT) demonstrated maternal ingestion of garlic during pregnancy resulted in a change in amniotic fluid odor, as detected by a sensory panel of adults.
- Six studies focused on the relationship between maternal ingestion of particular flavors during pregnancy and their child’s behavioral response to the flavor, during smelling or eating. Five of these studies focused on infants and one focused on older children:
  ○ Four studies (one non-randomized control trial and three cohort studies) indicated that maternal intake of garlic, anise or alcohol flavors during pregnancy resulted in greater acceptance (e.g. increase in appetitive behaviors such as head orientation towards odor, more mouthing or sucking, facial responses of liking) or more arousal (e.g. increase in body movements) by the infants when re-exposed to the respective odor from three hours to 10 days after birth compared to infants whose mothers did not ingest the respective flavor during pregnancy.
  ○ One RCT demonstrated that after weaning, infants whose mothers consumed carrot juice during pregnancy exhibited greater acceptance of carrot-flavored cereal relative to plain cereal as evidenced by fewer negative facial expressions and greater maternal perception of enjoyment when compared to infants whose mothers avoided carrot juice or carrots during pregnancy.
  ○ One study focused on the relationship between maternal ingestion of a particular flavor during pregnancy and the acceptance of the flavor during childhood: One RCT found that 8- to 9-year-old children of mothers who consumed garlic during the last four weeks of pregnancy ate more garlic-flavored potatoes when compared to children of mothers who were randomly assigned to not consume garlic during the last 4 weeks of pregnancy. There were no differences in maternal use of garlic or dietary intake of garlic during the preceding two weeks between the two groups of children.
- For at least one commonly consumed flavor (garlic), the convergence of findings from 3 separate studies revealed: 1) garlic ingestion by pregnant mothers in the second trimester alters the sensory properties of amniotic fluid; 2) newborns respond differently to the odor of garlic if their mothers ate garlic during the last month of pregnancy; and 3) experiences with garlic flavor during the last month of pregnancy resulted in greater child acceptance of garlic-flavored foods by the child 8-9 years later.
- Four longitudinal cohort studies found an association between maternal diet during pregnancy and diet quality or dietary patterns of children 9 months to 4 years of age. While this is important research, these studies cannot directly address the impact of maternal diet strictly during pregnancy on their children’s dietary intake due to serious methodological limitations. These limitations include: similarities between maternal prenatal and postpartum diet, maternal influences on what foods are offered to children, and maternal and child dietary measures based on maternal report without direct measurements of children’s acceptance of foods or flavors.

### Description of the evidence

The 11 included studies were published in peer-reviewed journals from January 1980 to June 21, 2017. The search included articles from countries with a high or very high Human Developmental Index (United Nations Development Program, 2014) to be generalizable to the U.S. population. Studies included generally healthy women and those at risk for chronic disease who were pregnant at the time of the dietary intervention or exposure. The outcomes were measured in generally healthy infants, toddlers, and children. Studies were not included if they exclusively enrolled infants with gestational age at birth of less than 37 weeks or infants who were small for gestational age (<2500g).

This systematic review includes 11 studies (3 RCTs, 1 Non-randomized controlled trial, 7 longitudinal cohort studies) that examined maternal diet during pregnancy (specific to alcohol, anise, carrot, and garlic flavors), changes in the flavor of amniotic fluid and how experiences with these flavors in amniotic fluid impact the infant’s and child’s responses when re-exposed to the flavor (or odor), as well as the child’s dietary intake, measured as diet quality or dietary patterns. Table 1 lists the type of method or methods used in each included study.

Table 1 Type of study outcomes used to assess the relationship between maternal diet during pregnancy on flavor transfer to amniotic fluid, children’s behavioral responses to flavor, and dietary intake

Maternal diet during pregnancy | Reference | Sensory analysis of AF | Children’s behavioral response to flavor | Children’s dietary intake
Flavor ingested by mothers during intervention or study^1^
Alcohol | Faas et al., 2000 | ––– | X | –––
Alcohol | Faas et al., 2015 | ––– | X | –––
Garlic | Mennella et al., 1995 | X | ––– | –––
Garlic | Hepper et al., 1995 | ––– | X | –––
Garlic | Hepper et al., 2013 | ––– | X | –––
Carrot | Mennella et al., 2001 | ––– | X | –––
Anise | Schaal et al., 2000 | ––– | X | –––
Maternal overall dietary assessment^2^
Dietary Quality and Variety | Jones et al., 2015 | ––– | ––– | X^3^
Dietary Quality and Variety | Ashman et al., 2016 | ––– | ––– | X3
Dietary Patterns | Okubo et al., 2014 | ––– | ––– | X^4^
Dietary Patterns | Lioret et al., 2015 | ––– | ––– | X4

1 Predominant flavor of the maternal dietary intervention or study, see Tables 2 and 3 for more details

2 Maternal dietary assessment, see Table 4 for more details

3 Children’s overall dietary intake measured as dietary quality and variety

4 Children’s overall dietary intake measured as dietary patterns

#### Study details: (See tables 2, 3, and 4)

- Study designs:
  ○ Three randomized controlled trials (RCTs): Hepper, 2013; Mennella, 1995; Mennella, 2001b;
  ○ One non-randomized controlled trials (NRCT): Schaal, 2000;
  ○ Seven longitudinal cohort studies: Faas, 2000; Faas, 2015; Hepper, 1995; Ashman, 2016; Jones, 2015; Lioret, 2015; Okubo, 2014.
- Independent variable: Maternal diet during pregnancy. This was reflected as an experimental manipulation (mothers ate or avoided particular flavors, foods or juices) during pregnancy or as a comparison between different maternal dietary patterns or diet quality during pregnancy
- Outcome measures:
  ○ Chemical analysis:
    ■ 0 studies
  ○ Adult sensory analysis:
    ■ 1 study: Mennella, 1995
  ○ Infant behavioral response:
    ■ 6 studies: Hepper, 1995; Faas, 2000; Faas, 2015; Schaal, 2000; Mennella 2001b; Hepper, 2013;
  ○ Child overall dietary intake:
    ■ 4 studies: Jones, 2015; Ashman, 2016; Lioret, 2015; Okubo, 2014
- Country:
  ○ Controlled trials (randomized and non-randomized):
    ■ United States: Mennella, 1995; Mennella, 2001b;
    ■ Northern Ireland: Hepper, 2013;
    ■ France: Schaal, 2000
  ○ Cohort studies:
    ■ Argentina: Faas, 2000; Faas, 2015;
    ■ Japan: Obuko, 2014;
    ■ Australia: Ashman, 2016; Lioret, 2015;
    ■ Northern Ireland: Hepper, 1995; and,
    ■ England and France: Jones, 2014.
- Sample size: There were no inclusion criteria related to sample size, and sample size varied substantially based on study design, the number of groups and purpose.
  ○ One RCT used a sensory panel to evaluate whether the odor of amniotic fluid changed based on maternal ingestion of garlic or placebo; 13 panelists evaluated the AF samples collected from 10 mothers (Mennella, 1995)
  ○ Studies evaluating maternal diet during pregnancy on postnatal infant response to either the odor or flavor (3 trials and 3 cohorts) ranged in size from 20 to 44 mother-infant dyads (Controlled trials: Hepper, 2013; Mennella 2001b; Schaal, 2000; Cohort studies: Faas, 2000; Faas, 2015; Hepper, 1995)
  ○ The four longitudinal cohort studies evaluating the relationship between maternal diet and infant overall dietary intake varied greatly:
    ■ 52 mother-infant dyads (Ashman, 2016);
    ■ 421 mother-infant dyads (Lioret, 2015);
    ■ 758 mother-infant dyads (Okubo, 2014);
    ■ 9649 mother-infant dyads (from 2 cohorts) (Jones, 2014)
- Sample characteristics:
  ○ Maternal age: At the start of the studies, mean maternal age ranged from 23 to 35 years.
  ○ Parity: Six studies reported parity; Ashman, 2016 reported 50% of subjects were nulliparous; Hepper, 2013 reported mothers had a mean of 0.78 children; Faas, 2000 indicated a mean parity of approximately 2.4; and Mennella, 2001b, Obuko, 2014, and Lioret, 2015 reported 35%, 50% and 100% women were primiparous, respectively.
  ○ Infant sex: In the seven studies that reported infant or child sex, the number of boys and girls was well balanced. Percent females ranged from 39 to 61% (Schaal, 2000, Faas, 2015, Jones, 2014, Lioret, 2015, Okubo, 2014, Hepper, 2013, Mennella, 2001b).
  ○ Race and ethnicity: race and ethnicity were rarely reported; Mennella, 1995 described the study population as 70% white and 30% black. Mennella, 2001b described the race or ethnicity of mothers: 85% white, 9% black, 4 % Hispanic and 2% Asian. The Okubo, 2014 study population was 100% Japanese. While the Lioret, 2015 study took place in Australia, the only information potentially related to race/ethnicity provided was that 21 percent of subjects were born outside of Australia.
  ○ Socioeconomic status (SES): Only five studies reported SES information; Variation in indicators used makes characterization difficult; however, each of these five studies indicated that many women were well-educated. Obuko, 2014 reported that 29% of Japanese mothers had greater than 15 years of education, 31% had a household annual income greater than 6 million yen (approximately $55,000 US dollars), 88% had a nuclear family structure, and 71% of mothers were unemployed, while 18% were employed full-time. Jones, 2014 reported that 40 to 58% of mothers had a high level of education, Lioret, 2015 reported that 59.4% of mothers had a university degree or higher, and Ashman, 2016 reported 75% of mothers were high school graduates. Hepper, 2013 reported 39% of mothers were employed full-time, 24% were employed part-time, and 36% were unemployed. Among those who were employed, 42% worked in skilled labor and 30% in professional and managerial level jobs.
  ○ Maternal weight characteristics: Only three studies described maternal weight status; Lioret, 2015 reported mean maternal pre-pregnancy BMI was 24.4 (SD=5.1). Ashman, 2016 reported 53% and 45% of women had a BMI in the normal and overweight/obesity range, respectively. Okubo, 2014 reported 73% of women had a BMI in the normal range, while 23% and 3% had a BMI in the underweight or overweight category, respectively.
  ○ Smoking status: Only two studies reported smoking status; Okubo, 2014 reported that 16% of mothers were current smokers and Ashman, 2016 reported 7.7% of women smoked at some point during pregnancy.
  ○ Fetal age at time of maternal diet manipulation (controlled trials):
    ■ 33.2 ±0.3 (mean±SD) weeks gestation and continued for 3 weeks (Mennella 2001b)
    ■ 35 weeks gestation and continued for 4 weeks (Hepper, 2013)
    ■ Second trimester, prior to a routine amniocentesis (Mennella, 1995).
    ■ Third trimester, last 15 days prior to expected delivery (Schaal, 2000)
  ○ Timing of maternal ingestion during pregnancy/dietary assessment period (cohort studies):
    ■ During last month of pregnancy (Hepper, 1995)
    ■ During pregnancy (measured retrospectively) (Faas, 2000)
    ■ During pregnancy (measured retrospectively) (Faas, 2015)
    ■ Diet collected during late pregnancy (Jones, 2015)
    ■ Diet collected at 19 and 36 wks gestation; data was averaged and used in analysis (Ashman, 2016)
    ■ Collected between 5-39 wks gestation for intake of previous month (Okubo, 2014)
    ■ Collected 3 months postpartum, retrospectively assessing diet during pregnancy (Lioret, 2015)
  ○ Infant age at time of outcome assessment: Infant age ranged from three hours to two years at the time of assessment and one study assessed food acceptance at 8-9 years.

#### Experimental Manipulation of Maternal Diet

In what follows, we list the beverages, encapsulated flavors, or foods ingested by the mothers.

- [underlined: Alcohol]: self-reported alcohol consumption, ≥1x per week during pregnancy measured retrospectively (Faas, 2000); self-reported alcohol consumption, ≥4x per month during pregnancy, measured retrospectively (Faas, 2015)
- [underlined: Garlic:] encapsulated garlic extract, 1.5 g, 1 time (Mennella, 1995); meals containing fresh garlic, >4 meals/week during last month of pregnancy (Hepper, 1995); meals containing fresh garlic, 3-4 meals/week for 4 weeks starting at 35 weeks gestation (~14 meals, 12-16) (Hepper, 2013)
- [underlined: Carrot juice:] 300 mL/day for 4 days/week for 3 consecutive weeks during last trimester of pregnancy (Mennella, 2001b)
- [underlined: Anise]: foods containing anethole, ~121.1 mg/d (SD=28.7) over the 5.6 d (SD=3.5) preceding delivery (Schaal, 2000)

#### Adult sensory analysis

One RCT evaluated the direct transfer of garlic volatiles from the maternal diet to AF (Mennella, 1995).

- In Mennella, 1995, five women ingested a capsule of garlic oil and five women ingested a placebo containing lactose approximately 45 minutes prior to a routine amniocentesis. Samples of AF were obtained and pairs of AF (one from a woman who ingested the garlic capsule and one from a woman that ingested the placebo) were compared by a panel of 13 adults who were blind to the hypothesis and group assignment of the pregnant mothers who donated the AF samples. Each pair was presented six times, in random order to each of the 13 panelists individually and each panelist indicated which of the pair smelled stronger or more like garlic. Panelists rated four of five pairs of samples of AF from women who had consumed a garlic capsule as smelling stronger of garlic than the AF from women who had consumed a placebo indicating that garlic ingestion by pregnant women alters the odor of AF.

Table 2 Summary of the evidence-base of the effect of maternal diet during pregnancy on flavor transfer to amniotic fluid: chemical and sensory analysis^1^

Reference;; Country;; Study design;; Participants | Intervention and analysis methods | Outcomes
Reference;; Country;; Study design;; Participants | Intervention and analysis methods | Chemical analysis | Adult sensory analysis
Flavor: Garlic
Mennella et al., 1995;; US;; RCT (within-subject);; 10 women; 13 adult sensory panelists | During 2nd trimester of pregnancy mothers were randomized to 2 groups:; Garlic Group: Pregnant women consumed 1.5 g garlic capsule (n=5 women);; Placebo Group: Pregnant women consumed placebo capsules containing lactose (n=5 women);; Capsules were ingested ∼45min [mean: 48.0 (9.6) min] prior to a scheduled amniocentesis where AF samples were obtained. | NA | For 4 of 5 pairs of samples, 13 sensory panelists rated AF from women who had consumed garlic supplements as smelling stronger than the AF of women who had consumed a placebo.; Pair 1: P=0.004; Pair 2: NS (women reported consuming garlic in the 24-h prior to amniocentesis); Pair 3: P=0.002; Pair 4: P=0.004; Pair 5: P=0.02.

1 USA, United States of America; NA, not applicable; NS, not significant (p>0.05); RCT, Randomized controlled trial; AF, amniotic fluid;

#### Children’s behavioral responses to odor or flavor

Six studies examined children’s response to a flavor that had been ingested by the mother during pregnancy compared to a control stimuli or control group of infants whose mothers did not ingest (or ingested less) of that flavor; 5 were on infants and one on older children. When testing infant response, four of these studies used an odor stimulus (Schaal, 2000; Faas, 2000 and 2015; Hepper, 1995) and two used a food (Mennella, 2001b; Hepper, 2013).

- In a cohort study by Hepper, 1995, mothers were assigned to one of two groups based on their liking or disliking of garlic. During the last month of pregnancy, mothers in the garlic group consumed a minimum of 4 meals per week containing fresh garlic, while mothers in the non-garlic group never ate meals containing garlic. Between 15 and 28 hours after birth, newborns were presented with two cotton swabs, one on each side of their cot. One swab had garlic paste and the other was unadulterated (neutral stimulus). The order of presentation, left or right side of the cot, was balanced. For 3 minutes, the baby’s head orientation to the odor was recorded. Preference for garlic was calculated based on a percentage of the time spent facing the garlic stimulus compared to the total time spent facing both the garlic and the neutral stimulus. Newborns whose mothers consumed garlic during the last month of pregnancy spent a greater percentage of time facing the garlic odor (60% ± 5.7) compared to newborns whose mothers did not eat garlic during pregnancy (35.6% ± 7.2, p=0.016).
- In a non-randomized control trial by Schaal, 2000, mothers were recruited based on their intake of anise-flavored foods and beverages and assigned to either an anise-consuming group or non-anise-consuming group. In the 15 days prior their due date, mothers in the anise-consuming group were given anise-flavored foods and beverages to consume ad libitum and completed diet records indicating the amount of anise-flavored food and beverages consumed. Mothers in the non-anise-consuming group did not consume anise flavors during this time. Anise-consuming mothers did not consume any anise between delivery and postnatal testing. Infant’s response to anise odor was evaluated within 8 hours from delivery (prior to their first postnatal ingestive experience) and when they were 4 days old. On each day, two tests were conducted. In the first test, infant reactions to two successive odor stimuli (anise and neutral) were recorded. The odor was presented on a cotton swab for 10 seconds, one at a time with at least 60 seconds separating the presentations. In the second test, odors were presented simultaneously, one on either side of infants’ head and the time that the infant oriented its head toward each smell was recorded. Differential reactions to anise odor were observed between newborns whose mothers consumed anise during pregnancy and those whose mothers did not. On the day of birth (within the first 8 hours of life), infants of mothers who did not consume anise had significantly greater frequency and duration of negative facial responses and fewer mouthing actions when presented with an anise odor compared to infants whose mothers consumed anise during pregnancy (p<0.01, p=0.003, p<0.01, respectively). Infants whose mothers consumed anise during pregnancy had a longer duration of mouthing actions and longer relative duration of head orientation when presented with anise odor compared to a neutral odor (p=0.004, p<0.01, respectively). Infants were more likely to orient their heads towards a neutral odor (versus an anise odor) if their mothers did not consume anise during pregnancy (p<0.05); meanwhile infants were more likely to orient their heads towards an anise odor (versus neutral odor) if their mothers consumed anise during pregnancy (p<0.05). Four days following birth, there was no difference between groups in negative facial actions, mouthing, or duration of these responses to anise odor. However, infants of mothers who consumed anise during pregnancy oriented their heads toward the anise odor longer than the control odor (p<0.005). Among infants whose mothers did not consume anise, there was no difference in head orientation between the two stimulants (<0.003).
- In Faas, 2000 and Faas, 2015, each cohort study had two groups of women formed based on maternal consumption of alcohol during pregnancy: frequent drinkers and infrequent drinkers. In Faas, 2000, healthy newborn infants between 24 and 48 hours old were presented with a series of 11 odor stimulants, either primarily ethanol (the dishabituating odor was lemon) or primarily lemon (the dishabituating odor was ethanol). The first and last odors were presented 5 times in a row and the middle (dishabituating) odor was presented once. Each stimuli was presented for 15 seconds with a 45 second break before the next. Overall body activity and head and facial movements were measured. In Faas 2015, the same procedure was employed but infant mean age was 10 days old and facial expressions were clustered into ‘appetitive’ (mouthing/suckling, tongue protrusion and smiling) and ‘aversive’ (gaping, eye blinking and brow wrinkling). (Note: none of these babies had been diagnosed with a genetic or congenital disease among other congenital pathologies, Fetal Alcohol Syndrome or Fetal Alcohol Spectrum Disorders, and all were deemed by doctors to be in optimal health.) Babies responded differently depending on if their mothers were frequent or infrequent alcohol consumers. In Faas, 2000, there was a difference in head and facial movements between the two groups of infants. Babies born to frequent drinkers had significantly more head and facial movements in response to ethanol when it was presented in the first and seventh position (i.e. after presented with the control, dishabituating odor lemon). There were no differences in responses between the two groups when lemon was the primary stimulant, providing evidence that response was specific to ethanol. Faas, 2015 reported that newborns whose mothers were frequent alcohol drinkers during pregnancy, when compared to newborns of infrequent drinkers, exhibited significantly higher frequencies of appetitive facial responses, specifically tongue protrusion, when primarily stimulated with alcohol odor (19.4 ± 2.2 vs. 11.20 ± 1.6, p<0.03). No significant difference was found between groups for overall general activity, duration of appetitive facial reaction, and duration and frequency of aversive facial expressions. Faas, 2015 also found maternal ethanol consumption was positively and significantly correlated with the frequencies of appetitive facial reactions, specifically tongue protrusion, to the primarily alcohol sequence (r=0.52, p<0.05). There was no correlation between maternal alcohol consumption with aversive facial reactions or with any reaction when lemon was the primarily stimulant, providing evidence the response was specific to ethanol and olfactory acuity was similar for the control odor lemon.
- In an RCT by Mennella, 2001b, pregnant women were randomized to one of three groups. In one group, women consumed 300mL of carrot juice 4 days per week for 3 consecutive weeks during the last trimester of pregnancy and consumed water (while avoiding carrots) during the first 2 months of lactation. In a second group, women drank water (and avoided carrots) during the last trimester of pregnancy and drank carrot juice during the first two months of lactation. The control group drank water during both pregnancy and lactation and avoided carrots throughout the study period. On two separate days of testing, approximately four days apart (order counterbalanced), recently weaned infants (mean of 5.7 months of age) were fed cereal prepared with water or with carrot juice. Proportional differences of total cereal intake (carrot/(carrot+plain), frequency of negative facial expressions, length of feedings, and mothers’ ratings of their infants’ enjoyment of the food were assessed to evaluate differences between the groups in the infants’ acceptance of carrot flavor. The groups of infants responded differently to carrot-flavored versus plain cereal. Infants whose mothers drank carrot juice during pregnancy showed fewer negative facial expressions when consuming carrot-flavored cereal compared to plain cereal (4.0 ± 0.8 vs 5.4 ± 0.8, p<0.05) and their mothers rated their enjoyment of carrot-flavored cereal greater than plain cereal (7.5 ± 0.5 vs 5.3 ± 0.6, p<0.05) when compared to the control group; however, there were no significant differences between the groups in the proportional amount of carrot flavored cereal ingested relative to plain cereal or in the proportional length of time spent feeding carrot flavored cereal relative to plain cereal.
- An RCT by Hepper, 2013 examined the effect of maternal consumption of garlic during pregnancy on child’s consumption of a garlic flavored food 8-9 years later. Mothers were selected if they did not dislike garlic, have a strong preference for garlic, cook with or eat garlic more than once per week. Mothers were randomized into one of two groups; the garlic group consumed 3 to 4 meals per week containing fresh garlic (~14 meals) from 35 weeks gestation for 4 weeks and the mothers in the non-garlic group did not eat any meals with garlic during this time. When their children were 8 to 9 years old, the children participated in two test meals at their home, one month apart, at the typical mealtime. Based on a detailed two-week food diary and an interview with mothers regarding their cooking with garlic, purchasing garlic-flavored food or ready meals, there was no significant difference in the foods eaten by the children or postnatal garlic experience between the two groups from the time of maternal garlic intake during pregnancy to testing. Each child was presented with a meal containing a beef burger, beans and two, four oz servings of potato gratin (one with and one without garlic). Parents told children to taste each gratin and then eat as much as they wished. Plates were weighed before and after the test. Acceptability of garlic flavor was determined by proportionally comparing the amount of garlic-flavored potatoes consumed to the total amount of potatoes consumed (garlic and non-garlic-flavored potatoes). They found that children whose mothers consumed garlic during pregnancy consumed a greater percentage of garlic potatoes than children whose mothers did not consume garlic during pregnancy (20.3% vs. 12.7%, p<0.001). Caution is advised when interpreting these findings because this is the only study that measured the impact of maternal diet during pregnancy on a child’s subsequent preferences several years (8-9 years) later.

Table 3 Summary of the evidence-base on the effect of maternal diet during pregnancy on the flavor of amniotic fluid: children’s behavioral response^1^

Reference;; Country;; Study design;; Participants;; Child age at testing | Maternal intervention and child testing and assessment methods | Effect of maternal diet intervention on children’s behavioral response to flavor
Flavor: Alcohol
Faas et al., 2000;; Argentina;; Cohort Study;; 44 mother-infant dyads;; 24- 48 h (mean=35.97 ± 7.51) | Women divided into 2 groups based on self-report of overall alcohol intake;; Type of maternal drinker during pregnancy (measured retrospectively) (n):; [underlined: Frequent drinkers] (n=17 women): ≥1x per wk;; [underlined: Infrequent drinkers] (n=33 women): <4x per mo;; Infants were quasi-randomly assigned by maternal drinking. Infants were presented with ETOH or lemon.odors on swabs placed 2.5 cm from infant’s nostrils for 60 s;; [underlined: Olfactory condition during testing (sequence odor tests)]: Lemon primary odor, ethanol dishabituating odor (Lem–EtOH–Lem), lemon tested during trials 1–5 and 7–11, alcohol during trial 6; Alcohol primary odor, lemon dishabituating odor (EtOH–Lem–EtOH), trials 1–5 and 7–11 tested alcohol, trial 6 lemon. | Overall motor activity: There was no difference in duration of either sequence of alcohol or lemon odors between babies of frequent or infrequent drinkers: NS.; Overall head and facial movements: There were significant differences between babies of frequent and infrequent drinkers when ethanol was the primary stimulant. Babies born to frequent drinkers had significantly more head and facial movements in response to ethanol when it was presented in the first and seventh position compared to babies born to infrequent drinkers: NR; There were no differences between babies of frequent or infrequent drinkers when a non-ethanol stimulus, lemon, was the primary stimulant: NS.
Faas et al., 2015;; Argentina;; Cohort Study;; 43 mother-infants dyads;; 7-14 d (mean 9.9 ± 1.6) | Women divided into 2 groups based on self-report of overall alcohol intake;; Type of maternal drinker during pregnancy (measured retrospectively) (n):; [underlined: Frequent drinkers] (n=16 women): ≥ 4x per mo;; [underlined: Infrequent drinkers] (n=27 women): <4x per mo;; Infants were quasi-randomly assigned by maternal drinking. Infants were presented with ETOH or lemon odors on swabs placed 2.5 cm from infant’s nostrils for 60 s;; [underlined: Olfactory condition during testing (sequence odor tests):] Lemon primary odor, ethanol dishabituating odor sequence (Lem–EtOH– Lem), lemon tested during trials 1–5 and 7–11, alcohol during trial 6; Alcohol primary odor, lemon dishabituating odor (EtOH–Lem–EtOH), trials 1–5 and 7–11 tested alcohol, trial 6 lemon. | Duration of aversive responses: babies born to frequent drinkers exhibited significantly longer episodes of gaping during trial 9 compared to trial 2 (p<0.05); babies of frequent drinkers had longer durations of eye blinking during trials 10-11 compared with age counterparts in trials 5 and 9 of infrequent drinkers (p<0.05).; Frequency of aversive responses: NS.; Duration of appetitive responses: NS.; Frequency of appetitive responses:; Babies born to frequent drinkers had higher frequencies of appetitive responses compared to babies of infrequent drinkers when mainly stimulated with EtOH (19.4 ± 2.2 vs 11.2 ± 1.6, p<0.025); With lemon as the primary stimulant, NS.; Monthly levels of absolute maternal alcohol consumption positively and significantly correlated with the frequencies of appetitive facial reactions to alcohol (p<0.05), but not when lemon was the primary stimulant. No significant correlations were observed when considering duration.
Flavor: Garlic
Hepper et al., 1995;; Northern Ireland;; Cohort Study;; 20 mother-infant dyads;; 15-28 h | Dyads assigned to groups based upon mother’s self-reported liking or disliking garlic:; Garlic Group (n=10): During the last mo of pregnancy, ate ≥4 meals per wk with garlic.; [underlined: Non-garlic Group] (n=10): During the last mo of pregnancy, did not eat any garlic.; 2-choice odor preference test. | Newborns, whose mothers reported they ate garlic during last mo of pregnancy, spent a greater percentage of time orienting to the garlic odor (60% ± 5.7) when compared to newborns whose mothers did not eat garlic during pregnancy (vs 35.6% ± 7.2, p=0.016).
Hepper et al., 2013;; Northern Ireland; RCT (within and between subjects);; 33 mother-infant dyads;; 8-9 y | Mothers randomized at 24-27 wk gestation:; [underlined: Garlic Group (n=16):] At 35 wk gestation, consumed 3-4 meals per wk with garlic for 4 wk (∼14 meals, ranged 12-16 meals);; [underlined: Non-garlic Group (control) (n=17):] At 35 wk gestation, did not eat any meals with garlic for 4 wk;; At 8 y, all mothers reported that they did not cook with garlic, nor purchase garlic flavored food; validated via detailed 2 wk food diaries.; Child (8-9 y) presented with a meal at home containing beef burger, beans and 2, 4 ounce servings of potato gratin (with and without garlic). | There was no significant difference in the foods eaten by the children in each group during the period from prenatal exposure to testing.; % Garlic Flavored Potato Eaten: Significant effect of trial: A higher percentage of garlic flavored potato was eaten on trial 1 (18.4%) than trial 2 (14.6%), p=0.014;; Significant effect of group: Children whose mothers ate garlic during pregnancy ate a greater amount of garlic potato (20.3%) than children whose mothers did not eat garlic during pregnancy (12.7%), p<0.001;; Trial by group effect: Children whose mothers ate garlic during pregnancy consumed significantly more garlic potato in trial 1 (p<0.001) and trial 2 (p=0.038) than children whose mothers did not eat garlic during pregnancy, p=0.026; Children whose mothers ate garlic during pregnancy ate a higher percentage of garlic flavored potato in the trial 1 than trial 2 (24% vs 16%) whereas children whose mothers did not eat garlic, did not.; Total Amount of Potato Consumed: Children whose mothers ate garlic during pregnancy, ate more total gratin than children whose mothers ate garlic during pregnancy in trial 2 (p=0.041) but not in trial 1.; There was a significant correlation between % garlic eaten (p=0 .042) and total amount of potato eaten (p=0.004), in trials 1 and 2.
Flavor: Carrot
Mennella et al., 2001;; US;; RCT (within-and between-subjects);; 29 mother-infant dyads [total from control and pregnancy group only];; ∼5.7 mo | Pregnant women randomized to 1 of 3 groups:; Group 1 (lactation): mothers ingested water (avoided carrots) 4 d/wk during the last trimester of pregnancy and 300 mL of carrot juice 4 d/wk for 3 consecutive w during first 2 mo of lactation; Group 2 (control): mothers ingested water during both last trimester of pregnancy and first 2 mo of lactation and avoided carrots throughout;; Group 3 (pregnancy): mothers ingested carrot juice during last trimester of pregnancy and water (avoided carrots) during first 2 mo of lactation;; Mothers fed infants cereal prepared with carrot juice on 1 d or with water on another d; testing order counter balanced. | Total cereal intake: There was no difference in proportional intake of carrot-flavored cereal between the pregnancy group and the control group: NS.; Length of feedings: There was no difference in length of feed of carrot-flavored cereal between the pregnancy group and the control group: NS.; Frequency of negative facial expressions: There was a significant interaction between group and flavor (p=0.05); Infants whose mothers drank carrot juice during pregnancy exhibited less negative facial responses when fed cereal with carrot compared to plain cereal (4.0 ± 0.8 vs 5.4 ± 0.8, p<0.05); No significant difference between carrot-flavored and plain cereal for infants from control group.; Mothers’ ratings of their infants’ enjoyment of the food: There was a significant interaction between group and flavor (p=0.04); Infants whose mothers drank carrot juice during pregnancy were perceived as enjoying the carrot-flavored cereal over the plain cereal (7.5 ± 0.5 vs 5.3 ± 0.6, p<0.05); For control group, no significant difference in rating of enjoyment between carrot-flavored and plain cereal.
Flavor: Anise
Schaal et al., 2000;; France;; NRCT (within- and between-subjects); ∼24 mother-infant dyads;; Within 8 h (mean age 2.9 ± 1.9 h, range 0.5-8 h) and in a follow-up test conducted on d 4 (mean age 87.3 ± 10.7 h, range 68-110 h) | Mothers recruited during pregnancy and allocated based on self-reported intake of anise flavored foods or drinks.; [underlined: Anise-consuming pregnant mothers] (AC): (n=12 dyads) consumed ~121.1 mg/d (SD=28.7) of anethole, the pure anise flavor, over the 5.6 d (SD=3.5) preceding delivery.; [underlined: Anise-non-consuming pregnant mothers (nAC)]: (n=12 dyads) consumed no foods in which anise was the dominant flavor over the same time period.; [underlined: Oro-facial test:] Neonate presented with 2 successive anethole or control odor for 10 s;; [underlined: Head orientation test]: 2 gauze pads with either anethole dilution or pure paraffin oil presented to each side of the infant’s face. | [underlined: D 1 [AC (n=11) vs nAC (n=12)]:]; Negative facial responses: Frequency of negative facial responses to anise odor between groups: AC 18.2% < nAC 83.3%, p<0.01; Frequency of negative facial responses to anise odor relative to control odor: AC: NS; nAC: 83.3% vs 25.0%, p=NR; Duration of negative facial responses to anise odor relative to control odor: AC: NS; nAC: p<0.003; p-interaction=0.003;; Mouthing actions: Frequency of mouthing actions: AC 90.9% > nAC 33.3%, p<0.01; Duration of mouthing actions to anise relative to control: AC > nAC, p<0.02; AC, p=0.004, nAC, NS; Mouthing actions to control: AC: NS; nAC: NS;; Head orientation: Relative duration of head orientation to anise odor vs control odor: AC: p<0.01; nAC: NS; More AC infants oriented for longer to anise relative to control; nAC showed reverse pattern; p<0.05.; [underlined: D 4 [AC (n=10) vs nAC (n=10) ]:]; Frequency and duration of infants displaying negative facial actions and mouthing in response to anise odor between infants from AC vs nAC mothers: NS;; Relative duration of head orientation to anise relative to control odor: AC: p<0.005; nAC: NS;; Number of newborns orienting head towards anise relative to control odor: AC: anise>control; nAC: anise<control; p<0.003;; Responsiveness of both breast- and bottle-fed infants to anise odor on d 4 did not affect the behavioral outcomes including duration of negative facial response, duration of mouthing and relative duration of head orientation, respectively, p>0.05 in all cases.

1 US, United States, NRCT, non-randomized controlled trial; SD, standard deviation; NR, not reported NS, not significant (p>0.05); AC, anise-consuming pregnant mothers; nAC, anise-non-consuming pregnant mothers;

#### Child overall dietary intake

Four longitudinal cohort studies examined the relationship between maternal diet during pregnancy and infant or child subsequent dietary intake; two of these measured diet quality (Ashman, 2016; Jones, 2015) and two reported dietary patterns (Okubo, 2014; Lioret, 2015). None of these studies measured intake of foods or beverages containing particular flavors.

- Jones, 2015 defined diet quality in terms of a Healthy Plate Variety Score (HPVS) for mothers and their children enrolled in the ALSPAC and EDEN cohorts. The HPVS is an index that assesses dietary variety against five food groups (starchy foods, fruit, vegetable, meat and dairy). Data used to calculate the HPVS was collected from mothers who completed a validated food frequency questionnaire (FFQ) during late pregnancy and FFQs for children reported by parents when children were 2 and 3 years old (ALSPAC and EDEN cohorts) and at 4 years of age (ALSPAC only). Maternal HPVS scores measured during pregnancy were positively associated with higher child HPVS scores at all ages in the ALSPAC (age 2: β=0.22, age 3: β=0.32, age 4: β=0.31, all p<0.05) and EDEN (age 2: β=0.25, age 3: β=0.25, both p<0.05) cohorts were positively associated with higher child HPVS scores at all ages.
- Ashman, 2016 explored whether intake of a wider variety of fruits and vegetables and overall higher diet quality during pregnancy was correlated with acceptance of a greater variety of these foods and better diet quality in children. Authors defined diet quality, fruit variety, and vegetable variety using the Australian Recommended Food Score for mothers, and the Australian Child and Adolescent Recommended Food Score for children. Prenatal maternal dietary data were collected at 19 and 36 weeks gestation using a validated 74-item Dietary Questionnaire for Epidemiology Studies FFQ and child and maternal postnatal dietary intake information was collected from mothers when children were 2 and 3 years of age using a validated 19-item Australian Child and Adolescent Eating Survey FFQ. Analysis revealed that maternal diet during pregnancy and child’s diet at 2 and 3 years were correlated for overall diet quality (r=0.66, p< 0.001); fruit variety (r=0.46, p< 0.001) and vegetable variety (r=0.52, p< 0.001). Only a small subset of the total cohort (52 of 180 recruited) were included in this analysis (only seven mother-child dyads completed FFQs at all time points). Further, mediation analysis showed the effect of maternal diet during pregnancy on child’s diet, specifically for fruits, is mediated significantly through the maternal post-natal diet.
- Okubo, 2014 examined the relationship between dietary patterns among Japanese infants with maternal socioeconomic, diet, and lifestyle characteristics. Authors defined dietary patterns in Japanese pregnant women and infants 16 to 24 months of age using diet history questionnaires completed by mothers at 5 to 39 weeks gestation and 18 months post-partum. Cluster analysis was used to identify three maternal diet clusters and two infant diet clusters. Three maternal diet clusters were identified: “meat and eggs”, “wheat products” and “rice, fish and vegetables”, and two infant dietary patterns: “fruits, 38 vegetables and high-protein foods” and “confectionaries and sweetened beverages”. After adjustment for all other predictors, maternal dietary patterns were independently associated with dietary patterns of infants. Infants in the “confectionaries and sweetened beverages” pattern had a higher proportion of mothers in the “wheat products” pattern and a lower proportion in the “rice, fish and vegetables” pattern (p<0.001). Infants in the “fruits, vegetables and high-protein foods” pattern had a higher proportion of mothers in the “rice, fish and vegetables” pattern and a lower proportion in the “wheat products” pattern (p<0.001).
- Lioret, 2015 examined whether the relationship between maternal education and infants’ diet is mediated by mothers’ diet. Authors retrospectively collected maternal dietary information from pregnancy through three months postpartum using a validated FFQ. Four maternal dietary patterns, accounting for 24% of variation, were identified through principal component analysis (PCA): “fruits and vegetables”, “high-energy snack and processed foods”, “high-fat foods”, and “cereals and sweet foods”. When children were nine months old, trained nutritionists assessed infant’s diet through telephone administered multi-pass 24-hour recalls with parents on two or three non-consecutive days. PCA was used to identify three child dietary patterns in 9-month olds accounting for 25% of variation: “balanced weaning diet”, “formula”, and “high-energy snack and processed foods”; and four dietary patterns in mothers: “fruits and vegetables”, “high-energy snack and processed foods”, “high-fat foods”, and “cereals and sweet foods”. After accounting for education level, mothers’ with higher adherence to a “fruits and vegetables” pattern predicted higher children scores in the “balanced weaning diet” pattern (0.16, 95% CI [0.07, 0.24], p<0.05) and lower scores in the “formula pattern” (−0.12, 95% CI [−0.20, −0.05], p<0.05). There were no other significant relationships between maternal diet and infant diet patterns.

Table 4 Summary of the evidence-base on the relationship between maternal dietary intake during pregnancy and children’s dietary intake^1^

Reference;; Study design;; Country;; Participants;; Child age at assessment | Maternal and child overall dietary intake assessment methods | Relationship between maternal dietary intake and child dietary intake
Jones et al., 2015;; Longitudinal Cohort Study; [underlined: ALSPAC]: British Avon Longitudinal Study of Parents and Children cohort;; England;; 8,308 mother-infant dyads;; 2, 3, and 4 y;; [underlined: EDEN]: French Etude des Déterminants pre et postnatals de la santé et du développement de L’Enfant cohort;; France;; 1,341 mother-infant dyads;; 2 and 3 y | Mothers’ diets during late pregnancy assessed by self-reported validated FFQ’s; FFQ data used to calculate Healthy Plate Variety Score (HPVS): index that assessed maternal dietary variety against 5 food groups (starchy foods, fruit, vegetable, meat and fish, dairy). Final HPVS is sum of 5 food groups scores (potential of 5);; Parents completed child’s FFQ; ALSPAC (31-33 items) and EDEN (19-20 items derived from mother’s validated FFQ); FFQ used to calculate child HPVS;; Maternal post-natal diet not controlled for in analysis. | Maternal HPVS scores measured during pregnancy were positively associated with higher child HPVS scores at all ages in the ALSPAC (age 2: β=0.22, age 3: β=0.32, age 4: β=0.31, all p<0.05) and EDEN (age 2: β=0.25, age 3: β=0.25, both p<0.05) cohorts.
Ashman et al., 2016;; Australia;; Longitudinal Cohort Study;; Women and Their Children’s Health (WATCH) study;; 52 mother-infants dyads;; 2 and 3 y | Mothers completed a validated FFQ at 19 and 36 wk gestation; an average of scores was used in analysis. Australian Recommended Food Score used to calculate maternal diet quality scores for total diet quality, vegetable variety and fruit variety;; Mothers completed validated toddler FFQ. The Australian Child and Adolescent Recommended Food Score used to calculate diet quality and variety scores;; Child diet quality scores were calculated for total diet quality, vegetable variety and fruit variety. | Maternal pregnancy diet and child diet at 2-3 y were correlated: Diet quality: (r=0.66, p< 0.001); Fruit variety: (r=0.46, p< 0.001); Vegetable variety (r=0.52, p< 0.001); Maternal post-natal diet (2-3 y) and child diet at 2-3 y were correlated: Diet quality: (r=0.65, p< 0.001); Fruit variety: (r=0.59, p< 0.001); Vegetable variety: (r=0.61, p< 0.001);; Mediation Analysis: Diet quality- Effect of maternal pregnancy diet on the total quality of the child diet: Direct effect: NS; Indirect effect: NS; Total effect: 0.64 (95%CI: 0.28, 0.99);; Fruit variety- Maternal pregnancy diet had an indirect effect on child fruit variety mediated through maternal post-natal diet: Direct effect: NS; Indirect effect: 0.32 (95%CI: 0.01, 0.64); Total effect: 0.46 (95%CI: 0.10, 0.83);; Vegetable variety- Maternal pregnancy diet had a total effect on child diet: Direct effect: NS; Indirect effect: NS; Total effect: 0.39 (95%CI: 0.04, 0.74).
Okubo et al., 2014;; Japan;; Longitudinal cohort study;; The Osaka Maternal and Child Health Study;; 758 mother-infant dyads16-24 mos | Mothers reported dietary intake during previous mo using self-administered diet history questionnaire;; Dietary patterns of mothers were collected at baseline during 5-39 wk gestation and grouped into 3 clusters using k-means cluster analysis;; Dietary patterns of infants based on maternal report of frequency of infants weekly consumption (portion sizes not specified) of 15 food groups during the previous mo were grouped into 2 clusters using k-means cluster analysis. | Infants whose mothers had a “rice, fish and vegetables” dietary pattern (OR: 0.56, 95% CI: 0.36, 0.87) were less likely to belong to the “confectionaries and sweetened beverages” pattern than the “fruits, vegetables and high-protein foods” pattern.; Infants whose mothers had an educational level more than 13 y (OR: 0.65, 95% CI: 0.44, 0.95) and the “rice, fish and vegetables” dietary pattern (OR: 0.56, 95% CI: 0.36, 0.87) were less likely to belong to the “confectionaries and sweetened beverages” pattern compared to the “fruits, vegetables and high-protein foods” pattern.; Infants whose mothers had a higher number of infant’s older siblings (OR: 1.79, 95% CI: 1.24, 2.58) and the “wheat product” dietary pattern (OR: 1.51, 95% CI: 1.04, 2.21) were more likely to belong to the “confectionaries and sweetened beverages” than the “fruits, vegetables and high-protein foods” pattern.; Infants whose mothers had a “wheat product dietary” pattern (OR: 1.51, 95% CI: 1.04, 2.21) were more likely to belong to “confectionaries and sweetened beverages” pattern than “fruits, vegetables and high-protein foods pattern”.; Infants in the “fruits, vegetables and high-protein foods” pattern had a higher proportion of mothers in the “rice, fish and vegetables” pattern and a lower proportion in the “wheat products” pattern, with a relatively high intake of bread, confectionaries and soft drinks (p<0.001). Infants in the “confectionaries and sweetened beverages” pattern had a higher proportion of mothers in the “wheat products” pattern and a lower proportion in the “rice, fish and vegetables” pattern (p<0.001).
Lioret et al., 2015;; Australia;; Longitudinal cohort study;; 421 mother-infant dyads;; ∼9 mos | Mothers completed a validated 98 item Melbourne FFQ when infants were 3 mo (retrospectively assessed over the past 12 mo);; 4 dietary patterns (accounting for 24% of variation) were identified through principal component analysis;; Infant nutrition assessed through multi-pass 24 h recalls on 2 or 3 non-consecutive ds; Nutrient intakes were evaluated using 2007 AUSNUT Database;; 3 dietary patterns identified through principal component analysis. | After accounting for education level, higher adherence of mothers to a “fruits and vegetables” pattern predicted higher scores for their children in a “balanced weaning diet” pattern (0.16,95% CI: 0.07, 0.24, p<0.05), predicted lower scores in “formula pattern” (−0.12, 95% CI: −0.20, −0.05, p<0.05), and was not associated with the children’s “high energy snack and processed foods” pattern.; Mothers’ “high energy snack and processed foods” pattern predicted higher scores for children in the “formula” pattern (0.09, 95% CI: 0, 0.19, p<0.05), but there was no association with the children’s “balanced weaning diet” or “high energy snack and processed foods” patterns.; There was no association between a mothers’ adherence to a “high-fat foods” pattern with children’s dietary patterns.

1 NS, not significant (p>0.05); NR, not reported;

#### Limitations

The NEL Bias Assessment Tool was used to evaluate the internal validity of each included study.

Limitations of the evidence examining flavor transfer via sensory panel or infant response: (7 studies: 3 RCTs, 1NRCT, 3 cohorts)

- Mennella 1995 (RCT) – Sensory analysis
  ○ Mothers assigned to ingest either placebo or garlic capsule; there was no indication of randomization.
  ○ Pairs of samples randomized when presented to sensory panelists; cannot determine how randomization sequence was generated.
- Mennella 2001b (RCT) – Infant response
  ○ Pregnant women randomly assigned to 1 of 3 groups; cannot determine how randomization sequence was generated.
  ○ Mothers not blinded to conditions (consumed carrot juice or water; fed infants carrot-flavored cereal and plain cereal; reported perceived liking of carrot-flavored cereal and plain cereal), but were unaware of the hypothesis of the study.
- Hepper 2013 (RCT) – Child response
  ○ Mothers randomly assigned to 1 of 2 groups; Cannot determine how randomization sequence was generated.
  ○ Mothers not blinded to conditions; Mothers prepared and served the test foods to their children during outcome assessment; Taste and smell of test foods differed; likely but unclear that children were unaware of hypothesis.
- Schaal 2000 (NRCT) – Infant response
  ○ Non-randomized; participants recruited based on habitual intake of anise-flavored foods and drinks.
  ○ The following potential confounders were not assessed: SES, race/ethnicity, pre-pregnancy BMI, or smoking status.
- Hepper 1995 (Cohort) – Infant response
  ○ Not-randomized; women were assigned to a group based on garlic liking or disliking.
  ○ Unclear if the outcome assessors were blinded.
  ○ Investigators did not control for potential confounders including: maternal diet outside of study foods, tobacco and drug use, race/ethnicity, SES, household composition, or parity.
- Faas 2000 (Cohort) – Infant response
  ○ Non-random assignment to groups based on maternal alcohol consumption.
  ○ Outcome assessor was aware of stimulant but used coding and computer-based program for assessment.
  ○ The following potential confounders were not assessed: SES, household composition, race/ethnicity, tobacco, and drug use.
- Faas 2015 (Cohort) – Infant response
  ○ Non-random assignment to groups based on maternal alcohol consumption.
  ○ The following potential confounders were not assessed: SES, household composition, race/ethnicity, tobacco, and drug use.

There were several limitations within the 4 cohort studies assessing the relationship between maternal diet during pregnancy only and overall dietary intake of the child: (4 studies)

- A women’s diet is relatively consistent before, during, and after pregnancy; therefore, is it difficult to isolate the impact of a women’s diet during pregnancy alone on child dietary intake.
- Self-reported data can include bias, or involve greater measurement error than other forms of data collection.
- Mothers reported both maternal and child dietary intake which is likely to inflate the association between the two reports.
- Dietary intake measures in very young children are a reflection of what they are fed rather than a valid measure of their food acceptability.
- No direct measure of infant/child food acceptability
- Potential confounders highlighted in the Analytic Framework were not consistently accounted for across studies.

### Evidence synthesis

To address the systematic review question about the relationship between maternal diet during pregnancy, amniotic fluid flavor, and infant response, 11 studies were reviewed. One study used a sensory panel to detect the presence of a flavor in amniotic fluid after maternal ingestion; six studies measured infant response to flavors that had been ingested by their mother during pregnancy; and four studies analyzed the relationship between maternal diet during pregnancy and the subsequent diet of the child. All studies reported an indication that maternal diet during pregnancy impacted either the flavor of amniotic fluid, infant response, or child’s diet.

Although the number of studies and the number of flavors investigated are limited, evidence was consistent in showing that the flavor volatiles (alcohol, anise (anethole), carrot, and garlic), consumed by the mother in these studies, transfer from the maternal diet to amniotic fluid and have an impact on infant and child response during subsequent presentation to the odor or flavor. One study that assessed flavor transfer from maternal ingestion to amniotic fluid found that garlic odors were detectable in amniotic fluid 45 minutes after maternal ingestion of garlic tablets via an adult sensory panel. Four studies found a differential response to an odor stimulant (garlic, ethanol, or anise) by infants within the first two weeks of life whose mothers consumed beverages or foods containing the odor volatiles during pregnancy using a range of body and facial response measures, including head orientation, facial responses, and mouthing actions (Hepper, 1995; Faas, 2000 and 2015; Schaal, 2000, respectively). In infants at the time of weaning, Mennella (2001b) found that infants responded differently to carrot-flavored versus unflavored cereal if their mother’s had consumed carrot juice prenatally when compared to infants whose mothers did not consume carrot juice prenatally. Hepper (2013) showed that maternal diet during pregnancy may have a lasting effect into childhood. Eight- and nine-year old children of mothers who consumed garlic during pregnancy ate more garlic-flavored potatoes at a test meal than children whose mothers did not consume garlic during pregnancy.

Additionally, for one commonly consumed flavor (garlic), the convergence of findings from three separate studies revealed: 1) garlic ingestion by pregnant mothers alters the sensory properties of amniotic fluid; 2) newborns respond differently to the odor of garlic if their mothers ate garlic during late pregnancy; and 3) prenatal experiences with garlic resulted in greater child acceptance of garlic flavored foods eight to nine years after mothers diet during pregnancy was the experimentally manipulated.

This research provides evidence that some flavors from the maternal diet during pregnancy transfer to and flavor amniotic fluid; and, the flavors within amniotic fluid are detected by the fetus and recognized after birth as evidenced by differential behavior response. To date, the flavors tested, which are complex and contain many volatiles, include alcohol, anise, carrot, and garlic, and the extent to which other flavors are transferred is unknown. More research is needed to determine the extent of transfer of other volatiles from the maternal diet to amniotic fluid.

A conclusion could not be drawn to address the relationship between maternal diet during pregnancy alone and child’s dietary intake. While four longitudinal studies showed an association between maternal diet during pregnancy and child’s diet quality (Ashman, 2016; Jones, 2015) or dietary patterns (Lioret, 2015; Okubo, 2014), these studies need to be interpreted with caution. A woman’s diet is relatively consistent before, during, and after pregnancy; therefore, is it difficult to isolate the impact of a women’s diet during pregnancy alone on child dietary intake. Dietary intake in very young children is primarily a measure of what they are fed, not a measure of food acceptability and therefore there was no direct measure of food acceptability. Other limitations included maternal report of both maternal and child’s diet without any direct assessment of child acceptance, heterogeneity of diet assessment methods, and that key potential confounders were not accounted for consistently across studies.

#### Assessment of the body of evidence

- Internal validity (determined with NEL Bias Assessment Tool): Internal validity was strong for the controlled trials, and weaker for cohort studies due to incomplete assessment of confounders and maternal report of both exposure and outcome data.
- Adequacy: There were 11 studies in total, 4 controlled trials and 7 cohort studies, from 8 distinct research groups. Sample sizes varied based on the study design. Controlled trials included 20 to 44 mothers or dyads, while cohort studies ranged from 52 to 8,308 mother-infant dyads. Power calculations were generally not reported.
- Consistency: All studies showed a significant impact of maternal diet during pregnancy on an infant/child’s response to an odor or flavor as well as on child’s dietary intake or dietary patterns. However, consistency is limited due to heterogeneity of exposure flavors and outcome measures.
- Impact: This evidence highlights the importance of maternal diet on infant’s response to flavors; however, the body of evidence is limited to a small number of flavors, and it is unknown what component(s) of those flavor compounds are transferred and detected by the fetus.
- Generalizability: This evidence should be expanded to more diverse populations; however, the physiological mechanism of flavor transfer from maternal diet through amniotic fluid and infant response should be generalizable to all demographics. Little is known about how different flavor components (volatiles) transfer from maternal diet to the amniotic fluid and are detected by the infant (e.g., molecular weight and size, polarity, etc.). This research focused on four specific flavors and, therefore, should not be generalized to all flavors.

### Included articles

1 Ashman AM, Collins CE, Hure AJ, Jensen M, Oldmeadow C. Maternal diet during early childhood, but not pregnancy, predicts diet quality and fruit vegetable acceptance in offspring. Matern Child Nutr. 2016 Jul;12(3):579–90. PMID:25294406. https://www.ncbi.nlm.gov/pubmed/25294406 25294406
2 Faas, AE, March, SM, Moya, PR, Molina, JC. Alcohol odor elicits appetitive facial expressions in human neonates prenatally exposed to the drug. Physiol Behav.2015;148: 78–86. PMID:25707382. https://www.ncbi.nlm.nih.gov/pubmed/25707382 25707382
3 Faas, AE, Sponton, ED, Moya, PR, Molina, JC. Differential responsiveness to alcohol odor in human neonates: effects of maternal consumption during gestation. Alcohol. 2000 Aug;22(1):7–17.. PMID:11109023. https://www.ncbi.nlm.nih.gov/pubmed/11109023 (https://www.ncbi.nlm.nih.gov/pubmed/25707382) 11109023
4 Hepper, PG. Human fetal ‘‘olfactory’’ learning. International Journal of Prenatal and Perinatal Psychology & Medicine, 1995; 7, 147–151.
5 Hepper PG, Wells DL, Dornan JC, Lynch C. Long-term flavor recognition in humans with prenatal garlic experience. Dev Psychobiol. 2013 Jul;55(5):568–74. Epub 2012 Jul 2. PubMed PMID: 22753112. http://www.ncbi.nlm.nih.gov/pubmed/?term=22753112 22753112
6 Jones L, Moschonis G, Oliveira A, de Lauzon-Guillain B, Manios Y, Xepapadaki P, Lopes C, Moreira P, Charles MA, Emmett P. The influence of early feeding practices on healthy diet variety score among pre-school children in four European birth cohorts. Public Health Nutr. 2015;18(10):1774–84. PMID:25409628. https://www.ncbi.nlm.nih.gov/pubmed/25409628 25409628
7 Lioret S, Cameron AJ, McNaughton SA, Crawford D, Spence AC, Hesketh K, Campbell KJ. Association between maternal education and diet of children at 9 months is partially explained by mothers’ diet. Matern Child Nutr. 2015;11(4):936–47. PMID:23560743. https://www.ncbi.nlm.nih.gov/pubmed/2356074 23560743
8 Mennella JA, Jagnow CP, Beauchamp GK. Prenatal and postnatal flavor learning by human infants. Pediatrics. 2001;107(6):E88. PMID:11389286. http://www.ncbi.nlm.nih.gov/pubmed/11389286 11389286
9 Mennella JA, Johnson A, Beauchamp, GK. Garlic ingestion by pregnant women alters the odor of amniotic fluid. Chem. Senses. 1995;20,207–209. https://www.ncbi.nlm.nih.gov/pubmed/?term=7583013 7583013
10 Okubo H, Miyake Y, Sasaki S, Tanaka K, Murakami K, Hirota Y. Dietary patterns in infancy and their associations with maternal socio-economic and lifestyle factors among 758 Japanese mother-child pairs: the Osaka Maternal and Child Health Study. Matern Child Nutr. 2014;10(2):213–25. PMID:22462517. https://www.ncbi.nlm.nih.gov/pubmed/22462517 22462517
11 Schaal B, Marlier L, Soussignan R. Human foetuses learn odours from their pregnant mother’s diet. Chem Senses. 2000 Dec;25(6):729–37. PubMed PMID:11114151. https://www.ncbi.nlm.nih.gov/pubmed/?term=11114151 11114151