# Project methods

Herein, we present an overview of the methods specific to the rapid reviews and evidence scans to inform the Thrifty Food Plan, 2021, including all deviations or modifications made to NESR standard systematic review methods (https://nesr.usda.gov/nutrition-evidence-systematic-review-methodology).

Four rapid reviews were conducted to support the Thrifty Food Plan, 2021 project. A rapid review is a type of evidence synthesis project in which the methods of a systematic review are modified or streamlined to produce results in a timely and cost-effective manner.^a^ Although systematic review methods are modified to expedite the process, a rapid review is still characterized by rigorous, transparent, and reproducible methods. The methodology utilized for each rapid review is informed by and tailored to the scientific question being answered and the specific needs of the requester (e.g., timeline, purpose, scope, circumstances, and stakeholders) while retaining scientific integrity. Best practices and recommendations from other research and health organizations, including the World Health Organization, Cochrane, the Agency for Healthcare Research and Quality, and the Center for Evidence-Based Medicine at the University of Oxford, inform the process by which NESR conducts rapid reviews.^a,b,c,d^

a Tricco AC, Langlois EV, Straus SE, editors. Rapid reviews to strengthen health policy and systems: a practical guide. Geneva: World Health Organization. 2017. https://apps.who.int/iris/handle/10665/258698.

b Garritty C, Gartlehner G, Nussbaumer-Streit B, King VJ, Hamel C, Kamel C, Affengruber L, Stevens A. Cochrane Rapid Reviews Methods Group offers evidence-informed guidance to conduct rapid reviews. J Clin Epi. 2020;130:13–22.

c Hartling L, Guise J-M, Kato E, Anderson J, Aronson N, Belinson S, Berliner E, Dryden D, Featherstone R, Foisy M, Mitchell M, Motu’apuaka M, Noorani H, Paynter R, Robinson KA, Schoelles K, Umscheid CA, Whitlock E. EPC Methods: An Exploration of Methods and Context for the Production of Rapid Reviews. Research White Paper. (Prepared by the Scientific Resource Center under Contract No. 290-2012-00004-C.) AHRQ Publication No. 15-EHC008-EF. Rockville, MD: Agency for Healthcare Research and Quality; February 2015. www.effectivehealthcare.ahrq.gov/reports/final.cfm.

d Plüddemann A, Aronson JK, Onakpoya I, Heneghan C, Mahtani KR. Redefining rapid reviews: a flexible framework for restricted systematic reviews. BMJ Evid Based Med. 2018;23(6):201–203. doi:10.1136/bmjebm-2018-110990

Three evidence scans were conducted for the Thrifty Food Plan, 2021 project. A NESR evidence scan is a systematic and exploratory process used to provide objective data on the volume and characteristics of research available on a topic or question. Evidence scans involve the following: development/refinement of the research question, evidence scan protocol development, search for and screen studies, minimal data extraction, and summarizing study characteristics. NESR evidence scans do not include: 1) data extraction of study results, 2) assessment of risk of bias, 3) synthesis of the evidence, 4) development of conclusion statements, or 5) grading the strength of the evidence. Two of the evidence scans were conducted to inform protocol development for 2 of the rapid reviews and 1 to describe the volume and characteristics of studies available on a topic of interest related to the Thrifty Food Plan, 2021.

The process by which NESR developed rigorous a priori methods and protocols for this series of rapid reviews and evidence scans, and the type and extent of modifications made to NESR systematic review methods, are transparently documented and described below. Any additional methodological modifications made for individual reviews are acknowledged under their respective sections of the report. The summary statements in this series of rapid reviews should be interpreted in light of these modifications, and noted limitations.

## Develop a protocol

For each rapid review question or evidence scan, the NESR team collaborated with the NEAT team to develop a protocol. A rapid review or evidence scan protocol has the same elements as a systematic review protocol, and is a plan for how a specific review will be conducted. The protocol includes:

- Analytic framework
- Literature search and screening plan
  ○ Inclusion and exclusion criteria
  ○ Electronic databases and search terms
- Literature search and screening results
  ○ Flow chart of literature search and screening results
  ○ List of included articles
  ○ List of excluded articles, with rationale

The protocols were established before any evidence was reviewed and synthesized. This allowed the establishment of protocols that would capture the most appropriate, relevant, and direct body of evidence to answer each question. Any revisions to protocols that occurred after the start of a specific review were documented and are noted in the below report.

A description of NESR’s methodology for developing an analytic framework is below. NESR’s methodology for developing inclusion and exclusion criteria and the search strategy, as well as processes related to screening and selecting studies for inclusion in a review, is described, below, in “Search for, screen, and select literature.”

### Develop analytic frameworks

Analytic frameworks were developed for each rapid review and evidence scan question. An analytic framework defines the core elements of the review question, includes definitions for key terms, identifies key confounders and other factors that could affect the relationships examined, and helps to ensure that important contributing elements in the causal chain will be examined and evaluated. The analytic framework serves as the foundation for the rest of the review process, and informs the inclusion/exclusion criteria and literature search strategy, data extraction and risk of bias assessments, and the strategy for synthesizing the evidence to develop summary statements.

A standard framework, called the PICO framework, was used to define core elements of each review question. The elements of the PICO framework are the Population (for both the intervention/exposure and for the outcome), Intervention and/or exposure, Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcomes. Key terms, key confounders, and other factors to be considered (i.e., mediators, moderators, covariates) were also identified and included in the analytic framework where appropriate. Key confounders are considered during review and evaluation of the evidence, particularly during risk of bias assessment (see “Assess risk of bias,” below) and evidence synthesis.

### Search for, screen, and select literature

Systematic searching, screening, and selecting the scientific literature is a process through which NESR sought to identify the most complete and relevant body of evidence to answer the rapid review and evidence scan questions. The process started with defining inclusion and exclusion criteria a priori, followed by developing and implementing literature search strategies, and finally screening and identifying search results. The entire process was documented, including a complete list of articles that met criteria for inclusion in each rapid review or scan, and a list of excluded articles, with the rationale for exclusion.

#### Define inclusion and exclusion criteria

Inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in each review. These criteria were developed before any studies were reviewed to guide selection of the most relevant and appropriate body of evidence for each review question. Additionally, these criteria were framed to increase the utility for Thrifty Food Plan, 2021. To minimize bias, revisions to the criteria after studies had been reviewed were discouraged. Any revisions to the criteria that occurred after studies were reviewed are documented in the individual reviews in this report.

NESR analysts worked jointly with the NEAT staff to establish inclusion and exclusion criteria that were tailored to the specific review question addressed.

Criteria were established for a number of study characteristics, and although criteria were tailored to the unique characteristics of each review question being addressed, NESR also applied several standard criteria across this project. Deviations from the standard criteria that were appropriate for individual questions are documented in the report section for that question. The following is a description of criteria applied across this project:

- Study Design: Any study design that was not a narrative review, systematic review, or meta-analysis was included.
- Language: Articles published in English were included. Articles published in languages other than English were excluded.
- Publication status: Articles that had been peer-reviewed or grey literature in the form of reports that had not been peer reviewed, but were available from government and nongovernmental organizations were included.
- Publication date and data years: Studies published between January 2008 to present and had data collected inclusive of 2008 (e.g., 2000-2012; 2008-2009) were included. Articles published before January 2008 or articles with data collected prior to 2008 (e.g., 2000-2007; 1999-2005), regardless of publication date, were excluded. NESR and NEAT chose 2008 because of national and policy-relevant changes. The Food, Conservation, Energy Act of 2008 (which was a continuation of the 2002 Farm Bill that restored food and nutrition program eligibility of legal immigrants) increased benefits and eligibility for the Food Stamp Program (FSP), and increased funding and eligibility for free/reduced-price lunch and other food-assistance programs. In 2009, the FSP was renamed to the Supplemental Nutrition Assistance Program (SNAP). Therefore, the NEAT and NESR teams determined that the preponderance of the evidence most relevant to factors such as income, price, cost and Federal assistance would be captured by searching literature starting in the year 2008. For consistency, a starting date of 2008 was selected for multiple questions addressed in this project.
- Country: Studies were only included if they were conducted in the U.S.
- Study participants: Human participants/populations were included and all non-human participants (i.e., animal studies, in-vitro) were excluded.

### Developing and implementing the literature search strategy

Once the inclusion and exclusion criteria were set, the NESR librarian used the analytic framework and inclusion/exclusion criteria to guide development of a comprehensive literature search strategy. The literature search strategy included selecting and using the appropriate bibliographic databases (e.g., PubMed/MEDLINE, Business Source Premier, Web of Science), identifying search terms appropriate for the databases being searched, and employing search refinements, such as search filters. The librarian worked in collaboration with NESR staff to construct a preliminary search strategy using PubMed operators and search terms. This was used to conduct a test search, preview the results, and correct any syntax, spelling, or grammatical errors. The search strategy underwent multiple revisions to refine and adjust the search before it was finalized for use. The search strategies are included in this report for all rapid reviews completed. Unlike NESR systematic reviews, the search strategies for these rapid reviews were not peer-reviewed by a 2^nd^ librarian as a time-savings concession.

Literature search strategies for rapid reviews and evidence scans are developed with the same methods and were specific to each question. Evidence scans generally have broader questions and therefore broader search strategies. For the 2 questions where an evidence scan was conducted to inform the rapid review, the evidence scan confirmed that the scope of the question was adequate and the same search that was run for the evidence scan was used for the rapid review.

#### Identify bibliographic databases

The NESR librarian selected electronic bibliographic databases based on the systematic review topic. A team of staff at Economic Research Service consulted on appropriate databases on the topic of income and prices of food/food baskets, including a grey literature approach. This insight was applied across the project for additional questions and topics. PubMed/MEDLINE, Business Source Premier, Web of Science were the primary databases used for the project, and AgEcon, Google Scholar, and Google were used for the grey literature search.

#### Develop search terms and apply search filters

NESR analysts helped identify initial key terms and/or relevant articles to ensure that the NESR librarian had an understanding of the scope and intent of the systematic review question. The librarian was responsible for checking each bibliographic database’s search features to ensure that all related search terms for a particular review question were captured.

For this project, filters that were used include: English language, human studies, date, study design, and publication type (e.g., to filter out news, editorials, and comments).

#### Implement the literature search strategy

After finalizing the search strategies for each of the databases, the NESR librarian began the process of conducting all of the electronic searches. When searching multiple databases, overlap in the literature identified is common; the librarian electronically eliminated duplicate records at the search level using a citation management program (EndNote X9; Clarivate Analytics, Philadelphia, PA). Additional duplicates were identified by NESR analysts during the course of screening, and were removed from the search results. In addition, because some journals publish articles electronically, in advance of the print journal, the search captured these articles, and they were eligible for inclusion in the review, even though there was a possibility that they would be assigned an official publication date outside the window of the search date range.

In addition to the peer-reviewed primary studies retrieved from major biomedical databases, a complementary search of the grey literature was conducted in order to ensure that published and unpublished studies and reports relevant to the research questions were included in the search process. The grey literature search strategy included a broad search using similar key terms. More information about the sources selected and the searches conducted are included in each individual review. To determine which results to select for screening, the librarian limited the export of results to n pages where n= [pages with relevant results]+1. Relevant results were determined by the result’s title.

Once the electronic searches were done, the librarian documented the total number of unique articles identified, indicating how many were identified from each database searched. This documentation included the total, raw search results, as well as search results after removal of duplicates.

## Screen and select studies

The screening of search results was facilitated by the use of a web-based tool (i.e., DistillerSR) and screening forms that were developed based on the inclusion and exclusion criteria identified for each systemic review. For the rapid reviews and evidence scan included in this project, generally, 1 NESR analyst screened 100% of records and a 2^nd^ analyst screened 20% of records. In some cases, 1 analyst screened 100% of records, and a 2^nd^ analyst verified the decisions. A re-ranking function was utilized in DistillerSR to reorder the most relevant articles first. The goal of screening was to review the search results and exclude those that did not meet the inclusion criteria. Screening was generally completed at 3 levels. The first level of screening was completed using only the title of each article. If an article was not excluded at this level, it moved forward to the 2^nd^ level, where the abstract was screened. Finally, if an article passed the first 2 levels, it moved to the third level, where the full text of the article was screened. In this project, title and abstract screening were sometimes combined into 1 level. Any disagreements between analysts were reconciled between the 2 screenings. If necessary, a third analyst was consulted to resolve differences. These screening distinctions are noted in each individual review section of this report.

If multiple articles were identified that presented effectively the same data from the same study or cohort, the article that most directly addressed the review question was included to avoid duplicative data. However, if the articles addressed unique data related to the question, or were needed to comprehensively present information from a study or cohort, then all articles were included. Included articles from the same study or cohort were noted in the review, and this was taken in consideration when weighing the amount of evidence to answer a question.

Screening for rapid reviews and evidence scans for this project used consistent methods in order to ensure that the screening completed for the scan could also be applied to the rapid review. In cases where the focus of the rapid review question was narrowed after the evidence scan, additional screening was completed to exclude any studies that would no longer be included when the rapid review protocol elements were applied to the body of evidence.

### Conduct manual searches

NESR analysts also completed manual searches on the rapid reviews in this project. Manual searching was done to find articles not identified through the electronic database search. This was typically due to inadequate indexing or filtering limitations of a database. The primary approach used for the manual search was hand searching, in which an analyst systematically searched the reference sections of included articles and related systematic reviews and meta-analyses. Potential articles also may have been suggested by others engaged in the process. Any identified citations were then screened for inclusion or exclusion as outlined above.

### Document the search results

After the electronic and manual searches were completed, NESR analysts and the librarian documented the literature search and screening results by compiling lists of the included and excluded citations, along with the rationale for exclusion at the full-text level.

## Extract data and assess risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer a rapid review question or inform an evidence scan. For rapid reviews, NESR analysts assessed the risk of bias for each included article. Risk of bias assessments were not completed for evidence scans. The extracted data and assessment of risk of bias were used to populate evidence tables to present the key data used in the synthesis for the review.

### Extract data

To expedite data extraction, only the most essential data for answering the question were extracted. For the rapid reviews, information on the following elements were generally extracted: Study design, analytic N, geographic location and/or population description, intervention/exposure, outcomes, results, key confounders, and data source. For evidence scans, only minimal descriptive information was extracted, and no results were included.

Once the types of data to be extracted were determined, a data extraction form was developed and used to facilitate accurate, consistent, and efficient data extraction. This form ensured that the same information from each article was formatted consistently, which made the content easier to compare and contrast during synthesis. NESR analysts used DistillerSR to extract data.

One NESR analyst extracted data from each included article using the data extraction form. In some cases, the required data were not reported in the article. In those situations, the data were recorded as “not reported.” However, if the required data were reported in an article’s protocol or related publication, the analyst extracted the data and noted the publication from which it was extracted. Next, a 2^nd^ analyst reviewed only the extracted results for completeness, accuracy, and consistent presentation and formatting. Evidence tables were created by NESR analysts using the extracted data.

### Assess risk of bias

Each article included in a rapid review underwent a formal risk of bias assessment. Risk of bias assessments were not completed for evidence scans. Risk of bias is the likelihood of a systematic error or deviation from the truth, in results or interferences, which can lead to underestimation or overestimation of either the true effect of an intervention on an outcome or the true association between an exposure and outcome.

NESR assessed the risk of bias of RCTs, including parallel group trials, cluster-randomized trials, and cross-over trials, using the “Cochrane risk-of-bias tool for randomized trials” (RoB 2.0; August 2016 version).^a^ NESR assessed the risk of bias of non-RCTs using the “Risk of Bias in Non-randomized Studies.^b^ NESR assessed the risk of bias of observational studies using the Risk of Bias for Nutrition Observational Studies tool (RoB-NObs) (Appendix 0-b).

a Higgins JPT, Sterne JAC, Savović J, et al. A revised tool for assessing risk of bias in randomized trials. In: Chandler J, Clarke M, McKenzie J, Boutron I, Welch V, eds. Cochrane Methods. Vol 10(Suppl 1): Cochrane Database of Syst Rev.; 2016. doi: 10.1002/14651858.CD201601.

b Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in nonrandomised studies of interventions. BMJ. 2016;355:i4919. doi:10.1136/bmj.i4919.27733354

For each article included in a rapid review, 1 NESR analyst completed the risk of bias tool appropriate for the study’s design and the assessment was verified by a 2^nd^ analyst. Analysts answered the signaling questions based only on the data that was extracted for the rapid review for a specific result, and determined domain-level risk of bias judgements (e.g., Low, Moderate, Serious, Critical). If necessary, analysts referred to previous and/or related publications to obtain information to complete items in the tool. The analysts’ reconciled disagreements and if a disagreement could not be resolved by the 2 analysts, an additional member of the NESR staff was asked to provide a third-party consultation.

The results of each risk of bias assessment were displayed in a risk of bias table. This table provides transparency to the domain-level risk of bias judgements for each included article using a color-coded system. Limitations identified during risk of bias assessments were also described and considered.

## Synthesize evidence, assessment of evidence, develop summary statements, and identify research recommendations

### Synthesize evidence

Evidence synthesis was conducted for each rapid review, which is the process by which evidence from multiple studies is described, compared and contrasted, and combined qualitatively, or narratively, to answer the review question. This synthesis of the body of evidence involves identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors may have affected the relationships being examined. Evidence synthesis conducted as part of the rapid reviews in this project align with that of NESR systematic reviews, but are more concise.

NESR analysts drafted a description of the studies included in the review to begin the process of synthesizing the evidence using the analytic framework and review protocol to guide how the evidence was organized and described.

Next, NESR analysts reviewed the included articles individually, and the body of evidence collectively. The following were considered in each review: study design, key associations between the intervention/exposure and outcome(s) of interest in the review question, along with considerations of key factors for assessing the body of evidence (risk of bias, consistency, directness, precision, and generalizability). Patterns of agreement and disagreement among the findings were examined, and methodological differences between the studies were assessed to potentially help explain disagreement. Gaps in the body of evidence also were identified.

Synthesis, assessment of evidence, and developing summary statements were not completed for evidence scans because no results were extracted nor was risk of bias assessed. However, research recommendations were developed based on the type and amount of literature included in the scan.

### Develop summary statements

NESR analysts developed summary statements outlining the main themes from the synthesis. Because modifications were made to NESR’s standard systematic review methods and these reviews included limited expert involvement, conclusion statements and grades were not developed to answer the research questions. However, the grading elements (i.e., risk of bias, consistency, precision, directness, generalizability) were referenced to assess the evidence, determine limitations, and inform the development of summary statements.

### Identify research recommendations

Research gaps and methodological limitations identified during data extraction, synthesis, and discussions with the NEAT team are documented and included in this report for each question. They are framed as research recommendations that detail areas where further research is needed to strengthen the body of evidence on the research question of interest.